# ACKNOWLEDGEMENTS

Dietary Patterns Subcommittee:

- Carol Boushey, PhD, MPH, RD, University of Hawaii, Subcommittee Chair
- Jamy Ard, MD, Wake Forest School of Medicine
- Lydia Bazzano, MD, PhD, Tulane University and Ochsner Health System
- Steven Heymsfield, MD, Louisiana State University, Pennington Biomedical Research Center
- Elizabeth Mayer-Davis, PhD, RD, University of North Carolina at Chapel Hill
- Joan Sabaté, MD, DrPH, Loma Linda University
- Linda Snetselaar, PhD, RDN, University of Iowa
- Linda Van Horn, PhD, RDN, LD, Northwestern University
- Barbara Schneeman, PhD, University of California, Davis, Chair of the 2020 Dietary Guidelines Advisory Committee

Nutrition Evidence Systematic Review (NESR) Team:

- Laural Kelly English, PhD, Analyst, Panum Group^i^
- Marlana Bates, MPH, RD, Analyst, Panum Group^i^
- Emily Callahan, MS, Analyst, Nutrition Guidance and Analysis Division (NGAD), Center for Nutrition Policy and Promotion (CNPP), Food and Nutrition Service (FNS), U.S. Department of Agriculture (USDA)
- Sudha Venkatramanan, PhD, Analyst, Panum Group^i^
- Gisela Butera, MLIS, MEd, Systematic Review Librarian, Panum Group^i^
- Nancy Terry, MS, MLS, Biomedical Librarian, National Institutes of Health (NIH) Library, U.S. Department of Health and Human Services (HHS)
- Julie Obbagy, PhD, RD, Project Lead, NGAD, CNPP, FNS, USDA

Federal Liaisons:

- Elizabeth Rahavi, RD, NGAD, CNPP, FNS, USDA
- Clarissa (Claire) Brown, MS, MPH, RD, NGAD, CNPP, FNS, USDA

Project Leadership:

- Eve Stoody, PhD, Designated Federal Officer and Director, NGAD, CNPP, FNS, USDA
- Janet de Jesus, MS, RD, Nutrition Advisor, Office of Disease Prevention and Health Promotion, Office of the Assistant Secretary for Health, HHS

USDA and HHS implemented a process to identify topics and scientific questions to be examined by the 2020 Dietary Guidelines Advisory Committee. The Committee conducted its review of evidence in subcommittees for discussion by the full Committee during its public meetings. The role of the Committee members involved establishing all aspects of the protocol, which presented the plan for how they would examine the scientific evidence, including the inclusion and exclusion criteria; reviewing all studies that met the criteria they set; deliberating on the body of evidence for each question; and writing and grading the conclusion statements to be included in the scientific report the 2020 Committee submitted to USDA and HHS. The NESR team with assistance from Federal Liaisons and Project Leadership, supported the Committee by facilitating, executing, and documenting the work necessary to ensure the reviews were completed in accordance with NESR methodology. More information about the 2020 Dietary Guidelines Advisory Committee, including the process used to identify topics and questions, can be found at www.DietaryGuidelines.gov. More information about NESR can be found at NESR.usda.gov.

The Committee and NESR staff thank USDA’s Agricultural Research Service for coordinating the peer review of this systematic review, and the Federal scientist peer reviewers for their time and expertise.

i Under contract with the Food and Nutrition Service, United States Department of Agriculture.