# List of abbreviations

Abbreviation: Full name
AHEI-2010: Alternative Healthy Eating Index-2010
aMED: Alternate Mediterranean diet score
A-MeDi: Alternate Mediterranean diet
APDQS: A Priori Diet Quality Score
BSD: Baltic Sea Diet
CERAD: Consortium to Establish a Registry for Alzheimer’s Disease
CVD: Cardiovascular disease
DASH: Dietary Approaches to Stop Hypertension
HHS: United States Department of Health and Human Services
EVOO: Extra virgin olive oil
FFQ: Food frequency questionnaire
HEI-2010: Healthy Eating Index-2010
HHS: Health and Human Services
hPDI: Healthful plant-based diet index
MIND: Mediterranean-DASH diet Intervention for Neurodegenerative Delay
MMSE: Mini-Mental State Examiniation
mo: Month(s)
MUFA: Monounsaturated fatty acids
NESR: Nutrition Evidence Systematic Review
NHLBI: National Heart, Lung, and Blood Institute
NIH: National Institutes of Health
PDI: Plant-based diet index
PUFA: Polyunsaturated fatty acids
RCT: Randomized controlled trial
RRR: Reduced rank regression
SF-EMSE: Short Form Extended Mental State Exam
USDA: United States Department of Agriculture
WHI: Women’s Health Initiative
wk: Week(s)
y: Year(s)