# METHODOLOGY

The NESR team used its rigorous, protocol-driven methodology to support the 2020 Dietary Guidelines Advisory Committee in conducting this update to an existing systematic review.

NESR’s systematic review methodology involves:

- Developing a protocol,
- Searching for and selecting studies,
- Extracting data from and assessing the risk of bias of each included study,
- Synthesizing the evidence,
- Developing conclusion statements,
- Grading the evidence underlying the conclusion statements, and
- Recommending future research.

A detailed description of the methodology used in conducting this update to an existing systematic review is available on the NESR website: https://nesr.usda.gov/2020-dietary-guidelines-advisory-committee-systematic-reviews, and can be found in 2020 Dietary Guidelines Advisory Committee Report, Part C: Methodology.^x^ This systematic review was peer reviewed by Federal scientists, and information about the peer review process can also be found in the Committee’s Report, Part C. Methodology. Additional information about this systematic review, including a description of and rationale for any modifications made to the protocol can be found in the 2020 Dietary Guidelines Advisory Committee Report, Part D: Chapter 8. Dietary Patterns.

The systematic review described in this document updates an existing systematic review conducted by the 2015 Dietary Guidelines Advisory Committee with support from USDA’s Nutrition Evidence Systematic Review (NESR) team. Information about the 2015 Dietary Guidelines Advisory Committee’s review of the evidence on dietary patterns and cancer can be found in their report, which is available at the following website: https://nesr.usda.gov/dietary-patterns-foods-and-nutrients-and-health-outcomes-subcommittee.

Below are details of the final protocol, as it (https://www.dietaryguidelines.gov/current-dietary-guidelines/process-develop-2015-2020-dg/advisory-committee) was applied to the systematic review described herein, including the:

- Analytic framework
- Literature search and screening plan
- Literature search and screening results

## ANALYTIC FRAMEWORK

The analytic framework (Figure 1) illustrates the overall scope of this update to an existing systematic review, including the population, the interventions and/or exposures, comparators, and outcomes of interest. It also includes definitions of key terms and identifies key confounders and other factors considered in the systematic review. The inclusion and exclusion criteria that follow provide additional information about how parts of the analytic framework were defined and operationalized for the review.

Figure 1 Analytic framework

An analytic framework visually represents the overall scope of the systematic review question, and depicts the contributing elements that were examined and evaluated, including the target population, exposure, comparison, outcomes, and key confounders. This is the analytic framework for the systematic review question on dietary patterns consumed and neurocognitive health. For this systematic review, the target population for the intervention/exposure was children through older adults, who are healthy and/or at risk of chronic disease. The target population for the outcome was adults and older adult. The interventions or exposures considered were consumption of and/or adherence to a dietary pattern and their comparators were consumption of and/or adherence to a different dietary pattern or different levels of consumption of and/or adherence to a dietary pattern. The outcomes considered were cognitive decline, mild cognitive impairment, dementia, and/or Alzheimer’s disease. The key confounders were sex, age, race/ethnicity, socioeconomic status, alcohol intake (in adults), physical activity, anthropometry, smoking, and family history of neurocognitive disorders. The other factors to be considered were medications, family history of chronic disease (e.g., diabetes, hypertension, cancer), supplement usage, multiple caregivers, and total energy intake.

## LITERATURE SEARCH AND SCREENING PLAN

### Inclusion and exclusion criteria

This table provides the inclusion and exclusion criteria for this update to an existing systematic review. The inclusion and exclusion criteria are a set of characteristics that were used to determine which articles identified in the literature search were included in or excluded from the systematic review.

Table 5 Inclusion and exclusion criteria

Category | Inclusion Criteria | Exclusion Criteria
Study design | - Randomized controlled trials; - Non-randomized controlled trials, including quasi-experimental and controlled before and after studies; - Prospective cohort studies; - Retrospective cohort studies; - Nested case-control studies | - Uncontrolled trials; - Cross-sectional studies; - Uncontrolled before-and-after studies; - Narrative reviews; - Systematic reviews; - Meta-analyses; - Case-control studies
Intervention/exposure | - Studies that examine consumption of and/or adherence to a dietary pattern [i.e., the quantities, proportions, variety, or combination of different foods, drinks, and nutrients (when available) in diets, and the frequency with which they are habitually consumed], including, at a minimum, a description of the foods and beverages in the pattern; ○ Dietary patterns may be measured or derived using a variety of approaches, such as adherence to a priori patterns (indices/scores), data driven patterns (factor or cluster analysis), reduced rank regression, or other methods, including clinical trials | - Studies that do not provide a description of the dietary pattern, which at minimum, must include the foods and beverages in the pattern (i.e., studies that examine a labeled dietary pattern, but do not describe the foods and beverages consumed)
Comparator | - Consumption of and/or adherence to a different dietary pattern; - Different levels of consumption of and/or adherence to a dietary pattern | - N/A
Outcomes | - Cognitive decline, mild cognitive impairment, and dementia; - Alzheimer’s disease
Date of publication | - August 2014 - February 2020 (this date range is in addition to the original systematic review, which included articles published from January 1980-August 2014) | - Articles published prior to January 1980 or after February 2020
Publication status | Articles that have been peer-reviewed | Articles that have not been peer-reviewed and are not published in peer-reviewed journals (e.g., unpublished data, manuscripts, reports, abstracts, pre-prints, and conference proceedings)
Language of publication | Articles published in English | Articles published in languages other than English
Country ^xi^ | Studies conducted in countries ranked as high or higher human development | Studies conducted in countries ranked as medium or lower human development
Study participants | - Human participants; - Males; - Females; - Women during pregnancy and lactation | - Non-human participants (i.e., animals)
Age of study participants | - Age at intervention or exposure:; ○ Children and adolescents (ages 2-18 years); ○ Adults (ages 19-64 years); ○ Older adults (ages 65 years and older); - Age at outcome:; ○ Adults (ages 19-64 years); ○ Older adults (ages 65 years and older) | - Age at intervention or exposure:; ○ Infants and toddlers (birth to 24 months); - Age at outcome:; ○ Infants and toddlers (birth to 24 months)
Study duration | - Minimum length of intervention of 12 weeks | - Interventions < 12 weeks
Size of study groups | - 30 participants per-arm for interventions, or; - A power calculation included for interventions; - n≥ 1,000 for observational studies | - Fewer than 30 participants per arm for interventions, or; - No power calculation reported for interventions; - Fewer than 1000 participants for observational studies
Health status of study participants | - Studies that enroll participants who are healthy and/or at risk for chronic disease, including those with obesity; - Studies that enroll some participants diagnosed with a disease; - Studies that enroll some participants diagnosed with mild cognitive impairment, dementia, or Alzheimer’s disease | - Studies that exclusively enroll participants diagnosed with a disease or hospitalized with illness or injury. (For this criterion, studies that exclusively enroll subjects with obesity will be included.); - Studies that exclusively enroll participants with mild cognitive impairment, dementia, or Alzheimer’s disease (i.e., studies that aim to treat participants who have already been diagnosed with the outcome of interest)

### Electronic databases and search strategy

Listed below are the databases searched to identify all potentially relevant articles that have been published to address this update to an existing systematic review.

#### PubMed

- Provider: U.S. National Library of Medicine
- Date(s) Searched: February 4, 2020
- Date range searched: January 1, 2014 - February 4, 2020
- Search Terms:
  - #1 - dietary pattern* OR diet pattern* OR eating pattern* OR food pattern* OR diet quality* OR eating habit* OR dietary habit* OR diet habit* OR food habit* OR beverage habit* OR “Feeding Behavior”[Mesh:NoExp] OR feeding behavior*[tiab] OR dietary profile* OR food profile* OR diet profile* OR eating profile* OR dietary guideline* OR dietary recommendation* OR dietary intake* OR eating style* OR “Diet, Mediterranean”[Mesh] OR Mediterranean Diet*[tiab] OR “Dietary Approaches To Stop Hypertension”[Mesh] OR Dietary Approaches To Stop Hypertension Diet* OR DASH diet* OR “Diet, Gluten-Free"[Mesh] OR Gluten Free diet* OR prudent diet* OR “Diet, Paleolithic”[Mesh] OR Paleolithic Diet* OR “Diet, Vegetarian”[Mesh] OR vegetarian diet*[tiab] OR vegan diet* OR “Diet, Healthy”[Mesh] OR healthy diet* OR plant based diet* OR “Diet, Western”[Mesh] OR western diet* OR “Diet, Carbohydrate-Restricted"[Mesh] OR low-carbohydrate diet* OR high carbohydrate diet* OR Ketogenic Diet* OR Nordic Diet* OR “Diet, Fat-Restricted"[Mesh] OR “Diet, High-Fat"[Mesh] OR “Diet, High-Protein"[Mesh] OR high protein diet*[tiab] OR protein intake* OR high‐fat diet* OR low fat diet* OR “Diet, Protein-Restricted"[Mesh] OR low protein diet* OR “Diet, Sodium-Restricted"[Mesh] OR low-sodium diet* OR low salt diet* OR ((“Guideline Adherence”[Mesh] OR guideline adherence*) AND (diet[tiab] OR dietary[tiab] OR food[tiab] OR beverage*[tiab] OR nutrition*[tiab])) OR diet score* OR diet quality score* OR diet quality index* OR kidmed OR diet index* OR dietary index* OR food score* OR MedDietScore OR healthy eating index[tiab] OR ((pattern[tiab] OR patterns[tiab] OR consumption[tiab] OR habit*[tiab]) AND (“Diet"[Mesh:NoExp] OR diet[tiab] OR diets[tiab] OR dietary[tiab] OR “Food"[Mesh] OR food[tiab] OR foods[tiab] OR “Beverages"[Mesh] OR beverage[tiab] OR beverages[tiab]))
  - #2 - “Cognition Disorders”[Mesh] OR “Cognition”[Mesh] OR cognition[tiab] OR metacognition[tiab] OR neurocognitive[tiab] OR “Dementia"[Mesh] OR dementia[tiab] OR Alzheimer*[tiab] OR senility[tiab] OR senile[tiab] OR presenile[tiab] OR (cognit*[tiab] AND (function*[tiab] OR dysfunction*[tiab] OR declin*[tiab] OR deteriorat* OR degenerat*[tiab] OR disorder*[tiab] OR dysfunction*[tiab] OR reduct*[tiab] OR impair*[tiab] OR deficit*[tiab] OR deficien* OR progress*[tiab] OR perform*[tiab] OR abilit*[tiab]))
  - #3 - (#1 AND #2)
  - #4 - (#1 AND #2) NOT (“Animals”[Mesh] NOT (“Animals”[Mesh] AND “Humans”[Mesh])) NOT (editorial[ptyp] OR comment[ptyp] OR news[ptyp] OR letter[ptyp] OR review[ptyp] OR systematic review[ptyp] OR systematic review[ti] OR meta-analysis[ptyp] OR meta-analysis[ti] OR meta-analyses[ti] OR retracted publication[ptyp] OR retraction of publication[ptyp] OR retraction of publication[tiab] OR retraction notice[ti]) Filters: Publication date from 2014/01/01 to 2020/02/04; English

#### Cochrane Central Register of Controlled Trials (CENTRAL)

- Provider: John Wiley & Sons
- Date(s) Searched: February 4, 2020
- Date range searched: January 1, 2014 - February 4, 2020
- Search Terms:
  - #1 - [mh ^"Feeding Behavior”] OR [mh “Diet, Mediterranean”] OR [mh “Dietary Approaches To Stop Hypertension”] OR [mh “Diet, Gluten-Free”] OR [mh “Diet, Paleolithic”] OR [mh “Diet, Vegetarian”] OR [mh “Diet, Healthy”] OR [mh “Diet, Western”] OR [mh “Diet, Carbohydrate-Restricted”] OR [mh “Diet, Fat-Restricted”] OR [mh “Diet, High-Fat”] OR [mh “Diet, High-Protein”] OR [mh “Diet, Protein-Restricted”] OR [mh “Diet, Sodium-Restricted”]
  - #2 - (“dietary pattern*” OR “diet pattern*” OR “eating pattern*” OR “food pattern*” OR “diet quality*” OR “eating habit*” OR “dietary habit*” OR “diet habit*” OR “food habit*” OR “beverage habit*” OR “feeding behavior*” OR “dietary profile*” OR “food profile*” OR “diet profile*” OR “eating profile*” OR “dietary guideline*” OR “dietary recommendation*” OR “dietary intake*” OR “eating style*” OR “Mediterranean Diet*” OR “Dietary Approaches To Stop Hypertension Diet*” OR “DASH diet*” OR “Gluten Free diet*” OR “prudent diet*” OR “Paleolithic Diet*” OR “vegetarian diet*” OR “vegan diet*” OR “healthy diet*” OR “plant based diet*” OR “western diet*” OR “low-carbohydrate diet*” OR “high carbohydrate diet*” OR “Ketogenic Diet*” OR “Nordic Diet*” OR “high protein diet*” OR “protein intake*” OR “high‐fat diet*” OR “low fat diet*” OR “low protein diet*” OR “low-sodium diet*” OR “low salt diet*”):ti,ab,kw
  - #3 - (([mh “Guideline Adherence”] OR guideline adherence*) NEAR/6 (diet OR dietary OR food OR beverage* OR nutrition*))
  - #4 - (“diet score*” OR “diet quality score*” OR “diet quality index*” OR kidmed OR “diet index*” OR “dietary index*” OR “food score*” OR MedDietScore OR “healthy eating index*”):ti,ab,kw
  - #5 - ((pattern OR patterns OR consumption OR habit*) NEAR/6 ([mh ^"Diet”] OR diet OR diets OR dietary OR [mh “Food”] OR food OR foods OR [mh “Beverages”] OR beverage OR beverages))
  - #6 - #1 OR #2 OR #3 OR #4 OR #5
  - #7 - [mh “Cognition Disorders”] OR [mh “Cognition”] OR [mh “Dementia”]
  - #8 - (cognition OR metacognition OR neurocognitive OR dementia OR Alzheimer* OR senility OR senile OR presenile):ti,ab,kw
  - #9 - ((cognit* NEAR/6 (function* OR dysfunction* OR declin* OR deteriorat* OR degenerat* OR disorder* OR dysfunction* OR reduct* OR impair* OR deficit* OR deficien* OR progress* OR perform* OR abilit*))):ti,ab,kw
  - #10 - #7 OR #8 OR #9
  - #11 - #6 AND #10" with Publication Year from 2014 to 2020, in Trials (Word variations have been searched)

#### Embase

- Provider: Elsevier
- Date(s) Searched: February 4, 2020
- Date range searched: January 1, 2014 - February 4, 2020
- Search Terms:
  - #1 - ‘feeding behavior’/de OR ‘mediterranean diet’/exp OR ‘dash diet’/exp OR ‘gluten free diet’/exp OR ‘paleolithic diet’/de OR ‘vegetarian diet’/exp OR ‘healthy diet’/exp OR ‘western diet’/de OR ‘low carbohydrate diet’/exp OR ‘low fat diet’/de OR ‘lipid diet’/exp OR ‘protein diet’/exp OR ‘protein restriction’/exp OR ‘sodium restriction’/exp
  - #2 - ‘dietary pattern*’:ab,ti OR ‘diet pattern*’:ab,ti OR ‘eating pattern*’:ab,ti OR ‘food pattern*’:ab,ti OR ‘diet quality*’:ab,ti OR ‘eating habit*’:ab,ti OR ‘dietary habit*’:ab,ti OR ‘diet habit*’:ab,ti OR ‘food habit*’:ab,ti OR ‘beverage habit*’:ab,ti OR ‘feeding behavior*’:ab,ti OR ‘dietary profile*’:ab,ti OR ‘food profile*’:ab,ti OR ‘diet profile*’:ab,ti OR ‘eating profile*’:ab,ti OR ‘dietary guideline*’:ab,ti OR ‘dietary recommendation*’:ab,ti OR ‘dietary intake*’:ab,ti OR ‘eating style*’:ab,ti OR ‘mediterranean diet*’:ab,ti OR ‘dietary approaches to stop hypertension diet*’:ab,ti OR ‘dash diet*’:ab,ti OR ‘gluten free diet*’:ab,ti OR ‘prudent diet*’:ab,ti OR ‘paleolithic diet*’:ab,ti OR ‘vegetarian diet*’:ab,ti OR ‘vegan diet*’:ab,ti OR ‘healthy diet’:ab,ti OR ‘plant based diet*’:ab,ti OR ‘western diet*’:ab,ti OR ‘low-carbohydrate diet*’:ab,ti OR ‘high carbohydrate diet*’:ab,ti OR ‘ketogenic diet*’:ab,ti OR ‘nordic diet*’:ab,ti OR ‘high protein diet*’:ab,ti OR ‘protein intake*’:ab,ti OR ‘high‐fat diet*’:ab,ti OR ‘low fat diet*’:ab,ti OR ‘low protein diet*’:ab,ti OR ‘low-sodium diet*’:ab,ti OR ‘low salt diet*’:ab,ti
  - #3 - (‘guideline adherence*’ NEAR/6 (diet OR dietary OR food OR beverage* OR nutrition*)):ab,ti
  - #4 - ‘diet score*’:ab,ti OR ‘diet quality score*’:ab,ti OR ‘diet quality index*’:ab,ti OR kidmed:ab,ti OR ‘diet index*’:ab,ti OR ‘dietary index*’:ab,ti OR ‘food score*’:ab,ti OR meddietscore:ab,ti OR ‘healthy eating index*’:ab,ti
  - #5 - ((pattern OR patterns OR consumption OR habit*) NEAR/6 (diet OR diets OR dietary OR food OR foods OR beverage OR beverages)):ab,ti
  - #6 - #1 OR #2 OR #3 OR #4 OR #5
  - #7 - ‘cognitive defect’/exp OR ‘cognition’/exp OR ‘dementia’/exp
  - #8 - cognition:ab,ti OR metacognition:ab,ti OR neurocognitive:ab,ti OR dementia:ab,ti OR alzheimer*:ab,ti OR senility:ab,ti OR senile:ab,ti OR presenile:ab,ti
  - #9 - (cognit* NEAR/6 (function* OR dysfunction* OR declin* OR deteriorat* OR degenerat* OR disorder* OR dysfunction* OR reduct* OR impair* OR deficit* OR deficien* OR progress* OR perform* OR abilit*)):ab,ti
  - #10 - #7 OR #8 OR #9
  - #11 - #6 AND #10
  - #12 - #6 AND #10 AND ([article]/lim OR [article in press]/lim) AND [humans]/lim AND [english]/lim AND [2014-2020]/py NOT ([conference abstract]/lim OR [conference paper]/lim OR [conference review]/lim OR [editorial]/lim OR [erratum]/lim OR [letter]/lim OR [note]/lim OR [review]/lim OR [systematic review]/lim OR [meta analysis]/lim)

## LITERATURE SEARCH AND SCREENING RESULTS

The flow chart (Figure 2) below illustrates the literature search and screening results for articles examining the update to this systematic review question. The results of the electronic database searches, after removal of duplicates, were screened independently by two NESR analysts using a step-wise process by reviewing titles, abstracts, and full-texts to determine which articles met the inclusion criteria. Refer to Table 6 for the rationale for exclusion for each excluded full-text article. A manual search was done to find articles that were not identified when searching the electronic databases; all manually identified articles were also screened to determine whether they meet criteria for inclusion.

Figure 2 Flow chart of literature search and screening results

This flow chart illustrates the literature search and screening results for articles examining the relationship between dietary patterns and neurocognitive health. The literature search yielded 5621 raw results of articles. During title screening, 3257 articles were screened out. During abstract screening, 293 articles were screened out. During full-text screening, 60 articles were screened out. During the hand search, 0 additional articles were identified to include. A total of 26 articles were included in the systematic review at the end of the search and screening process.

### Excluded Articles

The table below lists the articles excluded after full-text screening for the update to this systematic review question. At least one reason for exclusion is provided for each article, though this may not reflect all possible reasons. Information about articles excluded after title and abstract screening is available upon request.

Table 6 Articles excluded after full text screening with rationale for exclusion

| Citation | Rationale
1 | Alavi-Naeini, A, Bagheri, M, Mirzaei, K, Maljaei, MB, Yekaninejad, MS, Yazdani, A. Relationship between dietary patterns and mild cognitive impairment (MCI) in elderly women. Progress in Nutrition. 2019. 21:270–280. doi:10.23751/pn.v21i1-S.6090 | Study Design, Power/Size
2 | Anastasiou, CA, Yannakoulia, M, Kontogianni, MD, Kosmidis, MH, Mamalaki, E, Dardiotis, E, Hadjigeorgiou, G, Sakka, P, Tsapanou, A, Lykou, A, Scarmeas, N. Mediterranean Lifestyle in Relation to Cognitive Health: Results from the HELIAD Study. Nutrients. 2018. 10. doi:10.3390/nu10101557 | Study Design
3 | Anastasiou, CA, Yannakoulia, M, Kosmidis, MH, Dardiotis, E, Hadjigeorgiou, GM, Sakka, P, Arampatzi, X, Bougea, A, Labropoulos, I, Scarmeas, N. Mediterranean diet and cognitive health: Initial results from the Hellenic Longitudinal Investigation of Ageing and Diet. PLoS One. 2017. 12:e0182048. doi:10.1371/journal.pone.0182048 28763509 | Study Design
4 | Ashby-Mitchell, K, Peeters, A, Anstey, KJ. Role of dietary pattern analysis in determining cognitive status in elderly Australian adults. Nutrients. 2015. 7:1052–67. doi:10.3390/nu7021052 25658241 | Power/Size
5 | Assmann, KE, Adjibade, M, Adriouch, S, Andreeva, VA, Julia, C, Hercberg, S, Galan, P, Kesse-Guyot, E. Association of diet quality and physical activity with healthy ageing in the French NutriNet-Sante cohort. Br J Nutr. 2019. 122:93–102. doi:10.1017/s0007114519000898 31162001 | Outcome
6 | Assmann, KE, Adjibade, M, Andreeva, VA, Hercberg, S, Galan, P, Kesse-Guyot, E. Association Between Adherence to the Mediterranean Diet at Midlife and Healthy Aging in a Cohort of French Adults. J Gerontol A Biol Sci Med Sci. 2018. 73:347–354. doi:10.1093/gerona/glx066 28460137 | Outcome
7 | Assmann, KE, Andreeva, VA, Camilleri, GM, Verger, EO, Jeandel, C, Hercberg, S, Galan, P, Kesse-Guyot, E. Dietary scores at midlife and healthy ageing in a French prospective cohort. Br J Nutr. 2016. 116:666–76. doi:10.1017/s0007114516002233 27301412 | Outcome
8 | Assmann, KE, Lassale, C, Andreeva, VA, Jeandel, C, Hercberg, S, Galan, P, Kesse-Guyot, E. A Healthy Dietary Pattern at Midlife, Combined with a Regulated Energy Intake, Is Related to Increased Odds for Healthy Aging. J Nutr. 2015. 145:2139–45. doi:10.3945/jn.115.210740 26246320 | Outcome
9 | Bajerska, J, Wozniewicz, M, Suwalska, A, Jeszka, J. Eating patterns are associated with cognitive function in the elderly at risk of metabolic syndrome from rural areas. Eur Rev Med Pharmacol Sci. 2014. 18:3234–45. doi: unavailable25487934 | Power/Size
10 | Blumenthal, JA, Smith, PJ, Mabe, S, Hinderliter, A, Welsh-Bohmer, K, Browndyke, JN, Doraiswamy, PM, Lin, PH, Kraus, WE, Burke, JR, Sherwood, A. Longer Term Effects of Diet and Exercise on Neurocognition: 1-Year Follow-up of the ENLIGHTEN Trial. J Am Geriatr Soc. 2019. doi:10.1111/jgs.16252 | Health Status
11 | Chan, R, Leung, J, Woo, J. Dietary patterns and risk of frailty in Chinese community-dwelling older people in Hong Kong: A prospective cohort study. Nutrients. 2015. 7:7070–7084. doi:10.3390/nu7085326 26305253 | Study Design, Outcome
12 | Chen, YC, Jung, CC, Chen, JH, Chiou, JM, Chen, TF, Chen, YF, Tang, SC, Yeh, SJ, Lee, MS. Association of Dietary Patterns With Global and Domain-Specific Cognitive Decline in Chinese Elderly. J Am Geriatr Soc. 2017. 65:1159–1167. doi:10.1111/jgs.14741 28092399 | Power/Size
13 | Cheung, BHK, Ho, ICH, Chan, RSM, Sea, MMM, Woo, J. Current evidence on dietary pattern and cognitive function. 2014. 71:137–163. doi:10.1016/B978-0-12-800270-4.00004-3 | Study Design
14 | Chou, YC, Lee, MS, Chiou, JM, Chen, TF, Chen, YC, Chen, JH. Association of Diet Quality and Vegetable Variety with the Risk of Cognitive Decline in Chinese Older Adults. Nutrients. 2019. 11. doi:10.3390/nu11071666 | Power/Size
15 | Chuang, SY, Lo, YL, Wu, SY, Wang, PN, Pan, WH. Dietary Patterns and Foods Associated With Cognitive Function in Taiwanese Older Adults: The Cross-sectional and Longitudinal Studies. J Am Med Dir Assoc. 2019. 20:544–550.e4. doi:10.1016/j.jamda.2018.10.017 30630727 | Country
16 | Diener, HC. Multidimensional prevention of dementia diseases. MMW Fortschritte der Medizin. 2015. 157:39. doi:10.1007/s15006-015-3658-1 | Pub. Status
17 | Feng, Z, Cramm, JM, Nieboer, AP. A healthy diet and physical activity are important to promote healthy ageing among older Chinese people. Journal of International Medical Research. 2019. 47:6061–6081. doi:10.1177/0300060519882590 | Country
18 | Ferrand, C, Féart, C, Martinent, G, Albinet, C, André, N, Audiffren, M. Dietary patterns in French home-living older adults: Results from the PRAUSE study. Archives of Gerontology and Geriatrics. 2017. 70:180–185. doi:10.1016/j.archger.2017.01.015 28192753 | Power/Size
19 | Galbete, C, Toledo, E, Toledo, JB, Bes-Rastrollo, M, Buil-Cosiales, P, Marti, A, Guillen-Grima, F, Martinez-Gonzalez, MA. Mediterranean diet and cognitive function: the SUN project. J Nutr Health Aging. 2015. 19:305–12. doi:10.1007/s12603-015-0441-z 25732216 | Power/Size
20 | Gallucci, M, Pallucca, C, Di Battista, ME, Fougere, B, Grossi, E. Artificial Neural Networks Help to Better Understand the Interplay Between Cognition, Mediterranean Diet, and Physical Performance: Clues from TRELONG Study. J Alzheimers Dis. 2019. 71:1321–1330. doi:10.3233/jad-190609 31524170 | Power/Size
21 | Gardener, SL, Rainey-Smith, SR, Barnes, MB, Sohrabi, HR, Weinborn, M, Lim, YY, Harrington, K, Taddei, K, Gu, Y, Rembach, A, Szoeke, C, Ellis, KA, Masters, CL, Macaulay, SL, Rowe, CC, Ames, D, Keogh, JB, Scarmeas, N, Martins, RN. Dietary patterns and cognitive decline in an Australian study of ageing. Mol Psychiatry. 2015. 20:860–6. doi:10.1038/mp.2014.79 25070537 | Power/Size
22 | Gopinath, B, Russell, J, Kifley, A, Flood, VM, Mitchell, P. Adherence to Dietary Guidelines and Successful Aging Over 10 Years. J Gerontol A Biol Sci Med Sci. 2016. 71:349–55. doi:10.1093/gerona/glv189 26503376 | Outcome
23 | Gougeon, L, Payette, H, Morais, J, Gaudreau, P, Shatenstein, B, Gray-Donald, K. Dietary patterns and incidence of depression in a cohort of community-dwelling older Canadians. J Nutr Health Aging. 2015. 19:431–6. doi:10.1007/s12603-014-0562-9 25809807 | Outcome
24 | Granic, A, Davies, K, Adamson, A, Kirkwood, T, Hill, TR, Siervo, M, Mathers, JC, Jagger, C. Dietary Patterns High in Red Meat, Potato, Gravy, and Butter Are Associated with Poor Cognitive Functioning but Not with Rate of Cognitive Decline in Very Old Adults. J Nutr. 2016. 146:265–74. doi:10.3945/jn.115.216952 26740685 | Power/Size
25 | Hardman, RJ, Meyer, D, Kennedy, G, Macpherson, H, Scholey, AB, Pipingas, A. The association between adherence to a Mediterranean style diet and cognition in older people: The impact of medication. Clin Nutr. 2018. 37:2156–2165. doi:10.1016/j.clnu.2017.10.015 29217146 | Study Design, Intervention/Exposure
26 | Hill, E, Clifton, P, Goodwill, AM, Dennerstein, L, Campbell, S, Szoeke, C. Dietary patterns and beta-amyloid deposition in aging Australian women. Alzheimers Dement (N Y). 2018. 4:535–541. doi:10.1016/j.trci.2018.09.007 30386818 | Outcome
27 | Hosking, DE, Nettelbeck, T, Wilson, C, Danthiir, V. Retrospective lifetime dietary patterns predict cognitive performance in community-dwelling older Australians. Br J Nutr. 2014. 112:228–37. doi:10.1017/s0007114514000646 24709049 | Power/Size
28 | Kesse-Guyot, E, Andreeva, VA, Ducros, V, Jeandel, C, Julia, C, Hercberg, S, Galan, P. Carotenoid-rich dietary patterns during midlife and subsequent cognitive function. Br J Nutr. 2014. 111:915–23. doi:10.1017/s0007114513003188 24073964 | Date Overlaps with Existing Review
29 | Lee, J, Pase, M, Pipingas, A, Raubenheimer, J, Thurgood, M, Villalon, L, Macpherson, H, Gibbs, A, Scholey, A. Switching to a 10-day Mediterranean-style diet improves mood and cardiovascular function in a controlled crossover study. Nutrition. 2015. 31:647–52. doi:10.1016/j.nut.2014.10.008 25837207 | Study duration
30 | Lehtisalo, J, Levalahti, E, Lindstrom, J, Hanninen, T, Paajanen, T, Peltonen, M, Antikainen, R, Laatikainen, T, Strandberg, T, Soininen, H, . Dietary changes and cognition over 2 years within a multidomain intervention trial—The Finnish Geriatric Intervention Study to Prevent Cognitive Impairment and Disability (FINGER). Alzheimer’s & dementia. 2019. 15:410–417. doi:10.1016/j.jalz.2018.10.001 | Intervention/Exposure
31 | Lehtisalo, J, Levalahti, E, Lindstrom, J, Hanninen, T, Paajanen, T, Peltonen, M, Antikainen, R, Laatikainen, T, Strandberg, T, Soininen, H, Tuomilehto, J, Kivipelto, M, Ngandu, T. Dietary changes and cognition over 2 years within a multidomain intervention trial-The Finnish Geriatric Intervention Study to Prevent Cognitive Impairment and Disability (FINGER). Alzheimers Dement. 2019. 15:410–417. doi:10.1016/j.jalz.2018.10.001 30527596 | Intervention/Exposure, Comparator
32 | Li, J, Ogrodnik, M, Kolachalama, VB, Lin, H, Au, R. Assessment of the Mid-Life Demographic and Lifestyle Risk Factors of Dementia Using Data from the Framingham Heart Study Offspring Cohort. Journal of Alzheimer’s Disease. 2018. 63:1119–1127. doi:10.3233/JAD-170917 | Study Design, Intervention/Exposure
33 | Lutski, M, Weinstein, G, Ben-Zvi, S, Goldbourt, U, Tanne, D. Adherence to Mediterranean diet and subsequent cognitive decline in men with cardiovascular disease. Nutr Neurosci. 2020. 1–9. doi:10.1080/1028415x.2020.1715049 | Health Status
34 | Matthews, DC, Davies, M, Murray, J, Williams, S, Tsui, WH, Li, Y, Andrews, RD, Lukic, A, McHugh, P, Vallabhajosula, S, de Leon, MJ, Mosconi, L. Physical Activity, Mediterranean Diet and Biomarkers-Assessed Risk of Alzheimer’s: A Multi-Modality Brain Imaging Study. Adv J Mol Imaging. 2014. 4:43–57. doi:10.4236/ami.2014.44006 25599008 | Study Design, Outcome
35 | Mazza, E, Fava, A, Ferro, Y, Moraca, M, Rotundo, S, Colica, C, Provenzano, F, Terracciano, R, Greco, M, Foti, D, Gulletta, E, Russo, D, Bosco, D, Pujia, A, Montalcini, T. Impact of legumes and plant proteins consumption on cognitive performances in the elderly. J Transl Med. 2017. 15:109. doi:10.1186/s12967-017-1209-5 28532453 | Intervention/Exposure
36 | Milte, CM, Ball, K, Crawford, D, McNaughton, SA. Diet quality and cognitive function in mid-aged and older men and women. BMC Geriatr. 2019. 19:361. doi:10.1186/s12877-019-1326-5 31864295 | Power/Size
37 | Mohorko, N, Cernelic-Bizjak, M, Poklar-Vatovec, T, Grom, G, Kenig, S, Petelin, A, Jenko-Praznikar, Z. Weight loss, improved physical performance, cognitive function, eating behavior, and metabolic profile in a 12-week ketogenic diet in obese adults. Nutr Res. 2019. 62:64–77. doi:10.1016/j.nutres.2018.11.007 30803508 | Study Design, Intervention/Exposure
38 | Morris, MC, Tangney, CC, Wang, Y, Sacks, FM, Barnes, LL, Bennett, DA, Aggarwal, NT. MIND diet slows cognitive decline with aging. Alzheimers Dement. 2015. 11:1015–22. doi:10.1016/j.jalz.2015.04.011 26086182 | Power/Size
39 | Morris, MC, Tangney, CC, Wang, Y, Sacks, FM, Bennett, DA, Aggarwal, NT. MIND diet associated with reduced incidence of Alzheimer’s disease. Alzheimers Dement. 2015. 11:1007–14. doi:10.1016/j.jalz.2014.11.009 25681666 | Power/Size
40 | Munoz-Garcia, MI, Toledo, E, Razquin, C, Dominguez, LJ, Maragarone, D, Martinez-Gonzalez, J, Martinez-Gonzalez, MA. “A priori” Dietary Patterns and Cognitive Function in the SUN Project. Neuroepidemiology. 2020. 54:45–57. doi:10.1159/000502608 31600758 | Power/Size
41 | Olsson, E, Karlstrom, B, Kilander, L, Byberg, L, Cederholm, T, Sjogren, P. Dietary patterns and cognitive dysfunction in a 12-year follow-up study of 70 year old men. J Alzheimers Dis. 2015. 43:109–19. doi:10.3233/jad-140867 25062901 | Power/Size
42 | Panza, F, Solfrizzi, V, Giannini, M, Seripa, D, Pilotto, A, Logroscino, G. Nutrition, frailty, and Alzheimer’s disease. Frontiers in Aging Neuroscience. 2014. 6. doi:10.3389/fnagi.2014.00221 24570662 | Study Design
43 | Park, JE, Jeon, SY, Kim, SA, Kim, JH, Kim, SH, Lee, KW, Hwang, YJ, Jung, G, Suk, HW, Park, S, Lee, DY. A Multidomain Intervention for Modifying Lifestyle Habits Reduces the Dementia Risk in Community-Dwelling Older Adults: A Single-Blinded Randomized Controlled Pilot Study. J Alzheimers Dis. 2019. 70:51–60. doi:10.3233/jad-190016 31127782 | Intervention/Exposure
44 | Pelletier, A, Barul, C, Feart, C, Helmer, C, Bernard, C, Periot, O, Dilharreguy, B, Dartigues, JF, Allard, M, Barberger-Gateau, P, Catheline, G, Samieri, C. Mediterranean diet and preserved brain structural connectivity in older subjects. Alzheimers Dement. 2015. 11:1023–31. doi:10.1016/j.jalz.2015.06.1888 26190494 | Outcome
45 | Perrone, L, Grant, WB. Observational and ecological studies of dietary advanced glycation end products in national diets and Alzheimer’s disease incidence and prevalence. J Alzheimers Dis. 2015. 45:965–79. doi:10.3233/jad-140720 25633677 | Study Design
46 | Prinelli, F, Fratiglioni, L, Musicco, M, Johansson, I, Adorni, F, Shakersain, B, Rizzuto, D, Xu, W. The impact of nutrient-based dietary patterns on cognitive decline in older adults. Clin Nutr. 2019. 38:2813–2820. doi:10.1016/j.clnu.2018.12.012 30591381 | Intervention/Exposure
47 | Qin, B, Adair, LS, Plassman, BL, Batis, C, Edwards, LJ, Popkin, BM, Mendez, MA. Dietary Patterns and Cognitive Decline Among Chinese Older Adults. Epidemiology. 2015. 26:758–68. doi:10.1097/ede.0000000000000338 26133024 | Country
48 | Rainey-Smith, SR, Gu, Y, Gardener, SL, Doecke, JD, Villemagne, VL, Brown, BM, Taddei, K, Laws, SM, Sohrabi, HR, Weinborn, M, Ames, D, Fowler, C, Macaulay, SL, Maruff, P, Masters, CL, Salvado, O, Rowe, CC, Scarmeas, N, Martins, RN. Mediterranean diet adherence and rate of cerebral Abeta-amyloid accumulation: Data from the Australian Imaging, Biomarkers and Lifestyle Study of Ageing. Transl Psychiatry. 2018. 8:238. doi:10.1038/s41398-018-0293-5 30375373 | Outcome
49 | Seetharaman, S, Andel, R, McEvoy, C, Dahl Aslan, AK, Finkel, D, Pedersen, NL. Blood glucose, diet-based glycemic load and cognitive aging among dementia-free older adults. J Gerontol A Biol Sci Med Sci. 2015. 70:471–9. doi:10.1093/gerona/glu135 25149688 | Power/Size
50 | Tanaka, T, Talegawkar, SA, Jin, Y, Colpo, M, Ferrucci, L, Bandinelli, S. Adherence to a Mediterranean Diet Protects from Cognitive Decline in the Invecchiare in Chianti Study of Aging. Nutrients. 2018. 10. doi:10.3390/nu10122007 | Power/Size
51 | Tangney, CC, Li, H, Wang, Y, Barnes, L, Schneider, JA, Bennett, DA, Morris, MC. Relation of DASH- and Mediterranean-like dietary patterns to cognitive decline in older persons. Neurology. 2014. 83:1410–6. doi:10.1212/wnl.0000000000000884 25230996 | Power/Size
52 | Trichopoulou, A, Kyrozis, A, Rossi, M, Katsoulis, M, Trichopoulos, D, La Vecchia, C, Lagiou, P. Mediterranean diet and cognitive decline over time in an elderly Mediterranean population. Eur J Nutr. 2015. 54:1311–21. doi:10.1007/s00394-014-0811-z 25482573 | Power/Size
53 | Tsai, HJ. Dietary patterns and cognitive decline in Taiwanese aged 65 years and older. Int J Geriatr Psychiatry. 2015. 30:523–30. doi:10.1002/gps.4176 25043924 | Country
54 | Wade, AT, Davis, CR, Dyer, KA, Hodgson, JM, Woodman, RJ, Keage, HAD, Murphy, KJ. A Mediterranean diet supplemented with dairy foods improves mood and processing speed in an Australian sample: results from the MedDairy randomized controlled trial. Nutr Neurosci. 2018:1–13. doi:10.1080/1028415x.2018.1543148 | Study duration
55 | Wade, AT, Davis, CR, Dyer, KA, Hodgson, JM, Woodman, RJ, Keage, HAD, Murphy, KJ. A Mediterranean Diet with Fresh, Lean Pork Improves Processing Speed and Mood: Cognitive Findings from the MedPork Randomised Controlled Trial. Nutrients. 2019. 11. doi:10.3390/nu11071521 | Study duration
56 | Wade, AT, Elias, MF, Murphy, KJ. Adherence to a Mediterranean diet is associated with cognitive function in an older non-Mediterranean sample: findings from the Maine-Syracuse Longitudinal Study. Nutr Neurosci. 2019. 1–12. doi:10.1080/1028415x.2019.1655201 | Power/Size
57 | Yu, FN, Hu, NQ, Huang, XL, Shi, YX, Zhao, HZ, Cheng, HY. Dietary patterns derived by factor analysis are associated with cognitive function among a middle-aged and elder Chinese population. Psychiatry Res. 2018. 269:640–645. doi:10.1016/j.psychres.2018.09.004 30216915 | Study Design
58 | Yuan, L, Liu, J, Ma, W, Dong, L, Wang, W, Che, R, Xiao, R. Dietary pattern and antioxidants in plasma and erythrocyte in patients with mild cognitive impairment from China. Nutrition. 2016. 32:193–8. doi:10.1016/j.nut.2015.08.004 26690564 | Study Design, Power/Size
59 | Zbeida, M, Goldsmith, R, Shimony, T, Vardi, H, Naggan, L, Shahar, DR. Mediterranean diet and functional indicators among older adults in non-Mediterranean and Mediterranean countries. J Nutr Health Aging. 2014. 18:411–8. doi:10.1007/s12603-014-0003-9 24676323 | Study Design
60 | Zhao, X, Yuan, L, Feng, L, Xi, Y, Yu, H, Ma, W, Zhang, D, Xiao, R. Association of dietary intake and lifestyle pattern with mild cognitive impairment in the elderly. J Nutr Health Aging. 2015. 19:164–8. doi:10.1007/s12603-014-0524-2 25651441 | Power/Size

x Dietary Guidelines Advisory Committee. 2020. Scientific Report of the 2020 Dietary Guidelines Advisory Committee: Advisory Report to the Secretary of Health and Human Services and the Secretary of Agriculture. U.S. Department of Agriculture, Agricultural Research Service, Washington, DC .

xi The Human Development classification was based on the Human Development Index (HDI) ranking from the year the study intervention occurred or data were collected (UN Development Program. HDI 1990-2017 HDRO calculations based on data from UNDESA (2017a), UNESCO Institute for Statistics (2018), United Nations Statistics Division (2018b), World Bank (2018b), Barro and Lee (2016) and IMF (2018). Available from: http://hdr.undp.org/en/data). If the study did not report the year in which the intervention occurred or data were collected, the HDI classification for the year of publication was applied. HDI values are available from 1980, and then from 1990 to present. If a study was conducted prior to 1990, the HDI classification from 1990 was applied. If a study was conducted in 2018 or 2019, the most current HDI classification was applied. When a country was not included in the HDI ranking, the current country classification from the World Bank was used instead (The World Bank. World Bank country and lending groups. Available from: https://datahelpdesk.worldbank.org/knowledgebase/articles/906519-world-country-and-lending-groups).