# WHAT IS THE RELATIONSHIP BETWEEN DIETARY PATTERNS CONSUMED AND NEUROCOGNITIVE HEALTH?

## PLAIN LANGUAGE SUMMARY

### What is the question?

- The question is: What is the relationship between dietary patterns consumed and neurocognitive health?

### What is the answer to the question?

- Limited evidence suggests that dietary patterns containing vegetables, fruits, unsaturated vegetable oils and/or nuts, legumes, and fish or seafood consumed during adulthood are associated with lower risk of age-related cognitive impairment and/or dementia.

### Why was this question asked?

- This important public health question was identified by the U.S. Departments of Agriculture (USDA) and Health and Human Services (HHS) to be examined by the 2020 Dietary Guidelines Advisory Committee.

### How was this question answered?

- The 2020 Dietary Guidelines Advisory Committee, Dietary Patterns Subcommittee conducted a systematic review to answer this question with support from the Nutrition Evidence Systematic Review (NESR) team.
- Dietary patterns were defined as the quantities, proportions, variety, or combination of different foods, drinks, and nutrients (when available) in diets, and the frequency with which they are habitually consumed.

### What is the population of interest?

- For the intervention/exposure, children through older adults, age 2 years and older
- For the outcome, adults and older adults, age 19 years and older

### What evidence was found?

- This review identified 26 articles that met inclusion criteria.
- Most studies reported dietary patterns consumed during adulthood relate to improved cognitive measures or lower risk of cognitive impairment. These dietary patterns were higher in vegetables, fruits, unsaturated vegetable oils and/or nuts, legumes, and fish or seafood.
- Many limitations in study design and conduct were identified in the included studies. This includes differences in dietary patterns examined, cognitive assessment methods, and lack of accounting for possible changes in diet over time.
- The 2020 Committee updates and builds on the conclusion drawn by the 2015 Committee from an existing systematic review.

### How up-to-date is this systematic review?

- This review searched for studies published from January 2014 to February 2020, and updated an existing systematic review that included evidence from January 1980 to August 2014.

## FULL REVIEW

### Systematic review question

What is the relationship between dietary patterns consumed and neurocognitive health?

### Conclusion statement and grade

Limited evidence suggests that dietary patterns containing vegetables, fruits, unsaturated vegetable oils and/or nuts, legumes, and fish or seafood consumed during adulthood are associated with lower risk of age-related cognitive impairment and/or dementia. (Grade: Limited)

### Summary of the evidence

- This systematic review update includes 26 articles that met inclusion criteria and were published between January 2014 and February 2020.
  ○ Four studies were randomized controlled trials.^1–4^
  ○ Twenty-two articles were from observational studies, with 21 prospective cohort designs and 1 nested-case control design.^5–26^
  ○ This body of evidence updates and builds upon the existing systematic review, which consisted of 30 articles from a wide range of study designs that used different methods to measure neurocognitive outcomes but produced relatively consistent findings.
  ○ Dietary patterns were defined as the quantities, proportions, variety, or combination of different foods, drinks, and nutrients (when available) in diets, and the frequency with which they are habitually consumed.
- Studies in this update to the existing review produced similarly consistent results regarding the relationship between dietary patterns in adults and age-related cognitive decline, mild cognitive impairment, and/or dementia
  ○ Dietary patterns were examined using various approaches including 17 studies that examined adherence to a dietary pattern using indices/scores, 4 articles identified dietary patterns using factor/cluster analysis, and 1 study used reduced rank regression.
  ○ Outcomes were measured using various approaches and reported as global cognition, cognitive performance, mild cognitive impairment, and/or incident dementia.
    ■ The majority of significant findings reported dietary patterns consumed during adulthood were “protective” in either improving measures of cognitive impairment and/or reducing risk of cognitive impairment or dementia. These protective dietary patterns contained vegetables, fruits, unsaturated vegetable oils and/or nuts, legumes, and fish or seafood. Many of these dietary patterns also emphasized whole grains, non-refined grains, or (non-refined) breads/cereals.
    ■ Not all of these protective dietary patterns contained alcoholic beverages. The benefit of the overall dietary pattern with the outcome was still observed if alcoholic beverages, particularly red wine, were included.
  ○ Non-significant findings or those reporting mixed associations reported dietary patterns consumed during adulthood did not worsen cognitive outcomes.
  ○ There are numerous limitations across the body of evidence, including the lack of RCT’s, considerable variation in testing methods used, validity and reliability of the methods used, the dietary patterns and cognitive outcomes examined.
- The 2020 Dietary Guidelines Advisory Committee updates, concurs, and builds upon the conclusion drawn by the 2015 Dietary Guidelines Advisory Committee.^27^

### Description of the evidence

This systematic review update includes 26 articles that examined the relationship between dietary patterns and neurocognitive health. Four studies were randomized controlled trials (RCTs) and 22 articles were from observational studies, with 21 prospective cohort designs and 1 nested-case control.

#### Population/participant characteristics

The articles examining the relationship between dietary patterns and neurocognitive health were conducted in the following countries:

- Australia
- Finland
- France
- Japan
- Netherlands
- Singapore
- Sweden
- United Kingdom
- United States

Two articles were from studies conducted in participants from several countries: one was conducted in France, Italy, Netherlands, Poland, and United Kingdom^2^ and the other in 40 different countries.^21^ The analytic sample size ranged from 137 to 27,842.

Data from these studies represented several established cohorts, including the Nurses’ Health Study (NHS), Health Professionals’ Follow-up Study (HPFS), Women’s Health Initiative (WHI) Memory study, Atherosclerosis Risk in Communities (ARIC) study, Swedish National study on Aging and Care-Kungsholmen (SNAC-K), Whitehall II cohort, and EPIC-Norfolk. Although multiple articles from the same cohorts were included, the included articles represented unique data by examining different sub-samples, dietary patterns, neurocognitive health outcomes, or using different dietary pattern methods.

Studies included participants who were healthy and/or at risk of chronic disease, and primarily middle-aged or older adults. In two studies, baseline age at enrollment was < 30y.^13,26^ Several articles exclusively enrolled women^1,7,8,11,24,26^ or men.^9^ All other studies combined and/or stratified analyses of men and women. Several studies excluded participants with dementia or conditions that may cause cognitive impairment, prevalent chronic diseases (e.g., cancer, CVD) at baseline, or those who reported race other than White or Black.

#### Intervention/exposure

Dietary intake was primarily assessed using validated food frequency questionnaires (FFQs) at one time-point (i.e., baseline). However, several studies collected dietary data at multiple time points, used a cumulative average or mean of multiple time points, or used validated 24-h dietary recalls or history methods.

Dietary patterns were assessed with various methods. Four RCTs assigned participants to consume a particular dietary pattern as an intervention diet relative to control diet groups. Most (17) of the observational studies examined adherence to a dietary pattern using indices/scores, four articles identified dietary patterns using factor/cluster analysis, and one study used reduced rank regression.

#### Outcome assessment

Studies examined age-related cognitive impairment, decline, and/or dementia over follow-up (f/u) as short as 3mo (in RCTs) up to 30y (in observational studies). No studies that met inclusion criteria examined incidence of diagnosed Alzheimer’s disease. Among the included studies, cognitive impairment, cognitive function, and/or dementia were reported by studies using a variety of assessment methods including:

- Consortium to Establish a Registry for Alzheimer’s Disease (CERAD) Battery
- Mini-Mental State Examiniation (MMSE)
- Telephone Interview for Cognitive Status (TICS), a telephone-adaption of MMSE to assess overall cognitive performance
- Six-item screener (SIS) via telephone
- Short Form Extended Mental State Exam (SF-EMSE)
- Subjective memory complaints (SMCs)

### Evidence synthesis

#### Description of results

##### Randomized controlled trials (RCTs)

Four RCT’s examined the relationship between dietary patterns and cognitive impairment, global cognitive function/decline, or probable dementia that are summarized below and further in Table 1.

- Chlebowski et al^1^ reported from the Women’s Health Initiative Memory study that postmenopausal women, n=1606, who consumed the intervention diet aimed at reducing total fat to 20% energy/d, consuming 5 servings/d of fruits and vegetables, and 6 servings/d of grains, compared to the control group, reduced the risk of possible or mild cognitive impairment and probable dementia at ~8.5y f/u.
- Effects reported in Marseglia et al^2^ showed that n=1144 participants with higher vs. lower “Nu-AGE diet”, which provided participants with whole grain pasta, margarine rich in poly-unsaturated fatty acids (PUFA) and monounsaturated fatty acids (MUFA), low fat, low-salt cheese, extra virgin olive oil (EVOO) and frozen vegetable soup, had significant improvements in global cognition and episodic memory scores after 1y. However, no significant differences were observed between groups in cognitive domains after 1y.
- Two RCTs examined different versions of a “Mediterranean” diet.
  ○ Knight et al^3^ assigned participants to consume a “MedDiet”, consisting of: EVOO; breads and cereals; legumes; vegetables; fish; fruit; cheese; red wine (upon participants choice, not compulsory); Greek yoghurt; Nuts; potato (white); Milk; eggs provided; “Free foods”: legumes, Greek yoghurt, Australian EVOO, canned tuna, walnuts, peanuts, and almonds compared to control group consuming their customary diet. No significant effects were identified, n=137, between the “MedDiet” and control diet on better or worse cognitive function after 3 or 6mo.
  ○ Valls-Pedret et al^4^ examined n=334 participants randomized to consume either a control diet or one of two different Mediterranean diets, with each emphasizing abundant olive oil, vegetables, fresh fruit and juices, legumes, fish or seafood, nuts and seeds, select white meat instead of red or processed meats, cook regularly with tomato, garlic and onion; wine preferred if consuming alcohol; ad libitum nuts, eggs, fish, seafood, low-fat cheese, chocolate, and whole-grain cereals. Each intervention diet differed by the addition of either EVOO (Med+EVOO) or nuts (Med+Nuts), compared to control group consuming their customary diet. Valls-Pedret et al^4^ reported that participants consuming the Med+EVOO compared to control diets showed significantly better executive function and global cognition. However, participants in the Med+Nuts compared to control diet group showed significant effects for improved memory, but not executive function or global cognition after ~5y.

##### Observational studies

Twenty-two observational studies examined the relationship between dietary patterns and age-related cognitive outcomes, including global cognitive decline, risk of cognitive impairment, and/or risk of (probable) dementia. Studies are summarized below and described further in Table 2.

###### Indices/scores

###### Dietary Guidelines-related indices/scores

Studies reported lower risk of cognitive decline/impairment as follows:

- Smyth et al^21^ reported that extreme quintiles of highest vs. lowest adherence to the Alternative Healthy Eating Index (AHEI) was significantly associated with less cognitive decline during 5y f/u, both overall and in those with MMSE 26-28 or >28 at baseline, as well as those with moderate or high physical activity at baseline.
- Wu et al^25^ reported that higher vs. lower adherence to the AHEI-2010 was significantly associated with lower risk of cognitive impairment at 20y f/u.

Studies reported no significant associations as follows:

- Akbaraly et al^6^ reported that AHEI-2010 score during midlife was not significantly associated with subsequent risk for dementia or cognitive decline during 25y f/u.
- Haring et al^11^ reported that Healthy Eating Index-2010 (HEI-2010) or AHEI-2010 scores across quintiles were not significantly associated with mild cognitive impairment, probable dementia, or incidence of either at ~9y f/u.
- Richard et al^16^ reported no significant associations between AHEI-2010 adherence and cognitive outcomes.

###### Mediterranean related indices/scores

Studies reported lower risk of cognitive decline/impairment as follows:

- Richard et al^16^ reported that higher vs. lower adherence to the alternative Mediterranean (aMED) score was significantly associated with better cognitive function.
- Bhushan et al^9^ reported that higher vs. lower Mediterranean dietary pattern adherence is significantly associated prospectively with better cognitive function in men.
- Shannon et al^20^ reported that higher adherence to three Mediterranean diet (MedDiet) scores was significantly associated with better performance on global cognition during 14y f/u in middle-aged adults. There was no significant association with the diet scores and other aspects of cognitive performance (i.e., retrospective memory, attention, or complex processing speed). MedDiet pyramid adherence score was significantly associated with better performance in simple processing speed and retrospective memory, but the other two scores were not.
- Shakersain et al^19^ reported that higher vs. lower adherence (both continuously and categorically) the Mediterranean-DASH diet Intervention for Neurodegenerative Delay (MIND) pattern, and MedDiet score in older adults was significantly associated with less MMSE decline at 6y f/u.
- Wagner et al^24^ reported that cases of cognitive decline compared to controls without had lower adherence to A-MeDi after 1y f/u.
- Wu et al^25^ reported that aMED adherence was significantly associated with lower risk of cognitive impairment at 20y f/u.
- McEvoy et al^13^ reported that higher vs. lower MedDiet adherence was significantly associated with less decline in cognitive function during 30y f/u.

Studies reported no significant associations as follows:

- Haring et al^11^ reported that aMED score across quintiles was not significantly associated with mild cognitive impairment, probable dementia (PD), or incidence of either at ~9y f/u.
- Adjibade et al^5^ reported that MIND diet score was significantly associated with reduced risk of cognitive difficulty only in those age ≥70y, and not significantly associated with cognitive difficulty in total sample at 6y f/u.
- Berendsen et al^8^ reported that long-term MIND score adherence was not significantly associated with change over time in the global cognitive or TICS scores over 6y f/u in women.

###### DASH scores

Studies reported lower risk of cognitive decline/impairment as follows:

- Wu et al^25^ reported that higher vs. lower DASH score was significantly associated with lower risk of cognitive impairment at 20y f/u.

Studies reported no significant associations as follows:

- Haring et al^11^ reported that DASH score across quintiles was not significantly associated with mild cognitive impairment, probable dementia, or incidence of either at ~9y f/u.
- Berendsen et al^7^ reported that highest DASH diet quintile vs. lowest was significantly associated with average cognitive function, but not significantly associated with change in cognitive function over 4y f/u in women.
- McEvoy et al^13^ reported no significant association between DASH score and cognitive function.
- Shakersain et al^19^ reported that DASH adherence (continuous, or high vs. moderate) was not significantly associated with dementia over 6y f/u.

###### Country-specific indices/scores

Studies that reported lower risk of cognitive decline/impairment, as follows:

- Shakersain et al^18,19^ reported that higher vs. lower adherence (both continuously and categorically) to the Nordic Prudent dietary pattern in older adults was significantly associated with less MMSE decline at 6y f/u.
- Shakersain et al^19^ reported that BSD adherence, high vs. moderate, was not significantly associated with dementia over 6y f/u. However, when BSD was examined continuously with cognitive decline as MMSE ≤24, there was a significant association with lower risk of decline.

Studies that reported no significant associations, as follows:

- Voortman et al^23^ reported that Dutch Dietary Guidelines adherence score was not significantly associated with dementia at median 13.5y f/u.
- Mannikko et al^12^ reported that Nordic diet score was not significantly associated with cognitive function at 4y f/u.

###### Other indices/scores

Studies that reported significantly lower risk of cognitive decline/impairment, i.e., better health outcomes, as follows:

- McEvoy et al^13^ reported that higher vs. lower APDQS adherence was significantly associated with less decline in cognitive function during 30y f/u.
- Zhu et al^26^ reported that higher vs. lower APDQS was significantly associated with better cognitive test results at 25y f/u.
- Wu et al^25^ reported that higher vs. lower PDI or hPDI adherence scores were significantly associated with was significantly associated with lower risk of cognitive impairment at 20y f/u.

Studies that reported significantly higher risk of cognitive decline/impairment, as follows:

- Akbaraly et al^6^ reported that higher “Healthy food” scores at midline were significantly associated with greater cognitive decline during 25y f/u.

###### Reduced Rank Regression (RRR)

Ozawa et al^14^ reported higher vs. lower “inflammatory” dietary pattern consumption was significantly associated with greater decline in cognitive function over 10y f/u.

###### Factor/cluster

Studies that reported lower risk of cognitive decline/impairment, as follows:

- Pearson et al^15^ examined five dietary patterns identified by factor analysis. Higher vs. lower consumption of the “alcohol/salads” dietary pattern, characterized by high loadings of green-leafy vegetables, tomatoes, salad dressing, wine and liquor, was significantly associated with lower odds of cognitive decline at 7y f/u.
- Shakersain et al^17^ examined two dietary patterns identified by factor analysis: “Prudent” dietary pattern reflected more vegetables, fruit, cooking/dressing oil, cereals and legumes, whole grains, rice/pasta, fish, low-fat dairy, poultry, and water; whereas the “Western” dietary pattern reflected more red/processed meat, saturated/trans-fat, refined grains, sugar, beer, and spirits. Higher vs. lower adherence to the “Prudent” dietary pattern was significantly associated with less MMSE decline at 6y f/u. Highest adherence to the “Western” dietary pattern was significantly associated with more MMSE decline at 6y f/u, but this association was attenuated when accompanied by high “Prudent” dietary pattern adherence.
- Tomata et al^22^ reported higher adherence to the ‘Japanese dietary pattern’ (emphasizing fish, vegetables, mushrooms, potato, seaweeds, pickles, soybean, and fruits) was significantly associated with reduced dementia risk in older Japanese adults over a 6y f/u. There was no significant association between the ‘animal food’ pattern or ‘high-dairy’ pattern and dementia risk.

Studies that reported no significant association, as follows:

- Dearborn-Tomazos et al^10^ examined two dietary patterns identified by factor analysis. Consumption of either the “Western” or “Prudent” dietary patterns (“Western”: characterized by higher consumption of meats, refined grains, and fried foods; “Prudent”: characterized by higher amounts of fruits and vegetables, fish, chicken, whole grains, dairy, nuts, and alcohol) at midlife was not significantly associated with global cognitive function, 20y change in cognitive function, or risk of dementia.

#### Assessment of the evidence^ii^

Of the 26 articles, four were included from RCTs and 22 articles from observational studies. There were few well-designed controlled trials upon which to draw stronger conclusions. However, findings from the observational studies were generally supportive of the findings from the RCTs. Overall, there was limited evidence that suggests that dietary patterns containing vegetables, fruits, unsaturated vegetable oils and/or nuts, legumes, and fish or seafood consumed during adulthood are associated with lower risk of age-related cognitive impairment and/or dementia. See the summary of risk of bias for RCTs in Table 3 and observational studies in Table 4 for additional details. As outlined and described below, the body of evidence examining exposure and outcome was assessed for the following elements used when grading the strength of evidence

- Risk of bias: There were a number of potential risks of bias, or limitations, across the body of evidence (Table 3 and Table 4). While studies adjusted for most potential confounders, they did not adjust for all key confounders, including race/ethnicity and/or family history of neurocognitive disorders in particular. Several observational studies examined diet only once at baseline, and therefore, the effects of dietary patterns overtime may not be determined. However, several studies did examined diet at multiple time points over f/u, although there was a large range of time between assessments in some cases (e.g., a span of over 20 y). Several studies did not assess the impact of missing data, primarily due to criteria used when selecting subjects into the analyses. Many of the studies excluded participants with baseline dementia or conditions that may cause cognitive impairment, prevalent chronic diseases (e.g., cancer, CVD). Therefore, selected samples likely reflect generally healthier individuals. Some studies used telephone interviews to ascertain cognitive function outcomes of participants via self-reported data. Although the assessments were valid, these studies may be at higher risk of bias in outcome measurement.
- Consistency: Studies varied widely in the methods used to examine dietary patterns, including different indices/scores to examine adherence, factor/cluster analysis to identify dietary patterns, and reduced rank regression. Consistent direction and magnitude of effects were observed in 3 of the 4 RCTs, with generally supportive findings from many, but not all, observational studies. It is noteworthy that some studies showed either no significant associations or mixed associations when examining different dietary patterns among the same participants (i.e., within studies) or between studies. Despite variability in results, many of the studies supported dietary patterns associated with less cognitive decline or lower risk of dementia/cognitive impairment that share the following elements in common: vegetables, fruits, unsaturated vegetable oils and/or nuts, legumes, and fish or seafood. Less consistent elements that were considered across these “protective” dietary patterns included alcohol (wine preferred) and low-fat cheese and/or dairy products. Many of these dietary patterns also emphasized whole grains, non-refined grains, or (non-refined) breads/cereals. Fewer studies examined dietary patterns that relate to “worse” cognitive outcomes. Dietary patterns characterized as “unhealthy”, emphasizing fried foods, processed and/or red meats, refined grains, desserts (pies, chocolate, sweets), and high-fat dairy products showed inconsistent findings, some associating with greater cognitive decline but primarily non-significant associations overall. Additionally, there was considerable variation in the outcome assessment methods used between studies, which included cognitive assessment techniques that may be insensitive. There was relative inconsistency in the magnitude and direction of findings within individual studies if multiple behavioral measures were used.
- Precision: All of the RCTs conducted power calculations and identified an adequate number of cases of possible and/or mild cognitive impairment or probable dementia with analytic sample sizes ranging from n=137 to n=1606 over an average f/u between 3mo and 8.5y, with some degree of imprecision. Observational studies that reported significant results had relatively narrow confidence intervals, though results varied. Although these studies did not report sample size calculations, analytic sample sizes were generally large ranging from n=1140 to n=27,860.
- Directness: Most studies were designed to directly examine the relationship between the populations, intervention, comparators, and outcomes of interest related to the systematic review question. Several studies examined better/worse global cognition or performance on cognitive tests, which were less direct than the majority of studies examining incident cognitive impairment or dementia.
- Generalizability: The interventions and/or exposures, comparators, and outcomes examined in the body of evidence are likely applicable to the U.S. population. However, results are most generalizable to the generally healthy, older adults. Few studies reported information on or accounted for race/ethnicity of participants, and therefore, the results may be less generalizable in populations of diverse racial/ethnic backgrounds.

The 2020 Dietary Guidelines Advisory Committee updates, concurs, and builds upon the conclusion drawn by the 2015 Dietary Guidelines Advisory Committee. The 2015 Advisory Committee concluded that, limited evidence suggests that a dietary pattern containing an array of vegetables, fruits, nuts, legumes and seafood consumed during adulthood is associated with lower risk of age-related cognitive impairment, dementia and Alzheimer’s disease. In 2015, although the number of studies available on dietary patterns and neurodegenerative disease risk is expanding, that body of evidence was made up of high-quality observational studies that appeared only in recent years, was rapidly developing, and employed a wide range of methodology in study design, definition and measurement ascertainment of cognitive outcomes and dietary pattern assessment. The newly published body of evidence has similar results with a similar volume of articles, though a few additional RCTs.

### Research recommendations

In order to better assess the relationship between dietary patterns and neurocognitive health, future research may:

1. Examine the relationship between dietary patterns earlier in life and neurocognitive health to elucidate any preventative effects diet may have prior to the onset of cognitive impairment, after which diet may be less influential.
2. Explore objective measurements of brain function beyond the scope outlined for thisreview, such as structural magnetic resonance imaging scans with grey/white matter volume or density outputs (e.g., magnetization-prepared rapid acquisition with gradient echo (MPRAGE) data) and/or functional imaging techniques such as blood-oxygen level-dependent data (BOLD) (i.e., data from functional magnetic resonance imaging) or positron emission tomography (PET), which may provide additional insight into mechanisms that underlie cognitive impairment diagnoses and can potentially be connected to prevention strategies within the context of dietary patterns.
3. Utilize standardized behavioral assessments to determine cognitive decline.
4. Assess information regarding diet at more than one time-point, preferably during the course of follow-up, to facilitate determining change in dietary patterns over time.
5. Provide sufficient information and repeated measures on the quantification, i.e., types and amounts of foods/food groups comprising a dietary pattern, such as fruits and vegetables, and beverages such as alcohol, consumed.
6. Identify inadequate or excessive intakes of specific foods/food groups (e.g., fruits, vegetables, whole grains, legumes, EVOO, nuts, fish or seafood, and also, sugar sweetened beverages, processed foods including processed meats, added sugars, and salt) to better speak to diet quality due to the limited utility of the “total score” from a given dietary pattern (e.g., “Mediterranean diet”, aHEI, and DASH scores).
7. Explore the relationship between dietary patterns and neurocognitive health further, particularly beyond the capacity of the current review by investigating factors such as
  ○ weight status/BMI (e.g., to determine the response to dietary patterns in those who are classified as overweight or obese, or those with excess adiposity),
  ○ physical activity (e.g., to determine the response to dietary patterns in those who may be sedentary compared to active),
  ○ emerging biomarkers including metabolites and microbes reflecting different food-based patterns of intake and their associations with traditional chronic disease risk factors to more directly assess the relative preventative merits of various dietary patterns, and
  ○ household food insecurity status (e.g., to determine the response to dietary patterns in those with higher or lower food security, with progressing or persistent household food insecurity, or food security insufficiency).
8. Include diverse populations with varying race/ethnicity, socioeconomic background, and chronic disease status, while ensuring to report the racial/ethnic background of participants studied.
9. Include conducting systematic reviews with a continuous model to better document the current state of science on high priority topics, such as the role of dietary patterns and neurocognitive health.

### Included articles

1 Chlebowski RT, Rapp S, Aragaki AK, . Low-fat dietary pattern and global cognitive function: exploratory analyses of the Women’s Health Initiative (WHI) randomized Dietary Modification trial. EClinicalMedicine. 2020;18:100240. doi:10.1016/j.eclinm.2019.100240.31938786
2 Marseglia A, Xu W, Fratiglioni L, . Effect of the NU-AGE diet on cognitive functioning in older adults: a randomized controlled trial. Front Physiol. 2018;9:349. doi:10.3389/fphys.2018.00349.29670545
3 Knight A, Bryan J, Wilson C, Hodgson JM, Davis CR, Murphy KJ. The Mediterranean diet and cognitive function among healthy older adults in a 6-month randomised controlled trial: the MedLey Study. Nutrients. 2016;8(9). doi:10.3390/nu8090579.
4 Valls-Pedret C, Sala-Vila A, Serra-Mir M, . Mediterranean diet and age-related cognitive decline: a randomized clinical trial. JAMA Intern Med. 2015;175(7):1094–1103. doi:10.1001/jamainternmed.2015.1668.25961184
5 Adjibade M, Assmann KE, Julia C, Galan P, Hercberg S, Kesse-Guyot E. Prospective association between adherence to the MIND diet and subjective memory complaints in the French NutriNet-Sante cohort. J Neurol. 2019;266(4):942–952. doi:10.1007/s00415-019-09218-y.30706155
6 Akbaraly TN, Singh-Manoux A, Dugravot A, Brunner EJ, Kivimaki M, Sabia S. Association of midlife diet with subsequent risk for dementia. JAMA. 2019;321(10):957–968. doi:10.1001/jama.2019.1432.30860560
7 Berendsen AAM, Kang JH, van de Rest O, Feskens EJM, de Groot L, Grodstein F. The Dietary Approaches to Stop Hypertension diet, cognitive function, and cognitive decline in american older women. J Am Med Dir Assoc. 2017;18(5):427–432. doi:10.1016/j.jamda.2016.11.026.28108204
8 Berendsen AM, Kang JH, Feskens EJM, de Groot C, Grodstein F, van de Rest O. Association of long-term adherence to the MIND diet with cognitive function and cognitive decline in american women. J Nutr Health Aging. 2018;22(2):222–229. doi:10.1007/s12603-017-0909-0.29380849
9 Bhushan A, Fondell E, Ascherio A, Yuan C, Grodstein F, Willett W. Adherence to Mediterranean diet and subjective cognitive function in men. Eur J Epidemiol. 2018;33(2):223–234. doi:10.1007/s10654-017-0330-3.29147948
10 Dearborn-Tomazos JL, Wu A, Steffen LM, . Association of dietary patterns in midlife and cognitive function in later life in us adults without dementia. JAMA Netw Open. 2019;2(12):e1916641. doi:10.1001/jamanetworkopen.2019.16641.31800068
11 Haring B, Wu C, Mossavar-Rahmani Y, . No association between dietary patterns and risk for cognitive decline in older women with 9-year follow-up: data from the Women’s Health Initiative Memory Study. J Acad Nutr Diet. 2016;116(6):921–930.e921. doi:10.1016/j.jand.2015.12.017.27050728
12 Mannikko R, Komulainen P, Schwab U, . The Nordic diet and cognition-The DR’s EXTRA Study. Br J Nutr. 2015;114(2):231–239. doi:10.1017/s0007114515001890.26104270
13 McEvoy CT, Hoang T, Sidney S, . Dietary patterns during adulthood and cognitive performance in midlife: the CARDIA study. Neurology. 2019;92(14):e1589–e1599. doi:10.1212/wnl.0000000000007243.30842290
14 Ozawa M, Shipley M, Kivimaki M, Singh-Manoux A, Brunner EJ. Dietary pattern, inflammation and cognitive decline: the Whitehall II prospective cohort study. Clin Nutr. 2017;36(2):506–512. doi:10.1016/j.clnu.2016.01.013.26874911
15 Pearson KE, Wadley VG, McClure LA, Shikany JM, Unverzagt FW, Judd SE. Dietary patterns are associated with cognitive function in the REasons for Geographic And Racial Differences in Stroke (REGARDS) cohort. J Nutr Sci. 2016;5:e38. doi:10.1017/jns.2016.27.27752305
16 Richard EL, Laughlin GA, Kritz-Silverstein D, Reas ET, Barrett-Connor E, McEvoyLK. Dietary patterns and cognitive function among older community-dwelling adults. Nutrients. 2018;10(8). doi:10.3390/nu10081088.
17 Shakersain B, Santoni G, Larsson SC, . Prudent diet may attenuate the adverse effects of Western diet on cognitive decline. Alzheimers Dement. 2016;12(2):100–109. doi:10.1016/j.jalz.2015.08.002.26342761
18 Shakersain B, Rizzuto D, Wang HX, . An active lifestyle reinforces the effect of a healthy diet on cognitive function: a population-based longitudinal study. Nutrients. 2018;10(9). doi:10.3390/nu10091297.
19 Shakersain B, Rizzuto D, Larsson SC, Faxen-Irving G, Fratiglioni L, Xu WL. The Nordic Prudent diet reduces risk of cognitive decline in the Swedish older adults: a population-based cohort study. Nutrients. 2018;10(2). doi:10.3390/nu10020229.
20 Shannon OM, Stephan BCM, Granic A, . Mediterranean diet adherence andcognitive function in older UK adults: the European Prospective Investigation into Cancer and Nutrition-Norfolk (EPIC-Norfolk) Study. Am J Clin Nutr. 2019;110(4):938–948. doi:10.1093/ajcn/nqz114.31204785
21 Smyth A, Dehghan M, O’Donnell M, . Healthy eating and reduced risk ofcognitive decline: a cohort from 40 countries. Neurology. 2015;84(22):2258–2265. doi:10.1212/wnl.0000000000001638.25948720
22 Tomata Y, Sugiyama K, Kaiho Y, . Dietary patterns and incident dementia inelderly Japanese: the Ohsaki Cohort 2006 study. J Gerontol A Biol Sci Med Sci. 2016;71(10):1322–1328. doi:10.1093/gerona/glw117.27356978
23 Voortman T, Kiefte-de Jong JC, Ikram MA, . Adherence to the 2015 Dutchdietary guidelines and risk of non-communicable diseases and mortality in the Rotterdam Study. Eur J Epidemiol. 2017;32(11):993–1005. doi:10.1007/s10654-017-0295-2.28825166
24 Wagner M, Grodstein F, Proust-Lima C, Samieri C. Long-term trajectories of bodyweight, diet, and physical activity from midlife through late-life and subsequent cognitive decline in women. Am J Epidemiol. 2019. doi:10.1093/aje/kwz262.
25 Wu J, Song X, Chen GC, . Dietary pattern in midlife and cognitive impairment inlate life: a prospective study in Chinese adults. Am J Clin Nutr. 2019;110(4):912–920. doi:10.1093/ajcn/nqz150.31374567
26 Zhu N, Jacobs DR, Meyer KA, . Cognitive function in a middle aged cohort isrelated to higher quality dietary pattern 5 and 25 years earlier: the CARDIA study. J Nutr Health Aging. 2015;19(1):33–38. doi:10.1007/s12603-014-0491-7.25560814
27 Dietary Guidelines Advisory Committee. Scientific Report of the 2015 Dietary Guidelines Advisory Committee: Advisory Report to the Secretary of Health and Human Services and the Secretary of Agriculture. Washington, DC: US Department of Agriculture, Agricultural Research Service. https://health.gov/sites/default/files/2019-09/Scientific-Report-of-the-2015-Dietary-Guidelines-Advisory-Committee.pdf. Published 2015. Accessed June 25, 2020.

Table 1 Description of randomized controlled trials that examined the relationship between dietary patterns and cognitive impairment, dementia, or Alzheimer’s disease^iii^

Study and Participant Characteristics^iv^ | Intervention/Exposure | Results | Methodological Considerations
Chlebowski, 2020 ^1^; United States Women’s Health Initiative (WHI) Memory study; N=1606; 100% female, postmenopausal, Baseline age: ≥65y | [underlined: Other:]; Intervention: Guidance to reduce total fat from ~35% to 20% of energy, consume 5 servings/d fruits and vegetables, 6 serving/d grains; Control: Received written health-related materials only | Intervention n=41 vs. Control n=85 and overall possibile cognitive impairment [n=52] at ~8.5y f/u:; - HR: 0.59, 95% CI: 0.35, 0.91, p=0.01; Intervention n=20 vs. Control n=37 and mild cognitive impairment [n=57] at ~8.5y f/u:; - HR:0.65, 95% CI: 0.35, 1.19; Intervention n=7 vs. Control n=10 and probable dementia [n=17] at ~8.5y f/u:; - HR: 0.63, 95% CI: 0.19, 2.10; Effect of diet strongest in those with lowest MMSE scores; Effect of diet on risk of dementia remained when considering age, race/ethnicity, education, smotking, HRT, randomization, BMI, WC, HTN, and diabetes; | [underlined: Accounted for:] Sex, Age, Race/ethnicity, SES, Alcohol intake, Physical activity, Anthropometry, Smoking, Family history of NCD; [underlined: Limitations:]; - Did not account for: N/A; [underlined: Summary:] Intervention diet reduced the risk of possible or mild cognitive impairment and probable dementia in women; Funding: NHLBI; NIH; HHS
Knight, 2016 ^3^; Australia; MedLey study; N=137; Baseline age: ~72y; Exclusions: conditions that may cause cognitive impairment | Mediterranean diet, ‘MedDiet’, vs. Control diet, ‘HabDiet’; - MedDiet: Extra virgin olive oil (EVOO); breads and cereals; legumes; vegetables; fish; fruit; cheese; red wine (upon participants choice, not compulsory); Greek yoghurt; nuts; potato (white); milk; eggs provided; “Free foods”: legumes, Greek yoghurt, Australian EVOO, canned tuna, walnuts, peanuts and almonds; - Control: consume customary dietary pattern with supermarket gift vouchers | At 3mo or 6mo f/u:; - Total cognitive function: NS; - Age-related cognitive function: NS | [underlined: Accounted for:] Sex, Age, Race/ethnicity, SES, Alcohol intake, Physical activity, Anthropometry, Smoking, Family history of NCD; [underlined: Limitations:]; - Did not account for: N/A; [underlined: Summary:] MedDiet consumption did not improve or worsen cognitive function after 3 or 6mo; [underlined: Funding:] National Health Medical Research Council (NHMRC); University of South Australia Postgraduate Award
Marseglia, 2018 ^2^; France, Italy, Netherlands, Poland, United Kingdom; NU-AGE; N=1144; Baseline age: 65-79y; Exclusions: heart diseases, diabetes, chronic corticosteroid user, recent antibiotic user, recent change in habitual medication use, frailty, malnutrition, or those on special diets. | [underlined: Other:]; “Nu-AGE" diet (provided participants with whole grain pasta, margarine rich in PUFA and MUFA, low fat, low-salt cheese, extra virgin olive oil (EVOO) and frozen vegetable soup) adherence vs. habitual diet control group; analyzed in tertiles (low, moderate, high) | Nu-AGE vs. Control [ITT] and outcomes at 1y f/u:; - Δ in MMSE; NS; - Global cognition (CERAD + MMSE), NS; Nu-AGE vs. Control [adherence, tertiles] and outcomes at 1y f/u:; - Δ in MMSE; NS; - Global cognition (CERAD + MMSE):; ○ T2 vs. T1 ref: 0.20, 95% CI: 0.004, 0.39, p<0.05; ○ T3 vs. T1 ref: 0.16, 95% CI: 0.02, 0.35, p<0.10; Effects remained similar after exclusion of non-complete data, those with mental health conditions, or stratification by education, enrollment, baseline cognitive or pre-frail status | [underlined: Accounted for:] Sex, Age, SES: Education, Anthropometry, Other: Enrollment country, Interviewer, Pre-frailty; [underlined: Limitations:]; - Did not account for: Race/ethnicity, Alcohol intake, Physical activity, Smoking, Family history of NCD [data not shown regarding these factors]; [underlined: Summary:] Participants with higher vs. lower Nu-AGE diet adherence had significant improvements in global cognition and episodic memory scores. No significant differences between groups in global cognition or cognitive domains after 1y.; [underlined: Funding:] European Union’s Seventh Framework Program; Swedish Research Council; the National Natural Science Foundation of China; the Konung Gustaf V:s och Drottning Victorias Frimurare Foundation; European Union’s Horizon 2020 research and innovation programme
Valls-Pedret, 2015 ^4^; Spain; PREDIMED; N=334; Baseline age: 67y; Exclusively at-risk with either type 2 diabetes or ≥3 CVD-risk factors | Mediterranean diet plus nuts, Med+nuts or Mediterranean diet plus EVOO, Med+ EVOO vs. Control; - Med+nuts: abundant olive oil, vegetables, fresh fruit and juices, legumes, fish or seafood, nuts and seeds, select white meat instead of red or processed meats, cook regularly with tomato, garlic and onion; wine preferred (if consuming alcohol); ad libitum nuts, eggs, fish, seafood, low-fat cheese, chocolate, whole-grain cereals; + 15g/d walnuts, 7.5g/d almonds, and 7.5g/d hazelnuts; - Med+EVOO: abundant olive oil, vegetables, fresh fruit and juices, legumes, fish or seafood, nuts and seeds, select white meat instead of red or processed meats, cook regularly with tomato, garlic and onion; wine preferred if consuming alcohol; ad libitum nuts, eggs, fish, seafood, low-fat cheese, chocolate, whole-grain cereals + 15L EVOO; - Control diet, low-fat: advice to reduce dietary fat; Diet assesed with validated FFQ at baseline | Med+Nuts [n=8 incident cases of mild cognitive impairment] vs. Control [n=12 incident cases of mild cognitive impairment] and:; - Global cognitive function, NS; Med+EVOO [n=37 incident cases of mild cognitive impairment] vs. Control [n=12 incident cases of mild cognitive impairment] and:; - Global cognitive function, p<0.01 | [underlined: Accounted for:] Sex, Age, Race/ethnicity, SES, Alcohol intake, Physical activity, Anthropometry, Smoking, Family history of NCD; [underlined: Limitations:]; - Did not account for: N/A; [underlined: Summary:] Med+EVOO compared to control diets showed significant effects for better executive function and global cognition. Med+Nuts compared to control diets showed significant effects for improved memory.; [underlined: Funding:] Institute de Salud Carlos III, Ciber Fisiopatologia de la Obesidad y Nutrición

Table 2 Description of observational studies that examined the relationship between dietary patterns and cognitive impairment, dementia, or Alzheimer’s disease^v^

Study and Participant Characteristics^vi^ | Intervention/Exposure | Results | Methodological Considerations
Adjibade, 2019 ^5^; France; Prospective cohort study; NutriNet-Sante cohort; N=6011; Baseline age: ≥60y | [underlined: Index analysis:]; Mediterranean-DASH diet intervention for neurodegenerative delay (MIND) diet adherence score by tertiles and continuous; - “Healthy brain foods”: green leafy vegetables, other vegetables, nuts, berries, beans, whole grains, fish, poultry, olive oil, and wine; - “Unhealthy brain foods”: red meats, butter and margarine, cheese, pastries and sweets, and fast fried; Sensitivity analyses conducted with the dietary-only French Programme National Nutrition Santé-Guideline Score (mPNNS-GS); Diet collected every 2y with validated 24-h dietary records | MIND score and risk of high cognitive difficulties (Subjective memory complaints, SMC ≥43) at 6y f/u: NS; MIND score in age ≥60y and risk of high cognitive difficulties at 6y f/u: NS; MIND score in age 70+y and risk of high cognitive difficulties at 6y f/u:; - Continuous: HR: 0.87, 95% CI: 0.78; 0.98; p=0.02; - T3 vs. T1 ref: NS; - T2 vs. T1 ref: NS; mPNNS-GS and risk of high cognitive difficulties at 6y f/u: NS | [underlined: Accounted for:] Sex, Age, SES: Marital status, Education, Occupation, Income, Anthropometry: BMI, Alcohol: Part of dietary pattern, Physical activity, Smoking; Other: energy intake, number of recording days, inclusion month, comborbid conditions, depressive symptoms, baseline SMC; [underlined: Limitations:]; - Did not account for: Race/ethnicity, Family history of NCD; [underlined: Summary:] MIND diet score was significantly associated with reduced risk of cognitive difficulty only in those age ≥70y, and not significantly associated with cognitive difficulty in total sample at 6y f/u.; [underlined: Funding:] French Ministry of Health; French Public Health Agency; French National Institute for Health and Medical Research; Medical Research Foundation; French National Institute for Agricultural Research; National Conservatory for Arts and Crafts; National Institute for Prevention and Health Education; Paris 13 University
Akbaraly, 2019 ^6^; United Kingdom; Prospective cohort study; N=8225; Baseline age: ~50y | [underlined: Index analysis:]; Adherence to the Alternate Healthy Eating Index (AHEI)-2010 score, categorical tertiles and continuous per-1-SD increase; - Positive: vegetables, fruits, whole grains, nuts and legumes, n-3 fatty acids, and PUFAs;; - Negative: SSB and fruit juice, red and processed meat, trans fat, Na+;; - Moderate: Alcohol; [underlined: Factor analysis]; Adherence scores for two dietary patterns identified by factor analysis, categorical tertiles and continuous per-1-SD increase at 1991-1993; 1997-1999; and 2002-2004:; - “Healthy food”: high intake of vegetables, fruits, and fish; - “Western-type”: high consumption of fried food, processed and red meat, pies, chocolate, sweets, high-fat dairy products, and refined grains; Diet assesed at multiple time points at 1991-1993; 1997-1999; and 2002-2004 | aHEI-2010 and outcomes during ~25y f/u; - aHEI-2010 at 1991-1993, per-1-SD or tertiles; ○ Dementia, NS; ○ Global cogntive-z,NS; ○ 18-y Cognitive decline, NS; - aHEI-2010 at 1997-1999, per-1-SD or tertiles; ○ Dementia, NS; - aHEI-2010 at 2002-2004, per-1-SD or tertiles; ○ Dementia, NS; “Healthy food” and outcomes during ~25y f/u; - “Healthy food”, per-1-SD or tertiles; ○ Dementia, NS; ○ Global cogntive-z, NS; ○ 18-y Cognitive decline,; ■ Per-1-SD: HR: −0.03, 95% CI: −0.05, −0.01, p=0.007; ■ T3 vs. T1 ref: HR: −0.06, 95% CI: −0.11, −0.01; ■ T2 vs. T1 ref: NS; - “Healthy food” at 1997-1999, per-1-SD or tertiles; ○ Dementia, NS; - “Healthy food” at 2002-2004, per-1-SD or tertiles; ○ Dementia, NS; "Western-type" and outcomes during ~25y f/u; - “Western-type" at 1991-1993, per-1-SD or tertiles; ○ Dementia, NS; ○ Global cogntive-z, NS; ○ 18-y Cognitive decline, NS; - “Western-type" at 1997-1999; ○ Dementia, NS; - “Western-type" at 2002-2004; ○ Dementia, NS | [underlined: Accounted for:] Sex, Age, Race/ethnicity, SES, Anthropometry, Alcohol intake, Physical activity, Smoking, Other: chronic diseases, depressive symptoms, CVD-medication, dementia status over f/u; [underlined: Limitations:]; - Did not account for: Family history of NCD; [underlined: Summary:] AHEI-2010 scores during midlife was not significantly associated with subsequent risk for dementia or cognitive decline; higher “Healthy food” scores at midline were significantly associated with greater cognitive decline during 25y f/u; [underlined: Funding:] UK Medical Research Council; British Heart Foundation; British Health and Safety Executive; NHLBI; NIA; Economic and Social Research Council
Berendsen, 2018 ^8^; United States; Prospective cohort study Nurses’ Health Study (NHS); N=16058; 100% female, Baseline age: ≥70y | [underlined: Index analysis:]; MIND diet adherence by quintile; - “Healthy brain foods”: green leafy vegetables, other vegetables, nuts, berries, beans, whole grains, fish, poultry, olive oil, and wine; - “Unhealthy brain foods”: red meats, butter and margarine, cheese, pastries and sweets, and fried/fast food; Diet assesed five times between 1984-1998, MIND score based on mean over 5 assessments | MIND diet across quintiles and mean difference in cognition over 6y:; - Global cognition, NS; - Cognitive performance (TICS), NS; MIND diet across quintiles and cognitive change over 6y:; - Global cognition, NS; - Cognitive performance (TICS), NS | [underlined: Accounted for:] Sex, Age, SES: Education, Anthropometry, Alcohol intake, Physical activity, Smoking, Other: total energy intake, history of depression, multivitamin use, CVD factors; [underlined: Limitations:]; - Did not account for Race/ethnicity, Family history of NCD; [underlined: Summary:] Long-term MIND score adherence was not significantly associated with change over time in the global cognitive or TICS scores over 6y f/u in women; [underlined: Funding:] NIH; National Cancer Institute; National Institute of Diabetes and Digestive and Kidney Diseases; NIA; NHLBI
Berendsen, 2017 ^7^; United States; Prospective cohort study Nurses’ Health Study (NHS); N=16144; 100% female, Baseline age:≥70y | [underlined: Index analysis:]; Dietary Approaches to Stop Hypertension (DASH) diet adherence score; - DASH score: based on high intake of fruits, vegetables, nuts and legumes, whole grains, low-fat dairy products, and low intake of sodium, red and processed meats, and sweetened beverages; MUFA+PUFA; Diet assesed five times between 1984-1998 | DASH diet across quintiles and average cognitive function over 4y:; Global cognition; - Q3, Q2 vs. Q1 ref, NS; - Q4 vs. Q1 ref: 0.04, 95% CI: 0.01, 0.07; - Q5 vs. Q1 ref: 0.03, 95% CI: 0.00, 0.06; - P-trend=0.009; Cognitive performance (TICS); - Q2, Q3, Q4 vs. Q1 ref, NS; - Q5 vs. Q1 ref: 0.16, 95% CI: 0.03, 0.29; - P-trend=0.002; - No interaction for age, high blood pressure, or ApoE e4 status; no mediation by blood pressure; DASH diet across quintiles and cognitive change over 4y:; - Global cognition, NS; - Cognitive performance (TICS), NS | [underlined: Accounted for:] Sex, Age, SES: Education, Anthropometry, Alcohol intake, Physical activity, Smoking, Other: total energy intake, history of depression, multivitamin use, CVD factors; [underlined: Limitations:]; - Did not account for Race/ethnicity, Family history of NCD; [underlined: Summary:] Highest DASH diet quintile vs. lowest was significantly associated with average cognitive function, but not significantly associated with cognitive change over 4y f/u in women.; [underlined: Funding:] NIH; National Cancer Institute; National Institute of Diabetes and Digestive and Kidney Diseases; NIA; NHLBI
Bhushan, 2018 ^9^; United States; Prospective cohort study Health Professionals’ Follow-up Study (HPFS); N=27842; 0% female, Baseline age: 40-75y | [underlined: Index analysis:]; Adherence to the Mediterranean diet score (MDS):; - Positive components: vegetables, legumes, fruits and nuts, cereals, MUFA: SFA ratio, and fish; - Negative components: red meat, poultry, and dairy products; - Moderate: alcohol; Diet assesed five times between 1986-2002, MDS based on mean over 5 assessments | Highest vs. lowest mean MDS and outcomes at f/u:; Moderate cognitive function (SCF 1-2); - Q2 or Q3 vs. Q1 ref, NS; - Q4 vs. Q1 ref: OR: 0.84, 95 % CI: 0.77, 0.91; - Q5 vs. Q1 ref: OR: 0.76, 95 % CI: 0.70, 0.83; - P-trend<0.001; Poor cognitive function (SCF ≥ 3); - Q2 vs. Q1 ref, NS; - Q3 vs. Q1 ref: OR: 0.74, 95 % CI: 0.64, 0.86; - Q4 vs. Q1 ref: OR: 0.67, 95 % CI: 0.57, 0.78; - Q5 vs. Q1 ref: OR: 0.64, 95 % CI: 0.55, 0.75; - P-trend<0.001 | [underlined: Accounted for:] Sex, Age, Anthropometry, Alcohol intake: Part of dietary pattern, Physical activity, Smoking, Other: diabetes, hypertension, depression, hypercholesterolemia; [underlined: Limitations:]; - Did not account for: Race/ethnicity, SES, Physical activity, Anthropometry, Family history of NCD; [underlined: Summary:] Higher vs. lower Mediterranean dietary pattern adherence is significantly associated prospectively with better cognitive function in men; [underlined: Funding:] Harvard T H Chan School of Public Health; NIH
Dearborn-Tomazos, 2019 ^10^; United States; Prospective cohort study; Atherosclerosis Risk in Communities (ARIC); N=13588; Baseline age: ~55y; Excluded those who were neither white nor black | [underlined: Factor analysis:]; Two dietary patterns identifed:; - “Western”: characterized by higher consumption of meats, refined grains, and fried foods.; - “Prudent”: characterized by higher amounts of fruits and vegetables, fish, chicken, whole grains, dairy, nuts, and alcohol; Diet assesed once at baseline with FFQ | “Western" dietary pattern tertiles and outcomes:; - visit 2 cogntive function, NS; - 20y Δ in global cognitive function, NS; - Dementia risk, NS; “Prudent" dietary pattern tertiles and outcomes:; - visit 2 cogntive function, NS; - 20y Δ in global cognitive function, NS; - Dementia risk, NS | [underlined: Accounted for:] Sex, Age, Race/ethnicity, SES: Education, Anthropometry, Alcohol intake: Part of dietary pattern, Physical activity, Smoking, Other: race-field center, total energy intake, total cholesterol, CHD, history of hypertension, diabetes, stroke, ApoE4 status; [underlined: Limitations:]; - Did not account for Race/ethnicity, Family history of NCD; - Diet assessed only once at baseline; [underlined: Summary:] “Western" or “Prudent" dietary patterns at midlife was not significantly associated with global cognitive function, 20y change in cognitive function, or risk of dementia; [underlined: Funding:] NHLBI, NIH, DHHS
Haring, 2016 ^11^; United States; Prospective cohort study; Women’s Health Initiative (WHI) Memory study; N=6425; 100% female, Baseline age: 65-79y; Exclusively postmenopausal | [underlined: Index analysis:]; Adherence scores for multiple dietary patterns:; - alternate Mediterranean diet score aMED, (Fung, 2005): positively scored vegetables (not potatoes), fruit, legumes, nuts, whole grains, fish, MUFA/SFA, and moderate alcohol; negatively scored red and processed meat; - Healthy Eating Index-2010, HEI-2010 (Guenther, 2013): positively scored total vegetables and greens and beans, total and whole fruit, whole grains, fatty acids, seafood and plant proteins, and dairy; negatively scored refined grains, added sugars, solid fats, and excess alcohol (13g/1000 kcal) in “empty calories”, and sodium; - alternate Healthy Eating Index 2010, AHEI-2010 (Chiuve, 2012): positively scored vegetables (not potatoes, French fries), fruit, legumes and nuts, whole grains, long-chain fats and PUFA, moderate alcohol, and adjusted emphasis on plant proteins; negatively scored red and processed meat, sugar-sweetened beverages and fruit juice, trans fat, and sodium; - Dietary Approach to Stop Hypertension (DASH) score (Fung, 2008): positively scored vegetables (not potatoes), fruit and fruit juice, legumes and nuts, whole grains, and low-fat dairy; negatively scored red and processed meat, sugar-sweetened beverages, and sodium; Diet assesed once at baseline with validated FFQ | aMED and risk over ~9y f/u:; - Mild Cognitive Impairment (MCI), NS; - Probable Dementia (PD), NS; ○ Q3 vs. Q1 ref: HR: 1.47, 95% CI: 1.05,2.06; - MCI or PD, NS; HEI-2010 and risk over ~9y f/u:; - MCI, NS; - PD, p-trend=0.02; ○ Q4 vs. Q1 ref. HR: 1.58, 95% CI: 1.09,2.30; ○ Q5 vs. Q1 ref. HR: 1.60, 95% CI: 1.10,2.33; - MCI or PD, NS; AHEI-2010 and risk over ~9y f/u:; - MCI: NS; - PD: NS; - MCI or PD: NS; DASH and risk over ~9y f/u:; - MCI: NS; - PD: NS; - MCI or PD: NS | [underlined: Accounted for:]; Sex, Age, Race/ethnicity, SES: Education, Income, Anthropometry, Alcohol: Part of dietary pattern, Physical activity, Smoking, Other: Hormone trial arm, baseline 3MSE, diabetes, hypertension status, depression, history of CVD, total energy intake [underlined: Limitations:]; - Did not account for Family history of NCD; - Diet assessed only once at baseline; [underlined: Summary:] aMED, HEI-2010, AHEI-2010, or DASH scores across quintiles were not significantly associated with mild Cognitive Impairment, Probable Dementia (PD), or incidence of either at ~9y f/u; [underlined: Funding:] NHLBI, NIH, DHHS
Mannikko, 2015 ^12^; Finland; Prospective cohort study; N=1140; Baseline age:~66y; Excluded those that had health conditions that impair exercise, malignancies and conditions preventing co-operation | [underlined: Index analysis:]; Adherence for the Nordic Diet Score (modified Kanerva, 2014); - Consumption, g/d: fatty and lean fish and processed fish products; vegetables including root, non-root vegetables, mushrooms; legumes and nuts, but not potatoes; fruit and berries; whole-grain bread; meat including beef, pork, poultry, game, sausage and giblets; alcohol; alpha-linolenic acid/rapeseed oil; MUFA+PUFA/SFA ratio; Diet assesed once at baseline with validated methods | In the total cohort, n=1140, and those with normal cognition at baseline, n=1042:; - Global cognition (CERAD) at 4y f/u: NS; - Global cognition (MMSE) at 4y f/u: NS | [underlined: Accounted for:]; Sex, Age, , SES: education , Smoking, Other: VO_2max_, antihypertensive medication, lipid-lowering medication, antidiabeteic medication, energy intake study group (IV), baseline CERAD total score or MMSE, symptoms of depression; [underlined: Limitations:]; - Did not account for: Race/ethnicity, Alcohol intake, Physical activity, Anthropometry, Family history of NCD; - Diet assessed only once at baseline (for the applicable analysis); [underlined: Summary:] Nordic diet score was not significantly associated with cognitive function at 4y f/u; [underlined: Funding:] Ministry of Education and Culture in Finland; Academy of Finland; European Commission FP6 Integrated Project; the City of Kuopio; Finnish Diabetes Association; Finnish Foundation for Cardiovascular Research; Kuopio University Hospital; the Social Insurance Institution of Finland; Palvikki and Sakari Sohlberg Foundation; Juho Vainio Foundation; Aarne and Aili Turunen Foundation; The Finnish Graduate School on Applied Bioscience: Bioengineering, Food and Nutrition, Environment; Finnish Cultural Foundation, North Savo Regional fund
McEvoy, 2019 ^13^; United States; Coronary Artery Risk Development in Young Adults (CARDIA); Prospective cohort study; N=2621; Baseline age: 25y; Excluded those that were not healthy black or white adults | [underlined: Index analysis:]; Adherence to dietary patterns by per-SD increase or tertiles:; - MedDietScore, (modified Panagiotakos, 2007):; ○ increasing intake of non-refined grains, fruits, vegetables, potatoes, legumes, fish, and olive oil (MUFA: SFA);; ○ decreasing intake of red meat, poultry, and full-fat dairy; moderate intake of alcohol.; - DASH score, (Folsom, 2007):; ○ Positive: whole grains, vegetables, fruit, low-fat dairy, legumes, and nuts;; ○ Negative: meat, fish and poultry, total fat, saturated fat, sweets, and sodium;; - A Priori Diet Quality Score (APDQS, (Sjitmsa, 2012):; ○ Positive: fruit, vegetables, legumes, low-fat dairy, fish, moderate alcohol intake; ○ Adverse: fried foods, salty snacks, desserts, high-fat dairy, and sugar-sweetened soft drinks foods; ○ Neutral: lean meat, shellfish, potato eggs, chocolate, fruit juices, diet beverages; Diet assesed at baseline, year 7, and year 20 with diet history | MedDiet and cognitive function at 30 y f/u; - per-SD increase: β: 0.08, 95% CI: 0.05, 0.10; - Low tertile: OR: 1, ref; - Mid tertile: OR: 0.66, 95% CI: 0.51, 0.85; - High tertile: OR: 0.54, 95% CI: 0.39, 0.74; DASH and cogntive function at 30 y f/u, NS; APDQS and cognitive function at 30 y f/u; - per-SD increase: β: 0.09, 95% CI: 0.06, 0.12; - Low tertile: OR: 1, ref; - Mid tertile: OR: 0.68, 95% CI: 0.52, 0.88; - High tertile: OR: 0.48, 95% CI: 0.33, 0.69 | [underlined: Accounted for:] Sex, Age, Race, SES: Education, Anthropometry: BMI, Smoking, Alcohol intake, Physical activity, Other: diabetes, total energy intake; [underlined: Limitations:]; - Did not account for: Family history of NCD; - Large gaps between dietary data collection; [underlined: Summary:] Higher vs. lower MedDiet or APDQS adherence was significantly associated with less decline in cognitive function during 30y f/u. No significant association between DASH score and cognitive function.; [underlined: Funding:] Beeson-CARDI Fellowship from the American Federation of Aging Research; NHLBI; NIA
Ozawa, 2017 ^14^; United Kingdom; Prospective cohort study; Whitehall II cohort; N=5083; Baseline age: 56y | [underlined: Reduced Rank Regression:]; Response variables: serum IL-6 and 37 food groups to derive the Inflammatory Dietary Pattern Score, examined by tertiles(T1,T2, T3); - Characterized by higher intake of red meat, processed meat, peas and legumes, and fried food, and lower intake of whole grains; Diet assessed at two time points (1991-1993, 1997-1999) with validated FFQ | Dietary pattern adherence and cognitive decline change over 10 y f/u:; Global cognitive score; - T2 vs. T1: ref.: −0.35, 95% CI: −0.37, −0.32; - T3 vs. T1 ref: −0.35, 95% CI: −0.38, −0.32; - p-trend=0.04; MMSE decline ≥ 3 points: NS | [underlined: Accounted for:] Sex, Age, Race/ethnicity, SES: Occupation, Education, Anthropometry: BMI, Smoking, Physical activity, Other: Total energy intake, diabetes, hypertension,; [underlined: Limitations:]; - Did not account for: Alcohol intake, Family history of NCD; - Diet assessed as average of two time points; [underlined: Summary:] Higher vs. lower inflammatory dietary pattern consumption was significantly associated with greater decline in cognitive function over 10y f/u; [underlined: Funding:] UNESCO- L’Oreal Foundation; Astellas Foundation for Research on Metabolic Disorders, the British Medical Research Council; the Economic and Social Research Council; NIA; NIH; British Heart Foundation
Pearson, 2016 ^15^; United States; Prospective cohort study REasons for Geographic And Racial Differences in Stroke (REGARDS); N=18080; Baseline age: 65y; Excluded those of race other than White or Black, undergoing treatment for cancer or medical conditions, nursing home residents, or non-English users. | [underlined: Factor analysis:]; Identified five dietary patterns:; - “Convenience”: mixed dishes with meat, pizza, Chinese food and Mexican dishes; - “Plant-based”: vegetables, fruits, fish and beans; - “Sweets/fats”: high loadings of miscellaneous sugars, desserts, candy, sweetened breakfast foods and added fats; - “Southern”: high loadings of added fats, fried food, eggs and egg dishes, organ meats, processed meats and sugar-sweetened beverages; - Alcohol/salads: high loadings of green-leafy vegetables, tomatoes, salad dressing, wine and liquor; Diet assesed once at baseline with validated FFQ | “Convenience”, Plant-based”,"Sweets/fats”, or “Southern" and cognitive impairment at 7y f/u: NS; “Alcohol/salads" and cognitive impairment at 7y f/u:; - Q1,n=397, OR: 1,ref; - Q2, n=343, OR: 0.94, 95% CI: 0.80, 1.12, NS; - Q3, n=271, OR: 0.81, 95% CI: 0.68, 0.97; - Q4, n=270, OR: 0.88, 95% CI: 0.73, 1.05, NS; - Q5, n=205, OR: 0.68, 95% CI: 0.56, 0.84; - P=0.0005 | [underlined: Accounted for:] Sex, Age, Race/ethnicity, SES: income, education, Anthropometry: BMI, Physical activity, Smoking status, Total energy intake, Other: region, HTN, diabetes, history of CVD, and score on CESD-4; [underlined: Limitations:]; - Did not account for: Alcohol intake, Family history of NCD; - Diet assessed once at baseline; [underlined: Summary:] Higher vs. lower “alcohol/salads" dietary pattern consumption was significantly associated with lower odds of cognitive decline at 7y f/u; [underlined: Funding:] National Institute of Neurological Disorders and Stroke, NIH, DHHS; General Mills Bell Institute of Health and Nutrition
Richard, 2018; United States; Prospective cohort study; Rancho Bernardo Study; N=1499; Baseline age: 73y; Exclusions: <50y | [underlined: Index analysis:]; Adherence to two indices by tertile:; - Alternate Mediterranean diet score,aMed (Fung, 2005):; ○ Positive: vegetables, legumes, fruits, nuts, whole grains, fish, red meat below median, MUFA/PUFA, Moderate alcohol; - Alternate Healthy Eating lndex,AHEI-2010, score (Chiuve, 2012):; ○ ‘vegetables, fruits, whole grains, sugar-sweetened beverages and fruit juice, nuts and legumes, red/processed meat, trans-fat, long-chain (n-3) fats, EPA, DHA, PUFAs, sodium, and alcohol within thresholds’; - Note: Patterns identified by factor analyses were based only on select nutrients/micronutrients (i. e., PUFA/Vitamin E), thus, are not described here.; Diet assesed once at baseline with validated FFQ | aMED; - MMSE at ~27y f/u:; ○ T2 vs. T1 ref.: 0.19, 95% CI: −0.006, 0.38, NS; ○ T3 vs. T1 ref.: 0.33, 95% CI: 0.11, 0.55; ○ P-trend=0.002; AHEI-2010; - MMSE at ~27y f/u; NS | [underlined: Accounted for:] Age, Sex, SES: Education, Smoking, Alcohol, Other: time, energy intake, retest effects, exercise; [underlined: Limitations:]; - Did not account for: Race/ethnicity, Physical activity, Anthropometry, Family history of NCD; - Diet was assessed once at baseline with a FFQ; [underlined: Summary:] Higher vs. lower aMED adherence dietary pattern consumption was significantly associated with better cognitive function. No significant associations were identified for AHEI-2010 adherence and cognitive outcomes.; [underlined: Funding:] National Institute on Alcohol Abuse and Alcoholism; NIA; National Institute of Diabetes and Digestive and Kidney Diseases
Shakersain, 2016 ^17^; Sweden; Prospective cohort study Swedish National study on Aging and Care-Kungsholmen (SNAC-K); N=2223; Baseline age: 71y; Excluded those with dementia | [underlined: Factor analysis:]; Two dietary patterns were identified:; - “Western”: characterized by more frequent intakes of red/processed meat, saturated/trans-fat, refined grains, sugar, beer, and spirits; - “Prudent”: characterized by more frequent intakes of vegetables, fruit, cooking/dressing oil, cereals and legumes, whole grains, rice/pasta, fish, low-fat dairy, poultry, and water; Diet assessed once at baseline with validated FFQ | “Western" and change in MMSE score over 6y f/u:; - Continuous: β: −0.045, 95% CI: −0.071, −0.019, p=0.001; - Q1: ref; - Q2: β: −0.075, 95% CI: −0.154, 0.004, NS; - Q3: β: −0.137, 95% CI: −0.217, −0.057; - Q4: β: −0.063, 95% CI: −0.144, 0.017, NS; - Q5: β: −0.156, 95% CI: −0.240, −0.073; "Prudent" and change in MMSE score over 6y f/u:; - Continuous: β: 0.043, 95% CI: 0.017, 0.068, p=0.001; - Q1: ref; - Q2: β: 0.001, 95% CI: −0.085, 0.083, NS; - Q3: β: 0.061, 95% CI: −0.021, 0.143, NS; - Q4: β: 0.122, 95% CI: 0.039, 0.204; - Q5: β: 0.106, 95% CI: 0.024, 0.189; Similar results obtained when accounting for missing data with imputation, | [underlined: Accounted for:] Age, Sex, SES: Education, Anthropometry: BMI, Smoking, Alcohol: Part of dietary pattern, Physical activity, Other: time, energy intake, civil status, vitamin or mineral supplements, vascular disorders, diabetes, cancer, depression, ApoE 4, and other dietary pattern.; [underlined: Limitations:]; - Did not account for: Race/ethnicity, Family history of NCD; - Diet assessed once at baseline; [underlined: Summary:] Higher vs. lower adherence to the “Prudent" dietary pattern at midlife was significantly associated with less MMSE decline at 6y f/u. Higher vs. lower adherence to the “Western" dietary pattern at midlife was significantly associated with more MMSE decline at 6y f/u, but was attenuated when accompanied by high “Prudent" dietary pattern adherence.; [underlined: Funding:] Ministry of Health and Social Affairs, Sweden; participating county councils and municipalities; Swedish Research Council for Health, Working Life and Welfare; Stiftelsen Ragnhild och Einar Lundstr€oms Minne; Gun och Bertil Stohnes Foundation; Demensfonden
Shakersain, 2018a ^18^; Sweden; Prospective cohort study Swedish National study on Aging and Care-Kungsholmen (SNAC-K); N=2223; Baseline age: 71y; Excluded those with dementia | [underlined: Index analysis:]; Nordic Prudent Dietary Pattern score, NPDP (Shakersain, 2018):; - Reflects high consumptions of non-root vegetables, apples/pears/peaches, pasta/rice, poultry, fish, vegetable oils (mainly rapeseed oil), tea, and water, light to moderate wine intake; - Reflects low consumptions of root vegetables (including potatoes), refined grains/cereals, high-fat dairy products, butter/margarine, sugar/sweets/pastries, and fruit juice. | NPDP adherence and change in MMSE over 6 y f/u:; - Low: T1: ref; - Moderate to High: p: 0.19, 95% CI: 0.14, 0.24; - Moderate: β: 0.14, 95% CI: 0.08, 0.20; - High: β: 0.24, 95% CI: 0.18, 0.30; - P-trend: <0.001 | [underlined: Accounted for:] Age, Sex, SES: Education, Anthropometry: BMI, Smoking, Alcohol: Part of dietary pattern, Physical activity, Other: time, energy intake, civil status, vitamin/supplement use, vascular disorders, diabetes, cancer, depression, ApoE 4, other dietary pattern, survival status, social activity, mental activity; [underlined: Limitations:]; - Did not account for: Race/ethnicity, Family history of NCD; - Diet assessed once at baseline; [underlined: Summary:] Higher vs. lower adherence to the Nordic Prudent dietary pattern in older adults was significantly associated with less MMSE decline at 6y f/u.; [underlined: Funding:] Ministry of Health and Social Affairs, Sweden; participating county councils and municipalities; Swedish Research Council; National Natural Science Foundation of China; Konung Gustaf V:s och Drottning Victorias Frimurare Foundation; Alzhermerfonden, and Demensfonden (Sweden); Fondazione Umberto Veronesi; European Union’s Horizon 2020 research and innovation programme
Shakersain, 2018b ^19^; Sweden; Prospective cohort study Swedish National study on Aging and Care-Kungsholmen (SNAC-K); N=2223; Baseline age: 71y; Excluded those with dementia. | [underlined: Index analysis:]; - Nordic Prudent Dietary Pattern, NPDP: See Shakersain, 2018a; - MIND, hybrid Mediterranean DASH index (Morris, 2015): scored based on 10 brain healthy food groups: green leafy vegetables, other vegetables, nuts, berries, beans, whole grains, fish, poultry, olive oil and wine and 5 unhealthy food groups: red meats, butter/margarine, cheese, pastries and sweets, and fried/fast food.; - MedDiet Score (Panagiotakos, 2007): Based on 11 items: non-refined cereals (whole grain bread and pasta, brown rice, etc), fruit, vegetables, legumes/beans, potatoes, fish, meat and meat products (red and processed meat), poultry, high-fat dairy products (like cheese, yoghurt, milk), as well as olive oil and alcohol (wine) intake.; - Dietary Approaches to Stop Hypertension, DASH (Morris, 2015): based on 10items: total grains /cereals, vegetables, fruits, dairy foods, meats/poultry/fish, legumes/beans, sugar/sweets/pastries; total fat, saturated fat and sodium.; - Baltic Sea Diet, BSD (Kanerva, 2014): Nordic vegetables: tomato, cucumber, leafy vegetables, roots, cabbages, legumes; (ii) Nordic fruits: apples, pears, and berries; (iii) Nordic wholegrain cereals: rye, oats and barley; potatoes; low-fat and fat-free milk products; Nordic fish: salmon and freshwater fish; E% from fat, ratio of PUFA/SFA+Trans fat, red and processed meat: beef, pork, processed meat products and sausage; and sweets | Diet indice/score adherence and rate of change in MMSE score over 6 y f/u:; NPDP:; - Continuous: β: 0.011, 95% CI: 0.008, 0.013; - Low adherence, ref; - Moderate adherence: β: 0.139, 95% CI: 0.077, 0.201; - High adherence: β: 0.238, 95% CI: 0.175, 0.300; MIND:; - Continuous: β: 0.006, 95% CI: 0.003, 0.009; - Low adherence, ref; - Moderate adherence: β: 0.075, 95% CI: 0.012,0.138; - High adherence: β: 0.126, 95% CI: 0.064, 0.188; MedDiet Score:; - Continuous: β: 0.006, 95% CI: 0.002, 0.009; - Low adherence, ref; - Moderate adherence: β: 0.063, 95% CI: −0.002, 0.129, NS; - High adherence: β: 0.099, 95% CI: 0.036, 0.163; DASH:; - Continuous: NS; - Categorical: NS; BSD:; - Continuous: β: 0.006, 95% CI: 0.002, 0.009; - Categorical: NS | [underlined: Accounted for:] Sex, Age, SES: Education, Anthropometry: BMI, Smoking, Alcohol: Part of dietary pattern, Physical activity, Other: Total calorie intake, civil status, vitamin/mineral supplementation, vascular disorders, diabetes, cancer, depression, APOE e4, dietary components other than those in each index; [underlined: Limitations:]; - Did not account for: Race/ethnicity, Family history of NCD; - Diet assessed once at baseline; [underlined: Summary:] Higher vs. lower adherence (both continuously and categorically) to the Nordic Prudent dietary pattern, the MIND pattern, and MedDiet score in older adults was significantly associated with less MMSE decline at 6y f/u. There was no significant relationship between DASH adherence and MMSE decline at 6 y f/u. Higher adherence to the Baltic Sea Diet was only significantly associated continuously with less MMSE decline at 6y f/u.; [underlined: Funding:] Ministry of Health and Social Affairs, Sweden; participating county councils and municipalities; the Swedish Research Council; the National Natural Science Foundation of China; European Union’s Horizon 2020 research and innovation programme; the Konung Gustaf V:s och Drottning Victorias Frimurare Foundation; Diabetes Foundation; Gun och Bertil Stohnes Foundation; Alzheimerfonden; and the Dementia Association (Sweden)
Shannon, 2019 ^20^; United Kingdom; Prospective cohort study; EPIC-Norfolk; N=8009; Baseline age: 55y | [underlined: Index analysis:]; Mediterranean Diet Scores:; - Mediterranean Diet Adherence Screener, MEDAS (Papadaki, 2018): categorical and continuous score; ○ Positive: Vegetables, Legumes, Fruit, Nuts, Seafood, Olive Oil, Olive oil as principal cooking fat More white meat than red meat, Wine, Sofrito (lasagne); - Negative: Sweets or pastries, Red Meat or Sausages (including lasagne), Sugar-Sweetened Beverages, Butter, margarine, or cream (including low-fat spread)MedDiet Pyramid (Tong, 2016): continuous score; ○ Positive: Vegetables, Legumes, Fruit, Nuts, Cereals, Fish, White meat, Eggs, Olive Oil; ○ Moderate: Alcohol; ○ Negative: Potato, Red meat, Processed meat, Sweets | Adherence to dietary pattern and global cognition (SF-EMSE) during 14yf/u:; - MEDAS: β: −0.004, SE: 0.002; - MEDAS Continuous: β: −0.005, SE: 0.002; - MedDiet Pyramid: per-1-point increase: β: −0.012, P<0.001 | [underlined: Accounted for:] Age, Sex, SES: Marital status, Employment, Education, Anthropometry: BMI and Waist Circumference, Smoking, Physical activity, Other: Self-reported medical conditions, self-reported medications, HDL and LDL cholesterol, total triglycerides, DBP, SBP, APOE E4; [underlined: Limitations:]; - Did not account for: Race/ethnicity, Alcohol intake, Family history of NCD; - Dietary intake evaluated once at baseline; [underlined: Summary:] Higher adherence to all three MedDiet scores was significantly associated with better performance on global cognition during 14y f/u in middle-aged adults. There was no significant association with the MedDiet scores and performance in retrospective memory, attention, or complex processing speed. MedDiet Pyramid adherence score was significantly associated with better performance in simple processing speed and retrospective memory, but the other two scores were not.; [underlined: Funding:] Alzheimer’s Research UK Prevention and Risk Reduction Fund
Smyth, 2015 ^21^; 40 Countries; Prospective cohort study ‘ONTARGET and TRANSCEND’; N=27860; Baseline age: 66y | [underlined: Index analysis:]; Modified Alternative Healthy Eating Index (AHEI) score (Dehghan, 2012) components, within specified limits:; - Vegetable, Fruits, Nuts and soy proteins, Whole grain, Deep-fried foods, Ratio of fish to meat and egg, Alcohol | Adherence to AHEI and cognitive decline over 5 y f/u:; - Q1: ref; - Q2, Q3, Q4 vs. Q1 ref. NS; - Q5 vs. Q1 ref.: HR: 0.76, 95% CI: 0.66, 0.86; Subgroup analysis:; - Excluding early cases in <2y f/u, composite outcomes, MMSE<24 at baseline, or those with cancer at baseline yeilded similar results; - Stratification by MMSE score at baseline: Increased adherence to the AHEI was significantly associated with a reduced cognitive decline when MMSE was 26-28 or >28 at baseline, but MMSE<26 was NS.; - Stratification by physical activity status at baseline: Increased adherence in AHEI was significantly associated with a reduced cognitive decline with moderate or high activity at baseline, but not sedentary. | [underlined: Accounted for:] Sex, Age, SES: Education, Anthropometry: BMI, Smoking, Alcohol: Part of dietary pattern, Physical activity, Other: trial enrollment, treatment allocation, geographical region, baseline MMSE score, SBP, history of stroke/TIA, DM, Ml, microalbuminuria, macroalbuminuria, serum creatinine, statin therapy, beta-blocker therapy, antithrombotic use, depression.; [underlined: Limitations:]; - Did not account for: Race/ethnicity, Family history of NCD; [underlined: Summary:] Higher adherence to the mAHEI was significantly associated with less cognitive decline during 5y f/u, both overall and in those with MMSE 26-28 or >28 at baseline, as well as those with moderate or high physical activity at baseline.; [underlined: Funding:] Boehringer Inqelheim
Tomata, 2016 ^22^; Japan; Prospective cohort study; N=14402; Baseline age: 74y; Excluded those that did not provide consent for review of their long-term care insurance information, those that had a disability before starting f/u, those that died or moved before the start of f/u, and those for which a doctor’s opinion paper was unavailable | [underlined: Factor analysis:]; - ‘Japanese’ pattern - loaded heavily on fish, vegetables, mushrooms, potato, seaweeds, pickles, soybean, and fruits; - ‘Animal food’ pattern - loaded heavily on various animal-derived foods (beef, pork, ham, sausage, chicken, liver, egg, and butter); - ‘High-dairy’ pattern - heavily loaded on dairy products (yoghurt, cheese, and butter), margarine, and black tea, Chinese tea, and negatively loaded on rice. | ‘Japanese’ pattern score and dementia over 6 y f/u:; - Q1: ref; - Q2 or Q3 vs. Q1 ref: NS; - Q4 vs. Q1 ref: HR: 0.80, 95% CI: 0.66, 0.97; ‘Animal food’ pattern and dementia over 6 y f/u: NS; ‘High-dairy’ pattern and dementia over 6 y f/u: NS | [underlined: Accounted for:] Sex, Age, SES: Education, Anthropometry: BMI, Smoking, Alcohol, Physical activity, Other: history of non-NCD chronic disease, psychological distress score, motor function score, number of remaining teeth, cognitive function score, energy intake, protein intake; [underlined: Limitations:]; - Did not account for: Race/ethnicity, Family history of NCD; [underlined: Summary:] Higher adherence to the ‘Japanese dietary pattern’ was significantly associated with reduced dementia risk in older Japanese adults over a 6 y f/u. There was no significant association between the ‘animal food’ pattern or ‘high-dairy’ pattern and dementia risk.; [underlined: Funding:] Honjo International Scholarship Foundation; Health Sciences Research grants from the Ministry of Health, Labour and Welfare of Japan
Voortman, 2017 ^23^; Netherlands; Prospective cohort study Rotterdam Study; N=9701; Baseline age: 64y; Excluded those with prevalent disease at baseline | [underlined: Index analysis:]; Dutch dietary guidelines score - 2015 (Voortman, 2017):; - Positive components: Vegetables, legumes, fruit, nuts, whole grains, fish, dairy products, unsaturated fats and oils, tea; - Negative components: Replace refined grains with whole-grain products, red meat, processed meat, alcohol, sodium | Adherence to Dutch Dietary guidelines score and risk of dementia over 12 y f/u: NS | [underlined: Accounted for:] Sex, Age, SES: Education, Anthropometry: BMI, Smoking, Alcohol: Part of dietary pattern, Physical activity, Other: Cohort, total energy intake; [underlined: Limitations:]; - Did not account for: Race/ethnicity, Family history of NCD; - Diet assessed once at baseline; [underlined: Summary:] Higher adherence to the Dutch Dietary Guidelines score by an older Dutch population over 12 y f/u was not significantly associated with a reduced risk of dementia.; [underlined: Funding:] Erasmus University Medical Center and Erasmus University Rotterdam; Netherlands Organization for Health Research and Development; Research Institute for Diseases in the Elderly; Netherlands Genomics Initiative; Ministry of Education, Culture and Science; Ministry of Health, Welfare and Sports; European Commission; Municipality of Rotterdam.
Wagner, 2019 ^24^; United States; Nested Case-Control; Nurses’ Health Study (NHS); N=1496 cases, 7478 controls; 100% female, Baseline age: ~61y | [underlined: Index analysis:]; alternate Mediterranean diet, A-MeDi (Cheng, 2018 modified Fung, 2005) score; - Positive components: Vegetables, legumes, fruit, nuts, whole grains, fish, MUFA:SFA ratio; - Moderate: Alcohol; - Negative components: red/processed meat | A-MeDi score in cases of cognitive decline (10% worst TICS slopes) remained lower than controls at 1y f/u: mean difference −0.19, 95% CI: −0.29, −0.09. | [underlined: Accounted for:] Sex, Age, SES: Education, Anthropometry: BMI part of design, Alcohol: Part of dietary pattern, Physical activity: part of design; [underlined: Limitations:]; - Did not account for: Race/ethnicity, Smoking, Family history of NCD; [underlined: Summary:] Cases of cognitive decline compared to controls had lower adherence to A-MeDi.; [underlined: Funding:] NIH
Wu, 2019 ^25^; Singapore; Prospective cohort study Singapore Chinese Health Study; N=16948; Baseline age: 53.5y; Excluded those with cancer or CVD at baseline | [underlined: Index analysis:]; - alternate Mediterranean diet (aMED) score (Fung, 2005): positively scored vegetables (not potatoes), fruit, legumes, nuts, whole grains, fish, MUFA/SFA, and moderate alcohol; negatively scored red and processed meat; - Dietary Approaches to Stop Hypertension (DASH) diet (modified Fung, 2008: positively scored vegetables (not potatoes), fruit and fruit juice, legumes and nuts, whole grains, and total dairy; negatively scored red and processed meat, sugar-sweetened beverages, and sodium; - alternative Healthy Eating Index (AHEI)-2010 score (adjusted Chiuve, 2012): positively scored vegetables (not potatoes, French fries), fruit, legumes and nuts, whole grains, long-chain fats and PUFA, and moderate alcohol; negatively scored red and processed meat, sugar-sweetened beverages and fruit juice, trans fat, and sodium; - Plant-based diet index (PDI) (Satija, 2016): positively scored “all plant foods” and negatively scored “animal foods”; - Healthful plant-based diet index (hPDI) (Satija, 2016): positively scored “healthy plant foods” and negatively scored “less healthy plant foods”; Diet assessed once at baseline with validated FFQ | Cognitive impairment (MMSE) at ~20y f/u; aMED,; - per-SD increment: OR: 0.84, 95% CI: 0.80, 0.88; - Q4 vs. Q1 ref.: OR: 0.67, 95% CI: 0.59, 0.77; - p-trend <0.001; - Stronger associations were observed in older adults, women, and those with no formal education.; DASH,; - per-SD increment: OR: 0.89, 95% CI: 0.84, 0.93; - Q4 vs. Q1 ref. OR 0.71, 95% CI: 0.62, 0.81; - p-trend <0.001; AHEI-2010; - per-SD increment:; - Q4 vs. Q1 ref. OR 0.75, 95% CI: 0.66, 0.85; - p-trend <0.001; - Stronger associations were observed in women; PDI; - per-SD increment: OR: 0.89, 95% CI: 0.85, 0.94; - Q4 vs. Q1 ref. OR 0.82, 95% CI: 0.71, 0.94; - p-trend <0.001; hPDI; - per-SD increment: OR: 0.93, 95% CI: 0.88, 0.97; - Q4 vs. Q1 ref. OR 0.78, 95% CI: 0.68, 0.90; - p-trend <0.001; - Stronger associations were observed in those with no formal education; In overall sub-analyses, associations were not significantly modified by sex, education level, BMI group, baseline hypertension, or diabetes. | [underlined: Accounted for:] Age, Sex, SES: Education, Marital Status, Anthropometry: BMI, Smoking, Alcohol: If not part of dietary pattern, Physical activity, Other: dialect, sleep, total energy intake, tea/coffee intake if not part of dietary pattern, history of hypertension, diabetes, cardiovascular disease, and cancer.; [underlined: Limitations:]; - Did not account for: Race/ethnicity, Family history of NCD; - Diet assessed once at baseline; [underlined: Summary:] Higher vs. lower adherence to all dietary pattern indices examined (aMED, DASH, AHEI-2010, PDI, hPDI) was significantly associated with lower risk of cognitive impairment at 20y f/u.; [underlined: Funding:] National Medical Research Council, Singapore; NIH; Saw Swee Hock School of Public Health, National University of Singapore; National Key Research and Development Program of China; Hubei Province Science Fund for Distinguished Young Scholars
Zhu, 2015 ^26^; United States; Prospective cohort study; CARDIA; N=2435; Baseline age: 18-30y; 52% African-American, 48% white | [underlined: Index analysis:]; A Priori Diet Quality Score, APDQS (Sjitsma, 2012); - Positive: fruit, vegetables, legumes, low-fat dairy, fish, coffee/tea, moderate alcohol intake; - Adverse: fried foods, high fat meat, salty snacks, desserts, high-fat dairy, and sugar-sweetened soft drinks; - Neutral: lean meat, shellfish, potato eggs, chocolate, fruit juices, diet beverages; Diet assessed twice, once at baseline and once at f/u with CARDIA study diet history | APDQS per 10-unit increase at baseline APDQS and RAVLT at 25y f/u: Slope=0.16, p=0.004; DSST: NS; higher; Stroop: NS; APDQS per 10-unit increase at 20y and RAVLT at 25y f/u: Slope=0.21, p=0.0003; DSST: Slope=0.82, p=0.002; Stroop: Slope=−0.58, p=0.007; APDQS per 10-unit increase change from baseline-20y f/u and RAVLT at 25y f/u: Slope=0.16, p=0.01; DSST: Slope=0.70, p=0.01; Stroop: Slope=−0.55, p=0.02 | [underlined: Accounted for:] Age, Sex, Race, SES: Education, Anthropometry: BMI, Physical activity, Alcohol: Part of dietary pattern, Smoking, Other: study center, energy intake, blood pressure, total cholesterol, diabetes, apoE4; [underlined: Limitations:]; - Did not account for: N/A; - Diet assessment at two time points span 20y; [underlined: Summary:] Higher vs. lower APDQS adherence at 20y f/u or dietary change from baseline to 20y f/u was significantly associated with better cognitive test results at 25y f/u.; [underlined: Funding:] NHLBI; NIA

Table 3 Risk of bias for randomized controlled trials examining dietary patterns and cognitive impairment, dementia, or Alzheimer’s disease^vii,^ ^viii^

| Randomization | Deviations from intended interventions - effect of assignment | Deviations from intended interventions-per-protocol | Missing outcome data | Outcome measurement | Selection of reported result
Chlebowski, 2020^1^ | Low | Low | Low | Low | Some concerns | Some concerns
Knight, 2016^3^ | Low | Low | Low | Low | Low | Some concerns
Marseglia, 2018^2^ | Some concerns | Low | Low | Low | Low | Some concerns
Valls-Pedret, 2015^4^ | Some concerns | Low | Low | Low | Low | Some concerns

Table 4 Risk of bias for observational studies examining dietary patterns and cognitive impairment, dementia, or Alzheimer’s disease^ix^

| Confounding | Selection of participants | Classification of exposures | Deviations from intended exposures | Missing data | Outcome measurement | Selection of reported result
Adjibade, 2019^5^ | Serious | Serious | Low | Serious | Moderate | Low | Serious
Akbaraly, 2019^6^ | Serious | Moderate | Low | Moderate | Moderate | Low | Moderate
Berendsen, 2017^7^ | Serious | Moderate | Low | Moderate | Moderate | Low | Serious
Berendsen, 2018^8^ | Serious | Moderate | Low | Moderate | Moderate | Low | Serious
Bhushan,2018^9^ | Serious | Moderate | Low | Moderate | Serious | Low | Moderate
Dearborn-Tomazos, 2019^10^ | Serious | Serious | Low | Serious | Serious | Low | Moderate
Haring, 2016^11^ | Serious | Moderate | Low | Serious | Moderate | Low | Moderate
Mannikko, 2015^12^ | Serious | Serious | Low | Moderate | Serious | Low | Moderate
McEvoy, 2019^13^ | Serious | Moderate | Low | Moderate | Serious | Low | Moderate
Ozawa, 2017^14^ | Serious | Serious | Low | Moderate | Serious | Low | Moderate
Pearson, 2016^15^ | Serious | Serious | Low | Serious | Serious | Moderate | Moderate
Richard, 2018^16^ | Serious | Moderate | Low | Moderate | Serious | Low | Low
Shakersain, 2016^17^ | Serious | Serious | Low | Moderate | Serious | Low | Moderate
Shakersain, 2018a^18^ | Serious | Serious | Low | Moderate | Serious | Low | Serious
Shakersain, 2018b^19^ | Serious | Serious | Low | Moderate | Serious | Low | Moderate
Shannon, 2019^20^ | Serious | Moderate | Low | Serious | No Information | Low | Moderate
Smyth, 2015^21^ | Serious | Serious | Low | Moderate | Serious | Low | Moderate
Tomata, 2016^22^ | Serious | Serious | Low | Moderate | Moderate | Low | Moderate
Voortman, 2017^23^ | Serious | Serious | Moderate | Serious | Moderate | Low | Moderate
Wagner, 2019^24^ | Serious | Serious | Low | Serious | Moderate | Serious | Moderate
Wu, 2019^25^ | Serious | Moderate | Low | Moderate | Moderate | Low | Moderate
Zhu, 2015^26^ | Moderate | Moderate | Low | Serious | Serious | Low | Moderate

ii A detailed description of the methodology used for grading the strength of the evidence is available on the NESR website: https://nesr.usda.gov/2020-dietary-guidelines-advisory-committee-systematic reviews (https://nesr.usda.gov/2020-dietary-guidelines-advisory-committee-systematic-reviews) and in Part C of the following reference: Dietary Guidelines Advisory Committee. 2020. Scientific Report of the 2020 Dietary Guidelines Advisory Committee: Advisory Report to the Secretary of Agriculture and the Secretary of Health and Human Services. U.S. Department of Agriculture, Agricultural Research Service, Washington, DC .

iii Abbreviations: CERAD, Consortium to Establish a Registry for Alzheimer’s Disease Battery; EVOO, extra-virgin olive oil; GMS, Geriatric Mental Schedule; HHS, Department of Health and Human Services; MIND, Mediterranean-DASH diet intervention for neurodegenerative delay; MMSE, Mini-Mental State Examination; mo, month(s); N/A, Not applicable; NCD, Neurocognitive disorder; NIA, National Institute on Aging; NHLBI, National Heart Lung and Blood Institute; NIH, National Institutes of Health; NS, Not significant; NR, Not reported; RAVLT, Rey’s Auditory Verbal Learning Test; SES, Socioeconomic status; SF-EMSE, Short Form Extended Mental State Exam; SMC, Subjective memory complaints; TICS, Telephone Interview for Cognitive Status – telephone adaption of MMSE to assess overall cognitive performance; wk, week(s); y, year(s)

iv Includes last name of first author, publication year, country, name of the cohort or study if reported, analytic sample size, and select participant characteristics of the analytic sample

v Abbreviations: CERAD, Consortium to Establish a Registry for Alzheimer’s Disease Battery; EVOO, extra-virgin olive oil; GMS, Geriatric Mental Schedule; HHS, Department of Health and Human Services; MIND, Mediterranean-DASH diet intervention for neurodegenerative delay; MMSE, Mini-Mental State Examination; mo, month(s); N/A, Not applicable; NCD, Neurocognitive disorder; NIA, National Institute on Aging; NHLBI, National Heart Lung and Blood Institute; NIH, National Institutes of Health; NS, Not significant; NR, Not reported; RAVLT, Rey’s Auditory Verbal Learning Test; SES, Socioeconomic status; SF-EMSE, Short Form Extended Mental State Exam; SMC, Subjective memory complaints; TICS, Telephone Interview for Cognitive Status – telephone adaption of MMSE to assess overall cognitive performance; wk, week(s); y, year(s)

vi Includes last name of first author, publication year, country, name of the cohort or study if reported, analytic sample size, and select participant characteristics of the analytic sample

vii A detailed description of the methodology used for assessing risk of bias is available on the NESR website: https://nesr.usda.gov/2020-dietary-guidelines-advisory-committee-systematic-reviews and in Part C of the following reference: Dietary Guidelines Advisory Committee. 2020. Scientific Report of the 2020 Dietary Guidelines Advisory Committee: Advisory Report to the Secretary of Agriculture and the Secretary of Health and Human Services. U.S. Department of Agriculture, Agricultural Research Service, Washington, DC .

viii Possible ratings of low, some concerns, or high determined using the “Cochrane Risk-of-bias 2.0" (RoB 2.0) (https://www.riskofbias.info/welcome/rob-2-0-tool) (August 2016 version)” ( Higgins JPT, Sterne JAC, Savović J, Page MJ, Hróbjartsson A, Boutron I, Reeves B, Eldridge S. A revised tool for assessing risk of bias in randomized trials In: Chandler J, McKenzie J, Boutron I, Welch V (editors). Cochrane Methods. Cochrane Database of Systematic Reviews 2016, Issue 10 (Suppl 1). 10.1002/14651858.CD201601 .)

ix Possible ratings of low, moderate, serious, critical, or no information determined using the “Risk of Bias for Nutrition Observational Studies” tool (RoB-NObs) ( Dietary Guidelines Advisory Committee. 2020. Scientific Report of the 2020 Dietary Guidelines Advisory Committee: Advisory Report to the Secretary of Agriculture and the Secretary of Health and Human Services. U.S. Department of Agriculture, Agricultural Research Service, Washington, DC .)