# References of the articles included in the evidence scan

1 Giordano G, Mastrantoni L, Terranova R, Colloca GF, Zuccalà G, Landi F. The role of Mediterranean diet in cancer incidence and mortality in the older adults. NPJ Aging. 2024;10(1):61.doi: 10.1038/s41514-024-00186-w.39639020
2 Furbatto M, Lelli D, Antonelli Incalzi R, Pedone C. Mediterranean Diet in Older Adults: Cardiovascular Outcomes and Mortality from Observational and Interventional Studies-A Systematic Review and Meta-Analysis. Nutrients. 2024;16(22).doi: 10.3390/nu16223947.
3 Yuan Y, Chen C, Liu Q, A network meta-analysis of the comparative efficacy of different dietary approaches on glycaemic control and weight loss in patients with type 2 diabetes mellitus and overweight or obesity. Food Funct. 2024;15(24):11961–11974.doi: 10.1039/d4fo00337c.39555961
4 Pourrajab B, Fotros D, Asghari P, Shidfar F. Effect of the Mediterranean Diet Supplemented With Olive Oil Versus the Low-Fat Diet on Serum Inflammatory and Endothelial Indexes Among Adults: A Systematic Review and Meta-analysis of Clinical Controlled Trials. Nutr Rev. 2024.doi: 10.1093/nutrit/nuae166.
5 Zhang L, Wang F, Tashiro S, Liu PJ. Effects of Dietary Approaches and Exercise Interventions on Gestational Diabetes Mellitus: A Systematic Review and Bayesian Network Meta-analysis. Adv Nutr. 2024;15(12):100330.doi: 10.1016/j.advnut.2024.100330.39481539
6 Yang B, Wei C, Zhang YC, Association between improved erectile function and dietary patterns: a systematic review and meta-analysis. Asian J Androl. 2024.doi: 10.4103/aja202485.
7 Liao T, Su J, Quan T, The impact of 3 different dietary interventions on overweight or obese adults: A network meta-analysis. Medicine (Baltimore). 2024;103(42):e39749.doi: 10.1097/md.0000000000039749.39432649
8 Jamil A, Chivese T, Elshaikh U, Sendall M. Efficacy of the Mediterranean diet in treating metabolic dysfunction-associated steatotic liver disease (MASLD) in children and adolescents: a systematic review and meta-analysis. BMC Public Health. 2024;24(1):2701.doi: 10.1186/s12889-024-19378-w.39363272
9 Valenzuela-Fuenzalida JJ, Bravo VS, Valarezo LM, Effectiveness of DASH Diet versus Other Diet Modalities in Patients with Metabolic Syndrome: A Systematic Review and Meta-Analysis. Nutrients. 2024;16(18).doi: 10.3390/nu16183054.
10 Moravejolahkami AR, Shakibaei M, Sharma M, Mohammadnezhad M, Devarakonda SLS. Effect of Mediterranean diet on body mass index and fatigue severity in patients with multiple sclerosis: A systematic review and meta-analysis of clinical trials. Heliyon. 2024;10(18):e37705.doi: 10.1016/j.heliyon.2024.e37705.39323842
11 Akbari M, Vali M, Rezaei S, Bazmi S, Tabrizi R, Lankarani KB. Comparison of weight loss effects among overweight/obese adults: A network meta-analysis of mediterranean, low carbohydrate, and low-fat diets. Clin Nutr ESPEN. 2024;64:7–15.doi: 10.1016/j.clnesp.2024.08.023.39255914
12 Shahid A, Thirumaran AJ, Christensen R, Comparison of weight loss interventions in overweight and obese adults with knee osteoarthritis: A systematic review and network meta-analysis of randomized trials. Osteoarthritis Cartilage. 2024.doi: 10.1016/j.joca.2024.08.012.
13 Keshani M, Sadeghi N, Tehrani SD, Ahmadi AR, Sharma M. Mediterranean diet enriched with olive oil shows no consistent benefits on cardiometabolic and anthropometric parameters: a systematic review with meta-analysis of randomized controlled trials. Eur J Nutr. 2024;63(8):2835–2857.doi: 10.1007/s00394-024-03478-9.39153124
14 Xiong Y, Shi X, Xiong X, A systematic review and meta-analysis of randomized controlled trials: effects of mediterranean diet and low-fat diet on liver enzymes and liver fat content of NAFLD. Food Funct. 2024;15(16):8248–8257.doi: 10.1039/d4fo01461h.39076035
15 López-Gil JF, García-Hermoso A, Martínez-González M, Rodríguez-Artalejo F. Mediterranean Diet and Cardiometabolic Biomarkers in Children and Adolescents: A Systematic Review and Meta-Analysis. JAMA Netw Open. 2024;7(7):e2421976.doi: 10.1001/jamanetworkopen.2024.21976.38995643
16 Waugh C, Pencheva N, Woolner A, Black M. Introduction of the Mediterranean diet in pregnancy and the incidence of gestational diabetes mellitus: A systematic review of randomised controlled trials and meta-analysis. Eur J Obstet Gynecol Reprod Biol. 2024;299:199–207.doi: 10.1016/j.ejogrb.2024.05.024.38889571
17 Guo H, Tian Q, Qin X, Luo Q, Gong X, Gao Q. Systematic evaluation and meta-analysis of the effects of major dietary patterns on cognitive function in healthy adults. Nutr Neurosci. 2024:1–17.doi: 10.1080/1028415x.2024.2342164.
18 Zheng X, Zhang W, Wan X, The effects of Mediterranean diet on cardiovascular risk factors, glycemic control and weight loss in patients with type 2 diabetes: a meta-analysis. BMC Nutr. 2024;10(1):59.doi: 10.1186/s40795-024-00836-y.38641818
19 Sebastian SA, Padda I, Johal G. Long-term impact of mediterranean diet on cardiovascular disease prevention: A systematic review and meta-analysis of randomized controlled trials. Curr Probl Cardiol. 2024;49(5):102509.doi: 10.1016/j.cpcardiol.2024.102509.38431146
20 Juhász AE, Stubnya MP, Teutsch B, Ranking the dietary interventions by their effectiveness in the management of polycystic ovary syndrome: a systematic review and network meta-analysis. Reprod Health. 2024;21(1):28.doi: 10.1186/s12978-024-01758-5.38388374
21 Bonekamp NE, Cruijsen E, Geleijnse JM, Diet in secondary prevention: the effect of dietary patterns on cardiovascular risk factors in patients with cardiovascular disease: a systematic review and network meta-analysis. Nutr J. 2024;23(1):18.doi: 10.1186/s12937-024-00922-8.38331867
22 Bizzozero-Peroni B, Martínez-Vizcaíno V, Fernández-Rodríguez R, The impact of the Mediterranean diet on alleviating depressive symptoms in adults: a systematic review and meta-analysis of randomized controlled trials. Nutr Rev. 2025;83(1):29–39.doi: 10.1093/nutrit/nuad176.38219230
23 Basri R, Alruwaili M, AlRuwaili R, Mohammad Albarrak A, Ali NH. Impact of Nutritional Interventions on Alzheimer's Disease: A Systematic Review and Meta-Analysis. Cureus. 2023;15(11):e49467.doi: 10.7759/cureus.49467.38152793
24 Xu J, Wang H, Bian J, Association between the Maternal Mediterranean Diet and Perinatal Outcomes: A Systematic Review and Meta-Analysis. Adv Nutr. 2024;15(2):100159.doi: 10.1016/j.advnut.2023.100159.38042258
25 Tsironikos GI, Potamianos P, Zakynthinos GE, Tsolaki V, Tatsioni A, Bargiota A. Effectiveness of Lifestyle Interventions during Pregnancy on Preventing Gestational Diabetes Mellitus in High-Risk Women: A Systematic Review and Meta-Analyses of Published RCTs. J Clin Med. 2023;12(22).doi: 10.3390/jcm12227038.
26 Cheng S, Shan L, You Z, Dietary patterns, uric acid levels, and hyperuricemia: a systematic review and meta-analysis. Food Funct. 2023;14(17):7853–7868.doi: 10.1039/d3fo02004e.37599588
27 Jing T, Zhang S, Bai M, Effect of Dietary Approaches on Glycemic Control in Patients with Type 2 Diabetes: A Systematic Review with Network Meta-Analysis of Randomized Trials. Nutrients. 2023;15(14).doi: 10.3390/nu15143156.
28 Yang J, Song Y, Gaskins AJ, Mediterranean diet and female reproductive health over lifespan: a systematic review and meta-analysis. Am J Obstet Gynecol. 2023;229(6):617–631.doi: 10.1016/j.ajog.2023.05.030.37506751
29 Wang T, Kroeger CM, Cassidy S, Vegetarian Dietary Patterns and Cardiometabolic Risk in People With or at High Risk of Cardiovascular Disease: A Systematic Review and Meta-analysis. JAMA Netw Open. 2023;6(7):e2325658.doi: 10.1001/jamanetworkopen.2023.25658.37490288
30 Doundoulakis I, Farmakis IT, Theodoridis X, Effects of dietary interventions on cardiovascular outcomes: a network meta-analysis. Nutr Rev. 2024;82(6):715–725.doi: 10.1093/nutrit/nuad080.37432782
31 Sahebkar A, Heidari Z, Kiani Z, The efficacy of dietary approaches to stop hypertension (DASH) diet on lipid profile: A systematic review and meta-analysis of clinical controlled trials. Curr Med Chem. 2023.doi: 10.2174/0929867331666230706102406.
32 Gohari S, Ghobadi S, Jafari A, Ahangar H, Gohari S, Mahjani M. The effect of dietary approaches to stop hypertension and ketogenic diets intervention on serum uric acid concentration: a systematic review and meta-analysis of randomized controlled trials. Sci Rep. 2023;13(1):10492.doi: 10.1038/s41598-023-37672-2.37380733
33 Del Bo C, Perna S, Allehdan S, Does the Mediterranean Diet Have Any Effect on Lipid Profile, Central Obesity and Liver Enzymes in Non-Alcoholic Fatty Liver Disease (NAFLD) Subjects? A Systematic Review and Meta-Analysis of Randomized Control Trials. Nutrients. 2023;15(10).doi: 10.3390/nu15102250.
34 Lin Q, Zhang Z, Meng Q, Effects of different dietary patterns during pregnancy on birth outcomes and glucose parameters in women with gestational diabetes mellitus: A systematic review and meta-analysis. Prim Care Diabetes. 2023;17(4):287–308.doi: 10.1016/j.pcd.2023.04.005.37127452
35 López-Gil JF, García-Hermoso A, Sotos-Prieto M, Cavero-Redondo I, Martínez-Vizcaíno V, Kales SN. Mediterranean Diet-Based Interventions to Improve Anthropometric and Obesity Indicators in Children and Adolescents: A Systematic Review with Meta-Analysis of Randomized Controlled Trials. Adv Nutr. 2023;14(4):858–869.doi: 10.1016/j.advnut.2023.04.011.37127186
36 Wang X, Jin X, Li H, Effects of various interventions on non-alcoholic fatty liver disease (NAFLD): A systematic review and network meta-analysis. Front Pharmacol. 2023;14:1180016.doi: 10.3389/fphar.2023.1180016.37063273
37 Karam G, Agarwal A, Sadeghirad B, Comparison of seven popular structured dietary programmes and risk of mortality and major cardiovascular events in patients at increased cardiovascular risk: systematic review and network meta-analysis. Bmj. 2023;380:e072003.doi: 10.1136/bmj-2022-072003.36990505
38 Xu Y, Mo G, Yao Y, Li C. The effects of vegetarian diets on glycemia and lipid parameters in adult patients with overweight and obesity: a systematic review and meta-analysis. Eur J Clin Nutr. 2023;77(8):794–802.doi: 10.1038/s41430-023-01283-x.36964271
39 Fuller H, Moore JB, Iles MM, Zulyniak MA. Ethnic-specific associations between dietary consumption and gestational diabetes mellitus incidence: A meta-analysis. PLOS Glob Public Health. 2022;2(5):e0000250.doi: 10.1371/journal.pgph.0000250.36962215
40 Chen KH, Ho MH, Wang CS, Chen IH. Effect of dietary patterns on cognitive functions of older adults: A systematic review and meta-analysis of randomized controlled trials: Dietary Patterns on Cognition of Older Adults. Arch Gerontol Geriatr. 2023;110:104967.doi: 10.1016/j.archger.2023.104967.36840986
41 Liang S, Mijatovic J, Li A, Dietary Patterns and Non-Communicable Disease Biomarkers: A Network Meta-Analysis and Nutritional Geometry Approach. Nutrients. 2022;15(1).doi: 10.3390/nu15010076.
42 Zeng BT, Pan HQ, Li FD, Ye ZY, Liu Y, Du JW. Comparative efficacy of different eating patterns in the management of type 2 diabetes and prediabetes: An arm-based Bayesian network meta-analysis. J Diabetes Investig. 2023;14(2):263–288.doi: 10.1111/jdi.13935.
43 Bonekamp NE, van Damme I, Geleijnse JM, Effect of dietary patterns on cardiovascular risk factors in people with type 2 diabetes. A systematic review and network meta-analysis. Diabetes Res Clin Pract. 2023;195:110207.doi: 10.1016/j.diabres.2022.110207.36513271
44 Kashyap A, Mackay A, Carter B, Fyfe CL, Johnstone AM, Myint PK. Investigating the Effectiveness of Very Low-Calorie Diets and Low-Fat Vegan Diets on Weight and Glycemic Markers in Type 2 Diabetes Mellitus: A Systematic Review and Meta-Analysis. Nutrients. 2022;14(22).doi: 10.3390/nu14224870.
45 Liu L, Zhou Y, He L. Mediterranean diet for the prevention of gestational diabetes: a meta-analysis of randomized controlled trials. J Matern Fetal Neonatal Med. 2022;35(26):10247–10252.doi: 10.1080/14767058.2021.1966764.36417937
46 Sánchez-Rosales AI, Guadarrama-López AL, Gaona-Valle LS, Martínez-Carrillo BE, Valdés-Ramos R. The Effect of Dietary Patterns on Inflammatory Biomarkers in Adults with Type 2 Diabetes Mellitus: A Systematic Review and Meta-Analysis of Randomized Controlled Trials. Nutrients. 2022;14(21).doi: 10.3390/nu14214577.
47 Wang L, Wu L, Qian C, The Beneficial Effect of a Healthy Dietary Pattern on Androgen Deprivation Therapy-Related Metabolic Abnormalities in Patients with Prostate Cancer: A Meta-Analysis Based on Randomized Controlled Trials and Systematic Review. Metabolites. 2022;12(10).doi: 10.3390/metabo12100969.
48 Snetselaar LG, Cheek JJ, Fox SS, Efficacy of Diet on Fatigue and Quality of Life in Multiple Sclerosis: A Systematic Review and Network Meta-analysis of Randomized Trials. Neurology. 2023;100(4):e357–e366.doi: 10.1212/wnl.0000000000201371.36257717
49 Massara P, Zurbau A, Glenn AJ, Nordic dietary patterns and cardiometabolic outcomes: a systematic review and meta-analysis of prospective cohort studies and randomised controlled trials. Diabetologia. 2022;65(12):2011–2031.doi: 10.1007/s00125–022-05760-z.36008559
50 Fu J, Tan LJ, Lee JE, Shin S. Association between the mediterranean diet and cognitive health among healthy adults: A systematic review and meta-analysis. Front Nutr. 2022;9:946361.doi: 10.3389/fnut.2022.946361.35967772
51 Haigh L, Kirk C, El Gendy K, The effectiveness and acceptability of Mediterranean diet and calorie restriction in non-alcoholic fatty liver disease (NAFLD): A systematic review and meta-analysis. Clin Nutr. 2022;41(9):1913–1931.doi: 10.1016/j.clnu.2022.06.037.35947894
52 Altemani AH, Alzaheb RA. The prevention of gestational diabetes mellitus (The role of lifestyle): a meta-analysis. Diabetol Metab Syndr. 2022;14(1):83.doi: 10.1186/s13098–022-00854–5.35706048
53 Termannsen AD, Clemmensen KKB, Thomsen JM, Effects of vegan diets on cardiometabolic health: A systematic review and meta-analysis of randomized controlled trials. Obes Rev. 2022;23(9):e13462.doi: 10.1111/obr.13462.35672940
54 Van Elswyk ME, Teo L, Lau CS, Shanahan CJ. Dietary Patterns and the Risk of Sarcopenia: A Systematic Review and Meta-Analysis. Curr Dev Nutr. 2022;6(5):nzac001.doi: 10.1093/cdn/nzac001.35542386
55 Fatima K, Rashid AM, Memon UAA, Mediterranean Diet and its Effect on Endothelial Function: A Meta-analysis and Systematic Review. Ir J Med Sci. 2023;192(1):105–113.doi: 10.1007/s11845–022-02944–9.35192097
56 Arnotti K, Bamber MD, Brewer V. Dietary interventions and blood pressure in overweight or obese individuals: A systematic review and meta-analysis. Clin Nutr. 2022;41(4):1001–1012.doi: 10.1016/j.clnu.2021.06.003.35031150
57 Schönenberger KA, Schüpfer AC, Gloy VL, Effect of Anti-Inflammatory Diets on Pain in Rheumatoid Arthritis: A Systematic Review and Meta-Analysis. Nutrients. 2021;13(12).doi: 10.3390/nu13124221.
58 Austin G, Ferguson JJA, Garg ML. Effects of Plant-Based Diets on Weight Status in Type 2 Diabetes: A Systematic Review and Meta-Analysis of Randomised Controlled Trials. Nutrients. 2021;13(11).doi: 10.3390/nu13114099.
59 McBean L, O'Reilly S. Diet quality interventions to prevent neurocognitive decline: a systematic review and meta-analysis. Eur J Clin Nutr. 2022;76(8):1060–1072.doi: 10.1038/s41430–021-01032-y.34732834
60 Koelman L, Egea Rodrigues C, Aleksandrova K. Effects of Dietary Patterns on Biomarkers of Inflammation and Immune Responses: A Systematic Review and Meta-Analysis of Randomized Controlled Trials. Adv Nutr. 2022;13(1):101–115.doi: 10.1093/advances/nmab086.34607347
61 Guo R, Li N, Yang R, Effects of the Modified DASH Diet on Adults With Elevated Blood Pressure or Hypertension: A Systematic Review and Meta-Analysis. Front Nutr. 2021;8:725020.doi: 10.3389/fnut.2021.725020.34557511
62 Houttu V, Csader S, Nieuwdorp M, Holleboom AG, Schwab U. Dietary Interventions in Patients With Non-alcoholic Fatty Liver Disease: A Systematic Review and Meta-Analysis. Front Nutr. 2021;8:716783.doi: 10.3389/fnut.2021.716783.34368214
63 Lari A, Sohouli MH, Fatahi S, The effects of the Dietary Approaches to Stop Hypertension (DASH) diet on metabolic risk factors in patients with chronic disease: A systematic review and meta-analysis of randomized controlled trials. Nutr Metab Cardiovasc Dis. 2021;31(10):2766–2778.doi: 10.1016/j.numecd.2021.05.030.34353704
64 Sangouni AA, Hassani Zadeh S, Mozaffari-Khosravi H, Hosseinzadeh M. Effect of Mediterranean diet on liver enzymes: a systematic review and meta-analysis of randomised controlled trials. Br J Nutr. 2022;128(7):1231–1239.doi: 10.1017/s0007114521002270.34165054
65 Kawaguchi T, Charlton M, Kawaguchi A, Effects of Mediterranean Diet in Patients with Nonalcoholic Fatty Liver Disease: A Systematic Review, Meta-Analysis, and Meta-Regression Analysis of Randomized Controlled Trials. Semin Liver Dis. 2021;41(3):225–234.doi: 10.1055/s-0041–1723751.34147036
66 Buzzetti E, Linden A, Best LM, Lifestyle modifications for nonalcohol-related fatty liver disease: a network meta-analysis. Cochrane Database Syst Rev. 2021;6(6):Cd013156.doi: 10.1002/14651858.CD013156.pub2.
67 Ghadimi M, Mohammadi R, Daneshzad E, Moazzami B, Mohammadpour Z. Effectiveness of dietary interventions on cardio-metabolic risk factors in patients with nonalcoholic fatty liver disease: a systematic review and meta-analysis of randomized controlled trials. Ann Gastroenterol. 2021;34(3):415–423.doi: 10.20524/aog.2021.0601.33948068
68 Frączek B, ięta A, Burda A, Mazur-Kurach P, Tyrała F. Paleolithic Diet-Effect on the Health Status and Performance of Athletes? Nutrients. 2021;13(3).doi: 10.3390/nu13031019.
69 Zhang Y, Xia M, Weng S, Wang C, Yuan P, Tang S. Effect of Mediterranean diet for pregnant women: a meta-analysis of randomized controlled trials. J Matern Fetal Neonatal Med. 2022;35(24):4824–4829.doi: 10.1080/14767058.2020.1868429.33632052
70 Rees K, Al-Khudairy L, Takeda A, Stranges S. Vegan dietary pattern for the primary and secondary prevention of cardiovascular diseases. Cochrane Database Syst Rev. 2021;2(2):Cd013501.doi: 10.1002/14651858.CD013501.pub2.33629376
71 Filippou CD, Thomopoulos CG, Kouremeti MM, Mediterranean diet and blood pressure reduction in adults with and without hypertension: A systematic review and meta-analysis of randomized controlled trials. Clin Nutr. 2021;40(5):3191–3200.doi: 10.1016/j.clnu.2021.01.030.33581952
72 Sohouli MH, Fatahi S, Lari A, The effect of paleolithic diet on glucose metabolism and lipid profile among patients with metabolic disorders: a systematic review and meta-analysis of randomized controlled trials. Crit Rev Food Sci Nutr. 2022;62(17):4551–4562.doi: 10.1080/10408398.2021.1876625.33492173
73 Pirouzeh R, Heidarzadeh-Esfahani N, Morvaridzadeh M, Effect of DASH diet on oxidative stress parameters: A systematic review and meta-analysis of randomized clinical trials. Diabetes Metab Syndr. 2020;14(6):2131–2138.doi: 10.1016/j.dsx.2020.10.031.33395773
74 Gibbs J, Gaskin E, Ji C, Miller MA, Cappuccio FP. The effect of plant-based dietary patterns on blood pressure: a systematic review and meta-analysis of controlled intervention trials. J Hypertens. 2021;39(1):23–37.doi: 10.1097/hjh.0000000000002604.33275398
75 Wu PY, Chen KM, Belcastro F. Dietary patterns and depression risk in older adults: systematic review and meta-analysis. Nutr Rev. 2021;79(9):976–987.doi: 10.1093/nutrit/nuaa118.33236111
76 Li S, Gan Y, Chen M, Effects of the Dietary Approaches to Stop Hypertension (DASH) on Pregnancy/Neonatal Outcomes and Maternal Glycemic Control: A Systematic Review and Meta-analysis of Randomized Clinical Trials. Complement Ther Med. 2020;54:102551.doi: 10.1016/j.ctim.2020.102551.33183669
77 Papadaki A, Nolen-Doerr E, Mantzoros CS. The Effect of the Mediterranean Diet on Metabolic Health: A Systematic Review and Meta-Analysis of Controlled Trials in Adults. Nutrients. 2020;12(11).doi: 10.3390/nu12113342.
78 Cowell OR, Mistry N, Deighton K, Effects of a Mediterranean diet on blood pressure: a systematic review and meta-analysis of randomized controlled trials and observational studies. J Hypertens. 2021;39(4):729–739.doi: 10.1097/hjh.0000000000002667.33060448
79 Fu J, Liu Y, Zhang L, Nonpharmacologic Interventions for Reducing Blood Pressure in Adults With Prehypertension to Established Hypertension. J Am Heart Assoc. 2020;9(19):e016804.doi: 10.1161/jaha.120.016804.32975166
80 Lin BB, Lin ME, Huang RH, Hong YK, Lin BL, He XJ. Dietary and lifestyle factors for primary prevention of nephrolithiasis: a systematic review and meta-analysis. BMC Nephrol. 2020;21(1):267.doi: 10.1186/s12882–020-01925–3.32652950
81 Shang Y, Zhou H, Hu M, Feng H. Effect of Diet on Insulin Resistance in Polycystic Ovary Syndrome. J Clin Endocrinol Metab. 2020;105(10).doi: 10.1210/clinem/dgaa425.
82 Akhlaghi M, Ghasemi-Nasab M, Riasatian M. Mediterranean diet for patients with non-alcoholic fatty liver disease, a systematic review and meta-analysis of observational and clinical investigations. J Diabetes Metab Disord. 2020;19(1):575–584.doi: 10.1007/s40200–019-00475–2.32550210
83 Lee KW, Loh HC, Ching SM, Devaraj NK, Hoo FK. Effects of Vegetarian Diets on Blood Pressure Lowering: A Systematic Review with Meta-Analysis and Trial Sequential Analysis. Nutrients. 2020;12(6).doi: 10.3390/nu12061604.
84 Asbaghi O, Choghakhori R, Ashtary-Larky D, Abbasnezhad A. Effects of the Mediterranean diet on cardiovascular risk factors in non-alcoholic fatty liver disease patients: A systematic review and meta-analysis. Clin Nutr ESPEN. 2020;37:148–156.doi: 10.1016/j.clnesp.2020.03.003.32359737
85 Filippou CD, Tsioufis CP, Thomopoulos CG, Dietary Approaches to Stop Hypertension (DASH) Diet and Blood Pressure Reduction in Adults with and without Hypertension: A Systematic Review and Meta-Analysis of Randomized Controlled Trials. Adv Nutr. 2020;11(5):1150–1160.doi: 10.1093/advances/nmaa041.32330233
86 Abbasnezhad A, Falahi E, Gonzalez MJ, Kavehi P, Fouladvand F, Choghakhori R. Effect of different dietary approaches compared with a regular diet on systolic and diastolic blood pressure in patients with type 2 diabetes: A systematic review and meta-analysis. Diabetes Res Clin Pract. 2020;163:108108.doi: 10.1016/j.diabres.2020.108108.32259613
87 Ge L, Sadeghirad B, Ball GDC, Comparison of dietary macronutrient patterns of 14 popular named dietary programmes for weight and cardiovascular risk factor reduction in adults: systematic review and network meta-analysis of randomised trials. Bmj. 2020;369:m696.doi: 10.1136/bmj.m696.32238384
88 Shannon OM, Mendes I, Köchl C, Mediterranean Diet Increases Endothelial Function in Adults: A Systematic Review and Meta-Analysis of Randomized Controlled Trials. J Nutr. 2020;150(5):1151–1159.doi: 10.1093/jn/nxaa002.32027740
89 Jamka M, Kulczyński B, Juruć A, Gramza-Michałowska A, Stokes CS, Walkowiak J. The Effect of the Paleolithic Diet vs. Healthy Diets on Glucose and Insulin Homeostasis: A Systematic Review and Meta-Analysis of Randomized Controlled Trials. J Clin Med. 2020;9(2).doi: 10.3390/jcm9020296.
90 Burden S, Jones DJ, Sremanakova J, Dietary interventions for adult cancer survivors. Cochrane Database Syst Rev. 2019;2019(11).doi: 10.1002/14651858.CD011287.pub2.
91 Ramezani-Jolfaie N, Mohammadi M, Salehi-Abargouei A. Effects of a healthy Nordic diet on weight loss in adults: a systematic review and meta-analysis of randomized controlled clinical trials. Eat Weight Disord. 2020;25(5):1141–1150.doi: 10.1007/s40519–019-00773-x.31522379
92 de Menezes EVA, Sampaio HAC, Carioca AAF, Influence of Paleolithic diet on anthropometric markers in chronic diseases: systematic review and meta-analysis. Nutr J. 2019;18(1):41.doi: 10.1186/s12937-019-0457-z.31337389
93 Neuenschwander M, Hoffmann G, Schwingshackl L, Schlesinger S. Impact of different dietary approaches on blood lipid control in patients with type 2 diabetes mellitus: a systematic review and network meta-analysis. Eur J Epidemiol. 2019;34(9):837–852.doi: 10.1007/s10654-019-00534-1.31201670
94 Zimorovat A, Mohammadi M, Ramezani-Jolfaie N, Salehi-Abargouei A. The healthy Nordic diet for blood glucose control: a systematic review and meta-analysis of randomized controlled clinical trials. Acta Diabetol. 2020;57(1):1–12.doi: 10.1007/s00592-019-01369-8.31172295
95 Ghaedi E, Mohammadi M, Mohammadi H, Effects of a Paleolithic Diet on Cardiovascular Disease Risk Factors: A Systematic Review and Meta-Analysis of Randomized Controlled Trials. Adv Nutr. 2019;10(4):634–646.doi: 10.1093/advances/nmz007.31041449
96 McEvoy CT, Leng Y, Peeters GM, Kaup AR, Allen IE, Yaffe K. Interventions involving a major dietary component improve cognitive function in cognitively healthy adults: a systematic review and meta-analysis. Nutr Res. 2019;66:1–12.doi: 10.1016/j.nutres.2019.02.008.31022563
97 Rees K, Takeda A, Martin N, Mediterranean-style diet for the primary and secondary prevention of cardiovascular disease. Cochrane Database Syst Rev. 2019;3(3):Cd009825.doi: 10.1002/14651858.CD009825.pub3.30864165
98 Lopez PD, Cativo EH, Atlas SA, Rosendorff C. The Effect of Vegan Diets on Blood Pressure in Adults: A Meta-Analysis of Randomized Controlled Trials. Am J Med. 2019;132(7):875–883.e877.doi: 10.1016/j.amjmed.2019.01.044.30851264
99 Becerra-Tomás N, Blanco Mejía S, Viguiliouk E, Mediterranean diet, cardiovascular disease and mortality in diabetes: A systematic review and meta-analysis of prospective cohort studies and randomized clinical trials. Crit Rev Food Sci Nutr. 2020;60(7):1207–1227.doi: 10.1080/10408398.2019.1565281.30676058
100 Al-Ghamdi S. The association between olive oil consumption and primary prevention of cardiovascular diseases. J Family Med Prim Care. 2018;7(5):859–864.doi: 10.4103/jfmpc.jfmpc_191_18.30598924
101 Sakhaei R, Ramezani-Jolfaie N, Mohammadi M, Salehi-Abargouei A. The healthy Nordic dietary pattern has no effect on inflammatory markers: A systematic review and meta-analysis of randomized controlled clinical trials. Nutrition. 2019;58:140–148.doi: 10.1016/j.nut.2018.06.020.30391693
102 Ramezani-Jolfaie N, Mohammadi M, Salehi-Abargouei A. The effect of healthy Nordic diet on cardiometabolic markers: a systematic review and meta-analysis of randomized controlled clinical trials. Eur J Nutr. 2019;58(6):2159–2174.doi: 10.1007/s00394-018-1804-0.30128767
103 Pan B, Wu Y, Yang Q, The impact of major dietary patterns on glycemic control, cardiovascular risk factors, and weight loss in patients with type 2 diabetes: A network meta-analysis. J Evid Based Med. 2019;12(1):29–39.doi: 10.1111/jebm.12312.30070019
104 Picasso MC, Lo-Tayraco JA, Ramos-Villanueva JM, Pasupuleti V, Hernandez AV. Effect of vegetarian diets on the presentation of metabolic syndrome or its components: A systematic review and meta-analysis. Clin Nutr. 2019;38(3):1117–1132.doi: 10.1016/j.clnu.2018.05.021.29907356
105 Chiavaroli L, Nishi SK, Khan TA, Portfolio Dietary Pattern and Cardiovascular Disease: A Systematic Review and Meta-analysis of Controlled Trials. Prog Cardiovasc Dis. 2018;61(1):43–53.doi: 10.1016/j.pcad.2018.05.004.29807048
106 Schwingshackl L, Chaimani A, Schwedhelm C, Comparative effects of different dietary approaches on blood pressure in hypertensive and pre-hypertensive patients: A systematic review and network meta-analysis. Crit Rev Food Sci Nutr. 2019;59(16):2674–2687.doi: 10.1080/10408398.2018.1463967.29718689
107 Mayr HL, Tierney AC, Thomas CJ, Ruiz-Canela M, Radcliffe J, Itsiopoulos C. Mediterranean-type diets and inflammatory markers in patients with coronary heart disease: a systematic review and meta-analysis. Nutr Res. 2018;50:10–24.doi: 10.1016/j.nutres.2017.10.014.29540268
108 Schwingshackl L, Chaimani A, Hoffmann G, Schwedhelm C, Boeing H. A network meta-analysis on the comparative efficacy of different dietary approaches on glycaemic control in patients with type 2 diabetes mellitus. Eur J Epidemiol. 2018;33(2):157–170.doi: 10.1007/s10654-017-0352-x.29302846
109 Martínez-González M, Hershey MS, Zazpe I, Trichopoulou A. Transferability of the Mediterranean Diet to Non-Mediterranean Countries. What Is and What Is Not the Mediterranean Diet. Nutrients. 2017;9(11).doi: 10.3390/nu9111226.
110 Schwingshackl L, Schwedhelm C, Galbete C, Hoffmann G. Adherence to Mediterranean Diet and Risk of Cancer: An Updated Systematic Review and Meta-Analysis. Nutrients. 2017;9(10).doi: 10.3390/nu9101063.
111 Loughrey DG, Lavecchia S, Brennan S, Lawlor BA, Kelly ME. The Impact of the Mediterranean Diet on the Cognitive Functioning of Healthy Older Adults: A Systematic Review and Meta-Analysis. Adv Nutr. 2017;8(4):571–586.doi: 10.3945/an.117.015495.28710144
112 Palmer SC, Maggo JK, Campbell KL, Dietary interventions for adults with chronic kidney disease. Cochrane Database Syst Rev. 2017;4(4):Cd011998.doi: 10.1002/14651858.CD011998.pub2.28434208
113 Soltani S, Chitsazi MJ, Salehi-Abargouei A. The effect of dietary approaches to stop hypertension (DASH) on serum inflammatory markers: A systematic review and meta-analysis of randomized trials. Clin Nutr. 2018;37(2):542–550.doi: 10.1016/j.clnu.2017.02.018.28302405
114 Han S, Middleton P, Shepherd E, Van Ryswyk E, Crowther CA. Different types of dietary advice for women with gestational diabetes mellitus. Cochrane Database Syst Rev. 2017;2(2):Cd009275.doi: 10.1002/14651858.CD009275.pub3.28236296
115 Liyanage T, Ninomiya T, Wang A, Effects of the Mediterranean Diet on Cardiovascular Outcomes-A Systematic Review and Meta-Analysis. PLoS One. 2016;11(8):e0159252.doi: 10.1371/journal.pone.0159252.27509006
116 Eichelmann F, Schwingshackl L, Fedirko V, Aleksandrova K. Effect of plant-based diets on obesity-related inflammatory profiles: a systematic review and meta-analysis of intervention trials. Obes Rev. 2016;17(11):1067–1079.doi: 10.1111/obr.12439.27405372
117 Neale EP, Batterham MJ, Tapsell LC. Consumption of a healthy dietary pattern results in significant reductions in C-reactive protein levels in adults: a meta-analysis. Nutr Res. 2016;36(5):391–401.doi: 10.1016/j.nutres.2016.02.009.27101757
118 Garcia M, Bihuniak JD, Shook J, Kenny A, Kerstetter J, Huedo-Medina TB. The Effect of the Traditional Mediterranean-Style Diet on Metabolic Risk Factors: A Meta-Analysis. Nutrients. 2016;8(3):168.doi: 10.3390/nu8030168.26999195
119 Soltani S, Shirani F, Chitsazi MJ, Salehi-Abargouei A. The effect of dietary approaches to stop hypertension (DASH) diet on weight and body composition in adults: a systematic review and meta-analysis of randomized controlled clinical trials. Obes Rev. 2016;17(5):442–454.doi: 10.1111/obr.12391.26990451
120 Gay HC, Rao SG, Vaccarino V, Ali MK. Effects of Different Dietary Interventions on Blood Pressure: Systematic Review and Meta-Analysis of Randomized Controlled Trials. Hypertension. 2016;67(4):733–739.doi: 10.1161/hypertensionaha.115.06853.26902492
121 Ndanuko RN, Tapsell LC, Charlton KE, Neale EP, Batterham MJ. Dietary Patterns and Blood Pressure in Adults: A Systematic Review and Meta-Analysis of Randomized Controlled Trials. Adv Nutr. 2016;7(1):76–89.doi: 10.3945/an.115.009753.26773016
122 Grosso G, Marventano S, Yang J, A comprehensive meta-analysis on evidence of Mediterranean diet and cardiovascular disease: Are individual components equal? Crit Rev Food Sci Nutr. 2017;57(15):3218–3232.doi: 10.1080/10408398.2015.1107021.26528631
123 Nissensohn M, Román-Viñas B, Sánchez-Villegas A, Piscopo S, Serra-Majem L. The Effect of the Mediterranean Diet on Hypertension: A Systematic Review and Meta-Analysis. J Nutr Educ Behav. 2016;48(1):42–53.e41.doi: 10.1016/j.jneb.2015.08.023.26483006
124 Lehert P, Villaseca P, Hogervorst E, Maki PM, Henderson VW. Individually modifiable risk factors to ameliorate cognitive aging: a systematic review and meta-analysis. Climacteric. 2015;18(5):678–689.doi: 10.3109/13697137.2015.1078106.26361790
125 Manheimer EW, van Zuuren EJ, Fedorowicz Z, Pijl H. Paleolithic nutrition for metabolic syndrome: systematic review and meta-analysis. Am J Clin Nutr. 2015;102(4):922–932.doi: 10.3945/ajcn.115.113613.26269362
126 Esposito K, Maiorino MI, Bellastella G, Chiodini P, Panagiotakos D, Giugliano D. A journey into a Mediterranean diet and type 2 diabetes: a systematic review with meta-analyses. BMJ Open. 2015;5(8):e008222.doi: 10.1136/bmjopen-2015-008222.
127 Siervo M, Lara J, Chowdhury S, Ashor A, Oggioni C, Mathers JC. Effects of the Dietary Approach to Stop Hypertension (DASH) diet on cardiovascular risk factors: a systematic review and meta-analysis. Br J Nutr. 2015;113(1):1–15.doi: 10.1017/s0007114514003341.25430608
128 Huo R, Du T, Xu Y, Effects of Mediterranean-style diet on glycemic control, weight loss and cardiovascular risk factors among type 2 diabetes individuals: a meta-analysis. Eur J Clin Nutr. 2015;69(11):1200–1208.doi: 10.1038/ejcn.2014.243.25369829
129 Zhao J, Peng Y, Lin Z, Gong Y. Association between Mediterranean diet adherence and Parkinson's disease: a systematic review and meta-analysis. J Nutr Health Aging. 2024;29(2):100451.doi: 10.1016/j.jnha.2024.100451.39693849
130 Fichtel-Epstein C, Huang J, Rich BJ, Taswell CS, Isrow D, Jin W. Ultra-Processed Food and Prostate Cancer Risk: A Systemic Review and Meta-Analysis. Cancers (Basel). 2024;16(23).doi: 10.3390/cancers16233953.
131 Errasti Viader J, Martínez González M, Campo Ezquibela A, Bes-Rastrollo M. Dietary patterns and asthma incidence in adult population. Systematic review and meta-analysis. Respir Med. 2024;236:107861.doi: 10.1016/j.rmed.2024.107861.39571825
132 Tan J, Zhang S, Jiang Y, Li J, Yang C. Plant-based diet and risk of all-cause mortality: a systematic review and meta-analysis. Front Nutr. 2024;11:1481363.doi: 10.3389/fnut.2024.1481363.39507899
133 Liu J, Shen Q, Wang X. Emerging EAT-Lancet planetary health diet is associated with major cardiovascular diseases and all-cause mortality: A global systematic review and meta-analysis. Clin Nutr. 2024;43(12):167–179.doi: 10.1016/j.clnu.2024.10.021.39489999
134 Fa-Binefa M, Clara A, Lamas C, Elosua R. Mediterranean Diet and Risk of Hip Fracture: A Systematic Review and Dose-Response Meta-Analysis. Nutr Rev. 2024.doi: 10.1093/nutrit/nuae141.
135 Hu XF, Zhang R, Chan HM. Identification of Chinese dietary patterns and their relationships with health outcomes: a systematic review and meta-analysis. Public Health Nutr. 2024;27(1):e209.doi: 10.1017/s1368980024001927.39397510
136 Veronese N, Ragusa FS, Maggi S, Effect of the Mediterranean diet on incidence of heart failure in European countries: a systematic review and meta-analysis of cohort studies. Eur J Clin Nutr. 2024.doi: 10.1038/s41430-024-01519-4.
137 Larruy-García A, Mahmood L, Miguel-Berges ML, Diet Quality Scores, Obesity and Metabolic Syndrome in Children and Adolescents: A Systematic Review and Meta-Analysis. Curr Obes Rep. 2024;13(4):755–788.doi: 10.1007/s13679-024-00589-6.39331350
138 Barbosa LB, Gama IRS, Vasconcelos NBR, Santos EAD, Ataide-Silva T, Ferreira HDS. Dietary patterns according to gender and ethnicity associated with metabolic syndrome: a systematic review and meta-analysis. Cien Saude Colet. 2024;29(10):e03662023.doi: 10.1590/1413-812320242910.03662023.39292035
139 Ungvari Z, Fekete M, Fekete JT, Grosso G, Ungvari A, Győrffy B. Adherence to the Mediterranean diet and its protective effects against colorectal cancer: a meta-analysis of 26 studies with 2,217,404 participants. Geroscience. 2024.doi: 10.1007/s11357-024-01296-9.
140 Jafari Nasab S, Ghanavati M, C CTC, Nasirian M. Adherence to Mediterranean dietary pattern and the risk of gestational diabetes mellitus: a systematic review and meta-analysis of observational studies. Nutr Diabetes. 2024;14(1):55.doi: 10.1038/s41387-024-00313-2.39039056
141 Abebe Z, Wassie MM, Mekonnen TC, Reynolds AC, Melaku YA. Difference in Gastrointestinal Cancer Risk and Mortality by Dietary Pattern Analysis: A Systematic Review and Meta-Analysis. Nutr Rev. 2024.doi: 10.1093/nutrit/nuae090.
142 Lim GH, Neelakantan N, Lee YQ, Dietary Patterns and Cardiovascular Diseases in Asia: A Systematic Review and Meta-Analysis. Adv Nutr. 2024;15(7):100249.doi: 10.1016/j.advnut.2024.100249.39009489
143 Shu W, Liu L, Jiang J, Yao Q. Dietary patterns and hepatocellular carcinoma risk: a systematic review and meta-analysis of cohort and case-control studies. Nutr Metab (Lond). 2024;21(1):47.doi: 10.1186/s12986-024-00822-y.38992637
144 López-Gil JF, Victoria-Montesinos D, García-Hermoso A. Is higher adherence to the mediterranean diet associated with greater academic performance in children and adolescents? A systematic review and meta-analysis. Clin Nutr. 2024;43(8):1702–1709.doi: 10.1016/j.clnu.2024.05.045.38896917
145 Luo MZ, Shu L, Ye XS. Association between priori and posteriori dietary patterns and gastric cancer risk: an updated systematic review and meta-analysis of observational studies. Eur J Cancer Prev. 2024.doi: 10.1097/cej.0000000000000900.
146 Quan X, Shen X, Li C, Li Y, Li T, Chen B. Adherence to the dietary approaches to stop hypertension diet reduces the risk of diabetes mellitus: a systematic review and dose-response meta-analysis. Endocrine. 2024;86(1):85–100.doi: 10.1007/s12020-024-03882-5.38816664
147 Papadaki A, Coy EM, Anastasilakis DA, Peradze N, Mantzoros CS. The role of plant-based dietary patterns in reducing COVID-19 risk and/or severity in adults: A systematic review and meta-analysis of observational studies. Clin Nutr. 2024;43(7):1657–1666.doi: 10.1016/j.clnu.2024.05.033.38810425
148 Nikparast A, Mirzaei P, Tadayoni ZS, Asghari G. The Association Between Overall, Healthy, and Unhealthy Plant-Based Diet Index and Risk of Prediabetes and Type 2 Diabetes Mellitus: A Systematic Review and Dose-Response Meta-Analysis of Prospective Studies. Nutr Rev. 2024.doi: 10.1093/nutrit/nuae049.
149 Arab A, Karimi E, Garaulet M, Scheer F. Dietary patterns and insomnia symptoms: A systematic review and meta-analysis. Sleep Med Rev. 2024;75:101936.doi: 10.1016/j.smrv.2024.101936.38714136
150 Angelia M, Amelia YS, Pratama KG. Mediterranean diet as a modifiable risk factor for age-related macular degeneration: A systematic review and meta-analysis. Tzu Chi Med J. 2024;36(2):223–230.doi: 10.4103/tcmj.tcmj_153_23.38645781
151 Nucci D, Sommariva A, Degoni LM, Association between Mediterranean diet and dementia and Alzheimer disease: a systematic review with meta-analysis. Aging Clin Exp Res. 2024;36(1):77.doi: 10.1007/s40520-024-02718-6.
152 Wen ZY, Wei YF, Sun YH, Ji WP. Dietary pattern and risk of hyperuricemia: an updated systematic review and meta-analysis of observational studies. Front Nutr. 2024;11:1218912.doi: 10.3389/fnut.2024.1218912.38481974
153 Hao X, Li D. The Healthy Eating Index-2015 and All-Cause/Cause-Specific Mortality: A Systematic Review and Dose-Response Meta-Analysis. Adv Nutr. 2024;15(3):100166.doi: 10.1016/j.advnut.2023.100166.38461130
154 Nikparast A, Etesami E, Rahmani J, Rafiei N, Ghanavati M. The association between plant-based diet indices and metabolic syndrome: a systematic review and dose-response meta-analysis. Front Nutr. 2023;10:1305755.doi: 10.3389/fnut.2023.1305755.38260063
155 Zhang H, Li M, Mo L, Luo J, Shen Q, Quan W. Association between Western Dietary Patterns, Typical Food Groups, and Behavioral Health Disorders: An Updated Systematic Review and Meta-Analysis of Observational Studies. Nutrients. 2023;16(1).doi: 10.3390/nu16010125.
156 Taylor RM, Haslam RL, Herbert J, Diet quality and cardiovascular outcomes: A systematic review and meta-analysis of cohort studies. Nutr Diet. 2024;81(1):35–50.doi: 10.1111/1747-0080.12860.38129766
157 Liu C, Kuang X, Gu M, Liu X, Lu J, Yu H. The impact of two dietary patterns on hyperuricemia in adults: A meta analysis of observational studies. Medicine (Baltimore). 2023;102(46):e35309.doi: 10.1097/md.0000000000035309.37986343
158 Sampathkumar S, Parkhi D, Ghebremichael-Weldeselassie Y, Sukumar N, Saravanan P. Effectiveness of pre-pregnancy lifestyle in preventing gestational diabetes mellitus-a systematic review and meta-analysis of 257,876 pregnancies. Nutr Diabetes. 2023;13(1):22.doi: 10.1038/s41387-023-00251-5.37973902
159 Jafari Nasab S, Clark CCT, Entezari M. Mediterranean diet and colorectal adenomas: a systematic review and meta-analysis of observational studies. Eur J Cancer Prev. 2024;33(3):223–231.doi: 10.1097/cej.0000000000000861.37942952
160 Fabiani R, La Porta G, Li Cavoli L, Rosignoli P, Chiavarini M. Adherence to Data-Driven Dietary Patterns and Lung Cancer Risk: A Systematic Review and Dose-Response Meta-Analysis. Nutrients. 2023;15(20).doi: 10.3390/nu15204406.
161 Zhu Y, Zheng Q, Huang L, The effects of plant-based dietary patterns on the risk of developing gestational diabetes mellitus: A systematic review and meta-analysis. PLoS One. 2023;18(10):e0291732.doi: 10.1371/journal.pone.0291732.37792722
162 Wang Y, Liu B, Han H, Associations between plant-based dietary patterns and risks of type 2 diabetes, cardiovascular disease, cancer, and mortality - a systematic review and meta-analysis. Nutr J. 2023;22(1):46.doi: 10.1186/s12937-023-00877-2.37789346
163 Zhu Q, Shu L, Zhou F, Chen LP, Feng YL. Adherence to the Mediterranean diet and risk of gastric cancer: a systematic review and dose-response meta-analysis. Front Nutr. 2023;10:1259453.doi: 10.3389/fnut.2023.1259453.37743920
164 Spei ME, Bellos I, Samoli E, Benetou V. Post-Diagnosis Dietary Patterns among Cancer Survivors in Relation to All-Cause Mortality and Cancer-Specific Mortality: A Systematic Review and Meta-Analysis of Cohort Studies. Nutrients. 2023;15(17).doi: 10.3390/nu15173860.
165 Bai X, Li X, Ding S, Dai D. Adherence to the Mediterranean Diet and Risk of Gastric Cancer: A Systematic Review and Meta-Analysis. Nutrients. 2023;15(17).doi: 10.3390/nu15173826.
166 Theodoridis X, Triantafyllou A, Chrysoula L, Impact of the Level of Adherence to the DASH Diet on Blood Pressure: A Systematic Review and Meta-Analysis. Metabolites. 2023;13(8).doi: 10.3390/metabo13080924.
167 Theodoridis X, Chourdakis M, Chrysoula L, Adherence to the DASH Diet and Risk of Hypertension: A Systematic Review and Meta-Analysis. Nutrients. 2023;15(14).doi: 10.3390/nu15143261.
168 Trauchburg A, Schwingshackl L, Hoffmann G. Association between Dietary Indices and Dietary Patterns and Mortality and Cancer Recurrence among Cancer Survivors: An Updated Systematic Review and Meta-Analysis of Cohort Studies. Nutrients. 2023;15(14).doi: 10.3390/nu15143151.
169 Kotzakioulafi E, Bakaloudi DR, Chrysoula L, High Versus Low Adherence to the Mediterranean Diet for Prevention of Diabetes Mellitus Type 2: A Systematic Review and Meta-Analysis. Metabolites. 2023;13(7).doi: 10.3390/metabo13070779.
170 Chen G, Leary S, Niu J, Perry R, Papadaki A. The Role of the Mediterranean Diet in Breast Cancer Survivorship: A Systematic Review and Meta-Analysis of Observational Studies and Randomised Controlled Trials. Nutrients. 2023;15(9).doi: 10.3390/nu15092099.
171 You Z, Shan L, Cheng S, Dietary intake patterns during pregnancy and excessive gestational weight gain: a systematic review and meta-analysis. Food Funct. 2023;14(13):5910–5920.doi: 10.1039/d3fo01550e.37347118
172 Winter HG, Rolnik DL, Mol BWJ, Can Dietary Patterns Impact Fertility Outcomes? A Systematic Review and Meta-Analysis. Nutrients. 2023;15(11).doi: 10.3390/nu15112589.
173 Hua H, Jiang Q, Sun P, Xu X. Risk factors for early-onset colorectal cancer: systematic review and meta-analysis. Front Oncol. 2023;13:1132306.doi: 10.3389/fonc.2023.1132306.37213277
174 Huang L, Tao Y, Chen H, Mediterranean-Dietary Approaches to Stop Hypertension Intervention for Neurodegenerative Delay (MIND) Diet and Cognitive Function and its Decline: A Prospective Study and Meta-analysis of Cohort Studies. Am J Clin Nutr. 2023;118(1):174–182.doi: 10.1016/j.ajcnut.2023.04.025.37105521
175 Zhao L, Kase B, Zheng J, Steck SE. Dietary Patterns and Risk of Lung Cancer: A Systematic Review and Meta-Analyses of Observational Studies. Curr Nutr Rep. 2023;12(2):338–357.doi: 10.1007/s13668-023-00469-w.37097371
176 Dominguez LJ, Donat-Vargas C, Sayon-Orea C, Rationale of the association between Mediterranean diet and the risk of frailty in older adults and systematic review and meta-analysis. Exp Gerontol. 2023;177:112180.doi: 10.1016/j.exger.2023.112180.37087024
177 Pant A, Gribbin S, McIntyre D, Primary prevention of cardiovascular disease in women with a Mediterranean diet: systematic review and meta-analysis. Heart. 2023;109(16):1208–1215.doi: 10.1136/heartjnl-2022-321930.36918266
178 Poursalehi D, Lotfi K, Saneei P. Adherence to the Mediterranean diet and risk of frailty and pre-frailty in elderly adults: A systematic review and dose-response meta-analysis with GRADE assessment. Ageing Res Rev. 2023;87:101903.doi: 10.1016/j.arr.2023.101903.36871780
179 Nucci D, Nardi M, Cinnirella A, Adherence to Mediterranean Diet and Risk of Pancreatic Cancer: Systematic Review and Meta-Analysis. Int J Environ Res Public Health. 2023;20(3).doi: 10.3390/ijerph20032403.
180 Shin S, Fu J, Shin WK, Huang D, Min S, Kang D. Association of food groups and dietary pattern with breast cancer risk: A systematic review and meta-analysis. Clin Nutr. 2023;42(3):282–297.doi: 10.1016/j.clnu.2023.01.003.36731160
181 Gao X, Zheng Q, Jiang X, Chen X, Liao Y, Pan Y. The effect of diet quality on the risk of developing gestational diabetes mellitus: A systematic review and meta-analysis. Front Public Health. 2022;10:1062304.doi: 10.3389/fpubh.2022.1062304.36699870
182 Shu L, Huang YQ, Zhang XY, Zheng PF, Zhu Q, Zhou JY. Adherence to the Dietary Approaches to Stop Hypertension diet reduces the risk of breast cancer: A systematic review and meta-analysis. Front Nutr. 2022;9:1032654.doi: 10.3389/fnut.2022.1032654.36698472
183 Shu L, Yu D, Jin F. Healthy dietary patterns, foods, and risk of glioma: A systematic review and meta-analysis of observational studies. Front Nutr. 2022;9:1077452.doi: 10.3389/fnut.2022.1077452.36687697
184 Haghighatdoost F, Riahi R, Safari S, Heidari Z. Dose-response association between dietary patterns and gestational diabetes mellitus risk: A systematic review and meta-analysis of observational studies. Food Sci Nutr. 2023;11(1):57–92.doi: 10.1002/fsn3.3042.36655080
185 Charkviani M, Thongprayoon C, Tangpanithandee S, Effects of Mediterranean Diet, DASH Diet, and Plant-Based Diet on Outcomes among End Stage Kidney Disease Patients: A Systematic Review and Meta-Analysis. Clin Pract. 2022;13(1):41–51.doi: 10.3390/clinpract13010004.36648844
186 Jiang K, Zhang Z, Fullington LA, Dietary Patterns and Obesity in Chinese Adults: A Systematic Review and Meta-Analysis. Nutrients. 2022;14(22).doi: 10.3390/nu14224911.
187 Rahmati M, Fatemi R, Yon DK, The effect of adherence to high-quality dietary pattern on COVID-19 outcomes: A systematic review and meta-analysis. J Med Virol. 2023;95(1):e28298.doi: 10.1002/jmv.28298.36367218
188 Bizzozero-Peroni B, Brazo-Sayavera J, Martínez-Vizcaíno V, High Adherence to the Mediterranean Diet is Associated with Higher Physical Fitness in Adults: a Systematic Review and Meta-Analysis. Adv Nutr. 2022;13(6):2195–2206.doi: 10.1093/advances/nmac104.36166848
189 Lee E, Kady V, Han E, Montan K, Normuminova M, Rovito MJ. Healthy Eating and Mortality among Breast Cancer Survivors: A Systematic Review and Meta-Analysis of Cohort Studies. Int J Environ Res Public Health. 2022;19(13).doi: 10.3390/ijerph19137579.
190 Siqueira C, Esteves LG, Duarte CK. Plant-based diet index score is not associated with body composition: A systematic review and meta-analysis. Nutr Res. 2022;104:128–139.doi: 10.1016/j.nutres.2022.05.005.35763983
191 Zhao Y, Zhan J, Wang Y, Wang D. The Relationship Between Plant-Based Diet and Risk of Digestive System Cancers: A Meta-Analysis Based on 3,059,009 Subjects. Front Public Health. 2022;10:892153.doi: 10.3389/fpubh.2022.892153.35719615
192 Moslehi N, Sakak FR, Teymoori F, Tehrani FR, Mirmiran P, Azizi F. The role of nutrition in the development and management of gestational diabetes among Iranian women: a systematic review and meta-analysis. J Diabetes Metab Disord. 2022;21(1):951–970.doi: 10.1007/s40200-021-00944-7.35673450
193 Shirota M, Watanabe N, Suzuki M, Kobori M. Japanese-Style Diet and Cardiovascular Disease Mortality: A Systematic Review and Meta-Analysis of Prospective Cohort Studies. Nutrients. 2022;14(10).doi: 10.3390/nu14102008.
194 Du H, Cao T, Lu X, Zhang T, Luo B, Li Z. Mediterranean Diet Patterns in Relation to Lung Cancer Risk: A Meta-Analysis. Front Nutr. 2022;9:844382.doi: 10.3389/fnut.2022.844382.35495942
195 Sarsangi P, Salehi-Abargouei A, Ebrahimpour-Koujan S, Esmaillzadeh A. Association between Adherence to the Mediterranean Diet and Risk of Type 2 Diabetes: An Updated Systematic Review and Dose-Response Meta-Analysis of Prospective Cohort Studies. Adv Nutr. 2022;13(5):1787–1798.doi: 10.1093/advances/nmac046.35472102
196 Bahrami A, Khalesi S, Makiabadi E, Alibeyk S, Hajigholam-Saryazdi M, Hejazi E. Adherence to the Mediterranean diet and the risk of lung cancer: a systematic review and dose-response meta-analysis of observational studies. Nutr Rev. 2022;80(5):1118–1128.doi: 10.1093/nutrit/nuab117.35224641
197 Noori M, Jayedi A, Khan TA, Moradi S, Shab-Bidar S. Mediterranean dietary pattern and bone mineral density: a systematic review and dose-response meta-analysis of observational studies. Eur J Clin Nutr. 2022;76(12):1657–1664.doi: 10.1038/s41430-022-01093-7.35173291
198 Castro-Espin C, Agudo A. The Role of Diet in Prognosis among Cancer Survivors: A Systematic Review and Meta-Analysis of Dietary Patterns and Diet Interventions. Nutrients. 2022;14(2).doi: 10.3390/nu14020348.
199 Dianatinasab M, Forozani E, Akbari A, Dietary patterns and risk of bladder cancer: a systematic review and meta-analysis. BMC Public Health. 2022;22(1):73.doi: 10.1186/s12889-022-12516-2.35016647
200 Zeraattalab-Motlagh S, Jayedi A, Shab-Bidar S. Mediterranean dietary pattern and the risk of type 2 diabetes: a systematic review and dose-response meta-analysis of prospective cohort studies. Eur J Nutr. 2022;61(4):1735–1748.doi: 10.1007/s00394-021-02761-3.35001218
201 Xu C, Wang S, Ti W, Role of dietary patterns and factors in determining the risk of knee osteoarthritis: A meta-analysis. Mod Rheumatol. 2022;32(4):815–821.doi: 10.1093/mr/roab059.34918108
202 Gan ZH, Cheong HC, Tu YK, Kuo PH. Association between Plant-Based Dietary Patterns and Risk of Cardiovascular Disease: A Systematic Review and Meta-Analysis of Prospective Cohort Studies. Nutrients. 2021;13(11).doi: 10.3390/nu13113952.
203 Quek J, Lim G, Lim WH, The Association of Plant-Based Diet With Cardiovascular Disease and Mortality: A Meta-Analysis and Systematic Review of Prospect Cohort Studies. Front Cardiovasc Med. 2021;8:756810.doi: 10.3389/fcvm.2021.756810.34805312
204 Bakaloudi DR, Chrysoula L, Leonida I, Kotzakioulafi E, Theodoridis X, Chourdakis M. Impact of the level of adherence to the Mediterranean Diet on blood pressure: A systematic review and meta-analysis of observational studies. Clin Nutr. 2021;40(12):5771–5780.doi: 10.1016/j.clnu.2021.10.002.34773865
205 Goldfarb G, Sela Y. The Ideal Diet for Humans to Sustainably Feed the Growing Population - Review, Meta-Analyses, and Policies for Change. F1000Res. 2021;10:1135.doi: 10.12688/f1000research.73470.1.37928317
206 García-Casares N, Gallego Fuentes P, Barbancho M, López-Gigosos R, García-Rodríguez A, Gutiérrez-Bedmar M. Alzheimer's Disease, Mild Cognitive Impairment and Mediterranean Diet. A Systematic Review and Dose-Response Meta-Analysis. J Clin Med. 2021;10(20).doi: 10.3390/jcm10204642.
207 Cui Y, Liao M, Xu A, Association of maternal pre-pregnancy dietary intake with adverse maternal and neonatal outcomes: A systematic review and meta-analysis of prospective studies. Crit Rev Food Sci Nutr. 2023;63(19):3430–3451.doi: 10.1080/10408398.2021.1989658.34666569
208 Tang C, Wang X, Qin LQ, Dong JY. Mediterranean Diet and Mortality in People with Cardiovascular Disease: A Meta-Analysis of Prospective Cohort Studies. Nutrients. 2021;13(8).doi: 10.3390/nu13082623.
209 Lotfi K, Saneei P, Hajhashemy Z, Esmaillzadeh A. Adherence to the Mediterranean Diet, Five-Year Weight Change, and Risk of Overweight and Obesity: A Systematic Review and Dose-Response Meta-Analysis of Prospective Cohort Studies. Adv Nutr. 2022;13(1):152–166.doi: 10.1093/advances/nmab092.34352891
210 Orlando L, Savel KA, Madigan S, Colasanto M, Korczak DJ. Dietary patterns and internalizing symptoms in children and adolescents: A meta-analysis. Aust N Z J Psychiatry. 2022;56(6):617–641.doi: 10.1177/00048674211031486.34313455
211 Matison AP, Mather KA, Flood VM, Reppermund S. Associations between nutrition and the incidence of depression in middle-aged and older adults: A systematic review and meta-analysis of prospective observational population-based studies. Ageing Res Rev. 2021;70:101403.doi: 10.1016/j.arr.2021.101403.34246793
212 Coelho-Júnior HJ, Trichopoulou A, Panza F. Cross-sectional and longitudinal associations between adherence to Mediterranean diet with physical performance and cognitive function in older adults: A systematic review and meta-analysis. Ageing Res Rev. 2021;70:101395.doi: 10.1016/j.arr.2021.101395.34153553
213 Nguyen HH, Wu F, Makin JK, Associations of dietary patterns with bone density and fractures in adults: A systematic review and meta-analysis. Aust J Gen Pract. 2021;50(6):394–401.doi: 10.31128/ajgp-02-20-5245.34059846
214 Jafari S, Hezaveh E, Jalilpiran Y, Plant-based diets and risk of disease mortality: a systematic review and meta-analysis of cohort studies. Crit Rev Food Sci Nutr. 2022;62(28):7760–7772.doi: 10.1080/10408398.2021.1918628.33951994
215 Bakaloudi DR, Chrysoula L, Kotzakioulafi E, Theodoridis X, Chourdakis M. Impact of the Level of Adherence to Mediterranean Diet on the Parameters of Metabolic Syndrome: A Systematic Review and Meta-Analysis of Observational Studies. Nutrients. 2021;13(5).doi: 10.3390/nu13051514.
216 Quan W, Zeng M, Jiao Y, Western Dietary Patterns, Foods, and Risk of Gestational Diabetes Mellitus: A Systematic Review and Meta-Analysis of Prospective Cohort Studies. Adv Nutr. 2021;12(4):1353–1364.doi: 10.1093/advances/nmaa184.
217 Abdollahi S, Soltani S, de Souza RJ, Forbes SC, Toupchian O, Salehi-Abargouei A. Associations between Maternal Dietary Patterns and Perinatal Outcomes: A Systematic Review and Meta-Analysis of Cohort Studies. Adv Nutr. 2021;12(4):1332–1352.doi: 10.1093/advances/nmaa156.33508080
218 Moradi S, Moloudi J, Moradinazar M, Sarokhani D, Nachvak SM, Samadi M. Adherence to Healthy Diet Can Delay Alzheimer's Diseases Development: A Systematic Review and Meta-Analysis. Prev Nutr Food Sci. 2020;25(4):325–337.doi: 10.3746/pnf.2020.25.4.325.33505926
219 He LQ, Wu XH, Huang YQ, Zhang XY, Shu L. Dietary patterns and chronic kidney disease risk: a systematic review and updated meta-analysis of observational studies. Nutr J. 2021;20(1):4.doi: 10.1186/s12937-020-00661-6.33419440
220 Jalilpiran Y, Jayedi A, Djafarian K, Shab-Bidar S. The Nordic diet and the risk of non-communicable chronic disease and mortality: a systematic review and dose-response meta-analysis of prospective cohort studies. Crit Rev Food Sci Nutr. 2022;62(11):3124–3136.doi: 10.1080/10408398.2020.1863906.33354987
221 Hassani Zadeh S, Mansoori A, Hosseinzadeh M. Relationship between dietary patterns and nonalcoholic fatty liver disease: A systematic review and meta-analysis. J Gastroenterol Hepatol. 2021;36(6):1470–1478.doi: 10.1111/jgh.15363.33269500
222 Hoang T, Kim H, Kim J. Dietary Intake in Association with All-Cause Mortality and Colorectal Cancer Mortality among Colorectal Cancer Survivors: A Systematic Review and Meta-Analysis of Prospective Studies. Cancers (Basel). 2020;12(11).doi: 10.3390/cancers12113391.
223 Morze J, Danielewicz A, Hoffmann G, Schwingshackl L. Diet Quality as Assessed by the Healthy Eating Index, Alternate Healthy Eating Index, Dietary Approaches to Stop Hypertension Score, and Health Outcomes: A Second Update of a Systematic Review and Meta-Analysis of Cohort Studies. J Acad Nutr Diet. 2020;120(12):1998–2031.e1915.doi: 10.1016/j.jand.2020.08.076.33067162
224 Liu YH, Gao X, Na M, Kris-Etherton PM, Mitchell DC, Jensen GL. Dietary Pattern, Diet Quality, and Dementia: A Systematic Review and Meta-Analysis of Prospective Cohort Studies. J Alzheimers Dis. 2020;78(1):151–168.doi: 10.3233/jad-200499.32955461
225 Hansrivijit P, Oli S, Khanal R, Ghahramani N, Thongprayoon C, Cheungpasitporn W. Mediterranean diet and the risk of chronic kidney disease: A systematic review and meta-analysis. Nephrology (Carlton). 2020;25(12):913–918.doi: 10.1111/nep.13778.32852121
226 Kim J, Hoang T, Bu SY, Associations of Dietary Intake with Cardiovascular Disease, Blood Pressure, and Lipid Profile in the Korean Population: a Systematic Review and Meta-Analysis. J Lipid Atheroscler. 2020;9(1):205–229.doi: 10.12997/jla.2020.9.1.205.32821732
227 Morze J, Danielewicz A, rzybyłowicz K, Zeng H, Hoffmann G, Schwingshackl L. An updated systematic review and meta-analysis on adherence to mediterranean diet and risk of cancer. Eur J Nutr. 2021;60(3):1561–1586.doi: 10.1007/s00394-020-02346-6.32770356
228 Moazzen S, van der Sloot KWJ, Bock GH, Alizadeh BZ. Systematic review and meta-analysis of diet quality and colorectal cancer risk: is the evidence of sufficient quality to develop recommendations? Crit Rev Food Sci Nutr. 2021;61(16):2773–2782.doi: 10.1080/10408398.2020.1786353.32613845
229 Moazzen S, van der Sloot KWJ, Vonk RJ, de Bock GH, Alizadeh BZ. Diet Quality and Upper Gastrointestinal Cancers Risk: A Meta-Analysis and Critical Assessment of Evidence Quality. Nutrients. 2020;12(6).doi: 10.3390/nu12061863.
230 Li T, Qiu Y, Yang HS, Systematic review and meta-analysis: Association of a pre-illness Western dietary pattern with the risk of developing inflammatory bowel disease. J Dig Dis. 2020;21(7):362–371.doi: 10.1111/1751-2980.12910.32463159
231 Parvizian MK, Dhaliwal M, Li J, Satia I, Kurmi OP. Relationship between dietary patterns and COPD: a systematic review and meta-analysis. ERJ Open Res. 2020;6(2).doi: 10.1183/23120541.00168-2019.
232 Dianatinasab M, Rezaian M, HaghighatNezad E, Dietary Patterns and Risk of Invasive Ductal and Lobular Breast Carcinomas: A Systematic Review and Meta-analysis. Clin Breast Cancer. 2020;20(4):e516–e528.doi: 10.1016/j.clbc.2020.03.007.32362500
233 Zhong Y, Zhu Y, Li Q, Association between Mediterranean diet adherence and colorectal cancer: a dose-response meta-analysis. Am J Clin Nutr. 2020;111(6):1214–1225.doi: 10.1093/ajcn/nqaa083.32359135
234 Soltani S, Arablou T, Jayedi A, Salehi-Abargouei A. Adherence to the dietary approaches to stop hypertension (DASH) diet in relation to all-cause and cause-specific mortality: a systematic review and dose-response meta-analysis of prospective cohort studies. Nutr J. 2020;19(1):37.doi: 10.1186/s12937-020-00554-8.32321528
235 Shareghfarid E, Sangsefidi ZS, Salehi-Abargouei A, Hosseinzadeh M. Empirically derived dietary patterns and food groups intake in relation with Attention Deficit/Hyperactivity Disorder (ADHD): A systematic review and meta-analysis. Clin Nutr ESPEN. 2020;36:28–35.doi: 10.1016/j.clnesp.2019.10.013.32220366
236 Hassani Zadeh S, Boffetta P, Hosseinzadeh M. Dietary patterns and risk of gestational diabetes mellitus: A systematic review and meta-analysis of cohort studies. Clin Nutr ESPEN. 2020;36:1–9.doi: 10.1016/j.clnesp.2020.02.009.32220350
237 Soltani S, Jayedi A. Adherence to healthy dietary pattern and risk of kidney disease: a systematic review and meta-analysis of observational studies. Int J Vitam Nutr Res. 2022;92(3–4):267–279.doi: 10.1024/0300-9831/a000647.32138628
238 Tangestani H, Salari-Moghaddam A, Ghalandari H, Emamat H. Adherence to the Dietary Approaches to Stop Hypertension (DASH) dietary pattern reduces the risk of colorectal cancer: A systematic review and meta-analysis. Clin Nutr. 2020;39(10):2975–2981.doi: 10.1016/j.clnu.2020.02.002.32063407
239 Du S, Li Y, Su Z, Index-based dietary patterns in relation to gastric cancer risk: a systematic review and meta-analysis. Br J Nutr. 2020;123(9):964–974.doi: 10.1017/s0007114519002976.31767045
240 Taghavi M, Sadeghi A, Maleki V, Adherence to the dietary approaches to stop hypertension-style diet is inversely associated with chronic kidney disease: a systematic review and meta-analysis of prospective cohort studies. Nutr Res. 2019;72:46–56.doi: 10.1016/j.nutres.2019.10.007.31740009
241 Khorshidi M, Djafarian K, Aghayei E, Shab-Bidar S. A posteriori dietary patterns and risk of inflammatory bowel disease: a meta-analysis of observational studies. Int J Vitam Nutr Res. 2020;90(3–4):376–384.doi: 10.1024/0300-9831/a000508.31711373
242 Mozaffari H, Ajabshir S, Alizadeh S. Dietary Approaches to Stop Hypertension and risk of chronic kidney disease: A systematic review and meta-analysis of observational studies. Clin Nutr. 2020;39(7):2035–2044.doi: 10.1016/j.clnu.2019.10.004.31669002
243 Zhang L, Huang S, Cao L, Ge M, Li Y, Shao J. Vegetable-Fruit-Soybean Dietary Pattern and Breast Cancer: A Meta-Analysis of Observational Studies. J Nutr Sci Vitaminol (Tokyo). 2019;65(5):375–382.doi: 10.3177/jnsv.65.375.31666473
244 Vernooij RWM, Zeraatkar D, Han MA, Patterns of Red and Processed Meat Consumption and Risk for Cardiometabolic and Cancer Outcomes: A Systematic Review and Meta-analysis of Cohort Studies. Ann Intern Med. 2019;171(10):732–741.doi: 10.7326/m19-1583.31569217
245 Bach KE, Kelly JT, Palmer SC, Khalesi S, Strippoli GFM, Campbell KL. Healthy Dietary Patterns and Incidence of CKD: A Meta-Analysis of Cohort Studies. Clin J Am Soc Nephrol. 2019;14(10):1441–1449.doi: 10.2215/cjn.00530119.31551237
246 Fabiani R, Naldini G, Chiavarini M. Dietary Patterns and Metabolic Syndrome in Adult Subjects: A Systematic Review and Meta-Analysis. Nutrients. 2019;11(9).doi: 10.3390/nu11092056.
247 Mohseni R, Mohseni F, Alizadeh S, Abbasi S. The Association of Dietary Approaches to Stop Hypertension (DASH) Diet with the Risk of Colorectal Cancer: A Meta-Analysis of Observational Studies. Nutr Cancer. 2020;72(5):778–790.doi: 10.1080/01635581.2019.1651880.31418286
248 Qian F, Liu G, Hu FB, Bhupathiraju SN, Sun Q. Association Between Plant-Based Dietary Patterns and Risk of Type 2 Diabetes: A Systematic Review and Meta-analysis. JAMA Intern Med. 2019;179(10):1335–1344.doi: 10.1001/jamainternmed.2019.2195.31329220
249 Cheng S, Zheng Q, Ding G, Li G. Mediterranean dietary pattern and the risk of prostate cancer: A meta-analysis. Medicine (Baltimore). 2019;98(27):e16341.doi: 10.1097/md.0000000000016341.31277188
250 Hou R, Wei J, Hu Y, Healthy dietary patterns and risk and survival of breast cancer: a meta-analysis of cohort studies. Cancer Causes Control. 2019;30(8):835–846.doi: 10.1007/s10552-019-01193-z.31165965
251 Ali Mohsenpour M, Fallah-Moshkani R, Ghiasvand R, Adherence to Dietary Approaches to Stop Hypertension (DASH)-Style Diet and the Risk of Cancer: A Systematic Review and Meta-Analysis of Cohort Studies. J Am Coll Nutr. 2019;38(6):513–525.doi: 10.1080/07315724.2018.1554460.31140934
252 Soltani S, Jayedi A, Shab-Bidar S, Becerra-Tomás N, Salas-Salvadó J. Adherence to the Mediterranean Diet in Relation to All-Cause Mortality: A Systematic Review and Dose-Response Meta-Analysis of Prospective Cohort Studies. Adv Nutr. 2019;10(6):1029–1039.doi: 10.1093/advances/nmz041.31111871
253 Chia AR, Chen LW, Lai JS, Maternal Dietary Patterns and Birth Outcomes: A Systematic Review and Meta-Analysis. Adv Nutr. 2019;10(4):685–695.doi: 10.1093/advances/nmy123.31041446
254 Rashidi Pour Fard N, Amirabdollahian F, Haghighatdoost F. Dietary patterns and frailty: a systematic review and meta-analysis. Nutr Rev. 2019;77(7):498–513.doi: 10.1093/nutrit/nuz007.31038679
255 Zhang Y, Lin J, Fu W, Liu S, Gong C, Dai J. Mediterranean diet during pregnancy and childhood for asthma in children: A systematic review and meta-analysis of observational studies. Pediatr Pulmonol. 2019;54(7):949–961.doi: 10.1002/ppul.24338.30997754
256 Del-Ponte B, Quinte GC, Cruz S, Grellert M, Santos IS. Dietary patterns and attention deficit/hyperactivity disorder (ADHD): A systematic review and meta-analysis. J Affect Disord. 2019;252:160–173.doi: 10.1016/j.jad.2019.04.061.30986731
257 Wu XY, Zhuang LH, Li W, The influence of diet quality and dietary behavior on health-related quality of life in the general population of children and adolescents: a systematic review and meta-analysis. Qual Life Res. 2019;28(8):1989–2015.doi: 10.1007/s11136-019-02162-4.30875010
258 Chen GC, Neelakantan N, Martín-Calvo N, Adherence to the Mediterranean diet and risk of stroke and stroke subtypes. Eur J Epidemiol. 2019;34(4):337–349.doi: 10.1007/s10654-019-00504-7.30826941
259 Yang ZQ, Yang Z, Duan ML. Dietary approach to stop hypertension diet and risk of coronary artery disease: a meta-analysis of prospective cohort studies. Int J Food Sci Nutr. 2019;70(6):668–674.doi: 10.1080/09637486.2019.1570490.30810409
260 Alizadeh S, Djafarian K, Alizadeh M, Shab-Bidar S. The relation of healthy and Western dietary patterns to the risk of endometrial and ovarian cancers: a systematic review and meta-analysis. Int J Vitam Nutr Res. 2020;90(3–4):365–375.doi: 10.1024/0300-9831/a000514.30806608
261 Shafiei F, Salari-Moghaddam A, Larijani B, Esmaillzadeh A. Adherence to the Mediterranean diet and risk of depression: a systematic review and updated meta-analysis of observational studies. Nutr Rev. 2019;77(4):230–239.doi: 10.1093/nutrit/nuy070.30726966
262 Xiao Y, Xia J, Li L, Associations between dietary patterns and the risk of breast cancer: a systematic review and meta-analysis of observational studies. Breast Cancer Res. 2019;21(1):16.doi: 10.1186/s13058-019-1096-1.30696460
263 Fabiani R, Naldini G, Chiavarini M. Dietary Patterns in Relation to Low Bone Mineral Density and Fracture Risk: A Systematic Review and Meta-Analysis. Adv Nutr. 2019;10(2):219–236.doi: 10.1093/advances/nmy073.30657847
264 Denova-Gutiérrez E, Méndez-Sánchez L, Muñoz-Aguirre P, Tucker KL, Clark P. Dietary Patterns, Bone Mineral Density, and Risk of Fractures: A Systematic Review and Meta-Analysis. Nutrients. 2018;10(12).doi: 10.3390/nu10121922.
265 Eleftheriou D, Benetou V, Trichopoulou A, La Vecchia C, Bamia C. Mediterranean diet and its components in relation to all-cause mortality: meta-analysis. Br J Nutr. 2018;120(10):1081–1097.doi: 10.1017/s0007114518002593.30401007
266 Panahande B, Sadeghi A, Parohan M. Alternative healthy eating index and risk of hip fracture: a systematic review and dose-response meta-analysis. J Hum Nutr Diet. 2019;32(1):98–107.doi: 10.1111/jhn.12608.30357949
267 Milajerdi A, Namazi N, Larijani B, Azadbakht L. The Association of Dietary Quality Indices and Cancer Mortality: A Systematic Review and Meta-analysis of Cohort Studies. Nutr Cancer. 2018;70(7):1091–1105.doi: 10.1080/01635581.2018.1502331.30321058
268 Kibret KT, Chojenta C, Gresham E, Tegegne TK, Loxton D. Maternal dietary patterns and risk of adverse pregnancy (hypertensive disorders of pregnancy and gestational diabetes mellitus) and birth (preterm birth and low birth weight) outcomes: a systematic review and meta-analysis. Public Health Nutr. 2019;22(3):506–520.doi: 10.1017/s1368980018002616.30319090
269 Lassale C, Batty GD, Baghdadli A, Healthy dietary indices and risk of depressive outcomes: a systematic review and meta-analysis of observational studies. Mol Psychiatry. 2019;24(7):965–986.doi: 10.1038/s41380-018-0237-8.30254236
270 Feng Q, Fan S, Wu Y, Adherence to the dietary approaches to stop hypertension diet and risk of stroke: A meta-analysis of prospective studies. Medicine (Baltimore). 2018;97(38):e12450.doi: 10.1097/md.0000000000012450.30235731
271 Bonaccio M, Di Castelnuovo A, Costanzo S, Mediterranean diet and mortality in the elderly: a prospective cohort study and a meta-analysis. Br J Nutr. 2018;120(8):841–854.doi: 10.1017/s0007114518002179.30157978
272 Garcia-Larsen V, Morton V, Norat T, Dietary patterns derived from principal component analysis (PCA) and risk of colorectal cancer: a systematic review and meta-analysis. Eur J Clin Nutr. 2019;73(3):366–386.doi: 10.1038/s41430-018-0234-7.30050075
273 Silva R, Pizato N, da Mata F, Figueiredo A, Ito M, Pereira MG. Mediterranean Diet and Musculoskeletal-Functional Outcomes in Community-Dwelling Older People: A Systematic Review and Meta-Analysis. J Nutr Health Aging. 2018;22(6):655–663.doi: 10.1007/s12603-017-0993-1.29806854
274 Wu PY, Lin MY, Tsai PS. Alternate healthy eating index and risk of depression: A meta-analysis and systemematic review. Nutr Neurosci. 2020;23(2):101–109.doi: 10.1080/1028415x.2018.1477424.29804517
275 Wang Y, Hao Q, Su L, Liu Y, Liu S, Dong B. Adherence to the Mediterranean Diet and the Risk of Frailty in Old People: A Systematic Review and Meta-Analysis. J Nutr Health Aging. 2018;22(5):613–618.doi: 10.1007/s12603-018-1020-x.29717762
276 Shab-Bidar S, Golzarand M, Hajimohammadi M, Mansouri S. A posteriori dietary patterns and metabolic syndrome in adults: a systematic review and meta-analysis of observational studies. Public Health Nutr. 2018;21(9):1681–1692.doi: 10.1017/s1368980018000216.29559025
277 Kojima G, Avgerinou C, Iliffe S, Walters K. Adherence to Mediterranean Diet Reduces Incident Frailty Risk: Systematic Review and Meta-Analysis. J Am Geriatr Soc. 2018;66(4):783–788.doi: 10.1111/jgs.15251.29322507
278 Wang HF, Yao AL, Sun YY, Zhang AH. Empirically derived dietary patterns and ovarian cancer risk: a meta-analysis. Eur J Cancer Prev. 2018;27(5):493–501.doi: 10.1097/cej.0000000000000367.29215374
279 Rosato V, Temple NJ, La Vecchia C, Castellan G, Tavani A, Guercio V. Mediterranean diet and cardiovascular disease: a systematic review and meta-analysis of observational studies. Eur J Nutr. 2019;58(1):173–191.doi: 10.1007/s00394-017-1582-0.29177567
280 Schwingshackl L, Bogensberger B, Hoffmann G. Diet Quality as Assessed by the Healthy Eating Index, Alternate Healthy Eating Index, Dietary Approaches to Stop Hypertension Score, and Health Outcomes: An Updated Systematic Review and Meta-Analysis of Cohort Studies. J Acad Nutr Diet. 2018;118(1):74–100.e111.doi: 10.1016/j.jand.2017.08.024.29111090
281 Molendijk M, Molero P, Ortuño Sánchez-Pedreño F, Van der Does W, Angel Martínez-González M. Diet quality and depression risk: A systematic review and dose-response meta-analysis of prospective studies. J Affect Disord. 2018;226:346–354.doi: 10.1016/j.jad.2017.09.022.29031185
282 Grosso G, Bella F, Godos J, Possible role of diet in cancer: systematic review and multiple meta-analyses of dietary patterns, lifestyle factors, and cancer risk. Nutr Rev. 2017;75(6):405–419.doi: 10.1093/nutrit/nux012.28969358
283 Borge TC, Aase H, Brantsæter AL, Biele G. The importance of maternal diet quality during pregnancy on cognitive and behavioural outcomes in children: a systematic review and meta-analysis. BMJ Open. 2017;7(9):e016777.doi: 10.1136/bmjopen-2017-016777.
284 Mu M, Xu LF, Hu D, Wu J, Bai MJ. Dietary Patterns and Overweight/Obesity: A Review Article. Iran J Public Health. 2017;46(7):869–876.doi.28845396
285 Malmir H, Saneei P, Larijani B, Esmaillzadeh A. Adherence to Mediterranean diet in relation to bone mineral density and risk of fracture: a systematic review and meta-analysis of observational studies. Eur J Nutr. 2018;57(6):2147–2160.doi: 10.1007/s00394-017-1490-3.28638994
286 Li Y, Lv MR, Wei YJ, Dietary patterns and depression risk: A meta-analysis. Psychiatry Res. 2017;253:373–382.doi: 10.1016/j.psychres.2017.04.020.28431261
287 Jannasch F, Kröger J, Schulze MB. Dietary Patterns and Type 2 Diabetes: A Systematic Literature Review and Meta-Analysis of Prospective Studies. J Nutr. 2017;147(6):1174–1182.doi: 10.3945/jn.116.242552.28424256
288 Kunutsor SK, Laukkanen JA, Whitehouse MR, Blom AW. Adherence to a Mediterranean-style diet and incident fractures: pooled analysis of observational evidence. Eur J Nutr. 2018;57(4):1687–1700.doi: 10.1007/s00394-017-1432-0.28331983
289 van den Brandt PA, Schulpen M. Mediterranean diet adherence and risk of postmenopausal breast cancer: results of a cohort study and meta-analysis. Int J Cancer. 2017;140(10):2220–2231.doi: 10.1002/ijc.30654.28260236
290 Wu L, Sun D. Adherence to Mediterranean diet and risk of developing cognitive disorders: An updated systematic review and meta-analysis of prospective cohort studies. Sci Rep. 2017;7:41317.doi: 10.1038/srep41317.28112268
291 Lu PY, Shu L, Shen SS, Chen XJ, Zhang XY. Dietary Patterns and Pancreatic Cancer Risk: A Meta-Analysis. Nutrients. 2017;9(1).doi: 10.3390/nu9010038.
292 Pourmasoumi M, Karimbeiki R, Vosoughi N, Healthy Eating Index/Alternative Healthy Eating Index and Breast Cancer Mortality and Survival: A Systematic Review and Meta-analysis. Asia Pac J Oncol Nurs. 2016;3(3):297–305.doi: 10.4103/2347-5625.189819.27981174
293 Kelly JT, Palmer SC, Wai SN, Healthy Dietary Patterns and Risk of Mortality and ESRD in CKD: A Meta-Analysis of Cohort Studies. Clin J Am Soc Nephrol. 2017;12(2):272–279.doi: 10.2215/cjn.06190616.27932391
294 Bella F, Godos J, Ippolito A, Di Prima A, Sciacca S. Differences in the association between empirically derived dietary patterns and cancer: a meta-analysis. Int J Food Sci Nutr. 2017;68(4):402–410.doi: 10.1080/09637486.2016.1261087.27894200
295 Schwedhelm C, Boeing H, Hoffmann G, Aleksandrova K, Schwingshackl L. Effect of diet on mortality and cancer recurrence among cancer survivors: a systematic review and meta-analysis of cohort studies. Nutr Rev. 2016;74(12):737–748.doi: 10.1093/nutrit/nuw045.27864535
296 Cao L, Tan L, Wang HF, Dietary Patterns and Risk of Dementia: a Systematic Review and Meta-Analysis of Cohort Studies. Mol Neurobiol. 2016;53(9):6144–6154.doi: 10.1007/s12035-015-9516-4.26553347
297 Wang CJ, Shen YX, Liu Y. Empirically Derived Dietary Patterns and Hypertension Likelihood: A Meta-Analysis. Kidney Blood Press Res. 2016;41(5):570–581.doi: 10.1159/000443456.27554668
298 Fabiani R, Minelli L, Bertarelli G, Bacci S. A Western Dietary Pattern Increases Prostate Cancer Risk: A Systematic Review and Meta-Analysis. Nutrients. 2016;8(10).doi: 10.3390/nu8100626.
299 Onvani S, Haghighatdoost F, Surkan PJ, Larijani B, Azadbakht L. Adherence to the Healthy Eating Index and Alternative Healthy Eating Index dietary patterns and mortality from all causes, cardiovascular disease and cancer: a meta-analysis of observational studies. J Hum Nutr Diet. 2017;30(2):216–226.doi: 10.1111/jhn.12415.27620213
300 Rodríguez-Monforte M, Sánchez E, Barrio F, Costa B, Flores-Mateo G. Metabolic syndrome and dietary patterns: a systematic review and meta-analysis of observational studies. Eur J Nutr. 2017;56(3):925–947.doi: 10.1007/s00394-016-1305-y.27605002
301 Godos J, Zappalà G, Bernardini S, Giambini I, Bes-Rastrollo M, Martinez-Gonzalez M. Adherence to the Mediterranean diet is inversely associated with metabolic syndrome occurrence: a meta-analysis of observational studies. Int J Food Sci Nutr. 2017;68(2):138–148.doi: 10.1080/09637486.2016.1221900.27557591
302 Bloomfield HE, Koeller E, Greer N, MacDonald R, Kane R, Wilt TJ. Effects on Health Outcomes of a Mediterranean Diet With No Restriction on Fat Intake: A Systematic Review and Meta-analysis. Ann Intern Med. 2016;165(7):491–500.doi: 10.7326/m16-0361.27428849
303 Godos J, Bella F, Torrisi A, Sciacca S, Galvano F, Grosso G. Dietary patterns and risk of colorectal adenoma: a systematic review and meta-analysis of observational studies. J Hum Nutr Diet. 2016;29(6):757–767.doi: 10.1111/jhn.12395.27412573
304 Si CJ, Shu L, Zheng PF, Dietary patterns and endometrial cancer: a meta-analysis. Eur J Cancer Prev. 2017;26(4):336–345.doi: 10.1097/cej.0000000000000266.27139775
305 Sun Y, Li Z, Li J, Li Z, Han J. A Healthy Dietary Pattern Reduces Lung Cancer Risk: A Systematic Review and Meta-Analysis. Nutrients. 2016;8(3):134.doi: 10.3390/nu8030134.26959051
306 Feng YL, Shu L, Zheng PF, Dietary patterns and colorectal cancer risk: a meta-analysis. Eur J Cancer Prev. 2017;26(3):201–211.doi: 10.1097/cej.0000000000000245.26945285
307 Zheng PF, Shu L, Si CJ, Zhang XY, Yu XL, Gao W. Dietary Patterns and Chronic Obstructive Pulmonary Disease: A Meta-analysis. Copd. 2016;13(4):515–522.doi: 10.3109/15412555.2015.1098606.26678388
308 Schwingshackl L, Hoffmann G. Adherence to Mediterranean diet and risk of cancer: an updated systematic review and meta-analysis of observational studies. Cancer Med. 2015;4(12):1933–1947.doi: 10.1002/cam4.539.26471010
309 Rodríguez-Monforte M, Flores-Mateo G, Sánchez E. Dietary patterns and CVD: a systematic review and meta-analysis of observational studies. Br J Nutr. 2015;114(9):1341–1359.doi: 10.1017/s0007114515003177.26344504
310 Zhang XY, Shu L, Si CJ, Dietary Patterns, Alcohol Consumption and Risk of Coronary Heart Disease in Adults: A Meta-Analysis. Nutrients. 2015;7(8):6582–6605.doi: 10.3390/nu7085300.26262641
311 Zhang X, Shu L, Si C, Dietary Patterns and Risk of Stroke in Adults: A Systematic Review and Meta-analysis of Prospective Cohort Studies. J Stroke Cerebrovasc Dis. 2015;24(10):2173–2182.doi: 10.1016/j.jstrokecerebrovasdis.2015.05.035.26232888
312 Maghsoudi Z, Ghiasvand R, Salehi-Abargouei A. Empirically derived dietary patterns and incident type 2 diabetes mellitus: a systematic review and meta-analysis on prospective observational studies. Public Health Nutr. 2016;19(2):230–241.doi: 10.1017/s1368980015001251.25917191
313 Hou L, Li F, Wang Y, Association between dietary patterns and coronary heart disease: a meta-analysis of prospective cohort studies. Int J Clin Exp Med. 2015;8(1):781–790.doi. Published 20150115.25785058
314 Schwingshackl L, Hoffmann G. Diet quality as assessed by the Healthy Eating Index, the Alternate Healthy Eating Index, the Dietary Approaches to Stop Hypertension score, and health outcomes: a systematic review and meta-analysis of cohort studies. J Acad Nutr Diet. 2015;115(5):780–800.e785.doi: 10.1016/j.jand.2014.12.009.25680825
315 Li F, Hou LN, Chen W, Associations of dietary patterns with the risk of all-cause, CVD and stroke mortality: a meta-analysis of prospective cohort studies. Br J Nutr. 2015;113(1):16–24.doi: 10.1017/s000711451400289x.25430485