# Results

## Literature search and screening results

The literature search (Appendix 2: Literature search strategy) yielded 2,497 search results after the removal of duplicates (see Figure 2). Dual-screening resulted in the exclusion of 2,045 articles based on their titles and abstracts, and 137 full-text articles. Reasons for full-text exclusion are in Appendix 3: Excluded articles. The body of evidence included 315 articles.

Figure 2 Literature search and screen flowchart

## Description of the evidence

### Study design and publication year

The evidence scan identified 315 systematic reviews with meta-analysis that met inclusion criteria (see Table 2). A variety of study designs were included across the meta-analyses, including RCTs (128 articles),^1–128^ observational studies (including cohort studies, cross-sectional studies, and case-control studies; 208 articles),^1,2,6,23,24,26,28,39,49,50,54,75,78,80,82,99,104,109–111,122,129–315^ and, less commonly, NRCTs (8 articles).^8,31,44,51,52,74,77,118^ The number of articles published each year tended to increase over time (see Figure 3), with 12 articles published in 2015,^8,31,44,51,52,74,77,118^ and 51 articles published in 2024.^1–22,24,30,129–153,156,159^

Figure 3 Number of articles published by year

#### Randomized and non-randomized controlled trials

Among the 128 articles that meta-analyzed RCTs, most (99 articles) only included RCTs.^3–5,7,9–22,25,27,29,30,32–38,40–43,45–48,53,55–73,76,79,81,83–98,100–103,105–108,112–117,119–121,123–128^ The remaining studies also included observational studies (21 articles)^1,2,6,23,24,26,28,39,49,50,54,75,78,80,82,99,104,109–111,122^ or NRCTs (8 articles).^8,31,44,51,52,74,77,118^ Typically, the RCTs were analyzed separately from the observational studies (17 articles).^23,24,26,28,39,49,50,54,75,78,80,82,99,104,110,111,122^ However, a few articles reported including both RCTs and observational studies in some or all meta-analyses.^1,2,6,26,39,75,104,109^ In contrast, the NRCTs were typically combined in meta-analyses with the RCTs,^8,31,51,74,77,118^ although a few articles analyzed NRCTs separately from RCTs.^44,52,77^

#### Observational studies

Of the 208 articles that meta-analyzed observational studies, most (187 articles) only included observational studies.^129–315^ Eighty-two of the articles meta-analyzed observational studies of a single design (e.g., PCS).^2,24,28,49,50,99,109,111,122,131,134,141,148,153,156,158,161,164,169,170,174,176,177,185,189,193,195,198,200,202,203,207–209,211,214,216,217,220,222–225,233,234,236–238,240,243–245,248,250–252,258,259,265,267,270,271,273,275,277,280,281,283,285,287,289,290,292,293,295,296,302,311–315^ Fourteen articles analyzed observational studies with different designs in separate meta-analyses,^80,132,139,167,178,188,191,231,239,261,264,282,300,309^ 43 articles pooled observational studies with different designs together in meta-analyses,^1,6,23,39,54,82,133,136,137,142–144,149,150,155,159,162,168,172,173,179,190,192,197,201,204–206,213,215,218,221,235,253,255,257,268,276,284,288,294,299,307^ and 69 articles analyzed observational studies with different designs both together and separately, often using study design as a subgrouping variable.^26,75,78,104,110,129,130,135,138,140,145–147,151,152,154,157,160,163,165,166,171,175,180–184,186,187,194,196,199,210,212,219,226–230,232,241,242,246,247,249,254,256,260,262,263,266,269,272,274,278,279,286,291,297,298,301,303–306,308,310^

### Dietary patterns

#### Randomized and non-randomized controlled trials

The systematic reviews with meta-analysis that included trials (RCTs and NRCTs) examined a wide range of dietary interventions. Many articles focused on a single type of dietary pattern, such as the Dietary Approaches to Stop Hypertension (DASH) diet,^9,31,61,63,73,76,79,80,85,113,114,119,127^ Nordic diet,^49,91,94,101,102^ plant-based diet,^29,44,53,58,70,98,105^ paleolithic diet^68l,72,89,92,95,125^ and, most commonly, Mediterranean diet.^1,2,4,8,10,13–16,18,19,22,24,28,33,35,45,50,51,55,64–66,69,71,77,78,82,84,88,97,99,100,107,109,111,115,118,122–124,126,128^ Other articles included a broader range of dietary patterns in meta-analyses, combining dietary patterns defined by authors as “healthy”, emphasizing similar foods and/or beverages, or dietary interventions more broadly.^3,5–7,11,12,17,20,21,23,25–27,30,32,34,36–43,46–48,52,54,56,57,59,60,62,67,74,75,81,83,86,87,90,93,96,103,104,106,108,110,112,116,117,120,121,186^ Subgroup analyses were sometimes used in these articles to then examine more specific groupings of dietary patterns.^1,6,17,25,29,34,39,46,51,55–59,67,75,77,81,83,99,116,117,120–122^ In the case of network meta-analyses, a variety of dietary interventions were typically included and then compared against each other or to other lifestyle interventions.^3,5,7,11,12,20,21,27,30,36,37,41–43,48,66,79,87,93,103,106,108,124^

#### Observational studies

Among the 208 articles that meta-analyzed observational studies, 171 included primary studies that identified dietary patterns using a priori methods (e.g., scores and indices such as the Mediterranean Diet Score and the Healthy Eating Index [HEI]),^1,2,6,23,24,26,28,39,49,50,54,75,78,80,82,99,109–111,122,129–134,136,137,139,140,142–151,153,154,156–159,161–172,174–185,187–191,193–212,214,215,217–234,236–240,242,244,245,247–259,261,265–271,273–275,277–281,285–290,292,293,295,296,299,301,302,305,307,308,310,311,314^ while 96 articles included primary studies that identified dietary patterns using a posteriori methods (i.e., data-driven). These a posteriori methods included principal component analysis (PCA) and factor analysis (81 articles),^23,28,75,78,110,131,135,138,141,142,145,149,152,157,160,161,168,171,175,180,184,186,192,193,199,202,210–213,216,219,221,224,227,231,232,235,236,241,243–246,248,250,253,254,256,260,262–264,268,272,276,278,281–284,286,287,291,293–295,297,298,300,303–306,308–313,315^ cluster analysis (17 articles),^75,135,138,142,149,160,171,175,244,254,264,286,287,294,300,305,309^ reduced rank regression (RRR; 19 articles),^75,135,138,141,160,184,219,224,244,246,250,253,254,263,264,268,284,286,287^ and other or unspecified methods (23 articles).^26,39,135,143,155,157,164,172,180,183,191,210,213,217,218,221,222,226,230,237,246,253,307^ Sixty-one of the articles included primary studies with dietary patterns identified using both a priori and a posteriori methods, analyzed together,^23,28,78,110,131,157,191,193,199,202,210,211,218,219,221,227,230,232,236,245,248,256,278,286,293,307,308,310,311^ separately,^143,145,149,164,168,175,180,222,226,237,287,295^ or both together and separately.^26,39,75,142,161,171,172,183,184,212,217,224,231,244,250,253,254,268,281,305^ Figure 4 illustrates how these different methodologies and approaches to analysis were distributed across the included articles. Two additional articles did not clearly report the method to identify dietary patterns.^104,173^

Figure 4 Inclusion of a priori and a posteriori dietary patterns in individual studies and approach to analysis^*^ * The size of each box is proportionate to the number of articles per category of included methodology to assess dietary patterns (a priori, a posteriori, and both a priori and a posteriori), as well as the approach to analysis when both a priori and a posteriori dietary patterns are included (together, separate, and both).

Articles that only included a priori dietary patterns (110 articles)^1,2,6,24,49,50,54,80,82,99,109,111,122,129,130,132–134,136,137,139,140,144,146–148,150,151,153,154,156,158,159,162,163,165–167,169,170,174,176–179,181,182,185,187–190,194–198,200,201,203–209,214,215,220,223,225,228,229,233,234,238–240,242,247,249,251,252,255,257–259,261,265–267,269–271,273–275,277,279,280,285,288–290,292,296,299,301,302,314^ primarily analyzed a single dietary pattern—which often included multiple indices assessing variations of the same type of dietary pattern. These articles tended to focus on Mediterranean diet indices (e.g., Trichopolou’s Mediterranean Diet Score [MDS], Mediterranean Diet Adherence Screener [MEDAS], Mediterranean Diet Quality Index for children and adolescents [KIDMED]),^1,2,6,24,50,54,82,99,109,111,122,129,134,137,139,140,144,147,150,151,156,159,163,165,169,170,176–179,181,185,187–189,194–197,200,201,204–209,215,225,228,233,239,249,252,255,258,265,267,269,271,273,275,277,279,285,288–290,296,301,302^ plant-based diet indices (e.g., plant-based dietary index [PDI]),^6,132,133,147,148,154,162,181,185,187,190,201,203,214^ and the DASH diet,^80,146,147,166,167,181,182,189,201,223,228,234,238,240,242,247,251,259,267,269,270,280,314^ as well as scores based on dietary guidelines,^49,153,198,220,266,274,292,299^ such as the HEI, the Alternative Healthy Eating Index (AHEI), and Nordic dietary patterns (e.g., Nordic diet, New Nordic Diet). Alternatively, these dietary patterns were sometimes grouped together and described as “healthy” patterns.^6,54,133,136,147,156,158,181,185,189,201,205,207,223,228,257,267,269,280,314^ Although similarities in the foods and beverages emphasized in these patterns were not always described, they were often characterized by higher intakes of vegetables, fruits, nuts, legumes, beans, soy, fish/seafood, and whole grains and sometimes low-fat dairy and lower intakes of red meat, refined grains, and added sugar. Plant-based foods, including plant-based oils such as olive oil, and whole foods were often emphasized as well. In these cases, specific indices or groups of indices were often also analyzed as subgroups.

The 35 articles that only included dietary patterns identified via a posteriori methods generally combined dietary patterns based on similar foods and/or beverages. Some articles simply referred to “healthy” and “prudent” dietary patterns or “unhealthy” and “Western” dietary patterns without specific descriptions of commonalities across the included studies or criteria for similarity. However, more frequently, the articles noted that studies were combined based on a similar pattern of factor loadings and provided a description of the foods and beverages representative of the overarching pattern.^138,141,160,192,213,235,241,243,246,260,262,263,272,276,284,291,297,298,300,303,304,306,309,312,313,315^ As in the analyses of a priori dietary patterns, “healthy” and/or “prudent” patterns were typically characterized by higher intakes of vegetables, fruits, nuts, legumes, beans, soy, fish/seafood, and whole grains, as well as higher intakes of mono- and poly-unsaturated fats and lower intakes of saturated and trans-fats. In contrast, “unhealthy” and “Western” dietary patterns were commonly characterized by higher intakes of processed foods, red/high-fat meat, refined grains, sugar in foods and beverages, high-fat dairy, eggs, fried foods, animal-based foods, snacks, and sodium.

For those articles examining a priori and a posteriori dietary patterns separately from one another, the groupings for analyses took similar approaches as articles that only included a priori or a posteriori patterns. Specifically, the a priori patterns were commonly separately analyzed by “name” (e.g., Mediterranean diet, DASH diet), in addition to some meta-analyzing “healthy” dietary patterns together, while the a posteriori patterns were generally combined as “healthy” and “prudent” or “unhealthy” and “Western”, often based on similarity in the foods and beverages emphasized, but this was not always described explicitly. Similarly, articles that analyzed a priori and a posteriori dietary patterns together generally combined studies based on similarities in the foods and beverages with higher or lower intake and factor loadings, commonly leading to “healthy” and “prudent” dietary patterns or “unhealthy” and “Western” dietary patterns. Finally, articles that analyzed a priori and a posteriori patterns both together and separately typically conducted primary analyses with all dietary patterns that emphasized similar foods and beverages (as outlined above), followed by subgroup analyses based on the method of dietary pattern assessment (a priori versus a posteriori). As an example, Lim et al.^142^ gave a detailed description of methods for combining dietary patterns:

“index-based and data-driven dietary patterns were broadly categorized as high-quality if they were characterized by high intakes of three or more of the following food groups: 1) fruits and vegetables, 2) whole grains, 3) healthy protein sources (legumes and nuts, fish and seafood, low-fat dairy, and lean meat and poultry), and 4) liquid plant oils. High-quality dietary patterns were further subdivided into groups based on their derivation methods (i.e., data-driven or indices, which were further subcategorized into Asian or non-Asian indices and plant-based indices)…Dietary patterns were categorized as low-quality if they were characterized by high intakes of two or more of the following food/beverage groups described in the 2021 AHA Dietary Guidance: 5) ultraprocessed food, 6) beverages and foods with added sugars, 7) foods high in salt, and 8) alcoholic beverages…Common dietary patterns, regardless of the naming of the dietary pattern, were grouped and meta-analyzed if they shared similar constituent foods.”

However, most articles did not provide this level of detail.

### Statistical methods

#### Data preparation

##### Effect size transformations and combinations

Depending on the effect sizes included in the meta-analysis and the assumptions made in the article, the data may or may not have been converted to a common effect size prior to analysis. Forty-nine articles completed transformations to combine different effect sizes.^10,13,19,24,26,35,38,39,41,42,46,54,63,65,72,75–77,87,88,90,98,111,127,144^ ^Luo, 2024 #197,146,152,163,166,172,181,188,191,204,206,209–212,215,218,228,229,254,268,269,274,283^ The most common transformations included those: between odds ratios, risk ratios, hazard ratios, and/or prevalence ratios (18 articles)^19,24,26,39,145,146,152,163,172,181,191,206,211,212,218,228,229,268^; from medians to means (14 articles)^10,13,38,41,42,46,65,87,98,127,166,204,212,215^; from regression coefficients to odds ratios or risk ratios (8 articles)^26,75,188,212,254,268,269,274^; from means or mean differences into odds ratios (3 articles)^54,188,212^; and from a variety of effect sizes to Cohen’s d.^35,88,188^ Although most of these articles did not report combining different effect sizes without transforming to a common effect size (or what was reported was unclear), 10 did report combining hazard ratios, risk ratios, and/or odds ratios without transformation.^145,152,163,206,211,218,229,254,268,269^ The remaining two-hundred sixty-six articles did not complete any effect size transformations to combine effect sizes or it was not clear or reported if transformations were completed. Of these, most articles did not report combining different effect sizes without transforming to a common effect size, or the information was unclear or not provided. Eighty-seven articles, however, analyzed different effect sizes within a single meta-analysis,^1,28,48,49,99,106,109,110,116,117,129,131–133,138,140,141,143,147,155,157,160,161,168,169,173,176–178,183,184,186,193–195,198–201,207,208,214,216,217,219–224,226,227,230,232–237,240–243,245,246,249–252,259,260,262,263,272,276,279,280,286,292,297–299,301–303,308,314^ most commonly pooling odds ratios, risk ratios, and/or hazard ratios together.

##### Dietary patterns modeled categorically and continuously in observational studies

When considering meta-analyses of observational data, most (183 articles) examined dietary patterns as a categorical exposure variable.^1,2,24,26,28,39,49,50,75,78,80,82,99,104,110,122,129–135,137,138,140–148,150,153–172,175–180,182–196,198–205,207,209–224,226–229,231–233,235–251,253–270,272–282,284–287,289–293,295,297–315^ Of these, 93% compared the highest category of adherence to the lowest.^2,24,26,28,39,49,75,80,82,99,110,122,129–135,138,140–143,145–148,150,153–157,159–172,175–180,182–186,188–196,198–200,202,203,207,209–211,213,214,216–224,226–229,231–233,235–251,253–270,272–282,284–287,289–293,295,297–315^ Seven of these studies additionally examined comparisons between moderate or medium adherence levels and the lowest adherence levels,^134,150,187,247,277,281,290^ Twelve additional studies may have also compared the highest and lowest dietary pattern adherence categories, however, this was not clearly reported and the studies were instead classified as comparing unspecified higher and lower adherence categories.^50,78,104,137,144,^ ^20^,^24,158,191,201,204,205,212,215^ Other comparisons, such as one dietary pattern compared to another^135,214^ or comparing the average values of the higher adherence levels compared to the lowest,^1^ were uncommon.

Fewer articles examined dietary patterns as a continuous exposure variable (40 articles).^1,26,99,109–111,131,136,138,144,147,153,174,175,178,188,197,198,200,206,208,212,214,218,225,234,237,246,252,256,258,265,269,271,274,279,283,285,288,290,308^ Eighteen of these articles incorporated data that was analyzed categorically in the source studies by converting it to be a continuous exposure variable for the meta-analysis (18 articles)^99,109,111,136,174,178,197,198,200,206,208,234,237,252,258,279,285,288^

Several articles analyzed dietary patterns as both a continuous and categorical variable (27 articles), either in separate analyses or together without transformation.^1,26,99,110,131,138,144,147,153,175,178,188,198,200,212,214,218,237,246,258,265,269,274,279,285,290,308^ Finally, 12 articles did not report or make clear the format of the dietary pattern exposure variable.^6,23,54,139,149,151,152,173,181,230,294,296^

#### Data analysis

##### Statistical models

Nearly all (97%) of the included articles used random effects models for one or more of the completed meta-analyses. In contrast, only 73 (23%) of the included studies used fixed effect models for at least one of the completed meta-analyses.^5,6,9,13,14,17,18,23,27,33,34,36,38,42,47,49,50,52,61,62,65,66,84–86,89,90,92,99,100,114,115,118,124,128–130,132,149,151,153,161,162,169–171,173,179,182,183,206,219,220,223,237,240,241,243,247,248,252,254,255,260,265,271,277,280,284,292,293,305,311^ Of these, 11 exclusively used fixed effect models.^17,23,92,100,115,130,161,173,243,292,305^ The remaining 62 articles, initial random effects meta-analyses were repeated using a fixed effect model (or vice versa)^14,18,42,62,65,118,124,128,151,162,169,170,179,206,223,240,248,255,265,271,280,293^ or fixed effect and random effects models were used differentially based on predetermined criteria such as the I^2^ value or the number of included studies.^5,6,9,13,27,33,34,36,38,47,49,50,52,61,66,84–86,89,90,99,114,129,132,149,153,171,182,183,219,220,237,241,247,252,254,260,277,284,311^ Fixed effect and random effects models were used in analyses of both trials and observational studies. Outside of dose-response meta-analyses and network meta-analyses, only 2 studies specifically reported using multi-level models to account for dependent data within a single meta-analysis,^2,283^ despite many studies including multiple data points from a single article in a meta-analysis. It is possible that other studies may have accounted for dependence using multi-level models but did not report this explicitly or clearly.

##### Subgroup and meta-regression analyses

Approximately 76% of the articles conducted subgroup and/or meta-regression analyses to examine variables that may be associated with the relationship between dietary patterns and health outcomes.^1–6,12–14,17,18,24–29,31,32,34–39,42,46,50,51,53,55–61,63–65,67,68,71,72,74,75,77–88,90,91,93,94,98,99,101,102,104,106,108,110,111,113,115–122,125,127–133,135–148,150–157,159–169,171,172,175–184,186–189,191,194–197,199–204,206,208–210,212,214–217,219,221–230,232–234,236–254,256,258–260,262,263,265–270,272,274,275,277–286,290–295,297–306,308–310,312–315^ Study-level variables that were commonly assessed through subgroup and/or meta-regression included study design, sex, age, body mass index, geographic location, duration of intervention or follow-up, dietary pattern assessment method (e.g., a priori versus a posteriori), and type of dietary pattern (e.g., Mediterranean diet versus DASH diet).

##### Dose-response meta-analysis

Thirty-nine articles reported conducting a dose-response meta-analysis.^39,49,99,134,146,148,153,154,160,161,163,178,184,194–197,200–202,206,207,209,220,233,234,237,248,252,258,259,266,270,271,279,281,285,290,298^ The methods described by Greenland and Longnecker,^*^ Orsini,^†^,^‡^ and Liu^§^ (among others) were frequently cited as informing the dose-response meta-analyses. The dose-response meta-analyses focused on observational studies, with most analyzing dietary patterns based solely on a priori indices or scales.^49,99,134,146,148,153,154,161,163,178,194–197,200–202,206,207,209,220,233,234,237,248,252,258,259,266,270,271,279,285,290^ Dose-response meta-analyses of these a priori defined patterns were generally limited to a single, named dietary pattern, such as the Mediterranean diet or DASH diet. Few studies included a posteriori defined dietary patterns in the dose-response meta-analyses. ^39,160,184,281,298^ The dose-response meta-analyses were commonly illustrated graphically.

* Greenland S, Longnecker MP. Methods for trend estimation from summarized dose-response data, with applications to meta-analysis. Am J Epidemiol. 1992;135:1301–1309. doi: 10.1093/oxfordjournals.aje.a116237 1626547

† Orsini N, Bellocco R, Greenland S. Generalized least squares for trend estimation of summarized dose-response data. Stata J. 2006;6:40–57. doi: 10.1177/1536867X0600600103

‡ Orsini N, Li R, Wolk A, Khudyakov P, Spiegelman D. Meta-analysis for linear and nonlinear dose-response relations: examples, an evaluation of approximations, and software. Am J Epidemiol. 2012;175:66–73. doi: 10.1093/aje/kwr265 22135359

§ Liu Q, Cook NR, Bergström A, Hsieh CC. A two-stage hierarchical regression model for meta-analysis of epidemiologic nonlinear dose–response data. Comput Statistics Data Anal. 2009;53:4157–4167. doi: 10.1016/j.csda.2009.05.001

##### Network meta-analysis

Twenty-three articles conducted network meta-analyses, all of which only included RCTs.^3,5,7,11,12,20,21,27,30,36,37,41–43,48,66,79,87,93,103,106,108,124^ The number of network meta-analyses published each year tended to increase over time, such that over 50% of the articles that used this technique were published in the past 2 years relative to the 10 year time period that the evidence scan covers (see Figure 5). The methods of the network meta-analyses were commonly informed by those described by Lumley,^*^ Higgins,^†^ Salanti,^‡^,^§^ and Chaimani,^**^,^††^ among others. Two different statistical frameworks were used across the network meta-analyses: 12 used a frequentist framework for analysis^3,7,11,12,27,30,37,48,93,103,108,124^ while 8 used a Bayesian framework,^5,20,21,42,43,66,79,87^. Three additional studies did not specify the framework used.^36,41,106^ Most studies reported assessing inconsistency/incoherence in the network,^3,5,7,11,12,20,21,27,30,41–43,48,66,79,87,93,103,106,108^ while approximately half of the studies explicitly reported assessing transitivity.^3,5,21,41,43,48,66,79,87,93,106,108^ Fifteen articles reported using the surface under the cumulative ranking curve (SUCRA) to evaluate the relative rankings of the different interventions tested in the network meta-analysis.^7,20,21,27,36,37,41–43,66,79,87,93,106,108^ Most of the network meta-analyses were illustrated using network diagrams.^3,5,7,11,12,20,21,27,30,36,37,41–43,48,66,79,87,93,103,106,108^

* Lumley T. Network meta-analysis for indirect treatment comparisons. Stat Med. 2002; 21:2313–2324. doi: 10.1002/sim.1201 12210616

† Higgins JP, Jackson D, Barrett JK, Lu G, Ades AE, White IR. Consistency and inconsistency in network meta-analysis: concepts and models for multi-arm studies. Res Synth Methods. 2012;3:98–110. doi: 10.1002/jrsm.1044 26062084

‡ Salanti G, Higgins JPT, Ades AE, Ioannidis JPA. Evaluation of networks of randomized trials. Stat Methods Med Res. 2008;17(3):279–301. doi: 10.1177/0962280207080643 17925316

§ Salanti G, Ades AE, Ioannidis JPA. Graphical methods and numerical summaries for presenting results from multiple-treatment meta-analysis: An overview and tutorial. J Clin Epidemiol. 2011;64(2):163–71. Doi: 10.1016/j.jclinepi.2010.03.016 20688472

** Chaimani A, Higgins JP, Mavridis D, . Graphical tools for network meta analysis in STATA. PLoS One. 2013;8:e76654. doi: 10.1371/journal.pone.0076654 24098547

†† Chaimani A, Caldwell DM, Li T, Higgins JPT, Salanti G. Chapter 11: Undertaking network meta-analyses [last updated October 2019]. In: Higgins JPT, Thomas J, Chandler J, Cumpston M, Li T, Page MJ, Welch VA (editors). Cochrane Handbook for Systematic Reviews of Interventions version 6.5. Cochrane, 2024 .

Figure 5 Number of network meta-analyses by year

##### Publication bias

Most (76%) of the included systematic reviews with meta-analysis included an assessment of publication bias.^2–5,7–10,12,13,15,17,18,25–31,34–36,39–42,46,48,50,51,53,54,56–61,63–65,67,68,71–82,84–86,88,91,93–96,98,99,101,102,104,106,108,110,111,113,116–120,122,124,127–134,136,138–149,151–166,168,169,171,172,177–184,186–189,191–196,200–206,208–212,214–219,221–229,232–238,240–243,245–254,256–263,265–267,269,270,272,274,276,278–292,294,296–301,303–315^ The most common assessment methods included:

- funnel plots (196 articles),^2–5,7–9,12,13,17,18,25–27,29,30,39–42,46,48,50,51,53,54,57–61,63,65,71–74,76–81,84–86,88,93,94,96,98,99,101,102,104,106,108,110,111,113,116–120,122,124,127,129–134,136,138–143,145–149,151–156,158–166,168,169,171,172,177,179,180,182,183,186–188,191,194,196,200,202–204,206,209–212,214–217,219,221–224,226–229,232,234–237,240–243,245,246,248,249,251–254,257–260,262,263,265,269,270,272,274,276,278,280,282–284,286,287,290–292,294,296–301,303–314^
- Egger’s test (180 articles),^3,4,10,12,13,17,25–28,30,31,34,36,40,42,48,50,51,54,56,58,60,63–65,67,71,72,74,75,77,78,80–82,84–88,91,95,96,98,99,101,102,104,110,111,116–119,127–129,131–134,136,139–143,145,146,148,149,151–154,157–166,169,171,172,177–181,183,184,186–189,191–196,200,204,206,208,210–212,214,215,217–219,221–229,232–238,242,243,246–250,252–254,256–259,261–263,265–267,269,270,272,274,276,279–281,283,285–288,290,292,297–299,305–309,312–315^
- Begg’s test (90 articles),^10,13,28,34,36,42,50,56,64,65,71,74,85,86,91,95,96,99,101,102,118,119,128,129,133,140,146,148,152,154,156,157,160–163,165,177,178,180,182–184,187,194,201,206,208,209,214,219,221,232–237,240,241,243,246–249,252,258,260,262,263,265,269,274,278,279,284,285,289–291,296,298,299,304,307,310–313,315^ and
- trim-and-fill (36 articles).^4,12,13,26,31,56,60,71,80,95,98,116,118,129,136,151,162,177,179,183,191,196,202,210,212,217,221,228,232,248,252,254,262,270,274,283^

Of the articles that presented funnel plots, most used a traditional format and approach, plotting standard errors (or, less commonly, the inverse of the standard error) against the effect sizes for each included data point with the funnel centered at the average effect size. A few studies presented a contour-enhanced funnel plot (6 articles),^60,130,142,149,253,269^ which centers the funnel at zero and illustrates levels of statistical significance of individual points by shading regions of the graph,^*^ or a comparison-adjusted funnel plot (7 articles),^27,30,42,79,93,106,108^ which was used to assess publication bias as part of network meta-analyses. Less frequently used methods to assess publication bias included Egger’s linear regression plots (4 articles),^133,165,218,233^ Doi plots (4 articles),^8,15,35,144^ the Luis Furuya-Kanamori Index (3 articles),^15,35,144^ fail-safe N (2 articles),^4,274^ a radial plot (1 article),^205^ and a Thompson-Sharp test (1 article).^42^ Among the 76 articles that did not assess publication bias, 33 noted that there were not enough included studies to complete this assessment,^1,6,14,19,22,24,32,38,45,49,62,69,70,87,90,97,105,112,114,115,126,167,170,173,175,185,190,197,220,230,231,239,275^ while 42 gave no reason for not conducting or presenting publication bias assessments.^11,16,20,21,23,33,37,43,44,47,52,55,66,68,83,89,92,100,103,107,109,121,123,125,135,137,150,174,176,198,199,207,213,244,264,268,271,273,^ ^277,293,295,302^ A single study noted that they did not conduct an assessment of publication bias because some data were from the same study.^255^

* Peters JL, Sutton AJ, Jones DR, Abrams KR, Rushton L. Contour-enhanced meta-analysis funnel plots help distinguish publication bias from other causes of asymmetry. J Clin Epidemiol. 2008;61:991–996. doi: 10.1016/j.jclinepi.2007.11.010.18538991

## Considerations for future work

- Adhere to published guidance and standards for reporting of meta-analysis methods. [underlined: Elaboration]: Many articles included in the evidence scan did not report, or did not thoroughly report, the methods used in the meta-analysis. Reporting checklists should be used to facilitate transparent reporting of methods for the purposes of clarity and reproducibility, including established tools, such as MOOSE (Meta-analyses Of Observational Studies in Epidemiology)^†^ and PRISMA (Preferred Reporting Items for Systematic reviews and Meta-Analyses),^‡^ and emerging tools as they become available, such as MATES (Meta-analysis Appraisal Tool for Environmental Sciences).^*^ NESR’s methodology manual,^†^ as well as NESR’s procedural guide for systematic reviews with meta-analysis, should continue to be routinely checked and updated to ensure alignment with current reporting guidance.
  † Stroup DF, Berlin JA, Morton SC, . Meta-analysis of observational studies in epidemiology: a proposal for reporting. Meta-analysis Of Observational Studies in Epidemiology (MOOSE) group. JAMA. 2000;283(15):2008–2012. doi: 10.1001/jama.283.15.2008.10789670
  ‡ Page MJ, McKenzie JE, Bossuyt PM, . The PRISMA 2020 statement: an updated guideline for reporting systematic reviews. BMJ. 2021;372:n71. doi: 10.1136/bmj.j4008.33782057
  * Morrison K, Pottier P, Pollo P, . MATES: A tool for evaluating the quality of reporting of meta-analyses. MetaArXiv. Preprint posted online January 13, 2025. doi:10.31222/osf.io/n3cta.
  † USDA Nutrition Evidence Systematic Review Branch. USDA Nutrition Evidence Systematic Review: Methodology Manual. February 2023. U.S. Department of Agriculture, Food and Nutrition Service, Center for Nutrition Policy and Promotion, Nutrition Evidence Systematic Review. Available at: https://nesr.usda.gov/methodology-overview.
- Report detailed information from the individual studies included in the meta-analysis. [underlined: Elaboration]: Many articles in the evidence scan omitted information from the individual, included studies such as the method(s) used to identify dietary patterns in observational studies and the specific type of effect size reported. Other contextual information, such as details of the specific foods and beverages emphasized in individual dietary patterns and the specific comparisons extracted (e.g., comparison of quintiles versus comparison of tertiles), were sometimes not described in the articles. The inclusion of this information would clarify the comparability of the data being pooled in the systematic review with meta-analysis, as well as enhance transparency and reproducibility of the meta-analysis. NESR’s templates for data extraction and evidence tables should continue to be routinely checked and updated to ensure that data critical to the meta-analysis is extracted and clearly reported.
- Report detailed information on how to group different dietary patterns for meta-analysis [underlined: Elaboration]: Although some studies provided detailed descriptions of how the authors determined which dietary patterns were sufficiently similar that they could be statistically combined, most provided minimal or no information about this process. As NESR develops standard methods for meta-analyzing studies of dietary patterns, this should include guidance for reporting how dietary patterns will be considered similar enough to combine statistically, including specific consideration of the food and beverage components of individual dietary patterns.
- Use appropriate and high-quality methods when conducting systematic reviews with meta-analysis. [underlined: Elaboration]: This evidence scan did not have inclusion and exclusion criteria related to the quality of the systematic reviews with meta-analysis. Therefore, although certain methods identified in the evidence scan may have been common, this does not necessarily mean that those methods were appropriate. Further, inclusion in the evidence scan does not indicate endorsement of the methods of any individual systematic review with meta-analysis. NESR’s methodology manual,^†^ as well as NESR’s procedural guide for systematic reviews with meta-analysis, should continue to be routinely checked and updated to ensure that methods are in alignment with standards for a high quality review (e.g., Cochrane^‡^ and the Campbell Collaboration).^§^
  ‡ Higgins JPT, Thomas J, Chandler J, Cumpston M, Li T, Page MJ, Welch VA (editors). Cochrane Handbook for Systematic Reviews of Interventions version 6.5 (updated August 2024). Cochrane, 2024. Available from www.training.cochrane.org/handbook.
  § Aloe AM, Dewidar O, Hennessy EA, . Campbell Standards Modernizing Campbell’s Methodologic Expectations for Campbell Collaboration Intervention Reviews (MECCIR). Campbell Syst Rev. 2024;4:e1445. doi: 10.1002/cl2.1445.39376895

Table 2 Evidence answering the evidence scan question: What methods have been used to meta-analyze studies examining the relationship between dietary patterns and health outcomes?^*^ * Abbreviations: DP: dietary pattern; LFK index: Luis Furuya-Kanamori index; NR: not reported; NRCT: non-randomized controlled trial; PCA: principal component analysis; RCT: randomized controlled trial; RRR: reduced rank regression

Article | Included Study Designs | Dietary Patterns Methods | Data Preparation | Data Analysis
Abbasnezhad, 2020 ^86^ | RCTs | Interventions | Transformations to combine different effect sizes: No/unclear/NR; Combining different effect sizes without transformation: No/unclear/NR | Model(s): Fixed effect and random effects; Additional analyses:; - Subgroup analysis and/or meta-regression; Publication bias: Assessed; - Funnel plot, Egger’s test, Begg’s test
Abdollahi, 2021 ^217^ | Observational studies | a priori DPs, a posteriori DPs (Other/NR method); - a priori and a posteriori analyzed: Both together and separately | Transformations to combine different effect sizes: No/unclear/NR; Combining different effect sizes without transformation: Yes; Observational DPs examined: Categorically (Highest vs lowest) | Model(s): Random effects; Additional analyses:; - Subgroup analysis and/or meta-regression; Publication bias: Assessed; - Funnel plot, Trim-and-fill, Egger’s test
Abebe, 2024 ^141^ | Observational studies | a posteriori DPs (PCA/factor, RRR) | Transformations to combine different effect sizes: No/unclear/NR; Combining different effect sizes without transformation: Yes; Observational DPs examined: Categorically (Highest vs lowest) | Model(s): Random effects; Additional analyses:; - Subgroup analysis and/or meta-regression; Publication bias: Assessed; - Funnel plot, Egger’s test
Akbari, 2024 ^11^ | RCTs | Interventions | Transformations to combine different effect sizes: No/unclear/NR; Combining different effect sizes without transformation: No/unclear/NR | Model(s): Random effects; Additional analyses:; - Network meta-analysis; Publication bias: Not assessed; - No rationale for lack of assessment given
Akhlaghi, 2020 ^82^ | RCTs, Observational studies; - Trials and observational studies analyzed: Separately | Interventions, a priori DPs | Transformations to combine different effect sizes: No/unclear/NR; Combining different effect sizes without transformation: No/unclear/NR; Observational DPs examined: Categorically (Highest vs lowest) | Model(s): Random effects; Additional analyses:; - Subgroup analysis and/or meta-regression; Publication bias: Assessed; - Egger’s test
Al-Ghamdi, 2018 ^100^ | RCTs | Interventions | Transformations to combine different effect sizes: No/unclear/NR; Combining different effect sizes without transformation: No/unclear/NR | Model(s): NR; Publication bias: Not assessed; - No rationale for lack of assessment given
Ali Mohsenpour, 2019 ^251^ | Observational studies | a priori DPs | Transformations to combine different effect sizes: No/unclear/NR; Combining different effect sizes without transformation: Yes; Observational DPs examined: Categorically (Highest vs lowest) | Model(s): Random effects; Additional analyses:; - Subgroup analysis and/or meta-regression; Publication bias: Assessed; - Funnel plot
Alizadeh, 2020 ^260^ | Observational studies | a posteriori DPs (PCA/factor) | Transformations to combine different effect sizes: No/unclear/NR; Combining different effect sizes without transformation: Yes; Observational DPs examined: Categorically (Highest vs lowest) | Model(s): Fixed effect and random effects; Additional analyses:; - Subgroup analysis and/or meta-regression; Publication bias: Assessed; - Funnel plot, Begg’s test
Altemani, 2022 ^52^ | RCTs, NRCTs; - RCTs and NRCTs analyzed: Separately | Interventions | Transformations to combine different effect sizes: No/unclear/NR; Combining different effect sizes without transformation: No/unclear/NR | Model(s): Fixed effect and random effects; Publication bias: Not assessed; - No rationale for lack of assessment given
Angelia, 2024 ^150^ | Observational studies | a priori DPs | Transformations to combine different effect sizes: No/unclear/NR; Combining different effect sizes without transformation: No/unclear/NR; Observational DPs examined: Categorically (Highest vs lowest, Other) | Model(s): Random effects; Additional analyses:; - Subgroup analysis and/or meta-regression; Publication bias: Not assessed; - No rationale for lack of assessment given
Arab, 2024 ^149^ | Observational studies | a priori DPs, a posteriori DPs (PCA/factor, Cluster); - a priori and a posteriori analyzed: Separately | Transformations to combine different effect sizes: No/unclear/NR; Combining different effect sizes without transformation: No/unclear/NR; Observational DPs examined: Unclear/NR DP | Model(s): Fixed effect and random effects; Publication bias: Assessed; - Funnel plot, Contour-enhanced funnel plot, Egger’s test
Arnotti, 2022 ^56^ | RCTs | Interventions | Transformations to combine different effect sizes: No/unclear/NR; Combining different effect sizes without transformation: No/unclear/NR | Model(s): Random effects; Additional analyses:; - Subgroup analysis and/or meta-regression; Publication bias: Assessed; - Trim-and-fill, Egger’s test, Begg’s test
Asbaghi, 2020 ^84^ | RCTs | Interventions | Transformations to combine different effect sizes: No/unclear/NR; Combining different effect sizes without transformation: No/unclear/NR | Model(s): Fixed effect and random effects; Additional analyses:; - Subgroup analysis and/or meta-regression; Publication bias: Assessed; - Funnel plot, Egger’s test
Austin, 2021 ^58^ | RCTs | Interventions | Transformations to combine different effect sizes: No/unclear/NR; Combining different effect sizes without transformation: No/unclear/NR | Model(s): Random effects; Additional analyses:; - Subgroup analysis and/or meta-regression; Publication bias: Assessed; - Funnel plot, Egger’s test
Bach, 2019 ^245^ | Observational studies | a priori DPs, a posteriori DPs (PCA/factor); - a priori and a posteriori analyzed: Together | Transformations to combine different effect sizes: No/unclear/NR; Combining different effect sizes without transformation: Yes; Observational DPs examined: Categorically (Highest vs lowest) | Model(s): Random effects; Additional analyses:; - Subgroup analysis and/or meta-regression; Publication bias: Assessed; - Funnel plot
Bahrami, 2022 ^196^ | Observational studies | a priori DPs | Transformations to combine different effect sizes: No/unclear/NR; Combining different effect sizes without transformation: No/unclear/NR; Observational DPs examined: Categorically (Highest vs lowest) | Model(s): Random effects; Additional analyses:; - Subgroup analysis and/or meta-regression; - Dose-response meta-analysis; Publication bias: Assessed; - Funnel plot, Trim-and-fill, Egger’s test
Bai, 2023 ^165^ | Observational studies | a priori DPs | Transformations to combine different effect sizes: No/unclear/NR; Combining different effect sizes without transformation: No/unclear/NR; Observational DPs examined: Categorically (Highest vs lowest) | Model(s): Random effects; Additional analyses:; - Subgroup analysis and/or meta-regression; Publication bias: Assessed; - Funnel plot, Egger’s test, Egger’s linear regression plot, Begg’s test
Bakaloudi, 2021a ^204^ | Observational studies | a priori DPs | Transformations to combine different effect sizes: Yes; Combining different effect sizes without transformation: No/unclear/NR; Observational DPs examined: Categorically (Higher vs lower categories unspecified) | Model(s): Random effects; Additional analyses:; - Subgroup analysis and/or meta-regression; Publication bias: Assessed; - Funnel plot, Egger’s test
Bakaloudi, 2021b ^215^ | Observational studies | a priori DPs | Transformations to combine different effect sizes: Yes; Combining different effect sizes without transformation: No/unclear/NR; Observational DPs examined: Categorically (Higher vs lower categories unspecified) | Model(s): Random effects; Additional analyses:; - Subgroup analysis and/or meta-regression; Publication bias: Assessed; - Funnel plot, Egger’s test
Barbosa, 2024 ^138^ | Observational studies | a posteriori DPs (PCA/factor, Cluster, RRR) | Transformations to combine different effect sizes: No/unclear/NR; Combining different effect sizes without transformation: Yes; Observational DPs examined: Continuously, Categorically (Highest vs lowest, Other) | Model(s): Random effects; Additional analyses:; - Subgroup analysis and/or meta-regression; Publication bias: Assessed; - Funnel plot
Basri, 2023 ^23^ | RCTs, Observational studies; - Trials and observational studies analyzed: Separately | Interventions, a priori DPs, a posteriori DPs (PCA/factor); - a priori and a posteriori analyzed: Together | Transformations to combine different effect sizes: No/unclear/NR; Combining different effect sizes without transformation: No/unclear/NR; Observational DPs examined: Unclear/NR DP | Model(s): Fixed effect; Publication bias: Not assessed; - No rationale for lack of assessment given
Becerra-Tomás, 2020 ^99^ | RCTs, Observational studies; - Trials and observational studies analyzed: Separately | Interventions, a priori DPs | Transformations to combine different effect sizes: No/unclear/NR; Combining different effect sizes without transformation: Yes; Observational DPs examined: Continuously, Categorically (Highest vs lowest) | Model(s): Fixed effect and random effects; Additional analyses:; - Subgroup analysis and/or meta-regression; - Dose-response meta-analysis; Publication bias: Assessed; - Funnel plot, Egger’s test, Begg’s test
Bella, 2017 ^294^ | Observational studies | a posteriori DPs (PCA/factor, Cluster) | Transformations to combine different effect sizes: No/unclear/NR; Combining different effect sizes without transformation: No/unclear/NR; Observational DPs examined: Unclear/NR DP | Model(s): Random effects; Additional analyses:; - Subgroup analysis and/or meta-regression; Publication bias: Assessed; - Funnel plot
Bizzozero-Peroni, 2025 ^22^ | RCTs | Interventions | Transformations to combine different effect sizes: No/unclear/NR; Combining different effect sizes without transformation: No/unclear/NR | Model(s): Random effects; Publication bias: Not assessed; - Not enough studies
Bizzozero-Peroni, 2022 ^188^ | Observational studies | a priori DPs | Transformations to combine different effect sizes: Yes; Combining different effect sizes without transformation: No/unclear/NR; Observational DPs examined: Continuously, Categorically (Highest vs lowest) | Model(s): Random effects; Additional analyses:; - Subgroup analysis and/or meta-regression; Publication bias: Assessed; - Funnel plot, Egger’s test
Bloomfield, 2016 ^302^ | Observational studies | a priori DPs | Transformations to combine different effect sizes: No/unclear/NR; Combining different effect sizes without transformation: Yes; Observational DPs examined: Categorically (Highest vs lowest) | Model(s): Random effects; Additional analyses:; - Subgroup analysis and/or meta-regression; Publication bias: Not assessed; - No rationale for lack of assessment given
Bonaccio, 2018 ^271^ | Observational studies | a priori DPs | Transformations to combine different effect sizes: No/unclear/NR; Combining different effect sizes without transformation: No/unclear/NR; Observational DPs examined: Continuously | Model(s): Fixed effect and random effects; Additional analyses:; - Dose-response meta-analysis; Publication bias: Not assessed; - No rationale for lack of assessment given
Bonekamp, 2024 ^21^ | RCTs | Interventions | Transformations to combine different effect sizes: No/unclear/NR; Combining different effect sizes without transformation: No/unclear/NR | Model(s): Random effects; Additional analyses:; - Network meta-analysis; Publication bias: Not assessed; - No rationale for lack of assessment given
Bonekamp, 2023 ^43^ | RCTs | Interventions | Transformations to combine different effect sizes: No/unclear/NR; Combining different effect sizes without transformation: No/unclear/NR | Model(s): Random effects; Additional analyses:; - Network meta-analysis; Publication bias: Not assessed; - No rationale for lack of assessment given
Borge, 2017 ^283^ | Observational studies | a posteriori DPs (PCA/factor) | Transformations to combine different effect sizes: Yes; Combining different effect sizes without transformation: No/unclear/NR; Observational DPs examined: Continuously | Model(s): Random effects; Additional analyses:; - Subgroup analysis and/or meta-regression; Publication bias: Assessed; - Funnel plot, Trim-and-fill, Egger’s test
Burden, 2019 ^90^ | RCTs | Interventions | Transformations to combine different effect sizes: Yes; Combining different effect sizes without transformation: No/unclear/NR | Model(s): Fixed effect and random effects; Additional analyses:; - Subgroup analysis and/or meta-regression; Publication bias: Not assessed; - Not enough studies
Buzzetti, 2021 ^66^ | RCTs | Interventions | Transformations to combine different effect sizes: No/unclear/NR; Combining different effect sizes without transformation: No/unclear/NR | Model(s): Fixed effect and random effects; Additional analyses:; - Network meta-analysis; Publication bias: Not assessed; - No rationale for lack of assessment given
Cao, 2016 ^296^ | Observational studies | a priori DPs | Transformations to combine different effect sizes: No/unclear/NR; Combining different effect sizes without transformation: No/unclear/NR; Observational DPs examined: Unclear/NR DP | Model(s): Random effects; Publication bias: Assessed; - Funnel plot, Begg’s test
Castro-Espin, 2022 ^198^ | Observational studies | a priori DPs | Transformations to combine different effect sizes: No/unclear/NR; Combining different effect sizes without transformation: Yes; Observational DPs examined: Continuously, Categorically (Highest vs lowest) | Model(s): Random effects; Publication bias: Not assessed; - No rationale for lack of assessment given
Charkviani, 2022 ^185^ | Observational studies | a priori DPs | Transformations to combine different effect sizes: No/unclear/NR; Combining different effect sizes without transformation: No/unclear/NR; Observational DPs examined: Categorically (Highest vs lowest) | Model(s): Random effects; Publication bias: Not assessed; - Not enough studies
Chen, 2023a ^170^ | Observational studies | a priori DPs | Transformations to combine different effect sizes: No/unclear/NR; Combining different effect sizes without transformation: No/unclear/NR; Observational DPs examined: Categorically (Highest vs lowest) | Model(s): Fixed effect and random effects; Publication bias: Not assessed; - Not enough studies
Chen, 2023b ^40^ | RCTs | Interventions | Transformations to combine different effect sizes: No/unclear/NR; Combining different effect sizes without transformation: No/unclear/NR | Model(s): Random effects; Publication bias: Assessed; - Funnel plot, Egger’s test
Chen, 2019 ^258^ | Observational studies | a priori DPs | Transformations to combine different effect sizes: No/unclear/NR; Combining different effect sizes without transformation: No/unclear/NR; Observational DPs examined: Continuously, Categorically (Highest vs lowest) | Model(s): Random effects; Additional analyses:; - Subgroup analysis and/or metaregression; - Dose-response meta-analysis; Publication bias: Assessed; - Funnel plot, Egger’s test, Begg’s test
Cheng, 2023 ^26^ | RCTs, Observational studies; - Trials and observational studies analyzed: Both together and separately | Interventions, a priori DPs, a posteriori DPs (Other/NR method); - a priori and a posteriori analyzed: Both together and separately | Transformations to combine different effect sizes: Yes; Combining different effect sizes without transformation: No/unclear/NR; Observational DPs examined: Continuously, Categorically (Highest vs lowest) | Model(s): Random effects; Additional analyses:; - Subgroup analysis and/or meta-regression; Publication bias: Assessed; - Funnel plot, Trim-and-fill, Egger’s test
Cheng, 2019 ^249^ | Observational studies | a priori DPs | Transformations to combine different effect sizes: No/unclear/NR; Combining different effect sizes without transformation: Yes; Observational DPs examined: Categorically (Highest vs lowest) | Model(s): Random effects; Additional analyses:; - Subgroup analysis and/or meta-regression; Publication bias: Assessed; - Funnel plot, Egger’s test, Begg’s test
Chia, 2019 ^253^ | Observational studies | a priori DPs, a posteriori DPs (PCA/factor, RRR, Other/NR method); - a priori and a posteriori analyzed: Both together and separately | Transformations to combine different effect sizes: No/unclear/NR; Combining different effect sizes without transformation: No/unclear/NR; Observational DPs examined: Categorically (Highest vs lowest) | Model(s): Random effects; Additional analyses:; - Subgroup analysis and/or meta-regression; Publication bias: Assessed; - Contour-enhanced funnel plot, Egger’s test
Chiavaroli, 2018 ^105^ | RCTs | Interventions | Transformations to combine different effect sizes: No/unclear/NR; Combining different effect sizes without transformation: No/unclear/NR | Model(s): Random effects; Publication bias: Not assessed; - Not enough studies
Coelho-Júnior, 2021 ^212^ | Observational studies | a priori DPs, a posteriori DPs (PCA/factor); - a priori and a posteriori analyzed: Both together and separately | Transformations to combine different effect sizes: Yes; Combining different effect sizes without transformation: No/unclear/NR; Observational DPs examined: Continuously, Categorically (Higher vs lower categories unspecified) | Model(s): Random effects; Additional analyses:; - Subgroup analysis and/or meta-regression; Publication bias: Assessed; - Funnel plot, Trim-and-fill, Egger’s test
Cowell, 2021 ^78^ | RCTs, Observational studies; - Trials and observational studies analyzed: Separately | Interventions, a priori DPs, a posteriori DPs (PCA/factor); - a priori and a posteriori analyzed: Together | Transformations to combine different effect sizes: No/unclear/NR; Combining different effect sizes without transformation: No/unclear/NR; Observational DPs examined: Categorically (Higher vs lower categories unspecified) | Model(s): Random effects; Additional analyses:; - Subgroup analysis and/or meta-regression; Publication bias: Assessed; - Funnel plot, Egger’s test
Cui, 2023 ^207^ | Observational studies | a priori DPs | Transformations to combine different effect sizes: No/unclear/NR; Combining different effect sizes without transformation: Yes; Observational DPs examined: Categorically (Highest vs lowest) | Model(s): Random effects; Additional analyses:; - Dose-response meta-analysis; Publication bias: Not assessed; - No rationale for lack of assessment given
de Menezes, 2019 ^92^ | RCTs | Interventions | Transformations to combine different effect sizes: No/unclear/NR; Combining different effect sizes without transformation: No/unclear/NR | Model(s): Fixed effect; Publication bias: Not assessed; - No rationale for lack of assessment given
Del Bo, 2023 ^33^ | RCTs | Interventions | Transformations to combine different effect sizes: No/unclear/NR; Combining different effect sizes without transformation: No/unclear/NR | Model(s): Fixed effect and random effects; Publication bias: Not assessed; - No rationale for lack of assessment given
Del-Ponte, 2019 ^256^ | Observational studies | a priori DPs, a posteriori DPs (PCA/factor); - a priori and a posteriori analyzed: Together | Transformations to combine different effect sizes: No/unclear/NR; Combining different effect sizes without transformation: No/unclear/NR; Observational DPs examined: Categorically (Highest vs lowest), Unclear/NR DP | Model(s): Random effects; Additional analyses:; - Subgroup analysis and/or meta-regression; Publication bias: Assessed; - Egger’s test
Denova-Gutiérrez, 2018 ^264^ | Observational studies | a posteriori DPs (PCA/factor, Cluster, RRR) | Transformations to combine different effect sizes: No/unclear/NR; Combining different effect sizes without transformation: No/unclear/NR; Observational DPs examined: Categorically (Highest vs lowest) | Model(s): Random effects; Publication bias: Not assessed; - No rationale for lack of assessment given
Dianatinasab, 2022 ^199^ | Observational studies | a priori DPs, a posteriori DPs (PCA/factor); - a priori and a posteriori analyzed: Together | Transformations to combine different effect sizes: No/unclear/NR; Combining different effect sizes without transformation: Yes; Observational DPs examined: Categorically (Highest vs lowest) | Model(s): Random effects; Additional analyses:; - Subgroup analysis and/or meta-regression; Publication bias: Not assessed; - No rationale for lack of assessment given
Dianatinasab, 2020 ^232^ | Observational studies | a priori DPs, a posteriori DPs (PCA/factor); - a priori and a posteriori analyzed: Together | Transformations to combine different effect sizes: No/unclear/NR; Combining different effect sizes without transformation: Yes; Observational DPs examined: Categorically (Highest vs lowest) | Model(s): Random effects; Additional analyses:; - Subgroup analysis and/or meta-regression; Publication bias: Assessed; - Funnel plot, Trim-and-fill, Egger’s test, Begg’s test
Dominguez, 2023 ^176^ | Observational studies | a priori DPs | Transformations to combine different effect sizes: No/unclear/NR; Combining different effect sizes without transformation: Yes; Observational DPs examined: Categorically (Highest vs lowest) | Model(s): Random effects; Additional analyses:; - Subgroup analysis and/or meta-regression; Publication bias: Not assessed; - No rationale for lack of assessment given
Doundoulakis, 2024 ^30^ | RCTs | Interventions | Transformations to combine different effect sizes: No/unclear/NR; Combining different effect sizes without transformation: No/unclear/NR | Model(s): Random effects; Additional analyses:; - Network meta-analysis; Publication bias: Assessed; - Comparison-adjusted funnel plot, Egger’s test
Du, 2022 ^194^ | Observational studies | a priori DPs | Transformations to combine different effect sizes: No/unclear/NR; Combining different effect sizes without transformation: Yes; Observational DPs examined: Categorically (Highest vs lowest) | Model(s): Random effects; Additional analyses:; - Subgroup analysis and/or meta-regression; - Dose-response meta-analysis; Publication bias: Assessed; - Funnel plot, Egger’s test, Begg’s test
Du, 2020 ^239^ | Observational studies | a priori DPs | Transformations to combine different effect sizes: No/unclear/NR; Combining different effect sizes without transformation: No/unclear/NR; Observational DPs examined: Categorically (Highest vs lowest) | Model(s): Random effects; Additional analyses:; - Subgroup analysis and/or meta-regression; Publication bias: Not assessed; - Not enough studies
Eichelmann, 2016 ^116^ | RCTs | Interventions | Transformations to combine different effect sizes: No/unclear/NR; Combining different effect sizes without transformation: Yes | Model(s): Random effects; Additional analyses:; - Subgroup analysis and/or meta-regression; Publication bias: Assessed; - Funnel plot, Trim-and-fill, Egger’s test
Eleftheriou, 2018 ^265^ | Observational studies | a priori DPs | Transformations to combine different effect sizes: No/unclear/NR; Combining different effect sizes without transformation: No/unclear/NR; Observational DPs examined: Continuously, Categorically (Highest vs lowest) | Model(s): Fixed effect and random effects; Additional analyses:; - Subgroup analysis and/or meta-regression; Publication bias: Assessed; - Funnel plot, Egger’s test, Begg’s test
Errasti Viader, 2024 ^131^ | Observational studies | a priori DPs, a posteriori DPs (PCA/factor); - a priori and a posteriori analyzed: Together | Transformations to combine different effect sizes: No/unclear/NR; Combining different effect sizes without transformation: Yes; Observational DPs examined: Continuously, Categorically (Highest vs lowest, Other) | Model(s): Random effects; Additional analyses:; - Subgroup analysis and/or meta-regression; Publication bias: Assessed; - Funnel plot, Egger’s test
Esposito, 2015 ^126^ | RCTs | Interventions | Transformations to combine different effect sizes: No/unclear/NR; Combining different effect sizes without transformation: No/unclear/NR | Model(s): Random effects; Publication bias: Not assessed; - Not enough studies
Fabiani, 2023 ^160^ | Observational studies | a posteriori DPs (PCA/factor, Cluster, RRR) | Transformations to combine different effect sizes: No/unclear/NR; Combining different effect sizes without transformation: Yes; Observational DPs examined: Categorically (Highest vs lowest) | Model(s): Random effects; Additional analyses:; - Subgroup analysis and/or meta-regression; - Dose-response meta-analysis; Publication bias: Assessed; - Funnel plot, Egger’s test, Begg’s test
Fabiani, 2019a ^246^ | Observational studies | a posteriori DPs (PCA/factor, RRR, Other/NR method) | Transformations to combine different effect sizes: No/unclear/NR; Combining different effect sizes without transformation: Yes; Observational DPs examined: Continuously, Categorically (Highest vs lowest) | Model(s): Random effects; Additional analyses:; - Subgroup analysis and/or meta-regression; Publication bias: Assessed; - Funnel plot, Egger’s test, Begg’s test
Fabiani, 2019b ^263^ | Observational studies | a posteriori DPs (PCA/factor, RRR) | Transformations to combine different effect sizes: No/unclear/NR; Combining different effect sizes without transformation: Yes; Observational DPs examined: Categorically (Highest vs lowest) | Model(s): Random effects; Additional analyses:; - Subgroup analysis and/or meta-regression; Publication bias: Assessed; - Funnel plot, Egger’s test, Begg’s test
Fabiani, 2016 ^298^ | Observational studies | a posteriori DPs (PCA/factor) | Transformations to combine different effect sizes: No/unclear/NR; Combining different effect sizes without transformation: Yes; Observational DPs examined: Categorically (Highest vs lowest) | Model(s): Random effects; Additional analyses:; - Subgroup analysis and/or meta-regression; - Dose-response meta-analysis; Publication bias: Assessed; - Funnel plot, Egger’s test, Begg’s test
Fa-Binefa, 2024 ^134^ | Observational studies | a priori DPs | Transformations to combine different effect sizes: No/unclear/NR; Combining different effect sizes without transformation: No/unclear/NR; Observational DPs examined: Categorically (Highest vs lowest, Other) | Model(s): Random effects; Additional analyses:; - Dose-response meta-analysis; Publication bias: Assessed; - Funnel plot, Egger’s test
Fatima, 2023 ^55^ | RCTs | Interventions | Transformations to combine different effect sizes: No/unclear/NR; Combining different effect sizes without transformation: No/unclear/NR | Model(s): Random effects; Additional analyses:; - Subgroup analysis and/or meta-regression; Publication bias: Not assessed; - No rationale for lack of assessment given
Feng, 2018 ^270^ | Observational studies | a priori DPs | Transformations to combine different effect sizes: No/unclear/NR; Combining different effect sizes without transformation: No/unclear/NR; Observational DPs examined: Categorically (Highest vs lowest) | Model(s): Random effects; Additional analyses:; - Subgroup analysis and/or meta-regression; - Dose-response meta-analysis; Publication bias: Assessed; - Funnel plot, Trim-and-fill, Egger’s test
Feng, 2017 ^306^ | Observational studies | a posteriori DPs (PCA/factor) | Transformations to combine different effect sizes: No/unclear/NR; Combining different effect sizes without transformation: No/unclear/NR; Observational DPs examined: Categorically (Highest vs lowest) | Model(s): Random effects; Additional analyses:; - Subgroup analysis and/or meta-regression; Publication bias: Assessed; - Funnel plot, Egger’s test
Fichtel-Epstein, 2024 ^130^ | Observational studies | a priori DPs | Transformations to combine different effect sizes: No/unclear/NR; Combining different effect sizes without transformation: No/unclear/NR; Observational DPs examined: Categorically (Highest vs lowest) | Model(s): Fixed effect; Additional analyses:; - Subgroup analysis and/or meta-regression; Publication bias: Assessed; - Contour-enhanced funnel plot
Filippou, 2021 ^71^ | RCTs | Interventions | Transformations to combine different effect sizes: No/unclear/NR; Combining different effect sizes without transformation: No/unclear/NR | Model(s): Random effects; Additional analyses:; - Subgroup analysis and/or meta-regression; Publication bias: Assessed; - Funnel plot, Trim-and-fill, Egger’s test, Begg’s test
Filippou, 2020 ^85^ | RCTs | Interventions | Transformations to combine different effect sizes: No/unclear/NR; Combining different effect sizes without transformation: No/unclear/NR | Model(s): Fixed effect and random effects; Additional analyses:; - Subgroup analysis and/or meta-regression; Publication bias: Assessed; - Funnel plot, Egger’s test, Begg’s test
Frqczek, 2021 ^68^ | RCTs | Interventions | Transformations to combine different effect sizes: No/unclear/NR; Combining different effect sizes without transformation: No/unclear/NR | Model(s): Random effects; Additional analyses:; - Subgroup analysis and/or meta-regression; Publication bias: Not assessed; - No rationale for lack of assessment given
Fu, 2022 ^50^ | RCTs, Observational studies; - Trials and observational studies analyzed: Separately | Interventions, a priori DPs | Transformations to combine different effect sizes: No/unclear/NR; Combining different effect sizes without transformation: No/unclear/NR; Observational DPs examined: Categorically (Higher vs lower categories unspecified), Unclear/NR DP | Model(s): Fixed effect and random effects; Additional analyses:; - Subgroup analysis and/or meta-regression; Publication bias: Assessed; - Funnel plot, Egger’s test, Begg’s test
Fu, 2020 ^79^ | RCTs | Interventions | Transformations to combine different effect sizes: No/unclear/NR; Combining different effect sizes without transformation: No/unclear/NR | Model(s): Random effects; Additional analyses:; - Subgroup analysis and/or meta-regression; - Network meta-analysis; Publication bias: Assessed; - Comparison-adjusted funnel plot
Fuller, 2022 ^39^ | RCTs, Observational studies; - Trials and observational studies analyzed: Both together and separately | Interventions, a priori DPs, a posteriori DPs (Other/NR method); - a priori and a posteriori analyzed: Both together and separately | Transformations to combine different effect sizes: Yes; Combining different effect sizes without transformation: No/unclear/NR; Observational DPs examined: Categorically (Highest vs lowest) | Model(s): Random effects; Additional analyses:; - Subgroup analysis and/or meta-regression; - Dose-response meta-analysis; Publication bias: Assessed; - Funnel plot
Furbatto, 2024 ^2^ | RCTs, Observational studies; - Trials and observational studies analyzed: Together | Interventions, a priori DPs | Transformations to combine different effect sizes: No/unclear/NR; Combining different effect sizes without transformation: No/unclear/NR; Observational DPs examined: Categorically (Highest vs lowest) | Model(s): Random effects; Additional analyses:; - Subgroup analysis and/or meta-regression; Publication bias: Assessed; - Funnel plot
Gan, 2021 ^202^ | Observational studies | a priori DPs, a posteriori DPs (PCA/factor); - a priori and a posteriori analyzed: Together | Transformations to combine different effect sizes: No/unclear/NR; Combining different effect sizes without transformation: No/unclear/NR; Observational DPs examined: Categorically (Highest vs lowest) | Model(s): Random effects; Additional analyses:; - Subgroup analysis and/or meta-regression; - Dose-response meta-analysis; Publication bias: Assessed; - Funnel plot, Trim-and-fill
Gao, 2022 ^181^ | Observational studies | a priori DPs | Transformations to combine different effect sizes: Yes; Combining different effect sizes without transformation: No/unclear/NR; Observational DPs examined: Unclear/NR DP | Model(s): Random effects; Additional analyses:; - Subgroup analysis and/or meta-regression; Publication bias: Assessed; - Egger’s test
Garcia, 2016 ^118^ | RCTs, NRCTs; - RCTs and NRCTs analyzed: Together | Interventions | Transformations to combine different effect sizes: No/unclear/NR; Combining different effect sizes without transformation: No/unclear/NR | Model(s): Fixed effect and random effects; Additional analyses:; - Subgroup analysis and/or meta-regression; Publication bias: Assessed; - Funnel plot, Trim-and-fill, Egger’s test, Begg’s test
Garcia-Casares, 2021 ^206^ | Observational studies | a priori DPs | Transformations to combine different effect sizes: Yes; Combining different effect sizes without transformation: Yes; Observational DPs examined: Continuously | Model(s): Fixed effect and random effects; Additional analyses:; - Subgroup analysis and/or meta-regression; - Dose-response meta-analysis; Publication bias: Assessed; - Funnel plot, Egger’s test, Begg’s test
Garcia-Larsen, 2019 ^272^ | Observational studies | a posteriori DPs (PCA/factor) | Transformations to combine different effect sizes: No/unclear/NR; Combining different effect sizes without transformation: Yes; Observational DPs examined: Categorically (Highest vs lowest) | Model(s): Random effects; Additional analyses:; - Subgroup analysis and/or meta-regression; Publication bias: Assessed; - Funnel plot, Egger’s test
Gay, 2016 ^120^ | RCTs | Interventions | Transformations to combine different effect sizes: No/unclear/NR; Combining different effect sizes without transformation: No/unclear/NR | Model(s): Random effects; Additional analyses:; - Subgroup analysis and/or meta-regression; Publication bias: Assessed; - Funnel plot
Ge, 2020 ^87^ | RCTs | Interventions | Transformations to combine different effect sizes: Yes; Combining different effect sizes without transformation: No/unclear/NR | Model(s): Random effects; Additional analyses:; - Subgroup analysis and/or meta-regression; - Network meta-analysis; Publication bias: Not assessed; - Not enough studies
Ghadimi, 2021 ^67^ | RCTs | Interventions | Transformations to combine different effect sizes: No/unclear/NR; Combining different effect sizes without transformation: No/unclear/NR | Model(s): Random effects; Additional analyses:; - Subgroup analysis and/or meta-regression; Publication bias: Assessed; - Egger’s test
Ghaedi, 2019 ^95^ | RCTs | Interventions | Transformations to combine different effect sizes: No/unclear/NR; Combining different effect sizes without transformation: No/unclear/NR | Model(s): Random effects; Publication bias: Assessed; - Trim-and-fill, Egger’s test, Begg’s test
Gibbs, 2021 ^74^ | RCTs, NRCTs; - RCTs and NRCTs analyzed: Together | Interventions | Transformations to combine different effect sizes: No/unclear/NR; Combining different effect sizes without transformation: No/unclear/NR | Model(s): Random effects; Additional analyses:; - Subgroup analysis and/or meta-regression; Publication bias: Assessed; - Funnel plot, Egger’s test, Begg’s test
Giordano, 2024 ^1^ | RCTs, Observational studies; - Trials and observational studies analyzed: Together | Interventions, a priori DPs | Transformations to combine different effect sizes: No/unclear/NR; Combining different effect sizes without transformation: Yes; Observational DPs examined: Continuously, Categorically (Average of higher categories vs lowest) | Model(s): Random effects; Additional analyses:; - Subgroup analysis and/or meta-regression; Publication bias: Not assessed; - Not enough studies
Godos, 2017 ^301^ | Observational studies | a priori DPs | Transformations to combine different effect sizes: No/unclear/NR; Combining different effect sizes without transformation: Yes; Observational DPs examined: Categorically (Highest vs lowest) | Model(s): Random effects; Additional analyses:; - Subgroup analysis and/or meta-regression; Publication bias: Assessed; - Funnel plot
Godos, 2016 ^303^ | Observational studies | a posteriori DPs (PCA/factor) | Transformations to combine different effect sizes: No/unclear/NR; Combining different effect sizes without transformation: Yes; Observational DPs examined: Categorically (Highest vs lowest) | Model(s): Random effects; Additional analyses:; - Subgroup analysis and/or meta-regression; Publication bias: Assessed; - Funnel plot
Gohari, 2023 ^32^ | RCTs | Interventions | Transformations to combine different effect sizes: No/unclear/NR; Combining different effect sizes without transformation: No/unclear/NR | Model(s): Random effects; Additional analyses:; - Subgroup analysis and/or meta-regression; Publication bias: Not assessed; - Not enough studies
Goldfarb, 2021 ^205^ | Observational studies | a priori DPs | Transformations to combine different effect sizes: No/unclear/NR; Combining different effect sizes without transformation: No/unclear/NR; Observational DPs examined: Categorically (Higher vs lower categories unspecified) | Model(s): Random effects; Publication bias: Assessed; - Radial plot
Grosso, 2017a ^282^ | Observational studies | a posteriori DPs (PCA/factor) | Transformations to combine different effect sizes: No/unclear/NR; Combining different effect sizes without transformation: No/unclear/NR; Observational DPs examined: Categorically (Highest vs lowest) | Model(s): Random effects; Additional analyses:; - Subgroup analysis and/or meta-regression; Publication bias: Assessed; - Funnel plot
Grosso, 2017b ^122^ | RCTs, Observational studies; - Trials and observational studies analyzed: Separately | Interventions, a priori DPs | Transformations to combine different effect sizes: No/unclear/NR; Combining different effect sizes without transformation: No/unclear/NR; Observational DPs examined: Categorically (Highest vs lowest) | Model(s): Random effects; Additional analyses:; - Subgroup analysis and/or meta-regression; Publication bias: Assessed; - Funnel plot
Guo, 2024 ^17^ | RCTs | Interventions | Transformations to combine different effect sizes: No/unclear/NR; Combining different effect sizes without transformation: No/unclear/NR | Model(s): Fixed effect; Additional analyses:; - Subgroup analysis and/or meta-regression; Publication bias: Assessed; - Funnel plot, Egger’s test
Guo, 2021 ^61^ | RCTs | Interventions | Transformations to combine different effect sizes: No/unclear/NR; Combining different effect sizes without transformation: No/unclear/NR | Model(s): Fixed effect and random effects; Additional analyses:; - Subgroup analysis and/or meta-regression; Publication bias: Assessed; - Funnel plot
Haghighatdoost, 2023 ^184^ | Observational studies | a priori DPs, a posteriori DPs (PCA/factor, RRR); - a priori and a posteriori analyzed: Both together and separately | Transformations to combine different effect sizes: No/unclear/NR; Combining different effect sizes without transformation: Yes; Observational DPs examined: Categorically (Highest vs lowest) | Model(s): Random effects; Additional analyses:; - Subgroup analysis and/or meta-regression; - Dose-response meta-analysis; Publication bias: Assessed; - Egger’s test, Begg’s test
Haigh, 2022 ^51^ | RCTs, NRCTs; - RCTs and NRCTs analyzed: Together | Interventions | Transformations to combine different effect sizes: No/unclear/NR; Combining different effect sizes without transformation: No/unclear/NR | Model(s): Random effects; Additional analyses:; - Subgroup analysis and/or meta-regression; Publication bias: Assessed; - Funnel plot, Egger’s test
Han, 2017 ^114^ | RCTs | Interventions | Transformations to combine different effect sizes: No/unclear/NR; Combining different effect sizes without transformation: No/unclear/NR | Model(s): Fixed effect and random effects; Publication bias: Not assessed; - Not enough studies
Hansrivijit, 2020 ^225^ | Observational studies | a priori DPs | Transformations to combine different effect sizes: No/unclear/NR; Combining different effect sizes without transformation: No/unclear/NR; Observational DPs examined: Continuously | Model(s): Random effects; Additional analyses:; - Subgroup analysis and/or meta-regression; Publication bias: Assessed; - Egger’s test
Hao, 2024 ^153^ | Observational studies | a priori DPs | Transformations to combine different effect sizes: No/unclear/NR; Combining different effect sizes without transformation: No/unclear/NR; Observational DPs examined: Continuously, Categorically (Highest vs lowest) | Model(s): Fixed effect and random effects; Additional analyses:; - Subgroup analysis and/or meta-regression; - Dose-response meta-analysis; Publication bias: Assessed; - Funnel plot, Egger’s test
Hassani Zadeh, 2021 ^221^ | Observational studies | a priori DPs, a posteriori DPs (PCA/factor, Other/NR method); - a priori and a posteriori analyzed: Together | Transformations to combine different effect sizes: No/unclear/NR; Combining different effect sizes without transformation: Yes; Observational DPs examined: Categorically (Highest vs lowest) | Model(s): Random effects; Additional analyses:; - Subgroup analysis and/or meta-regression; Publication bias: Assessed; - Funnel plot, Trim-and-fill, Egger’s test, Begg’s test
Hassani Zadeh, 2020 ^236^ | Observational studies | a priori DPs, a posteriori DPs (PCA/factor); - a priori and a posteriori analyzed: Together | Transformations to combine different effect sizes: No/unclear/NR; Combining different effect sizes without transformation: Yes; Observational DPs examined: Categorically (Highest vs lowest) | Model(s): Random effects; Additional analyses:; - Subgroup analysis and/or meta-regression; Publication bias: Assessed; - Funnel plot, Egger’s test, Begg’s test
He, 2021 ^219^ | Observational studies | a priori DPs, a posteriori DPs (PCA/factor, RRR); - a priori and a posteriori analyzed: Together | Transformations to combine different effect sizes: No/unclear/NR; Combining different effect sizes without transformation: Yes; Observational DPs examined: Categorically (Highest vs lowest) | Model(s): Fixed effect and random effects; Additional analyses:; - Subgroup analysis and/or meta-regression; Publication bias: Assessed; - Funnel plot, Egger’s test, Begg’s test
Hoang, 2020 ^222^ | Observational studies | a priori DPs, a posteriori DPs (Other/NR method); - a priori and a posteriori analyzed: Separately | Transformations to combine different effect sizes: No/unclear/NR; Combining different effect sizes without transformation: Yes; Observational DPs examined: Categorically (Highest vs lowest) | Model(s): Random effects; Additional analyses:; - Subgroup analysis and/or meta-regression; Publication bias: Assessed; - Funnel plot, Egger’s test
Hou, 2019 ^250^ | Observational studies | a priori DPs, a posteriori DPs (PCA/factor, RRR); - a priori and a posteriori analyzed: Both together and separately | Transformations to combine different effect sizes: No/unclear/NR; Combining different effect sizes without transformation: Yes; Observational DPs examined: Categorically (Highest vs lowest) | Model(s): Random effects; Additional analyses:; - Subgroup analysis and/or meta-regression; Publication bias: Assessed; - Egger’s test
Hou, 2015 ^313^ | Observational studies | a posteriori DPs (PCA/factor) | Transformations to combine different effect sizes: No/unclear/NR; Combining different effect sizes without transformation: No/unclear/NR; Observational DPs examined: Categorically (Highest vs lowest) | Model(s): Random effects; Additional analyses:; - Subgroup analysis and/or meta-regression; Publication bias: Assessed; - Funnel plot, Egger’s test, Begg’s test
Houttu, 2021 ^62^ | RCTs | Interventions | Transformations to combine different effect sizes: No/unclear/NR; Combining different effect sizes without transformation: No/unclear/NR | Model(s): Fixed effect and random effects; Publication bias: Not assessed; - Not enough studies
Hu, 2024 ^135^ | Observational studies | a posteriori DPs (PCA/factor, Cluster, RRR, Other/NR method) | Transformations to combine different effect sizes: No/unclear/NR; Combining different effect sizes without transformation: No/unclear/NR; Observational DPs examined: Categorically (Highest vs lowest, Other) | Model(s): Random effects; Additional analyses:; - Subgroup analysis and/or meta-regression; Publication bias: Not assessed; - No rationale for lack of assessment given
Hua, 2023 ^173^ | Observational studies | | Transformations to combine different effect sizes: No/unclear/NR; Combining different effect sizes without transformation: Yes; Observational DPs examined: Unclear/NR DP | Model(s): Fixed effect; Publication bias: Not assessed; - Not enough studies
Huang, 2023 ^174^ | Observational studies | a priori DPs | Transformations to combine different effect sizes: No/unclear/NR; Combining different effect sizes without transformation: No/unclear/NR; Observational DPs examined: Continuously | Model(s): Random effects; Publication bias: Not assessed; - No rationale for lack of assessment given
Huo, 2015 ^128^ | RCTs | Interventions | Transformations to combine different effect sizes: No/unclear/NR; Combining different effect sizes without transformation: No/unclear/NR | Model(s): Fixed effect and random effects; Additional analyses:; - Subgroup analysis and/or meta-regression; Publication bias: Assessed; - Egger’s test, Begg’s test
Jafari, 2022 ^214^ | Observational studies | a priori DPs | Transformations to combine different effect sizes: No/unclear/NR; Combining different effect sizes without transformation: Yes; Observational DPs examined: Continuously, Categorically (Highest vs lowest, Other) | Model(s): Random effects; Additional analyses:; - Subgroup analysis and/or meta-regression; Publication bias: Assessed; - Funnel plot, Egger’s test, Begg’s test
Jafari Nasab, 2024a ^140^ | Observational studies | a priori DPs | Transformations to combine different effect sizes: No/unclear/NR; Combining different effect sizes without transformation: Yes; Observational DPs examined: Categorically (Highest vs lowest) | Model(s): Random effects; Additional analyses:; - Subgroup analysis and/or meta-regression; Publication bias: Assessed; - Funnel plot, Egger’s test, Begg’s test
Jafari Nasab, 2024b ^159^ | Observational studies | a priori DPs | Transformations to combine different effect sizes: No/unclear/NR; Combining different effect sizes without transformation: No/unclear/NR; Observational DPs examined: Categorically (Highest vs lowest) | Model(s): Random effects; Additional analyses:; - Subgroup analysis and/or meta-regression; Publication bias: Assessed; - Funnel plot, Egger’s test
Jalilpiran, 2022 ^220^ | Observational studies | a priori DPs | Transformations to combine different effect sizes: No/unclear/NR; Combining different effect sizes without transformation: Yes; Observational DPs examined: Categorically (Highest vs lowest) | Model(s): Fixed effect and random effects; Additional analyses:; - Dose-response meta-analysis; Publication bias: Not assessed; - Not enough studies
Jamil, 2024 ^8^ | RCTs, NRCTs; - RCTs and NRCTs analyzed: Together | Interventions | Transformations to combine different effect sizes: No/unclear/NR; Combining different effect sizes without transformation: No/unclear/NR | Model(s): Random effects; Publication bias: Assessed; - Funnel plot, Doi plot
Jamka, 2020 ^89^ | RCTs | Interventions | Transformations to combine different effect sizes: No/unclear/NR; Combining different effect sizes without transformation: No/unclear/NR | Model(s): Fixed effect and random effects; Publication bias: Not assessed; - No rationale for lack of assessment given
Jannasch, 2017 ^287^ | Observational studies | a priori DPs, a posteriori DPs (PCA/factor, Cluster, RRR); - a priori and a posteriori analyzed: Separately | Transformations to combine different effect sizes: No/unclear/NR; Combining different effect sizes without transformation: No/unclear/NR; Observational DPs examined: Categorically (Highest vs lowest) | Model(s): Random effects; Publication bias: Assessed; - Funnel plot, Egger’s test
Jiang, 2022 ^186^ | Observational studies | a posteriori DPs (PCA/factor) | Transformations to combine different effect sizes: No/unclear/NR; Combining different effect sizes without transformation: Yes; Observational DPs examined: Categorically (Highest vs lowest) | Model(s): Random effects; Additional analyses:; - Subgroup analysis and/or meta-regression; Publication bias: Assessed; - Funnel plot, Egger’s test
Jing, 2023 ^27^ | RCTs | Interventions | Transformations to combine different effect sizes: No/unclear/NR; Combining different effect sizes without transformation: No/unclear/NR | Model(s): Fixed effect and random effects; Additional analyses:; - Subgroup analysis and/or meta-regression; - Network meta-analysis; Publication bias: Assessed; - Comparison-adjusted funnel plot, Egger’s test
Juhász, 2024 ^20^ | RCTs | Interventions | Transformations to combine different effect sizes: No/unclear/NR; Combining different effect sizes without transformation: No/unclear/NR | Model(s): Random effects; Additional analyses:; - Network meta-analysis; Publication bias: Not assessed; - No rationale for lack of assessment given
Karam, 2023 ^37^ | RCTs | Interventions | Transformations to combine different effect sizes: No/unclear/NR; Combining different effect sizes without transformation: No/unclear/NR | Model(s): Random effects; Additional analyses:; - Subgroup analysis and/or meta-regression; - Network meta-analysis; Publication bias: Not assessed; - No rationale for lack of assessment given
Kashyap, 2022 ^44^ | RCTs, NRCTs; - RCTs and NRCTs analyzed: Separately | Interventions | Transformations to combine different effect sizes: No/unclear/NR; Combining different effect sizes without transformation: No/unclear/NR | Model(s): Random effects; Publication bias: Not assessed; - No rationale for lack of assessment given
Kawaguchi, 2021 ^65^ | RCTs | Interventions | Transformations to combine different effect sizes: Yes; Combining different effect sizes without transformation: No/unclear/NR | Model(s): Fixed effect and random effects; Additional analyses:; - Subgroup analysis and/or meta-regression; Publication bias: Assessed; - Funnel plot, Egger’s test, Begg’s test
Kelly, 2017 ^293^ | Observational studies | a priori DPs, a posteriori DPs (PCA/factor); - a priori and a posteriori analyzed: Together | Transformations to combine different effect sizes: No/unclear/NR; Combining different effect sizes without transformation: No/unclear/NR; Observational DPs examined: Categorically (Highest vs lowest) | Model(s): Fixed effect and random effects; Additional analyses:; - Subgroup analysis and/or meta-regression; Publication bias: Not assessed; - No rationale for lack of assessment given
Keshani, 2024 ^13^ | RCTs | Interventions | Transformations to combine different effect sizes: Yes; Combining different effect sizes without transformation: No/unclear/NR | Model(s): Fixed effect and random effects; Additional analyses:; - Subgroup analysis and/or meta-regression; Publication bias: Assessed; - Funnel plot, Trim-and-fill, Egger’s test, Begg’s test
Khorshidi, 2020 ^241^ | Observational studies | a posteriori DPs (PCA/factor) | Transformations to combine different effect sizes: No/unclear/NR; Combining different effect sizes without transformation: Yes; Observational DPs examined: Categorically (Highest vs lowest) | Model(s): Fixed effect and random effects; Additional analyses:; - Subgroup analysis and/or meta-regression; Publication bias: Assessed; - Funnel plot, Begg’s test
Kibret, 2019 ^268^ | Observational studies | a priori DPs, a posteriori DPs (PCA/factor, RRR); - a priori and a posteriori analyzed: Both together and separately | Transformations to combine different effect sizes: Yes; Combining different effect sizes without transformation: Yes; Observational DPs examined: Categorically (Highest vs lowest) | Model(s): Random effects; Additional analyses:; - Subgroup analysis and/or meta-regression; Publication bias: Not assessed; - No rationale for lack of assessment given
Kim, 2020 ^226^ | Observational studies | a priori DPs, a posteriori DPs (Other/NR method); - a priori and a posteriori analyzed: Separately | Transformations to combine different effect sizes: No/unclear/NR; Combining different effect sizes without transformation: Yes; Observational DPs examined: Categorically (Highest vs lowest) | Model(s): Random effects; Additional analyses:; - Subgroup analysis and/or meta-regression; Publication bias: Assessed; - Funnel plot, Egger’s test
Koelman, 2022 ^60^ | RCTs | Interventions | Transformations to combine different effect sizes: No/unclear/NR; Combining different effect sizes without transformation: No/unclear/NR | Model(s): Random effects; Additional analyses:; - Subgroup analysis and/or meta-regression; Publication bias: Assessed; - Contour-enhanced funnel plot, Trim-and-fill, Egger’s test
Kojima, 2018 ^277^ | Observational studies | a priori DPs | Transformations to combine different effect sizes: No/unclear/NR; Combining different effect sizes without transformation: No/unclear/NR; Observational DPs examined: Categorically (Highest vs lowest, Other) | Model(s): Fixed effect and random effects; Additional analyses:; - Subgroup analysis and/or meta-regression; Publication bias: Not assessed; - No rationale for lack of assessment given
Kotzakioulafi, 2023 ^169^ | Observational studies | a priori DPs | Transformations to combine different effect sizes: No/unclear/NR; Combining different effect sizes without transformation: Yes; Observational DPs examined: Categorically (Highest vs lowest) | Model(s): Fixed effect and random effects; Additional analyses:; - Subgroup analysis and/or meta-regression; Publication bias: Assessed; - Funnel plot, Egger’s test
Kunutsor, 2018 ^288^ | Observational studies | a priori DPs | Transformations to combine different effect sizes: No/unclear/NR; Combining different effect sizes without transformation: No/unclear/NR; Observational DPs examined: Continuously | Model(s): Random effects; Publication bias: Assessed; - Egger’s test
Lari, 2021 ^63^ | RCTs | Interventions | Transformations to combine different effect sizes: Yes; Combining different effect sizes without transformation: No/unclear/NR | Model(s): Random effects; Additional analyses:; - Subgroup analysis and/or meta-regression; Publication bias: Assessed; - Funnel plot, Egger’s test
Larruy-García, 2024 ^137^ | Observational studies | a priori DPs | Transformations to combine different effect sizes: No/unclear/NR; Combining different effect sizes without transformation: No/unclear/NR; Observational DPs examined: Categorically (Higher vs lower categories unspecified) | Model(s): Random effects; Additional analyses:; - Subgroup analysis and/or meta-regression; Publication bias: Not assessed; - No rationale for lack of assessment given
Lassale, 2019 ^269^ | Observational studies | a priori DPs | Transformations to combine different effect sizes: Yes; Combining different effect sizes without transformation: Yes; Observational DPs examined: Continuously, Categorically (Highest vs lowest, Other) | Model(s): Random effects; Additional analyses:; - Subgroup analysis and/or meta-regression; Publication bias: Assessed; - Contour-enhanced funnel plot, Egger’s test, Begg’s test
Lee, 2022 ^189^ | Observational studies | a priori DPs | Transformations to combine different effect sizes: No/unclear/NR; Combining different effect sizes without transformation: No/unclear/NR; Observational DPs examined: Categorically (Highest vs lowest) | Model(s): Random effects; Additional analyses:; - Subgroup analysis and/or meta-regression; Publication bias: Assessed; - Egger’s test
Lee, 2020 ^83^ | RCTs | Interventions | Transformations to combine different effect sizes: No/unclear/NR; Combining different effect sizes without transformation: No/unclear/NR | Model(s): Random effects; Additional analyses:; - Subgroup analysis and/or meta-regression; Publication bias: Not assessed; - No rationale for lack of assessment given
Lehert, 2015 ^124^ | RCTs | Interventions | Transformations to combine different effect sizes: No/unclear/NR; Combining different effect sizes without transformation: No/unclear/NR | Model(s): Fixed effect and random effects; Additional analyses:; - Network meta-analysis; Publication bias: Assessed; - Funnel plot
Li, 2020a ^76^ | RCTs | Interventions | Transformations to combine different effect sizes: Yes; Combining different effect sizes without transformation: No/unclear/NR | Model(s): Random effects; Publication bias: Assessed; - Funnel plot
Li, 2020b ^230^ | Observational studies | a priori DPs, a posteriori DPs (Other/NR method); - a priori and a posteriori analyzed: Together | Transformations to combine different effect sizes: No/unclear/NR; Combining different effect sizes without transformation: Yes; Observational DPs examined: Unclear/NR DP | Model(s): Random effects; Additional analyses:; - Subgroup analysis and/or meta-regression; Publication bias: Not assessed; - Not enough studies
Li, 2017 ^286^ | Observational studies | a priori DPs, a posteriori DPs (PCA/factor, Cluster, RRR); - a priori and a posteriori analyzed: Together | Transformations to combine different effect sizes: No/unclear/NR; Combining different effect sizes without transformation: Yes; Observational DPs examined: Categorically (Highest vs lowest) | Model(s): Random effects; Additional analyses:; - Subgroup analysis and/or meta-regression; Publication bias: Assessed; - Funnel plot, Egger’s test
Li, 2015 ^315^ | Observational studies | a posteriori DPs (PCA/factor) | Transformations to combine different effect sizes: No/unclear/NR; Combining different effect sizes without transformation: No/unclear/NR; Observational DPs examined: Categorically (Highest vs lowest) | Model(s): Random effects; Additional analyses:; - Subgroup analysis and/or meta-regression; Publication bias: Assessed; - Egger’s test, Begg’s test
Liang, 2022 ^41^ | RCTs | Interventions | Transformations to combine different effect sizes: Yes; Combining different effect sizes without transformation: No/unclear/NR | Model(s): Random effects; Additional analyses:; - Network meta-analysis; Publication bias: Assessed; - Funnel plot
Liao, 2024 ^7^ | RCTs | Interventions | Transformations to combine different effect sizes: No/unclear/NR; Combining different effect sizes without transformation: No/unclear/NR | Model(s): Random effects; Additional analyses:; - Network meta-analysis; Publication bias: Assessed; - Funnel plot
Lim, 2024 ^142^ | Observational studies | a priori DPs, a posteriori DPs (PCA/factor, Cluster); - a priori and a posteriori analyzed: Both together and separately | Transformations to combine different effect sizes: No/unclear/NR; Combining different effect sizes without transformation: No/unclear/NR; Observational DPs examined: Categorically (Highest vs lowest) | Model(s): Random effects; Additional analyses:; - Subgroup analysis and/or meta-regression; Publication bias: Assessed; - Contour-enhanced funnel plot, Egger’s test
Lin, 2023 ^34^ | RCTs | Interventions | Transformations to combine different effect sizes: No/unclear/NR; Combining different effect sizes without transformation: No/unclear/NR | Model(s): Fixed effect and random effects; Additional analyses:; - Subgroup analysis and/or meta-regression; Publication bias: Assessed; - Egger’s test, Begg’s test
Lin, 2020 ^80^ | RCTs, Observational studies; - Trials and observational studies analyzed: Separately | a priori DPs | Transformations to combine different effect sizes: No/unclear/NR; Combining different effect sizes without transformation: No/unclear/NR; Observational DPs examined: Categorically (Highest vs lowest) | Model(s): Random effects; Additional analyses:; - Subgroup analysis and/or meta-regression; Publication bias: Assessed; - Funnel plot, Trim-and-fill, Egger’s test
Liu, 2024 ^133^ | Observational studies | a priori DPs | Transformations to combine different effect sizes: No/unclear/NR; Combining different effect sizes without transformation: Yes; Observational DPs examined: Categorically (Highest vs lowest) | Model(s): Random effects; Additional analyses:; - Subgroup analysis and/or meta-regression; Publication bias: Assessed; - Funnel plot, Egger’s test, Egger’s linear regression plot, Begg’s test
Liu, 2023 ^157^ | Observational studies | a priori DPs, a posteriori DPs (PCA/factor, Other/NR method); - a priori and a posteriori analyzed: Together | Transformations to combine different effect sizes: No/unclear/NR; Combining different effect sizes without transformation: Yes; Observational DPs examined: Categorically (Highest vs lowest) | Model(s): Random effects; Additional analyses:; - Subgroup analysis and/or meta-regression; Publication bias: Assessed; - Egger’s test, Begg’s test
Liu, 2022 ^45^ | RCTs | Interventions | Transformations to combine different effect sizes: No/unclear/NR; Combining different effect sizes without transformation: No/unclear/NR | Model(s): Random effects; Publication bias: Not assessed; - Not enough studies
Liu, 2020 ^224^ | Observational studies | a priori DPs, a posteriori DPs (PCA/factor, RRR); - a priori and a posteriori analyzed: Both together and separately | Transformations to combine different effect sizes: No/unclear/NR; Combining different effect sizes without transformation: Yes; Observational DPs examined: Categorically (Highest vs lowest) | Model(s): Random effects; Additional analyses:; - Subgroup analysis and/or meta-regression; Publication bias: Assessed; - Funnel plot, Egger’s test
Liyanage, 2016 ^115^ | RCTs | Interventions | Transformations to combine different effect sizes: No/unclear/NR; Combining different effect sizes without transformation: No/unclear/NR | Model(s): Fixed effect; Additional analyses:; - Subgroup analysis and/or meta-regression; Publication bias: Not assessed; - Not enough studies
Lopez, 2019 ^98^ | RCTs | Interventions | Transformations to combine different effect sizes: Yes; Combining different effect sizes without transformation: No/unclear/NR | Model(s): Random effects; Additional analyses:; - Subgroup analysis and/or meta-regression; Publication bias: Assessed; - Funnel plot, Trim-and-fill, Egger’s test
López-Gil, 2024a ^15^ | RCTs | Interventions | Transformations to combine different effect sizes: No/unclear/NR; Combining different effect sizes without transformation: No/unclear/NR | Model(s): Random effects; Publication bias: Assessed; - Doi plot, LFK index
López-Gil, 2024b ^144^ | Observational studies | a priori DPs | Transformations to combine different effect sizes: Yes; Combining different effect sizes without transformation: No/unclear/NR; Observational DPs examined: Continuously, Categorically (Higher vs lower categories unspecified) | Model(s): Random effects; Additional analyses:; - Subgroup analysis and/or meta-regression; Publication bias: Assessed; - Doi plot, LFK index
López-Gil, 2023 ^35^ | RCTs | Interventions | Transformations to combine different effect sizes: Yes; Combining different effect sizes without transformation: No/unclear/NR | Model(s): Random effects; Additional analyses:; - Subgroup analysis and/or meta-regression; Publication bias: Assessed; - Doi plot, LFK index
Lotfi, 2022 ^209^ | Observational studies | a priori DPs | Transformations to combine different effect sizes: Yes; Combining different effect sizes without transformation: No/unclear/NR; Observational DPs examined: Categorically (Highest vs lowest, Other) | Model(s): Random effects; Additional analyses:; - Subgroup analysis and/or meta-regression; - Dose-response meta-analysis; Publication bias: Assessed; - Funnel plot, Begg’s test
Loughrey, 2017 ^111^ | RCTs, Observational studies; - Trials and observational studies analyzed: Separately | Interventions, a priori DPs | Transformations to combine different effect sizes: Yes; Combining different effect sizes without transformation: No/unclear/NR; Observational DPs examined: Continuously | Model(s): Random effects; Additional analyses:; - Subgroup analysis and/or meta-regression; Publication bias: Assessed; - Funnel plot, Egger’s test
Lu, 2017 ^291^ | Observational studies | a posteriori DPs (PCA/factor) | Transformations to combine different effect sizes: No/unclear/NR; Combining different effect sizes without transformation: No/unclear/NR; Observational DPs examined: Categorically (Highest vs lowest) | Model(s): Random effects; Additional analyses:; - Subgroup analysis and/or meta-regression; Publication bias: Assessed; - Funnel plot, Begg’s test
Luo, 2024 ^145^ | Observational studies | a priori DPs, a posteriori DPs (PCA/factor); - a priori and a posteriori analyzed: Separately | Transformations to combine different effect sizes: Yes; Combining different effect sizes without transformation: Yes; Observational DPs examined: Categorically (Highest vs lowest) | Model(s): Random effects; Additional analyses:; - Subgroup analysis and/or meta-regression; Publication bias: Assessed; - Funnel plot, Egger’s test
Maghsoudi, 2016 ^312^ | Observational studies | a posteriori DPs (PCA/factor) | Transformations to combine different effect sizes: No/unclear/NR; Combining different effect sizes without transformation: No/unclear/NR; Observational DPs examined: Categorically (Highest vs lowest) | Model(s): Random effects; Additional analyses:; - Subgroup analysis and/or metaregression; Publication bias: Assessed; - Funnel plot, Egger’s test, Begg’s test
Malmir, 2018 ^285^ | Observational studies | a priori DPs | Transformations to combine different effect sizes: No/unclear/NR; Combining different effect sizes without transformation: No/unclear/NR; Observational DPs examined: Continuously, Categorically (Highest vs lowest) | Model(s): Random effects; Additional analyses:; - Subgroup analysis and/or meta-regression; - Dose-response meta-analysis; Publication bias: Assessed; - Egger’s test, Begg’s test
Manheimer, 2015 ^125^ | RCTs | Interventions | Transformations to combine different effect sizes: No/unclear/NR; Combining different effect sizes without transformation: No/unclear/NR | Model(s): Random effects; Additional analyses:; - Subgroup analysis and/or meta-regression; Publication bias: Not assessed; - No rationale for lack of assessment given
Martínez-González, 2017 ^109^ | RCTs, Observational studies; - Trials and observational studies analyzed: Together | Interventions, a priori DPs | Transformations to combine different effect sizes: No/unclear/NR; Combining different effect sizes without transformation: Yes; Observational DPs examined: Continuously | Model(s): Random effects; Publication bias: Not assessed; - No rationale for lack of assessment given
Massara, 2022 ^49^ | RCTs, Observational studies; - Trials and observational studies analyzed: Separately | Interventions, a priori DPs | Transformations to combine different effect sizes: No/unclear/NR; Combining different effect sizes without transformation: Yes; Observational DPs examined: Categorically (Highest vs lowest) | Model(s): Fixed effect and random effects; Additional analyses:; - Dose-response meta-analysis; Publication bias: Not assessed; - Not enough studies
Matison, 2021 ^211^ | Observational studies | a priori DPs, a posteriori DPs (PCA/factor); - a priori and a posteriori analyzed: Together | Transformations to combine different effect sizes: Yes; Combining different effect sizes without transformation: Yes; Observational DPs examined: Categorically (Highest vs lowest) | Model(s): Random effects; Publication bias: Assessed; - Funnel plot, Egger’s test
Mayr, 2018 ^107^ | RCTs | Interventions | Transformations to combine different effect sizes: No/unclear/NR; Combining different effect sizes without transformation: No/unclear/NR | Model(s): Random effects; Publication bias: Not assessed; - No rationale for lack of assessment given
McBean, 2022 ^59^ | RCTs | Interventions | Transformations to combine different effect sizes: No/unclear/NR; Combining different effect sizes without transformation: No/unclear/NR | Model(s): Random effects; Additional analyses:; - Subgroup analysis and/or meta-regression; Publication bias: Assessed; - Funnel plot
McEvoy, 2019 ^96^ | RCTs | Interventions | Transformations to combine different effect sizes: No/unclear/NR; Combining different effect sizes without transformation: No/unclear/NR | Model(s): Random effects; Publication bias: Assessed; - Funnel plot, Egger’s test, Begg’s test
Milajerdi, 2018 ^267^ | Observational studies | a priori DPs | Transformations to combine different effect sizes: No/unclear/NR; Combining different effect sizes without transformation: No/unclear/NR; Observational DPs examined: Categorically (Highest vs lowest) | Model(s): Random effects; Additional analyses:; - Subgroup analysis and/or meta-regression; Publication bias: Assessed; - Egger’s test
Moazzen, 2021 ^228^ | Observational studies | a priori DPs | Transformations to combine different effect sizes: Yes; Combining different effect sizes without transformation: No/unclear/NR; Observational DPs examined: Categorically (Highest vs lowest) | Model(s): Random effects; Additional analyses:; - Subgroup analysis and/or meta-regression; Publication bias: Assessed; - Funnel plot, Trim-and-fill, Egger’s test
Moazzen, 2020 ^229^ | Observational studies | a priori DPs | Transformations to combine different effect sizes: Yes; Combining different effect sizes without transformation: Yes; Observational DPs examined: Categorically (Highest vs lowest) | Model(s): Random effects; Additional analyses:; - Subgroup analysis and/or meta-regression; Publication bias: Assessed; - Funnel plot, Egger’s test
Mohseni, 2020 ^247^ | Observational studies | a priori DPs | Transformations to combine different effect sizes: No/unclear/NR; Combining different effect sizes without transformation: No/unclear/NR; Observational DPs examined: Categorically (Highest vs lowest, Other) | Model(s): Fixed effect and random effects; Additional analyses:; - Subgroup analysis and/or meta-regression; Publication bias: Assessed; - Egger’s test, Begg’s test
Molendijk, 2018 ^281^ | Observational studies | a priori DPs, a posteriori DPs (PCA/factor); - a priori and a posteriori analyzed: Both together and separately | Transformations to combine different effect sizes: No/unclear/NR; Combining different effect sizes without transformation: No/unclear/NR; Observational DPs examined: Categorically (Highest vs lowest, Other) | Model(s): Random effects; Additional analyses:; - Subgroup analysis and/or meta-regression; - Dose-response meta-analysis; Publication bias: Assessed; - Egger’s test
Moradi, 2020 ^218^ | Observational studies | a priori DPs, a posteriori DPs (Other/NR method); - a priori and a posteriori analyzed: Together | Transformations to combine different effect sizes: Yes; Combining different effect sizes without transformation: Yes; Observational DPs examined: Continuously, Categorically (Highest vs lowest, Other) | Model(s): Random effects; Publication bias: Assessed; - Egger’s test, Egger’s linear regression plot
Moravejolahkami, 2024 ^10^ | RCTs | Interventions | Transformations to combine different effect sizes: Yes; Combining different effect sizes without transformation: No/unclear/NR | Model(s): Random effects; Publication bias: Assessed; - Egger’s test, Begg’s test
Morze, 2020 ^223^ | Observational studies | a priori DPs | Transformations to combine different effect sizes: No/unclear/NR; Combining different effect sizes without transformation: Yes; Observational DPs examined: Categorically (Highest vs lowest) | Model(s): Fixed effect and random effects; Additional analyses:; - Subgroup analysis and/or meta-regression; Publication bias: Assessed; - Funnel plot, Egger’s test
Morze, 2021 ^227^ | Observational studies | a priori DPs, a posteriori DPs (PCA/factor); - a priori and a posteriori analyzed: Together | Transformations to combine different effect sizes: No/unclear/NR; Combining different effect sizes without transformation: Yes; Observational DPs examined: Categorically (Highest vs lowest) | Model(s): Random effects; Additional analyses:; - Subgroup analysis and/or meta-regression; Publication bias: Assessed; - Funnel plot, Egger’s test
Moslehi, 2022 ^192^ | Observational studies | a posteriori DPs (PCA/factor) | Transformations to combine different effect sizes: No/unclear/NR; Combining different effect sizes without transformation: No/unclear/NR; Observational DPs examined: Categorically (Highest vs lowest) | Model(s): Random effects; Publication bias: Assessed; - Egger’s test
Mozaffari, 2020 ^242^ | Observational studies | a priori DPs | Transformations to combine different effect sizes: No/unclear/NR; Combining different effect sizes without transformation: Yes; Observational DPs examined: Categorically (Highest vs lowest) | Model(s): Random effects; Additional analyses:; - Subgroup analysis and/or meta-regression; Publication bias: Assessed; - Funnel plot, Egger’s test
Mu, 2017 ^284^ | Observational studies | a posteriori DPs (PCA/factor, RRR) | Transformations to combine different effect sizes: No/unclear/NR; Combining different effect sizes without transformation: No/unclear/NR; Observational DPs examined: Categorically (Highest vs lowest) | Model(s): Fixed effect and random effects; Additional analyses:; - Subgroup analysis and/or meta-regression; Publication bias: Assessed; - Funnel plot, Begg’s test
Ndanuko, 2016 ^121^ | RCTs | Interventions | Transformations to combine different effect sizes: No/unclear/NR; Combining different effect sizes without transformation: No/unclear/NR | Model(s): Random effects; Additional analyses:; - Subgroup analysis and/or meta-regression; Publication bias: Not assessed; - No rationale for lack of assessment given
Neale, 2016 ^117^ | RCTs | Interventions | Transformations to combine different effect sizes: No/unclear/NR; Combining different effect sizes without transformation: Yes | Model(s): Random effects; Additional analyses:; - Subgroup analysis and/or meta-regression; Publication bias: Assessed; - Funnel plot, Egger’s test
Neuenschwander, 2019 ^93^ | RCTs | Interventions | Transformations to combine different effect sizes: No/unclear/NR; Combining different effect sizes without transformation: No/unclear/NR | Model(s): Random effects; Additional analyses:; - Subgroup analysis and/or meta-regression; - Network meta-analysis; Publication bias: Assessed; - Comparison-adjusted funnel plot
Nguyen, 2021 ^213^ | Observational studies | a posteriori DPs (PCA/factor, Other/NR method) | Transformations to combine different effect sizes: No/unclear/NR; Combining different effect sizes without transformation: No/unclear/NR; Observational DPs examined: Categorically (Highest vs lowest) | Model(s): Random effects; Publication bias: Not assessed; - No rationale for lack of assessment given
Nikparast, 2024 ^148^ | Observational studies | a priori DPs | Transformations to combine different effect sizes: No/unclear/NR; Combining different effect sizes without transformation: No/unclear/NR; Observational DPs examined: Categorically (Highest vs lowest) | Model(s): Random effects; Additional analyses:; - Subgroup analysis and/or meta-regression; - Dose-response meta-analysis; Publication bias: Assessed; - Funnel plot, Egger’s test, Begg’s test
Nikparast, 2023 ^154^ | Observational studies | a priori DPs | Transformations to combine different effect sizes: No/unclear/NR; Combining different effect sizes without transformation: No/unclear/NR; Observational DPs examined: Categorically (Highest vs lowest) | Model(s): Random effects; Additional analyses:; - Subgroup analysis and/or meta-regression; - Dose-response meta-analysis; Publication bias: Assessed; - Funnel plot, Egger’s test, Begg’s test
Nissensohn, 2016 ^123^ | RCTs | Interventions | Transformations to combine different effect sizes: No/unclear/NR; Combining different effect sizes without transformation: No/unclear/NR | Model(s): Random effects; Publication bias: Not assessed; - No rationale for lack of assessment given
Noori, 2022 ^197^ | Observational studies | a priori DPs | Transformations to combine different effect sizes: No/unclear/NR; Combining different effect sizes without transformation: No/unclear/NR; Observational DPs examined: Continuously | Model(s): Random effects; Additional analyses:; - Subgroup analysis and/or meta-regression; - Dose-response meta-analysis; Publication bias: Not assessed; - Not enough studies
Nucci, 2024 ^151^ | Observational studies | a priori DPs | Transformations to combine different effect sizes: No/unclear/NR; Combining different effect sizes without transformation: No/unclear/NR; Observational DPs examined: Unclear/NR DP | Model(s): Fixed effect and random effects; Additional analyses:; - Subgroup analysis and/or meta-regression; Publication bias: Assessed; - Funnel plot, Trim-and-fill, Egger’s test
Nucci, 2023 ^179^ | Observational studies | a priori DPs | Transformations to combine different effect sizes: No/unclear/NR; Combining different effect sizes without transformation: No/unclear/NR; Observational DPs examined: Categorically (Highest vs lowest) | Model(s): Fixed effect and random effects; Additional analyses:; - Subgroup analysis and/or meta-regression; Publication bias: Assessed; - Funnel plot, Trim-and-fill, Egger’s test
Onvani, 2017 ^299^ | Observational studies | a priori DPs | Transformations to combine different effect sizes: No/unclear/NR; Combining different effect sizes without transformation: Yes; Observational DPs examined: Categorically (Highest vs lowest) | Model(s): Random effects; Additional analyses:; - Subgroup analysis and/or meta-regression; Publication bias: Assessed; - Funnel plot, Egger’s test, Begg’s test
Orlando, 2022 ^210^ | Observational studies | a priori DPs, a posteriori DPs (PCA/factor, Other/NR method); - a priori and a posteriori analyzed: Together | Transformations to combine different effect sizes: Yes; Combining different effect sizes without transformation: No/unclear/NR; Observational DPs examined: Categorically (Highest vs lowest) | Model(s): Random effects; Additional analyses:; - Subgroup analysis and/or meta-regression; Publication bias: Assessed; - Funnel plot, Trim-and-fill, Egger’s test
Palmer, 2017 ^112^ | RCTs | Interventions | Transformations to combine different effect sizes: No/unclear/NR; Combining different effect sizes without transformation: No/unclear/NR | Model(s): Random effects; Publication bias: Not assessed; - Not enough studies
Pan, 2019 ^103^ | RCTs | Interventions | Transformations to combine different effect sizes: No/unclear/NR; Combining different effect sizes without transformation: No/unclear/NR | Model(s): Random effects; Additional analyses:; - Network meta-analysis; Publication bias: Not assessed; - No rationale for lack of assessment given
Panahande, 2019 ^266^ | Observational studies | a priori DPs | Transformations to combine different effect sizes: No/unclear/NR; Combining different effect sizes without transformation: No/unclear/NR; Observational DPs examined: Categorically (Highest vs lowest) | Model(s): Random effects; Additional analyses:; - Subgroup analysis and/or meta-regression; - Dose-response meta-analysis; Publication bias: Assessed; - Egger’s test
Pant, 2023 ^177^ | Observational studies | a priori DPs | Transformations to combine different effect sizes: No/unclear/NR; Combining different effect sizes without transformation: Yes; Observational DPs examined: Categorically (Highest vs lowest) | Model(s): Random effects; Additional analyses:; - Subgroup analysis and/or meta-regression; Publication bias: Assessed; - Funnel plot, Trim-and-fill, Egger’s test, Begg’s test
Papadaki, 2024 ^147^ | Observational studies | a priori DPs | Transformations to combine different effect sizes: No/unclear/NR; Combining different effect sizes without transformation: Yes; Observational DPs examined: Continuously, Categorically (Highest vs lowest) | Model(s): Random effects; Additional analyses:; - Subgroup analysis and/or meta-regression; Publication bias: Assessed; - Funnel plot
Papadaki, 2020 ^77^ | RCTs, NRCTs; - RCTs and NRCTs analyzed: Both together and separately | Interventions | Transformations to combine different effect sizes: Yes; Combining different effect sizes without transformation: No/unclear/NR | Model(s): Random effects; Additional analyses:; - Subgroup analysis and/or meta-regression; Publication bias: Assessed; - Funnel plot, Egger’s test
Parvizian, 2020 ^231^ | Observational studies | a priori DPs, a posteriori DPs (PCA/factor); - a priori and a posteriori analyzed: Both together and separately | Transformations to combine different effect sizes: No/unclear/NR; Combining different effect sizes without transformation: No/unclear/NR; Observational DPs examined: Categorically (Highest vs lowest) | Model(s): Random effects; Publication bias: Not assessed; - Not enough studies
Picasso, 2019 ^104^ | RCTs, Observational studies; - Trials and observational studies analyzed: Both together and separately | Interventions | Transformations to combine different effect sizes: No/unclear/NR; Combining different effect sizes without transformation: No/unclear/NR; Observational DPs examined: Categorically (Higher vs lower categories unspecified) | Model(s): Random effects; Additional analyses:; - Subgroup analysis and/or meta-regression; Publication bias: Assessed; - Funnel plot, Egger’s test
Pirouzeh, 2020 ^73^ | RCTs | Interventions | Transformations to combine different effect sizes: No/unclear/NR; Combining different effect sizes without transformation: No/unclear/NR | Model(s): Random effects; Publication bias: Assessed; - Funnel plot
Pourmasoumi, 2016 ^292^ | Observational studies | a priori DPs | Transformations to combine different effect sizes: No/unclear/NR; Combining different effect sizes without transformation: Yes; Observational DPs examined: Categorically (Highest vs lowest) | Model(s): Fixed effect; Additional analyses:; - Subgroup analysis and/or meta-regression; Publication bias: Assessed; - Funnel plot, Egger’s test
Pourrajab, 2024 ^4^ | RCTs | Interventions | Transformations to combine different effect sizes: No/unclear/NR; Combining different effect sizes without transformation: No/unclear/NR | Model(s): Random effects; Additional analyses:; - Subgroup analysis and/or meta-regression; Publication bias: Assessed; - Funnel plot, Trim-and-fill, Egger’s test, Fail-safe N
Poursalehi, 2023 ^178^ | Observational studies | a priori DPs | Transformations to combine different effect sizes: No/unclear/NR; Combining different effect sizes without transformation: Yes; Observational DPs examined: Continuously, Categorically (Highest vs lowest) | Model(s): Random effects; Additional analyses:; - Subgroup analysis and/or meta-regression; - Dose-response meta-analysis; Publication bias: Assessed; - Egger’s test, Begg’s test
Qian, 2019 ^248^ | Observational studies | a priori DPs, a posteriori DPs (PCA/factor); - a priori and a posteriori analyzed: Together | Transformations to combine different effect sizes: No/unclear/NR; Combining different effect sizes without transformation: No/unclear/NR; Observational DPs examined: Categorically (Highest vs lowest) | Model(s): Fixed effect and random effects; Additional analyses:; - Subgroup analysis and/or meta-regression; - Dose-response meta-analysis; Publication bias: Assessed; - Funnel plot, Trim-and-fill, Egger’s test, Begg’s test
Quan, 2024 ^146^ | Observational studies | a priori DPs | Transformations to combine different effect sizes: Yes; Combining different effect sizes without transformation: No/unclear/NR; Observational DPs examined: Categorically (Highest vs lowest) | Model(s): Random effects; Additional analyses:; - Subgroup analysis and/or meta-regression; - Dose-response meta-analysis; Publication bias: Assessed; - Funnel plot, Egger’s test, Begg’s test
Quan, 2021 ^216^ | Observational studies | a posteriori DPs (PCA/factor) | Transformations to combine different effect sizes: No/unclear/NR; Combining different effect sizes without transformation: Yes; Observational DPs examined: Categorically (Highest vs lowest) | Model(s): Random effects; Additional analyses:; - Subgroup analysis and/or meta-regression; Publication bias: Assessed; - Funnel plot
Quek, 2021 ^203^ | Observational studies | a priori DPs | Transformations to combine different effect sizes: No/unclear/NR; Combining different effect sizes without transformation: No/unclear/NR; Observational DPs examined: Categorically (Highest vs lowest) | Model(s): Random effects; Additional analyses:; - Subgroup analysis and/or meta-regression; Publication bias: Assessed; - Funnel plot
Rahmati, 2023 ^187^ | Observational studies | a priori DPs | Transformations to combine different effect sizes: No/unclear/NR; Combining different effect sizes without transformation: No/unclear/NR; Observational DPs examined: Categorically (Higher vs lower categories unspecified, Other) | Model(s): Random effects; Additional analyses:; - Subgroup analysis and/or meta-regression; Publication bias: Assessed; - Funnel plot, Egger’s test, Begg’s test
Ramezani-Jolfaie, 2019 ^102^ | RCTs | Interventions | Transformations to combine different effect sizes: No/unclear/NR; Combining different effect sizes without transformation: No/unclear/NR | Model(s): Random effects; Additional analyses:; - Subgroup analysis and/or meta-regression; Publication bias: Assessed; - Funnel plot, Egger’s test, Begg’s test
Ramezani-Jolfaie, 2020 ^91^ | RCTs | Interventions | Transformations to combine different effect sizes: No/unclear/NR; Combining different effect sizes without transformation: No/unclear/NR | Model(s): Random effects; Additional analyses:; - Subgroup analysis and/or meta-regression; Publication bias: Assessed; - Egger’s test, Begg’s test
Rashidi Pour Fard, 2019 ^254^ | Observational studies | a priori DPs, a posteriori DPs (PCA/factor, Cluster, RRR); - a priori and a posteriori analyzed: Both together and separately | Transformations to combine different effect sizes: Yes; Combining different effect sizes without transformation: Yes; Observational DPs examined: Categorically (Highest vs lowest) | Model(s): Fixed effect and random effects; Additional analyses:; - Subgroup analysis and/or meta-regression; Publication bias: Assessed; - Funnel plot, Trim-and-fill, Egger’s test
Rees, 2021 ^70^ | RCTs | Interventions | Transformations to combine different effect sizes: No/unclear/NR; Combining different effect sizes without transformation: No/unclear/NR | Model(s): Random effects; Publication bias: Not assessed; - Not enough studies
Rees, 2019 ^97^ | RCTs | Interventions | Transformations to combine different effect sizes: No/unclear/NR; Combining different effect sizes without transformation: No/unclear/NR | Model(s): Random effects; Publication bias: Not assessed; - Not enough studies
Rodríguez-Monforte, 2015 ^309^ | Observational studies | a posteriori DPs (PCA/factor, Cluster) | Transformations to combine different effect sizes: No/unclear/NR; Combining different effect sizes without transformation: No/unclear/NR; Observational DPs examined: Categorically (Highest vs lowest) | Model(s): Random effects; Additional analyses:; - Subgroup analysis and/or meta-regression; Publication bias: Assessed; - Funnel plot, Egger’s test
Rodríguez-Monforte, 2017 ^300^ | Observational studies | a posteriori DPs (PCA/factor, Cluster) | Transformations to combine different effect sizes: No/unclear/NR; Combining different effect sizes without transformation: No/unclear/NR; Observational DPs examined: Categorically (Highest vs lowest) | Model(s): Random effects; Additional analyses:; - Subgroup analysis and/or meta-regression; Publication bias: Assessed; - Funnel plot
Rosato, 2019 ^279^ | Observational studies | a priori DPs | Transformations to combine different effect sizes: No/unclear/NR; Combining different effect sizes without transformation: Yes; Observational DPs examined: Continuously, Categorically (Highest vs lowest) | Model(s): Random effects; Additional analyses:; - Subgroup analysis and/or meta-regression; - Dose-response meta-analysis; Publication bias: Assessed; - Egger’s test, Begg’s test
Sahebkar, 2023 ^31^ | RCTs, NRCTs; - RCTs and NRCTs analyzed: Together | Interventions | Transformations to combine different effect sizes: No/unclear/NR; Combining different effect sizes without transformation: No/unclear/NR | Model(s): Random effects; Additional analyses:; - Subgroup analysis and/or meta-regression; Publication bias: Assessed; - Trim-and-fill, Egger’s test
Sakhaei, 2019 ^101^ | RCTs | Interventions | Transformations to combine different effect sizes: No/unclear/NR; Combining different effect sizes without transformation: No/unclear/NR | Model(s): Random effects; Additional analyses:; - Subgroup analysis and/or meta-regression; Publication bias: Assessed; - Funnel plot, Egger’s test, Begg’s test
Sampathkumar, 2023 ^158^ | Observational studies | a priori DPs | Transformations to combine different effect sizes: No/unclear/NR; Combining different effect sizes without transformation: No/unclear/NR; Observational DPs examined: Categorically (Higher vs lower categories unspecified) | Model(s): Random effects; Publication bias: Assessed; - Funnel plot, Egger’s test
Sánchez-Rosales, 2022 ^46^ | RCTs | Interventions | Transformations to combine different effect sizes: Yes; Combining different effect sizes without transformation: No/unclear/NR | Model(s): Random effects; Additional analyses:; - Subgroup analysis and/or meta-regression; Publication bias: Assessed; - Funnel plot
Sangouni, 2022 ^64^ | RCTs | Interventions | Transformations to combine different effect sizes: No/unclear/NR; Combining different effect sizes without transformation: No/unclear/NR | Model(s): Random effects; Additional analyses:; - Subgroup analysis and/or meta-regression; Publication bias: Assessed; - Egger’s test, Begg’s test
Sarsangi, 2022 ^195^ | Observational studies | a priori DPs | Transformations to combine different effect sizes: No/unclear/NR; Combining different effect sizes without transformation: Yes; Observational DPs examined: Categorically (Highest vs lowest) | Model(s): Random effects; Additional analyses:; - Subgroup analysis and/or meta-regression; - Dose-response meta-analysis; Publication bias: Assessed; - Egger’s test
Schönenberger, 2021 ^57^ | RCTs | Interventions | Transformations to combine different effect sizes: No/unclear/NR; Combining different effect sizes without transformation: No/unclear/NR | Model(s): Random effects; Additional analyses:; - Subgroup analysis and/or meta-regression; Publication bias: Assessed; - Funnel plot
Schwedhelm, 2016 ^295^ | Observational studies | a priori DPs, a posteriori DPs (PCA/factor); - a priori and a posteriori analyzed: Separately | Transformations to combine different effect sizes: No/unclear/NR; Combining different effect sizes without transformation: No/unclear/NR; Observational DPs examined: Categorically (Highest vs lowest) | Model(s): Random effects; Additional analyses:; - Subgroup analysis and/or meta-regression; Publication bias: Not assessed; - No rationale for lack of assessment given
Schwingshackl, 2019 ^106^ | RCTs | Interventions | Transformations to combine different effect sizes: No/unclear/NR; Combining different effect sizes without transformation: Yes | Model(s): Random effects; Additional analyses:; - Subgroup analysis and/or meta-regression; - Network meta-analysis; Publication bias: Assessed; - Comparison-adjusted funnel plot
Schwingshackl, 2018a ^108^ | RCTs | Interventions | Transformations to combine different effect sizes: No/unclear/NR; Combining different effect sizes without transformation: No/unclear/NR | Model(s): Random effects; Additional analyses:; - Subgroup analysis and/or meta-regression; - Network meta-analysis; Publication bias: Assessed; - Funnel plot, Comparison-adjusted funnel plot
Schwingshackl, 2018b ^280^ | Observational studies | a priori DPs | Transformations to combine different effect sizes: No/unclear/NR; Combining different effect sizes without transformation: Yes; Observational DPs examined: Categorically (Highest vs lowest) | Model(s): Fixed effect and random effects; Additional analyses:; - Subgroup analysis and/or meta-regression; Publication bias: Assessed; - Funnel plot, Egger’s test
Schwingshackl, 2017 ^110^ | RCTs, Observational studies; - Trials and observational studies analyzed: Separately | a priori DPs, a posteriori DPs (PCA/factor); - a priori and a posteriori analyzed: Together | Transformations to combine different effect sizes: No/unclear/NR; Combining different effect sizes without transformation: Yes; Observational DPs examined: Continuously, Categorically (Highest vs lowest, Other) | Model(s): Random effects; Additional analyses:; - Subgroup analysis and/or meta-regression; Publication bias: Assessed; - Funnel plot, Egger’s test
Schwingshackl, 2015a ^308^ | Observational studies | a priori DPs, a posteriori DPs (PCA/factor); - a priori and a posteriori analyzed: Together | Transformations to combine different effect sizes: No/unclear/NR; Combining different effect sizes without transformation: Yes; Observational DPs examined: Continuously, Categorically (Highest vs lowest) | Model(s): Random effects; Additional analyses:; - Subgroup analysis and/or meta-regression; Publication bias: Assessed; - Funnel plot, Egger’s test
Schwingshackl, 2015b ^314^ | Observational studies | a priori DPs | Transformations to combine different effect sizes: No/unclear/NR; Combining different effect sizes without transformation: Yes; Observational DPs examined: Categorically (Highest vs lowest) | Model(s): Random effects; Additional analyses:; - Subgroup analysis and/or meta-regression; Publication bias: Assessed; - Funnel plot, Egger’s test
Sebastian, 2024 ^19^ | RCTs | Interventions | Transformations to combine different effect sizes: Yes; Combining different effect sizes without transformation: No/unclear/NR | Model(s): Random effects; Publication bias: Not assessed; - Not enough studies
Shab-Bidar, 2018 ^276^ | Observational studies | a posteriori DPs (PCA/factor) | Transformations to combine different effect sizes: No/unclear/NR; Combining different effect sizes without transformation: Yes; Observational DPs examined: Categorically (Highest vs lowest) | Model(s): Random effects; Publication bias: Assessed; - Funnel plot, Egger’s test
Shafiei, 2019 ^261^ | Observational studies | a priori DPs | Transformations to combine different effect sizes: No/unclear/NR; Combining different effect sizes without transformation: No/unclear/NR; Observational DPs examined: Categorically (Highest vs lowest) | Model(s): Random effects; Publication bias: Assessed; - Egger’s test
Shahid, 2024 ^12^ | RCTs | Interventions | Transformations to combine different effect sizes: No/unclear/NR; Combining different effect sizes without transformation: No/unclear/NR | Model(s): Random effects; Additional analyses:; - Subgroup analysis and/or meta-regression; - Network meta-analysis; Publication bias: Assessed; - Funnel plot, Trim-and-fill, Egger’s test
Shang, 2020 ^81^ | RCTs | Interventions | Transformations to combine different effect sizes: No/unclear/NR; Combining different effect sizes without transformation: No/unclear/NR | Model(s): Random effects; Additional analyses:; - Subgroup analysis and/or meta-regression; Publication bias: Assessed; - Funnel plot, Egger’s test
Shannon, 2020 ^88^ | RCTs | Interventions | Transformations to combine different effect sizes: Yes; Combining different effect sizes without transformation: No/unclear/NR | Model(s): Random effects; Additional analyses:; - Subgroup analysis and/or meta-regression; Publication bias: Assessed; - Funnel plot, Egger’s test
Shareghfarid, 2020 ^235^ | Observational studies | a posteriori DPs (PCA/factor) | Transformations to combine different effect sizes: No/unclear/NR; Combining different effect sizes without transformation: Yes; Observational DPs examined: Categorically (Highest vs lowest) | Model(s): Random effects; Publication bias: Assessed; - Funnel plot, Egger’s test, Begg’s test
Shin, 2023 ^180^ | Observational studies | a priori DPs, a posteriori DPs (PCA/factor, Other/NR method); - a priori and a posteriori analyzed: Separately | Transformations to combine different effect sizes: No/unclear/NR; Combining different effect sizes without transformation: No/unclear/NR; Observational DPs examined: Categorically (Highest vs lowest) | Model(s): Random effects; Additional analyses:; - Subgroup analysis and/or meta-regression; Publication bias: Assessed; - Funnel plot, Egger’s test, Begg’s test
Shirota, 2022 ^193^ | Observational studies | a priori DPs, a posteriori DPs (PCA/factor); - a priori and a posteriori analyzed: Together | Transformations to combine different effect sizes: No/unclear/NR; Combining different effect sizes without transformation: Yes; Observational DPs examined: Categorically (Highest vs lowest) | Model(s): Random effects; Publication bias: Assessed; - Egger’s test
Shu, 2024 ^143^ | Observational studies | a priori DPs, a posteriori DPs (Other/NR method); - a priori and a posteriori analyzed: Separately | Transformations to combine different effect sizes: No/unclear/NR; Combining different effect sizes without transformation: Yes; Observational DPs examined: Categorically (Highest vs lowest) | Model(s): Random effects; Additional analyses:; - Subgroup analysis and/or meta-regression; Publication bias: Assessed; - Funnel plot, Egger’s test
Shu, 2022a ^182^ | Observational studies | a priori DPs | Transformations to combine different effect sizes: No/unclear/NR; Combining different effect sizes without transformation: No/unclear/NR; Observational DPs examined: Categorically (Highest vs lowest) | Model(s): Fixed effect and random effects; Additional analyses:; - Subgroup analysis and/or meta-regression; Publication bias: Assessed; - Funnel plot, Begg’s test
Shu, 2022b ^183^ | Observational studies | a priori DPs, a posteriori DPs (Other/NR method); - a priori and a posteriori analyzed: Both together and separately | Transformations to combine different effect sizes: No/unclear/NR; Combining different effect sizes without transformation: Yes; Observational DPs examined: Categorically (Highest vs lowest) | Model(s): Fixed effect and random effects; Additional analyses:; - Subgroup analysis and/or meta-regression; Publication bias: Assessed; - Funnel plot, Trim-and-fill, Egger’s test, Begg’s test
Si, 2017 ^304^ | Observational studies | a posteriori DPs (PCA/factor) | Transformations to combine different effect sizes: No/unclear/NR; Combining different effect sizes without transformation: No/unclear/NR; Observational DPs examined: Categorically (Highest vs lowest) | Model(s): Random effects; Additional analyses:; - Subgroup analysis and/or meta-regression; Publication bias: Assessed; - Funnel plot, Begg’s test
Siervo, 2015 ^127^ | RCTs | Interventions | Transformations to combine different effect sizes: Yes; Combining different effect sizes without transformation: No/unclear/NR | Model(s): Random effects; Additional analyses:; - Subgroup analysis and/or meta-regression; Publication bias: Assessed; - Funnel plot, Egger’s test
Silva, 2018 ^273^ | Observational studies | a priori DPs | Transformations to combine different effect sizes: No/unclear/NR; Combining different effect sizes without transformation: No/unclear/NR; Observational DPs examined: Categorically (Highest vs lowest) | Model(s): Random effects; Publication bias: Not assessed; - No rationale for lack of assessment given
Siqueira, 2022 ^190^ | Observational studies | a priori DPs | Transformations to combine different effect sizes: No/unclear/NR; Combining different effect sizes without transformation: No/unclear/NR; Observational DPs examined: Categorically (Highest vs lowest) | Model(s): Random effects; Publication bias: Not assessed; - Not enough studies
Snetselaar, 2023 ^48^ | RCTs | Interventions | Transformations to combine different effect sizes: No/unclear/NR; Combining different effect sizes without transformation: Yes | Model(s): Random effects; Additional analyses:; - Network meta-analysis; Publication bias: Assessed; - Funnel plot, Egger’s test
Sohouli, 2022 ^72^ | RCTs | Interventions | Transformations to combine different effect sizes: Yes; Combining different effect sizes without transformation: No/unclear/NR | Model(s): Random effects; Additional analyses:; - Subgroup analysis and/or meta-regression; Publication bias: Assessed; - Funnel plot, Egger’s test
Soltani, 2020 ^234^ | Observational studies | a priori DPs | Transformations to combine different effect sizes: No/unclear/NR; Combining different effect sizes without transformation: Yes; Observational DPs examined: Continuously | Model(s): Random effects; Additional analyses:; - Subgroup analysis and/or meta-regression; - Dose-response meta-analysis; Publication bias: Assessed; - Funnel plot, Egger’s test, Begg’s test
Soltani, 2022 ^237^ | Observational studies | a priori DPs, a posteriori DPs (Other/NR method); - a priori and a posteriori analyzed: Separately | Transformations to combine different effect sizes: No/unclear/NR; Combining different effect sizes without transformation: Yes; Observational DPs examined: Continuously, Categorically (Highest vs lowest) | Model(s): Fixed effect and random effects; Additional analyses:; - Subgroup analysis and/or meta-regression; - Dose-response meta-analysis; Publication bias: Assessed; - Funnel plot, Egger’s test, Begg’s test
Soltani, 2019 ^252^ | Observational studies | a priori DPs | Transformations to combine different effect sizes: No/unclear/NR; Combining different effect sizes without transformation: Yes; Observational DPs examined: Continuously | Model(s): Fixed effect and random effects; Additional analyses:; - Subgroup analysis and/or meta-regression; - Dose-response meta-analysis; Publication bias: Assessed; - Funnel plot, Trim-and-fill, Egger’s test, Begg’s test
Soltani, 2018 ^113^ | RCTs | Interventions | Transformations to combine different effect sizes: No/unclear/NR; Combining different effect sizes without transformation: No/unclear/NR | Model(s): Random effects; Additional analyses:; - Subgroup analysis and/or meta-regression; Publication bias: Assessed; - Funnel plot
Soltani, 2016 ^119^ | RCTs | Interventions | Transformations to combine different effect sizes: No/unclear/NR; Combining different effect sizes without transformation: No/unclear/NR | Model(s): Random effects; Additional analyses:; - Subgroup analysis and/or meta-regression; Publication bias: Assessed; - Funnel plot, Egger’s test, Begg’s test
Spei, 2023 ^164^ | Observational studies | a priori DPs, a posteriori DPs (Other/NR method); - a priori and a posteriori analyzed: Separately | Transformations to combine different effect sizes: No/unclear/NR; Combining different effect sizes without transformation: No/unclear/NR; Observational DPs examined: Categorically (Highest vs lowest) | Model(s): Random effects; Additional analyses:; - Subgroup analysis and/or meta-regression; Publication bias: Assessed; - Funnel plot, Egger’s test
Sun, 2016 ^305^ | Observational studies | a priori DPs, a posteriori DPs (PCA/factor, Cluster); - a priori and a posteriori analyzed: Both together and separately | Transformations to combine different effect sizes: No/unclear/NR; Combining different effect sizes without transformation: No/unclear/NR; Observational DPs examined: Categorically (Highest vs lowest) | Model(s): Fixed effect; Additional analyses:; - Subgroup analysis and/or meta-regression; Publication bias: Assessed; - Funnel plot, Egger’s test
Taghavi, 2019 ^240^ | Observational studies | a priori DPs | Transformations to combine different effect sizes: No/unclear/NR; Combining different effect sizes without transformation: Yes; Observational DPs examined: Categorically (Highest vs lowest) | Model(s): Fixed effect and random effects; Additional analyses:; - Subgroup analysis and/or meta-regression; Publication bias: Assessed; - Funnel plot, Begg’s test
Tan, 2024 ^132^ | Observational studies | a priori DPs | Transformations to combine different effect sizes: No/unclear/NR; Combining different effect sizes without transformation: Yes; Observational DPs examined: Categorically (Highest vs lowest) | Model(s): Fixed effect and random effects; Additional analyses:; - Subgroup analysis and/or meta-regression; Publication bias: Assessed; - Funnel plot, Egger’s test
Tang, 2021 ^208^ | Observational studies | a priori DPs | Transformations to combine different effect sizes: No/unclear/NR; Combining different effect sizes without transformation: Yes; Observational DPs examined: Continuously | Model(s): Random effects; Additional analyses:; - Subgroup analysis and/or meta-regression; Publication bias: Assessed; - Egger’s test, Begg’s test
Tangestani, 2020 ^238^ | Observational studies | a priori DPs | Transformations to combine different effect sizes: No/unclear/NR; Combining different effect sizes without transformation: No/unclear/NR; Observational DPs examined: Categorically (Highest vs lowest) | Model(s): Random effects; Additional analyses:; - Subgroup analysis and/or meta-regression; Publication bias: Assessed; - Egger’s test
Taylor, 2024 ^156^ | Observational studies | a priori DPs | Transformations to combine different effect sizes: No/unclear/NR; Combining different effect sizes without transformation: No/unclear/NR; Observational DPs examined: Categorically (Highest vs lowest), Unclear/NR DP | Model(s): Random effects; Additional analyses:; - Subgroup analysis and/or meta-regression; Publication bias: Assessed; - Funnel plot, Begg’s test
Termannsen, 2022 ^53^ | RCTs | Interventions | Transformations to combine different effect sizes: No/unclear/NR; Combining different effect sizes without transformation: No/unclear/NR | Model(s): Random effects; Additional analyses:; - Subgroup analysis and/or meta-regression; Publication bias: Assessed; - Funnel plot
Theodoridis, 2023a ^166^ | Observational studies | a priori DPs | Transformations to combine different effect sizes: Yes; Combining different effect sizes without transformation: No/unclear/NR; Observational DPs examined: Categorically (Highest vs lowest) | Model(s): Random effects; Additional analyses:; - Subgroup analysis and/or meta-regression; Publication bias: Assessed; - Funnel plot, Egger’s test
Theodoridis, 2023b ^167^ | Observational studies | a priori DPs | Transformations to combine different effect sizes: No/unclear/NR; Combining different effect sizes without transformation: No/unclear/NR; Observational DPs examined: Categorically (Highest vs lowest) | Model(s): Random effects; Additional analyses:; - Subgroup analysis and/or meta-regression; Publication bias: Not assessed; - Not enough studies
Trauchburg, 2023 ^168^ | Observational studies | a priori DPs, a posteriori DPs (PCA/factor); - a priori and a posteriori analyzed: Separately | Transformations to combine different effect sizes: No/unclear/NR; Combining different effect sizes without transformation: Yes; Observational DPs examined: Categorically (Highest vs lowest) | Model(s): Random effects; Additional analyses:; - Subgroup analysis and/or meta-regression; Publication bias: Assessed; - Funnel plot
Tsironikos, 2023 ^25^ | RCTs | Interventions | Transformations to combine different effect sizes: No/unclear/NR; Combining different effect sizes without transformation: No/unclear/NR | Model(s): Random effects; Additional analyses:; - Subgroup analysis and/or meta-regression; Publication bias: Assessed; - Funnel plot, Egger’s test
Ungvari, 2024 ^139^ | Observational studies | a priori DPs | Transformations to combine different effect sizes: No/unclear/NR; Combining different effect sizes without transformation: No/unclear/NR; Observational DPs examined: Unclear/NR DP | Model(s): Random effects; Additional analyses:; - Subgroup analysis and/or meta-regression; Publication bias: Assessed; - Funnel plot, Egger’s test
Valenzuela-Fuenzalida, 2024 ^9^ | RCTs | Interventions | Transformations to combine different effect sizes: No/unclear/NR; Combining different effect sizes without transformation: No/unclear/NR | Model(s): Fixed effect and random effects; Publication bias: Assessed; - Funnel plot
van den Brandt, 2017 ^289^ | Observational studies | a priori DPs | Transformations to combine different effect sizes: No/unclear/NR; Combining different effect sizes without transformation: No/unclear/NR; Observational DPs examined: Categorically (Highest vs lowest) | Model(s): Random effects; Publication bias: Assessed; - Begg’s test
Van Elswyk, 2022 ^54^ | RCTs, Observational studies; - Trials and observational studies analyzed: Separately | Interventions, a priori DPs Together | Transformations to combine different effect sizes: Yes; Combining different effect sizes without transformation: No/unclear/NR; Observational DPs examined: Unclear/NR DP | Model(s): Random effects; Publication bias: Assessed; - Funnel plot, Egger’s test
Vernooij, 2019 ^244^ | Observational studies | a priori DPs, a posteriori DPs (PCA/factor, Cluster, RRR); - a priori and a posteriori analyzed: Both together and separately | Transformations to combine different effect sizes: No/unclear/NR; Combining different effect sizes without transformation: No/unclear/NR; Observational DPs examined: Categorically (Highest vs lowest) | Model(s): Random effects; Additional analyses:; - Subgroup analysis and/or meta-regression; Publication bias: Not assessed; - No rationale for lack of assessment given
Veronese, 2024 ^136^ | Observational studies | a priori DPs | Transformations to combine different effect sizes: No/unclear/NR; Combining different effect sizes without transformation: No/unclear/NR; Observational DPs examined: Continuously | Model(s): Random effects; Additional analyses:; - Subgroup analysis and/or meta-regression; Publication bias: Assessed; - Funnel plot, Trim-and-fill, Egger’s test
Wang, 2023a ^162^ | Observational studies | a priori DPs | Transformations to combine different effect sizes: No/unclear/NR; Combining different effect sizes without transformation: No/unclear/NR; Observational DPs examined: Categorically (Highest vs lowest) | Model(s): Fixed effect and random effects; Additional analyses:; - Subgroup analysis and/or meta-regression; Publication bias: Assessed; - Funnel plot, Trim-and-fill, Egger’s test, Begg’s test
Wang, 2023c ^29^ | RCTs | Interventions | Transformations to combine different effect sizes: No/unclear/NR; Combining different effect sizes without transformation: No/unclear/NR | Model(s): Random effects; Additional analyses:; - Subgroup analysis and/or meta-regression; Publication bias: Assessed; - Funnel plot
Wang, 2023b ^36^ | RCTs | Interventions | Transformations to combine different effect sizes: No/unclear/NR; Combining different effect sizes without transformation: No/unclear/NR | Model(s): Fixed effect and random effects; Additional analyses:; - Subgroup analysis and/or meta-regression; - Network meta-analysis; Publication bias: Assessed; - Egger’s test, Begg’s test
Wang, 2022 ^47^ | RCTs | Interventions | Transformations to combine different effect sizes: No/unclear/NR; Combining different effect sizes without transformation: No/unclear/NR | Model(s): Fixed effect and random effects; Publication bias: Not assessed; - No rationale for lack of assessment given
Wang, 2018a ^275^ | Observational studies | a priori DPs | Transformations to combine different effect sizes: No/unclear/NR; Combining different effect sizes without transformation: No/unclear/NR; Observational DPs examined: Categorically (Highest vs lowest) | Model(s): Random effects; Additional analyses:; - Subgroup analysis and/or meta-regression; Publication bias: Not assessed; - Not enough studies
Wang, 2018b ^278^ | Observational studies | a priori DPs, a posteriori DPs (PCA/factor); - a priori and a posteriori analyzed: Together | Transformations to combine different effect sizes: No/unclear/NR; Combining different effect sizes without transformation: No/unclear/NR; Observational DPs examined: Categorically (Highest vs lowest) | Model(s): Random effects; Additional analyses:; - Subgroup analysis and/or meta-regression; Publication bias: Assessed; - Funnel plot, Begg’s test
Wang, 2016 ^297^ | Observational studies | a posteriori DPs (PCA/factor) | Transformations to combine different effect sizes: No/unclear/NR; Combining different effect sizes without transformation: Yes; Observational DPs examined: Categorically (Highest vs lowest) | Model(s): Random effects; Additional analyses:; - Subgroup analysis and/or meta-regression; Publication bias: Assessed; - Funnel plot, Egger’s test
Waugh, 2024 ^16^ | RCTs | Interventions | Transformations to combine different effect sizes: No/unclear/NR; Combining different effect sizes without transformation: No/unclear/NR | Model(s): Random effects; Publication bias: Not assessed; - No rationale for lack of assessment given
Wen, 2024 ^152^ | Observational studies | a posteriori DPs (PCA/factor) | Transformations to combine different effect sizes: Yes; Combining different effect sizes without transformation: Yes; Observational DPs examined: Unclear/NR DP | Model(s): Random effects; Additional analyses:; - Subgroup analysis and/or meta-regression; Publication bias: Assessed; - Funnel plot, Egger’s test, Begg’s test
Winter, 2023 ^172^ | Observational studies | a priori DPs, a posteriori DPs (Other/NR method); - a priori and a posteriori analyzed: Both together and separately | Transformations to combine different effect sizes: Yes; Combining different effect sizes without transformation: No/unclear/NR; Observational DPs examined: Categorically (Highest vs lowest) | Model(s): Random effects; Additional analyses:; - Subgroup analysis and/or meta-regression; Publication bias: Assessed; - Funnel plot, Egger’s test
Wu, 2021 ^75^ | RCTs, Observational studies; - Trials and observational studies analyzed: Both together and separately | Interventions, a priori DPs, a posteriori DPs (PCA/factor, Cluster, RRR); - a priori and a posteriori analyzed: Both together and separately | Transformations to combine different effect sizes: Yes; Combining different effect sizes without transformation: No/unclear/NR; Observational DPs examined: Categorically (Highest vs lowest) | Model(s): Random effects; Additional analyses:; - Subgroup analysis and/or meta-regression; Publication bias: Assessed; - Egger’s test
Wu, 2019 ^257^ | Observational studies | a priori DPs | Transformations to combine different effect sizes: No/unclear/NR; Combining different effect sizes without transformation: No/unclear/NR; Observational DPs examined: Categorically (Highest vs lowest) | Model(s): Random effects; Publication bias: Assessed; - Funnel plot, Egger’s test
Wu, 2020 ^274^ | Observational studies | a priori DPs | Transformations to combine different effect sizes: Yes; Combining different effect sizes without transformation: No/unclear/NR; Observational DPs examined: Continuously, Categorically (Highest vs lowest, Other) | Model(s): Random effects; Additional analyses:; - Subgroup analysis and/or meta-regression; Publication bias: Assessed; - Funnel plot, Trim-and-fill, Egger’s test, Begg’s test, Fail-safe N
Wu, 2017 ^290^ | Observational studies | a priori DPs | Transformations to combine different effect sizes: No/unclear/NR; Combining different effect sizes without transformation: No/unclear/NR; Observational DPs examined: Continuously, Categorically (Highest vs lowest, Other) | Model(s): Random effects; Additional analyses:; - Subgroup analysis and/or meta-regression; - Dose-response meta-analysis; Publication bias: Assessed; - Funnel plot, Egger’s test, Begg’s test
Xiao, 2019 ^262^ | Observational studies | a posteriori DPs (PCA/factor) | Transformations to combine different effect sizes: No/unclear/NR; Combining different effect sizes without transformation: Yes; Observational DPs examined: Categorically (Highest vs lowest) | Model(s): Random effects; Additional analyses:; - Subgroup analysis and/or meta-regression; Publication bias: Assessed; - Funnel plot, Trim-and-fill, Egger’s test, Begg’s test
Xiong, 2024 ^14^ | RCTs | Interventions | Transformations to combine different effect sizes: No/unclear/NR; Combining different effect sizes without transformation: No/unclear/NR | Model(s): Fixed effect and random effects; Additional analyses:; - Subgroup analysis and/or meta-regression; Publication bias: Not assessed; - Not enough studies
Xu, 2024 ^24^ | RCTs, Observational studies; - Trials and observational studies analyzed: Separately | Interventions, a priori DPs | Transformations to combine different effect sizes: Yes; Combining different effect sizes without transformation: No/unclear/NR; Observational DPs examined: Categorically (Highest vs lowest) | Model(s): Random effects; Additional analyses:; - Subgroup analysis and/or meta-regression; Publication bias: Not assessed; - Not enough studies
Xu, 2023 ^38^ | RCTs | Interventions | Transformations to combine different effect sizes: Yes; Combining different effect sizes without transformation: No/unclear/NR | Model(s): Fixed effect and random effects; Additional analyses:; - Subgroup analysis and/or meta-regression; Publication bias: Not assessed; - Not enough studies
Xu, 2022 ^201^ | Observational studies | a priori DPs | Transformations to combine different effect sizes: No/unclear/NR; Combining different effect sizes without transformation: Yes; Observational DPs examined: Categorically (Higher vs lower categories unspecified) | Model(s): Random effects; Additional analyses:; - Subgroup analysis and/or meta-regression; - Dose-response meta-analysis; Publication bias: Assessed; - Begg’s test
Yang, 2024 ^6^ | RCTs, Observational studies; - Trials and observational studies analyzed: Together | Interventions, a priori DPs | Transformations to combine different effect sizes: No/unclear/NR; Combining different effect sizes without transformation: No/unclear/NR; Observational DPs examined: Unclear/NR DP | Model(s): Fixed effect and random effects; Additional analyses:; - Subgroup analysis and/or meta-regression; Publication bias: Not assessed; - Not enough studies
Yang, 2023 ^28^ | RCTs, Observational studies; - Trials and observational studies analyzed: Separately | Interventions, a priori DPs, a posteriori DPs (PCA/factor); - a priori and a posteriori analyzed: Together | Transformations to combine different effect sizes: No/unclear/NR; Combining different effect sizes without transformation: Yes; Observational DPs examined: Categorically (Highest vs lowest) | Model(s): Random effects; Additional analyses:; - Subgroup analysis and/or meta-regression; Publication bias: Assessed; - Egger’s test, Begg’s test
Yang, 2019 ^259^ | Observational studies | a priori DPs | Transformations to combine different effect sizes: No/unclear/NR; Combining different effect sizes without transformation: Yes; Observational DPs examined: Categorically (Highest vs lowest) | Model(s): Random effects; Additional analyses:; - Subgroup analysis and/or meta-regression; - Dose-response meta-analysis; Publication bias: Assessed; - Funnel plot, Egger’s test
You, 2023 ^171^ | Observational studies | a priori DPs, a posteriori DPs (PCA/factor, Cluster); - a priori and a posteriori analyzed: Both together and separately | Transformations to combine different effect sizes: No/unclear/NR; Combining different effect sizes without transformation: No/unclear/NR; Observational DPs examined: Categorically (Highest vs lowest) | Model(s): Fixed effect and random effects; Additional analyses:; - Subgroup analysis and/or meta-regression; Publication bias: Assessed; - Funnel plot, Egger’s test
Yuan, 2024 ^3^ | RCTs | Interventions | Transformations to combine different effect sizes: No/unclear/NR; Combining different effect sizes without transformation: No/unclear/NR | Model(s): Random effects; Additional analyses:; - Subgroup analysis and/or meta-regression; - Network meta-analysis; Publication bias: Assessed; - Funnel plot, Egger’s test
Zeng, 2023 ^42^ | RCTs | Interventions | Transformations to combine different effect sizes: Yes; Combining different effect sizes without transformation: No/unclear/NR | Model(s): Fixed effect and random effects; Additional analyses:; - Subgroup analysis and/or meta-regression; - Network meta-analysis; Publication bias: Assessed; - Comparison-adjusted funnel plot, Egger’s test, Begg’s test, Thompson-Sharpe test
Zeraattalab-Motlagh, 2022 ^200^ | Observational studies | a priori DPs | Transformations to combine different effect sizes: No/unclear/NR; Combining different effect sizes without transformation: Yes; Observational DPs examined: Continuously, Categorically (Highest vs lowest) | Model(s): Random effects; Additional analyses:; - Subgroup analysis and/or meta-regression; - Dose-response meta-analysis; Publication bias: Assessed; - Funnel plot, Egger’s test
Zhang, 2024 ^5^ | RCTs | Interventions | Transformations to combine different effect sizes: No/unclear/NR; Combining different effect sizes without transformation: No/unclear/NR | Model(s): Fixed effect and random effects; Additional analyses:; - Subgroup analysis and/or meta-regression; - Network meta-analysis; Publication bias: Assessed; - Funnel plot
Zhang, 2023 ^155^ | Observational studies | a posteriori DPs (Other/NR method) | Transformations to combine different effect sizes: No/unclear/NR; Combining different effect sizes without transformation: Yes; Observational DPs examined: Categorically (Highest vs lowest) | Model(s): Random effects; Additional analyses:; - Subgroup analysis and/or meta-regression; Publication bias: Assessed; - Funnel plot
Zhang, 2022 ^69^ | RCTs | Interventions | Transformations to combine different effect sizes: No/unclear/NR; Combining different effect sizes without transformation: No/unclear/NR | Model(s): Random effects; Publication bias: Not assessed; - Not enough studies
Zhang, 2019a ^243^ | Observational studies | a posteriori DPs (PCA/factor) | Transformations to combine different effect sizes: No/unclear/NR; Combining different effect sizes without transformation: Yes; Observational DPs examined: Categorically (Highest vs lowest) | Model(s): Fixed effect; Additional analyses:; - Subgroup analysis and/or meta-regression; Publication bias: Assessed; - Funnel plot, Egger’s test, Begg’s test
Zhang, 2019b ^255^ | Observational studies | a priori DPs | Transformations to combine different effect sizes: No/unclear/NR; Combining different effect sizes without transformation: No/unclear/NR; Observational DPs examined: Categorically (Highest vs lowest) | Model(s): Fixed effect and random effects; Publication bias: Not assessed; - Other reason
Zhang, 2015a ^310^ | Observational studies | a priori DPs, a posteriori DPs (PCA/factor); - a priori and a posteriori analyzed: Together | Transformations to combine different effect sizes: No/unclear/NR; Combining different effect sizes without transformation: No/unclear/NR; Observational DPs examined: Categorically (Highest vs lowest) | Model(s): Random effects; Additional analyses:; - Subgroup analysis and/or meta-regression; Publication bias: Assessed; - Funnel plot, Begg’s test
Zhang, 2015b ^311^ | Observational studies | a priori DPs, a posteriori DPs (PCA/factor); - a priori and a posteriori analyzed: Together | Transformations to combine different effect sizes: No/unclear/NR; Combining different effect sizes without transformation: No/unclear/NR; Observational DPs examined: Categorically (Highest vs lowest) | Model(s): Fixed effect and random effects; Publication bias: Assessed; - Funnel plot, Begg’s test
Zhao, 2024 ^129^ | Observational studies | a priori DPs | Transformations to combine different effect sizes: No/unclear/NR; Combining different effect sizes without transformation: Yes; Observational DPs examined: Categorically (Highest vs lowest) | Model(s): Fixed effect and random effects; Additional analyses:; - Subgroup analysis and/or meta-regression; Publication bias: Assessed; - Funnel plot, Trim-and-fill, Egger’s test, Begg’s test
Zhao, 2023 ^175^ | Observational studies | a priori DPs, a posteriori DPs (PCA/factor, Cluster); - a priori and a posteriori analyzed: Separately | Transformations to combine different effect sizes: No/unclear/NR; Combining different effect sizes without transformation: No/unclear/NR; Observational DPs examined: Continuously, Categorically (Highest vs lowest) | Model(s): Random effects; Additional analyses:; - Subgroup analysis and/or meta-regression; Publication bias: Not assessed; - Not enough studies
Zhao, 2022 ^191^ | Observational studies | a priori DPs, a posteriori DPs (Other/NR method); - a priori and a posteriori analyzed: Together | Transformations to combine different effect sizes: Yes; Combining different effect sizes without transformation: No/unclear/NR; Observational DPs examined: Categorically (Highest vs lowest, Higher vs lower categories unspecified, Other) | Model(s): Random effects; Additional analyses:; - Subgroup analysis and/or meta-regression; Publication bias: Assessed; - Funnel plot, Trim-and-fill, Egger’s test
Zheng, 2024 ^18^ | RCTs | Interventions | Transformations to combine different effect sizes: No/unclear/NR; Combining different effect sizes without transformation: No/unclear/NR | Model(s): Fixed effect and random effects; Additional analyses:; - Subgroup analysis and/or meta-regression; Publication bias: Assessed; - Funnel plot
Zheng, 2016 ^307^ | Observational studies | a priori DPs, a posteriori DPs (Other/NR method); - a priori and a posteriori analyzed: Together | Transformations to combine different effect sizes: No/unclear/NR; Combining different effect sizes without transformation: No/unclear/NR; Observational DPs examined: Categorically (Highest vs lowest) | Model(s): Random effects; Publication bias: Assessed; - Funnel plot, Egger’s test, Begg’s test
Zhong, 2020 ^233^ | Observational studies | a priori DPs | Transformations to combine different effect sizes: No/unclear/NR; Combining different effect sizes without transformation: Yes; Observational DPs examined: Categorically (Highest vs lowest) | Model(s): Random effects; Additional analyses:; - Subgroup analysis and/or meta-regression; - Dose-response meta-analysis; Publication bias: Assessed; - Egger’s test, Egger’s linear regression plot, Begg’s test
Zhu, 2023a ^161^ | Observational studies | a priori DPs, a posteriori DPs (PCA/factor); - a priori and a posteriori analyzed: Both together and separately | Transformations to combine different effect sizes: No/unclear/NR; Combining different effect sizes without transformation: Yes; Observational DPs examined: Categorically (Highest vs lowest) | Model(s): Fixed effect; Additional analyses:; - Subgroup analysis and/or meta-regression; - Dose-response meta-analysis; Publication bias: Assessed; - Funnel plot, Egger’s test, Begg’s test
Zhu, 2023b ^163^ | Observational studies | a priori DPs | Transformations to combine different effect sizes: Yes; Combining different effect sizes without transformation: Yes; Observational DPs examined: Categorically (Highest vs lowest) | Model(s): Random effects; Additional analyses:; - Subgroup analysis and/or meta-regression; - Dose-response meta-analysis; Publication bias: Assessed; - Funnel plot, Egger’s test, Begg’s test
Zimorovat, 2020 ^94^ | RCTs | Interventions | Transformations to combine different effect sizes: No/unclear/NR; Combining different effect sizes without transformation: No/unclear/NR | Model(s): Random effects; Additional analyses:; - Subgroup analysis and/or meta-regression; Publication bias: Assessed; - Funnel plot