# Methods

NESR’s methodology^‡^ was used to conduct this evidence scan. A NESR evidence scan is an exploratory evidence description project in which systematic methods are used to search for and describe the volume and characteristics of evidence available on a nutrition question or topic of public health importance. NESR evidence scans involve the following: development/refinement of the research question, protocol development, searching for and screening studies, minimal data extraction, and description of evidence. NESR evidence scans do not include: data extraction of study results, risk of bias assessment, synthesis of the evidence, development of conclusion statements, or grading the strength of the evidence.

‡ USDA Nutrition Evidence Systematic Review Branch. USDA Nutrition Evidence Systematic Review: Methodology Manual. February 2023. U.S. Department of Agriculture, Food and Nutrition Service, Center for Nutrition Policy and Promotion, Nutrition Evidence Systematic Review. Available at: https://nesr.usda.gov/methodology-overview

This section presents an overview of the specific methods used to answer the evidence scan question: What methods have been used to meta-analyze studies examining the relationship between dietary patterns and health outcomes?

## Develop a protocol

An evidence scan protocol is the plan for how NESR’s methodology will be used to conduct a specific evidence scan and is established a priori, before any evidence is reviewed. The protocol is designed to capture the most appropriate and relevant body of evidence to answer the evidence scan question. Development of the protocol involves discussion of the strengths and limitations of various methodological approaches relevant to the question, which then inform subsequent steps of the evidence scan process. The protocol describes the methods that will be used throughout the evidence scan process. Additionally, the protocol includes the following components, which are tailored to each evidence scan question: the analytic framework, the inclusion and exclusion criteria, and the evidence description plan. The protocol was posted online at nesr.usda.gov/protocols.^§^

§ Bahnfleth C, Becker BJ, Higgins M, . Methods to Meta-Analyze Studies of Dietary Patterns and Health Outcomes: An Evidence Scan Protocol. December 2024. U.S. Department of Agriculture, Food and Nutrition Service, Center for Nutrition Policy and Promotion, Nutrition Evidence Systematic Review. Available at: https://nesr.usda.gov/protocols

## Develop an analytic framework

An analytic framework visually represents the overall scope of the evidence scan question and depicts the contributing elements that will be examined and evaluated. Figure 1 is the analytic framework for the evidence scan and shows that: the intervention or exposure of interest was consumption of a dietary pattern during all life stages, including infants and young children (birth up to 24 months), children and adolescents (2 years up to 19 years), adults and older adults (19 years and older), and individuals during pregnancy, postpartum, and/or lactation; the comparators were different dietary patterns and different adherence to/consumption levels of the same dietary pattern; the outcome was health outcomes (operationalized broadly to include any health outcome, excluding dietary intake); and the concept was methods to meta-analyze studies examining consumption of dietary patterns and health outcomes.

Figure 1 Analytic framework for the evidence scan question: What methods have been used to meta-analyze studies examining the relationship between dietary patterns and health outcomes?

Population | Intervention/exposure | Comparator | Outcome | Concept
All life stages, including:; - Infants and young children (birth up to 24 months); - Children and adolescents (2 years up to 19 years); - Adults and older adults (19 years and older); - Individuals during pregnancy, postpartum, and/or lactation | Consumption of a dietary pattern | - Different dietary pattern(s); - Different adherence to/consumption levels of the same dietary pattern | Health outcomes | Methods to meta-analyze studies examining consumption of dietary patterns and health outcomes

Key definitions:

- [underlined: Dietary patterns]: the quantities, proportions, variety, or combination of different foods, drinks, and nutrients (when available) in diets, and the frequency with which they are habitually consumed.
- [underlined: Concept]: the main idea examined in the evidence scan.

## Develop inclusion and exclusion criteria

The inclusion and exclusion criteria provided an objective, consistent, and transparent framework for determining which articles to include in the evidence scan (Table 1). These criteria ensured that the most relevant and appropriate body of evidence was identified for the evidence scan question.

Table 1 Inclusion and exclusion criteria

Category | Inclusion Criteria | Exclusion Criteria
Study design | - Systematic reviews with meta-analyses | - Primary studies of any design; - Narrative reviews; - Systematic reviews without meta-analyses; - Umbrella reviews; - Modeling and simulation studies
Study designs included in meta-analysis | Meta-analysis includes 1 or more articles using the following study designs:; - Randomized controlled trials; - Non-randomized controlled trials^*^; * Including quasi-experimental and controlled before-and-after studies; - Prospective cohort studies; - Retrospective cohort studies; - Nested case-control studies | Meta-analysis [underlined: only] includes articles using the following study designs:; - Uncontrolled trials^†^; † Including uncontrolled before-and-after studies; - Case-control studies; - Cross-sectional studies; - Ecological studies; - Modeling and simulation studies
Publication date | - January 2015 – December 2024 | - Before January 2015, after December 2024
Population: Study participants | - Human | - Non-human
Population: Life stage | - Infants and young children (birth up to 24 months); - Children and adolescents (2 up to 19 years); - Adults and older adults (19 years and older); - Individuals during pregnancy; - Individuals during postpartum; - Individuals during lactation | - Not applicable
Intervention/exposure | - Consumption of and/or adherence to a dietary pattern [i.e., the quantities, proportions, variety, or combination of different foods, drinks, and nutrients (when available) in diets, and the frequency with which they are habitually consumed]; ○ Dietary patterns may be measured or derived using a variety of approaches, such as adherence to a priori patterns (indices/scores), data-driven patterns (factor or cluster analysis), reduced rank regression, or other methods, including clinical trials | - Consumption of and/or adherence to a dietary pattern not based on foods and beverages (e.g., macronutrient based, dietary inflammatory index) is sole intervention/exposure of the meta-analysis; - Multi-component interventions in which the isolated effect of the intervention of interest on the outcome(s) of interest is not provided or cannot be determined due to multiple components being the sole intervention/exposure of the meta-analysis
Comparator | - Consumption of and/or adherence to a different dietary pattern; - Different levels of consumption of and/or adherence to a dietary pattern | - Consumption of and/or adherence to a similar dietary pattern of which only a specific component or food source is different between groups
Outcome | - Health outcomes | - Dietary intake
Publication status | - Peer-reviewed articles published in research journals | - Non-peer-reviewed articles, unpublished data or manuscripts, pre-prints, reports, editorials, retracted articles, and conference abstracts or proceedings
Language | - Published in English | - Not published in English

## Search for and screen studies

The NESR librarian, in collaboration with NESR analysts, used the analytic framework and inclusion and exclusion criteria to develop a comprehensive literature search strategy. The literature search strategy included selecting and searching the appropriate bibliographic database, and employing search refinements, such as search filters. The full literature search is documented in Appendix 2: Literature search strategy.

The results of the electronic database search, after removal of duplicates, were screened independently by two NESR analysts using a step-wise process by first reviewing titles and abstracts and then reviewing full texts to determine which articles met the inclusion criteria. Any discrepancies were discussed and resolved by a third analyst. A manual search to find peer-reviewed articles not identified through the electronic database search was not conducted.

## Extract data

NESR analysts extracted the most essential data from each included article to describe key characteristics of the available evidence, such as the author, publication year, included study designs, intervention/exposure analysis methods (e.g., analyzing a priori methods and a posteriori methods separately or in combination), and quantitative synthesis methods (e.g., random effects models [univariate or multivariate], dose response meta-analysis, network meta-analysis). One NESR analyst extracted the data and a second NESR analyst reviewed the extracted data for accuracy.

## Describe the evidence

NESR analysts described the volume and characteristics of the included evidence, including information on the methods used in the meta-analyses, such as:

- whether studies of different designs (e.g., randomized controlled trial [RCT], non-RCT [NRCT], prospective cohort study [PCS], retrospective cohort study [RCS]) were analyzed separately or together,
- whether specific dietary patterns or groups of dietary patterns were analyzed separately or together,
- the methods used to analyze dietary patterns data from observational studies, and
- the analytic techniques used to examine potential moderating variables (e.g., subgroup analyses, multivariable models).

The evidence is presented in text, figures, and tables.

## Considerations for future work

NESR analysts identified and documented research gaps and methodological limitations throughout the evidence scan process to help inform the development of methods for conducting systematic reviews with meta-analysis of dietary patterns research.