# Introduction

USDA’s Nutrition Evidence Systematic Review (NESR)^*^ team has collaborated with multiple expert groups to conduct systematic reviews assessing the relationship between consumption of dietary patterns and a wide variety of health outcomes.^†^ However, previous NESR systematic reviews have not included a meta-analysis of dietary patterns studies. Prior to developing methods for conducting systematic reviews with meta-analysis on this topic, the NESR team conducted an evidence scan to examine the following question: What methods have been used to meta-analyze studies examining the relationship between dietary patterns and health outcomes?

* A list of abbreviations used in the report is provided in Appendix 1: Abbreviations

† English LK, Raghavan R, Obbagy JE, . Dietary patterns and health: Insights from NESR systematic reviews to inform the Dietary Guidelines for Americans. J Nutr Educ Behav. 2024 Jan;56(1):75–87. doi: 10.1016/j.jneb.2023.10.001.38185492