# Plain language summary

### What is the question?

The question is: What methods have been used to meta-analyze studies examining the relationship between dietary patterns and health outcomes?

### Why was this question asked?

To evaluate the volume and characteristics of evidence available to inform the development of methods to meta-analyze evidence on dietary patterns and health outcomes.

### How was this question answered?

Nutrition Evidence Systematic Review analysts conducted an evidence scan to answer this question.

### What is the answer to the question?

The body of evidence included 315 systematic reviews with meta-analysis. The meta-analyses commonly included observational studies and/or randomized controlled trials, while non-randomized controlled trials were infrequently included. Meta-analyses of observational studies examined dietary patterns based on a priori methods (i.e., indices or scores) more frequently than dietary patterns derived from a posteriori (i.e., data driven) methods, although some articles analyzed both.

Some articles performed calculations to achieve common effect sizes and many studies combined different effect sizes in meta-analysis without performing calculations (e.g., pooling odds ratios and risk ratios); however, most studies did not report doing either. Dietary patterns from observational studies were most commonly examined as a categorical exposure variable, comparing the highest and lowest category; fewer articles examined dietary patterns as a continuous exposure variable.

Random effects models were more frequently used than fixed effect models. Subgroup and meta-regression analyses were commonly conducted. Dose-response meta-analyses and network meta-analyses were also conducted, but less frequently. Publication bias was commonly assessed, using methods such as funnel plots, Egger’s test, and Begg’s test; some articles indicated that not enough studies were included to conduct a formal assessment of publication bias.

### How up-to-date is this evidence scan?

This evidence scan is based on articles published between January 2015 and December 2024.