# Acknowledgments and funding

The NESR team was involved in executing and documenting the work necessary to ensure the evidence scan was completed in accordance with NESR methodology, including: establishing all aspects of the protocol, which presents the plan for how they were planning to examine the scientific evidence, including the inclusion and exclusion criteria; extracting data from all studies that met the criteria; describing the body of evidence; and writing the final report.