# Appendix 3 Excluded articles

The following table lists the articles excluded after full-text screening for this evidence scan question. At least one reason for exclusion is provided for each article, though this may not reflect all possible reasons. Information about articles excluded after title and abstract screening is available upon request.

Table A 3 Articles excluded after full-text screening

| Citations | Reason for full-text exclusion
1 | Aalizadeh Y, Khamisi N, Asghari P, et al. The Mediterranean diet and periodontitis: A systematic review and meta-analysis. Heliyon. 2024;10:e35633. doi:10.1016/j.heliyon.2024.e35633. | Study Design in Meta-Analysis
2 | Alam MK, Abutayyem H, Alswairki HJ, et al. A systematic review and meta-analysis of the role of nutrition and its impact on orthodontic treatment/management. J Orthod Sci. 2023;12:41. doi:10.4103/jos.jos_85_23. | Intervention/Exposure, Outcome
3 | Aleksandrova K, Koelman L, Rodrigues CE. Dietary patterns and biomarkers of oxidative stress and inflammation: A systematic review of observational and intervention studies. Redox Biol. 2021;42:101869. doi:10.1016/j.redox.2021.101869. | Study Design
4 | Al-Khudairy L, Loveman E, Colquitt JL, et al. Diet, physical activity and behavioural interventions for the treatment of overweight or obese adolescents aged 12 to 17 years. Cochrane Database Syst Rev. 2017;6:Cd012691. doi:10.1002/14651858.Cd012691. | Intervention/Exposure
5 | Allen MS, Walter EE. Health-Related Lifestyle Factors and Sexual Dysfunction: A Meta-Analysis of Population-Based Research. J Sex Med. 2018;15:458–475. doi:10.1016/j.jsxm.2018.02.008. | Intervention/Exposure
6 | Antonogeorgos G, Kogias C, Douros K, et al. Greater fruit and vegetables consumption, and adherence to a Mediterranean type of diet reduces the risk for asthma in children; a systematic review and meta-analysis. Int J Food Sci Nutr. 2024;75:4–30. doi:10.1080/09637486.2023.2276033. | Study Design in Meta-Analysis
7 | Arab A, Rafie N, Mansourian M, et al. Dietary patterns and semen quality: a systematic review and meta-analysis of observational studies. Andrology. 2018;6:20–28. doi:10.1111/andr.12430. | Study Design in Meta-Analysis
8 | Arnoldy L, Gauci S, Young LM, et al. The association of dietary and nutrient patterns on neurocognitive decline: A systematic review of MRI and PET studies. Ageing Res Rev. 2023;87:101892. doi:10.1016/j.arr.2023.101892. | Study Design
9 | Askari M, Daneshzad E, Darooghegi Mofrad M, et al. Vegetarian diet and the risk of depression, anxiety, and stress symptoms: a systematic review and meta-analysis of observational studies. Crit Rev Food Sci Nutr. 2022;62:261–271. doi:10.1080/10408398.2020.1814991. | Intervention/Exposure
10 | Azzola LG, Fankhauser N, Srinivasan M. Influence of the vegan, vegetarian and omnivore diet on the oral health status in adults: a systematic review and meta-analysis. Evid Based Dent. 2023;24:43–44. doi:10.1038/s41432-023-00853-z. | Intervention/Exposure
11 | Badrooj N, Jayedi A, Shab-Bidar S. Ideal cardiovascular health metrics and risk of type 2 diabetes: A systematic review and dose-response meta-analysis of prospective cohort studies. Nutr Metab Cardiovasc Dis. 2023;33:2067–2075. doi:10.1016/j.numecd.2023.07.004 . | Intervention/Exposure
12 | Baguley BJ, Skinner TL, Wright ORL. Nutrition therapy for the management of cancer-related fatigue and quality of life: a systematic review and meta-analysis. Br J Nutr. 2019;122:527–541. doi:10.1017/s000711451800363x. | Intervention/Exposure, Outcome
13 | Bai T, Peng J, Zhu X, et al. Vegetarian diets and the risk of gastrointestinal cancers: a meta-analysis of observational studies. Eur J Gastroenterol Hepatol. 2023;35:1244–1252. doi:10.1097/meg.0000000000002643. | Intervention/Exposure
14 | Bakolis I, Hooper R, Bachert C, et al. Dietary patterns and respiratory health in adults from nine European countries-Evidence from the GA(2) LEN study. Clin Exp Allergy. 2018;48:1474–1482. doi:10.1111/cea.13243. | Study Design
15 | Baldwin C, Kimber KL, Gibbs M, et al. Supportive interventions for enhancing dietary intake in malnourished or nutritionally at-risk adults. Cochrane Database Syst Rev. 2016;12:Cd009840. doi:10.1002/14651858.CD009840.pub2. | Intervention/Exposure
16 | Barnard ND, Levin SM, Yokoyama Y. A systematic review and meta-analysis of changes in body weight in clinical trials of vegetarian diets. J Acad Nutr Diet. 2015;115:954–69. doi:10.1016/j.jand.2014.11.016. | Intervention/Exposure
17 | Barnett A, Wright C, Stone C, et al. Effectiveness of dietary interventions delivered by digital health to adults with chronic conditions: Systematic review and meta-analysis. J Hum Nutr Diet. 2023;36:632–656. doi:10.1111/jhn.13125. | Intervention/Exposure, Outcome
18 | Barrett EM, Afrin H, Rayner M, et al. Criterion validation of nutrient profiling systems: a systematic review and meta-analysis. Am J Clin Nutr. 2024;119:145–163. doi:10.1016/j.ajcnut.2023.10.013. | Intervention/Exposure
19 | Beckhaus AA, Garcia-Marcos L, Forno E, et al. Maternal nutrition during pregnancy and risk of asthma, wheeze, and atopic diseases during childhood: a systematic review and meta-analysis. Allergy. 2015;70:1588–604. doi:10.1111/all.12729. | Intervention/Exposure
20 | Benatar JR, Stewart RAH. Cardiometabolic risk factors in vegans; A meta-analysis of observational studies. PLoS One. 2018; 13:e0209086. doi:10.1371/journal.pone.0209086. | Intervention/Exposure
21 | Bolte LA, Vich Vila A, Imhann F, et al. Long-term dietary patterns are associated with pro-inflammatory and anti-inflammatory features of the gut microbiome. Gut. 2021;70:1287–1298. doi:10.1136/gutjnl-2020-322670. | Intervention/Exposure, Outcome
22 | Boyle BR, Ablett AD, Ochi C, et al. The effect of weight loss interventions for obesity on fertility and pregnancy outcomes: A systematic review and meta-analysis. Int J Gynaecol Obstet. 2023;161:335–342. doi:10.1002/ijgo.14597. | Intervention/Exposure
23 | Brain K, Burrows TL, Rollo ME, et al. A systematic review and meta-analysis of nutrition interventions for chronic noncancer pain. J Hum Nutr Diet. 2019;32:198–225. doi:10.1111/jhn.12601. | Intervention/Exposure
24 | Campisi SC, Zasowski C, Shah S, et al. Do Healthy Dietary Interventions Improve Pediatric Depressive Symptoms? A Systematic Review and Meta-Analysis. Adv Nutr. 2021;12:2495–2507. doi:10.1093/advances/nmab088. | Intervention/Exposure
25 | Chan DSM, Cariolou M, Markozannes G, et al. Post-diagnosis dietary factors, supplement use and colorectal cancer prognosis: A Global Cancer Update Programme (CUP Global) systematic literature review and meta-analysis. Int J Cancer. 2024;155:445–470. doi:10.1002/ijc.34906. | Study Design, Intervention/Exposure
26 | Chen M, Moran LJ, Harrison CL, et al. Ethnic differences in response to lifestyle intervention for the prevention of type 2 diabetes in adults: A systematic review and meta-analysis. Obes Rev. 2022;23:e13340. doi:10.1111/obr.13340. | Intervention/Exposure
27 | Chen P, Zhao Y, Chen Y. A vegan diet improves insulin resistance in individuals with obesity: a systematic review and meta-analysis. Diabetol Metab Syndr. 2022;14:114. doi:10.1186/s13098-022-00879-w. | Intervention/Exposure
28 | Chung Y, Melo P, Pickering O, et al. The association between dietary patterns and risk of miscarriage: a systematic review and meta-analysis. Fertil Steril. 2023;120:333–357. doi:10.1016/j.fertnstert.2023.04.011. | Intervention/Exposure
29 | Clarke ED, Stanford J, Gomez-Martin M, et al. Revisiting the impact of Health at Every Size® interventions on health and cardiometabolic related outcomes: An updated systematic review with meta-analysis. Nutr Diet. 2024;81:261–282. doi:10.1111/1747–0080.12869. | Intervention/Exposure
30 | Comeche JM, Gutierrez-Hervas A, Tuells J, et al. Predefined Diets in Patients with Inflammatory Bowel Disease: Systematic Review and Meta-Analysis. Nutrients. 2020;13:52. doi:10.3390/nu13010052. | Intervention/Exposure
31 | Cooper C, Sommerlad A, Lyketsos CG, et al. Modifiable predictors of dementia in mild cognitive impairment: a systematic review and meta-analysis. Am J Psychiatry. 2015;172:323–34. doi:10.1176/appi.ajp.2014.14070878. | Intervention/Exposure
32 | Craddock JC, Neale EP, Peoples GE, et al. Vegetarian-Based Dietary Patterns and their Relation with Inflammatory and Immune Biomarkers: A Systematic Review and Meta-Analysis. Adv Nutr. 2019;10:433–451. doi:10.1093/advances/nmy103. | Intervention/Exposure
33 | Cunha CM, Costa PRF, de Oliveira LPM, et al. Dietary patterns and cardiometabolic risk factors among adolescents: systematic review and meta-analysis. Br J Nutr. 2018;119:859–879. doi:10.1017/s0007114518000533. | Study Design in Meta-Analysis
34 | Damasceno YO, Leitao CVFS, de Oliveira GM, et al. Plant-based diets benefit aerobic performance and do not compromise strength/power performance: a systematic review and meta-analysis. Br J Nutr. 2024;131:829–840. doi:10.1017/s0007114523002258. | Intervention/Exposure
35 | Dimba NR, Mzimela N, Sosibo AM, et al. Effectiveness of Prebiotics and Mediterranean and Plant-Based Diet on Gut Microbiota and Glycemic Control in Patients with Prediabetes or Type 2 Diabetes: A Systematic Review and Meta-Analysis. Nutrients. 2024;16:3272. doi:10.3390/nu16193272. | Intervention/Exposure
36 | Dinu M, Abbate R, Gensini GF, et al. Vegetarian, vegan diets and multiple health outcomes: A systematic review with meta-analysis of observational studies. Crit Rev Food Sci Nutr. 2017;57:3640–3649. doi:10.1080/10408398.2016.1138447. | Intervention/Exposure
37 | Dong Y, Greenwood DC, Webster J, et al. Dose-Response Associations Between Diet and Risk of Rheumatoid Arthritis: A Meta-Analysis of Prospective Cohort Studies. Nutrients. 2024;16:4050. doi:10.3390/nu16234050. | Intervention/Exposure
38 | Dybvik JS, Svendsen M, Aune D. Vegetarian and vegan diets and the risk of cardiovascular disease, ischemic heart disease and stroke: a systematic review and meta-analysis of prospective cohort studies. Eur J Nutr. 2023;62:51–69. doi:10.1007/s00394-022-02942-8. | Intervention/Exposure
39 | Fazelian S, Sadeghi E, Firouzi S, et al. Adherence to the vegetarian diet may increase the risk of depression: a systematic review and meta-analysis of observational studies. Nutr Rev. 2022;80:242–254. doi:10.1093/nutrit/nuab013 . | Intervention/Exposure
40 | Field R, Pourkazemi F, Turton J, et al. Dietary Interventions Are Beneficial for Patients with Chronic Pain: A Systematic Review with Meta-Analysis. Pain Med. 2021;22:694–714. doi:10.1093/pm/pnaa378. | Intervention/Exposure
41 | García-Hermoso A, Ezzatvar Y, López-Gil JF, et al. Is adherence to the Mediterranean diet associated with healthy habits and physical fitness? A systematic review and meta-analysis including 565 421 youths. Br J Nutr. 2022;128:1433–1444. doi:10.1017/s0007114520004894. | Study Design in Meta-Analysis
42 | Gartlehner G, Vander Schaaf EB, Orr C, et al. Screening for Hypertension in Children and Adolescents: Updated Evidence Report and Systematic Review for the US Preventive Services Task Force. JAMA. 2020;324:1884–1895. doi:10.1001/jama.2020.11119. | Study Design
43 | Glenn AJ, Viguiliouk E, Seider M, et al. Relation of Vegetarian Dietary Patterns With Major Cardiovascular Outcomes: A Systematic Review and Meta-Analysis of Prospective Cohort Studies. Front Nutr. 2019;6:80. doi:10.3389/fnut.2019.00080. | Intervention/Exposure
44 | Godos J, Bella F, Sciacca S, et al. Vegetarianism and breast, colorectal and prostate cancer risk: an overview and meta-analysis of cohort studies. J Hum Nutr Diet. 2017;30:349–359. doi:10.1111/jhn.12426. | Intervention/Exposure
45 | Gómez-Gómez I, Barquero-Jiménez C, Johnson E, et al. Effectiveness of multiple health behavior change interventions in reducing symptoms of anxiety in the adult population: A systematic review and meta-analysis of randomized controlled trials. Prev Med. 2024;180:107847. doi:10.1016/j.ypmed.2024.107847. | Intervention/Exposure
46 | Gómez-Gómez I, Bellón JÁ, Resurrección DM, et al. Effectiveness of universal multiple-risk lifestyle interventions in reducing depressive symptoms: Systematic review and meta-analysis. Prev Med. 2020;134:106067. doi:10.1016/j.ypmed.2020.106067. | Intervention/Exposure, Comparator
47 | Gresham E, Bisquera A, Byles JE, et al. Effects of dietary interventions on pregnancy outcomes: a systematic review and meta-analysis. Matern Child Nutr. 2016;12:5–23. doi:10.1111/mcn.12142. | Intervention/Exposure
48 | Grisotto G, Farago JS, Taneri PE, et al. Dietary factors and onset of natural menopause: A systematic review and meta-analysis. Maturitas. 2022;159:15–32. doi:10.1016/j.maturitas.2021.12.008. | Intervention/Exposure
49 | Guest NS, Raj S, Landry MJ, et al. Vegetarian and Vegan Dietary Patterns to Treat Adult Type 2 Diabetes: A Systematic Review and Meta-Analysis of Randomized Controlled Trials. Adv Nutr. 2024;15:100294. doi:10.1016/j.advnut.2024.100294. | Intervention/Exposure
50 | Hall RL, George ES, Tierney AC, et al. Effect of Dietary Intervention, with or without Cointerventions, on Inflammatory Markers in Patients with Nonalcoholic Fatty Liver Disease: A Systematic Review and Meta-Analysis. Adv Nutr. 2023;14:475–499. doi:10.1016/j.advnut.2023.01.001. | Study Design, Intervention/Exposure
51 | Han HY, Masip G, Meng T, et al. Interactions between Polygenic Risk of Obesity and Dietary Factors on Anthropometric Outcomes: A Systematic Review and Meta-Analysis of Observational Studies. J Nutr. 2024;154:3521–3543. doi:10.1016/j.tjnut.2024.10.014. | Intervention/Exposure
52 | Hasan B, Nayfeh T, Alzuabi M, et al. Weight Loss and Serum Lipids in Overweight and Obese Adults: A Systematic Review and Meta-Analysis. J Clin Endocrinol Metab. 2020;105:3695–3703. doi:10.1210/clinem/dgaa673. | Intervention/Exposure, Outcome
53 | Hill E, Goodwill AM, Gorelik A, et al. Diet and biomarkers of Alzheimer’s disease: a systematic review and meta-analysis. Neurobiol Aging. 2019;76:45–52. doi:10.1016/j.neurobiolaging.2018.12.008. | Study Design, Study Design in Meta-Analysis
54 | Huang RY, Huang CC, Hu FB, et al. Vegetarian Diets and Weight Reduction: a Meta-Analysis of Randomized Controlled Trials. J Gen Intern Med. 2016;31:109–16. doi:10.1007/s11606-015-3390-7. | Intervention/Exposure
55 | Hui Y, Tu C, Liu D, et al. Risk factors for gastric cancer: A comprehensive analysis of observational studies. Front Public Health. 2022;10:892468. doi:10.3389/fpubh.2022.892468 . | Intervention/Exposure
56 | Iguacel I, Huybrechts I, Moreno LA, et al. Vegetarianism and veganism compared with mental health and cognitive outcomes: a systematic review and meta-analysis. Nutr Rev. 2021;79:361–381. doi:10.1093/nutrit/nuaa030. | Intervention/Exposure
57 | Iguacel I, Miguel-Berges ML, Gómez-Bruton A, et al. Veganism, vegetarianism, bone mineral density, and fracture risk: a systematic review and meta-analysis. Nutr Rev. 2019;77:1–18. doi:10.1093/nutrit/nuy045. | Intervention/Exposure
58 | Ilori TO, Zhen A, Velani RN, et al. The impact of dietary and lifestyle interventions on blood pressure management in sub-Saharan Africa: a systematic review and metanalysis. J Hypertens. 2023;41:918–925. doi:10.1097/hjh.0000000000003411. | Intervention/Exposure
59 | Jabri A, Kumar A, Verghese E, et al. Meta-analysis of effect of vegetarian diet on ischemic heart disease and all-cause mortality. Am J Prev Cardiol. 2021;7:100182. doi:10.1016/j.ajpc.2021.100182. | Intervention/Exposure
60 | Jannasch F, Dietrich S, Bishop TRP, et al. Associations between exploratory dietary patterns and incident type 2 diabetes: a federated meta-analysis of individual participant data from 25 cohort studies. Eur J Nutr. 2022;61:3649–3667. doi:10.1007/s00394-022-02909-9. | Study Design, Study Design in Meta-Analysis
61 | Jensen CF. Vitamin B12 levels in children and adolescents on plant-based diets: a systematic review and meta-analysis. Nutr Rev. 2023;81:951–966. doi:10.1093/nutrit/nuac096. | Intervention/Exposure
62 | Jeong J, Kim HS, Lee D, et al. Association between Four Dietary Patterns and the Risk of Periodontal Diseases: A Systematic Review and Meta-Analysis. Nutrients. 2022;14:4362. doi:10.3390/nu14204362. | Study Design in Meta-Analysis, Intervention/Exposure
63 | Keshani M, Feizi A, Askari G, et al. Effects of therapeutic lifestyle change diets on blood lipids, lipoproteins, glycemic parameters, and blood pressure: a systematic review and meta-analysis of clinical trials. Nutr Rev. 2024;82:176–192. doi:10.1093/nutrit/nuad051. | Intervention/Exposure
64 | Khademi Z, Pourreza S, Amjadifar A, et al. Dietary Patterns and Risk of Inflammatory Bowel Disease: A Systematic Review of Observational Studies. Inflamm Bowel Dis. 2024;30:2205–2216. doi:10.1093/ibd/izad297. | Study Design
65 | Khan MS, Khan F, Fonarow GC, et al. Dietary interventions and nutritional supplements for heart failure: a systematic appraisal and evidence map. Eur J Heart Fail. 2021;23:1468–1476. doi:10.1002/ejhf.2278. | Study Design, Study Design in Meta-Analysis
66 | Kinshella MW, Omar S, Scherbinsky K, et al. Maternal Dietary Patterns and Pregnancy Hypertension in Low- and Middle-Income Countries: A Systematic Review and Meta-analysis. Adv Nutr. 2021;12:2387–2400. doi:10.1093/advances/nmab057 . | Study Design, Intervention/Exposure
67 | Koch CA, Kjeldsen EW, Frikke-Schmidt R. Vegetarian or vegan diets and blood lipids: a meta-analysis of randomized trials. Eur Heart J. 2023;44:2609–2622. doi:10.1093/eurheartj/ehad211. | Intervention/Exposure
68 | Langer G, Wan CS, Fink A, et al. Nutritional interventions for preventing and treating pressure ulcers. Cochrane Database Syst Rev. 2024;2:Cd003216. doi:10.1002/14651858.CD003216.pub3. | Intervention/Exposure
69 | Lee Y, Park K. Adherence to a Vegetarian Diet and Diabetes Risk: A Systematic Review and Meta-Analysis of Observational Studies. Nutrients. 2017;9:603. doi:10.3390/nu9060603. | Intervention/Exposure
70 | Li M, Francis E, Hinkle SN, et al. Preconception and Prenatal Nutrition and Neurodevelopmental Disorders: A Systematic Review and Meta-Analysis. Nutrients. 2019;11:1628. doi:10.3390/nu11071628. | Study Design in Meta-Analysis, Intervention/Exposure
71 | Limketkai BN, Godoy-Brewer G, Parian AM, et al. Dietary Interventions for the Treatment of Inflammatory Bowel Diseases: An Updated Systematic Review and Meta-analysis. Clin Gastroenterol Hepatol. 2023;21:2508–2525.e10. doi:10.1016/j.cgh.2022.11.026. | Intervention/Exposure
72 | Liu Y, Zhu L, Li D, et al. Stroke risk with vegetarian, low-animal and high-animal diets: A systematic review and meta-analysis. Asia Pac J Clin Nutr. 2022;31:422–432. doi:10.6133/apjcn.202209_31(3).0010. | Intervention/Exposure, Outcome
73 | Lopez P, Newton RU, Taaffe DR, et al. Interventions for Improving Body Composition in Men with Prostate Cancer: A Systematic Review and Network Meta-analysis. Med Sci Sports Exerc. 2022;54:728–740. doi:10.1249/mss.0000000000002843. | Intervention/Exposure
74 | Louise J, Poprzeczny AJ, Deussen AR, et al. The effects of dietary and lifestyle interventions among pregnant women with overweight or obesity on early childhood outcomes: an individual participant data meta-analysis from randomised trials. BMC Med. 2021;19:128. doi:10.1186/s12916-021-01995-6. | Intervention/Exposure
75 | Malakou E, Linardakis M, Armstrong MEG, et al. The Combined Effect of Promoting the Mediterranean Diet and Physical Activity on Metabolic Risk Factors in Adults: A Systematic Review and Meta-Analysis of Randomised Controlled Trials. Nutrients. 2018;10:1577. doi:10.3390/nu10111577. | Intervention/Exposure, Comparator
76 | Marshall TA. Weak Evidence Suggests Vegetarian Diets May Be Associated With an Increased Risk of Dental Erosion. J Evid Based Dent Pract. 2021;21:101524. doi:10.1016/j.jebdp.2020.101524. | Study Design
77 | Martin A, Booth JN, Laird Y, et al. Physical activity, diet and other behavioural interventions for improving cognition and school achievement in children and adolescents with obesity or overweight. Cochrane Database Syst Rev. 2018;3:Cd009728. doi:10.1002/14651858.CD009728.pub4. | Intervention/Exposure
78 | Melgar B, Diaz-Arocutipa C, Huerta-Rengifo C, et al. Vegetarian diets on anthropometric, metabolic and blood pressure outcomes in people with overweight and obesity: a systematic review and meta-analysis of randomized controlled trials. Int J Obes (Lond). 2023;47:903–910. doi:10.1038/s41366-023-01357-7 . | Intervention/Exposure
79 | Meulenbroeks D, Otten E, Smeets S, et al. The Association of a Vegan Diet during Pregnancy with Maternal and Child Outcomes: A Systematic Review. Nutrients. 2024;16:3329. doi:10.3390/nu16193329. | Study Design, Intervention/Exposure
80 | Micha R, Shulkin ML, Penalvo JL, et al. Etiologic effects and optimal intakes of foods and nutrients for risk of cardiovascular diseases and diabetes: Systematic reviews and meta-analyses from the Nutrition and Chronic Diseases Expert Group (NutriCoDE). PLoS One. 2017;12:e0175149. doi:10.1371/journal.pone.0175149. | Study Design, Intervention/Exposure
81 | Mijatovic-Vukas J, Capling L, Cheng S, et al. Associations of Diet and Physical Activity with Risk for Gestational Diabetes Mellitus: A Systematic Review and Meta-Analysis. Nutrients. 2018;10:698. doi:10.3390/nu10060698. | Intervention/Exposure
82 | Neale EP, Rosario VD, Probst Y, et al. Lifestyle Interventions, Kidney Disease Progression, and Quality of Life: A Systematic Review and Meta-analysis. Kidney Med. 2023;5:100643. doi:10.1016/j.xkme.2023.100643. | Intervention/Exposure
83 | Nicolaou M, Colpo M, Vermeulen E, et al. Association of a priori dietary patterns with depressive symptoms: a harmonised meta-analysis of observational studies. Psychol Med. 2020;50:1872–1883. doi:10.1017/s0033291719001958. | Study Design
84 | Niklewicz A, Hannibal L, Warren M, et al. A systematic review and meta-analysis of functional vitamin B12 status among adult vegans. Nutr Bull. 2024;49:463–479. doi:10.1111/nbu.12712 . | Intervention/Exposure
85 | Nitschke E, Gottesman K, Hamlett P, et al. Impact of Nutrition and Physical Activity Interventions Provided by Nutrition and Exercise Practitioners for the Adult General Population: A Systematic Review and Meta-Analysis. Nutrients. 2022;14:1729. doi:10.3390/nu14091729. | Intervention/Exposure
86 | Norde MM, Collese TS, Giovannucci E, et al. A posteriori dietary patterns and their association with systemic low-grade inflammation in adults: a systematic review and meta-analysis. Nutr Rev. 2021;79:331–350. doi:10.1093/nutrit/nuaa010. | Study Design in Meta-Analysis
87 | Nsabimana P, Sombié OO, Pauwels NS, et al. Association between urbanization and metabolic syndrome in low- and middle-income countries: A systematic review and meta-analysis. Nutr Metab Cardiovasc Dis. 2024;34:235–250. doi:10.1016/j.numecd.2023.07.040. | Intervention/Exposure, Outcome
88 | Ocklenburg S, Borawski J. Vegetarian diet and depression scores: A meta-analysis. J Affect Disord. 2021;294:813–815. doi:10.1016/j.jad.2021.07.098. | Intervention/Exposure
89 | Okobi OE, Odoma VA, Okunromade O, et al. Effect of Avocado Consumption on Risk Factors of Cardiovascular Diseases: A Systematic Review and Meta-Analysis. Cureus. 2023;15:e41189. doi:10.7759/cureus.41189 . | Intervention/Exposure
90 | Orange ST, Hicks KM, Saxton JM. Effectiveness of diet and physical activity interventions amongst adults attending colorectal and breast cancer screening: a systematic review and meta-analysis. Cancer Causes Control. 2021;32:13–26. doi:10.1007/s10552-020-01362-5. | Intervention/Exposure
91 | Pang B, Zhao LH, Li XL, et al. Different intervention strategies for preventing type 2 diabetes mellitus in China: A systematic review and network meta-analysis of randomized controlled trials. Diabetes Obes Metab. 2018;20:718–722. doi:10.1111/dom.13121. | Intervention/Exposure
92 | Peng Y, Cao S, Yao Z, et al. Prevalence of the cardiovascular health status in adults: A systematic review and meta-analysis. Nutr Metab Cardiovasc Dis. 2018;28:1197–1207. doi:10.1016/j.numecd.2018.08.002. | Intervention/Exposure, Outcome
93 | Porras M, Rada G, Durán J. Effects of Mediterranean diet on the treatment of rheumatoid arthritis. Medwave. 2019;19:e7640. doi:10.5867/medwave.2019.05.7639. | Publication Language
94 | Pourmotabbed A, Awlqadr FH, Mehrabani S, et al. Ultra-Processed Food Intake and Risk of Insomnia: A Systematic Review and Meta-Analysis. Nutrients. 2024;16:3767. doi:10.3390/nu16213767 . | Study Design in Meta-Analysis, Intervention/Exposure
95 | Rai S, Kulkarni A, Ghoshal UC. Prevalence and risk factors for gastroesophageal reflux disease in the Indian population: A meta-analysis and meta-regression study. Indian J Gastroenterol. 2021;40:209–219. doi:10.1007/s12664-020-01104-0. | Intervention/Exposure
96 | Raji Lahiji M, Vafa S, de Souza RJ, et al. Effect of Dietary-Based Lifestyle Modification Approaches on Anthropometric Indices and Dietary Intake Parameters in Women with Breast Cancer: A Systematic Review and Meta-Analysis of Randomized Controlled Trials. Adv Nutr. 2022;13:1974–1988. doi:10.1093/advances/nmac062. | Intervention/Exposure
97 | Samimisedeh P, Afshar EJ, Ejtahed HS, et al. The impact of vegetarian diet on sperm quality, sex hormone levels and fertility: a systematic review and meta-analysis. J Hum Nutr Diet. 2024;37:57–78. doi:10.1111/jhn.13230. | Intervention/Exposure
98 | Santa K, Tamaki R, Watanabe K, et al. Comparative analysis of COVID-19 responses in Japan and Africa: diet, phytochemicals, vitamin D, and gut microbiota in reducing mortality-A systematic review and meta-analysis. Front Nutr. 2024;11:1465324. doi:10.3389/fnut.2024.1465324 . | Study Design in Meta-Analysis, Intervention/Exposure, Outcome
99 | Schwingshackl L, Missbach B, König J, et al. Adherence to a Mediterranean diet and risk of diabetes: a systematic review and meta-analysis. Public Health Nutr. 2015;18:1292–9. doi:10.1017/s1368980014001542. | Publication Date
100 | Schwingshackl L, Schwedhelm C, Hoffmann G, et al. Food Groups and Risk of Hypertension: A Systematic Review and Dose-Response Meta-Analysis of Prospective Studies. Adv Nutr. 2017;8:793–803. doi:10.3945/an.117.017178. | Intervention/Exposure
101 | Shafiei F, Salari-Moghaddam A, Larijani B, et al. Mediterranean diet and depression: reanalysis of a meta-analysis. Nutr Rev. 2023;81:889–890. doi:10.1093/nutrit/nuad023. | Study Design
102 | Shi X, Zhu P, Du M, et al. Dietary patterns and periodontitis: A systematic review. J Periodontal Res. 2024;doi:10.1111/jre.13346. | Study Design in Meta-Analysis
103 | Shieh C, Cullen DL, Pike C, et al. Intervention strategies for preventing excessive gestational weight gain: systematic review and meta-analysis. Obes Rev. 2018;19:1093–1109. doi:10.1111/obr.12691. | Intervention/Exposure
104 | Shrivastava R, Gupta A, Mehta N, et al. Dietary patterns and risk of oral and oropharyngeal cancers: A systematic review and metaanalysis. Cancer Epidemiol. 2024;93:102650. doi:10.1016/j.canep.2024.102650. | Study Design in Meta-Analysis
105 | Sivaratnam L, Selimin DS, Abd Ghani SR, et al. Behavior-Related Erectile Dysfunction: A Systematic Review and Meta-Analysis. J Sex Med. 2021;18:121–143. doi:10.1016/j.jsxm.2020.09.009. | Intervention/Exposure
106 | Smits KPJ, Listl S, Jevdjevic M. Vegetarian diet and its possible influence on dental health: A systematic literature review. Community Dent Oral Epidemiol. 2020;48:7–13. doi:10.1111/cdoe.12498. | Intervention/Exposure
107 | Spiga F, Davies AL, Tomlinson E, et al. Interventions to prevent obesity in children aged 5 to 11 years old. Cochrane Database Syst Rev. 2024;5:Cd015328. doi:10.1002/14651858.CD015328.pub2. | Intervention/Exposure
108 | Spiga F, Tomlinson E, Davies AL, et al. Interventions to prevent obesity in children aged 12 to 18 years old. Cochrane Database Syst Rev. 2024;5:Cd015330. doi:10.1002/14651858.CD015330.pub2. | Intervention/Exposure
109 | Steckhan N, Hohmann CD, Kessler C, et al. Effects of different dietary approaches on inflammatory markers in patients with metabolic syndrome: A systematic review and meta-analysis. Nutrition. 2016;32:338–48. doi:10.1016/j.nut.2015.09.010. | Intervention/Exposure
110 | Tan C, Zhao Y, Wang S. Is a vegetarian diet safe to follow during pregnancy? A systematic review and meta-analysis of observational studies. Crit Rev Food Sci Nutr. 2019;59:2586–2596. doi:10.1080/10408398.2018.1461062. | Intervention/Exposure
111 | Teasdale SB, Ward PB, Rosenbaum S, et al. Solving a weighty problem: systematic review and meta-analysis of nutrition interventions in severe mental illness. Br J Psychiatry. 2017;210:110–118. doi:10.1192/bjp.bp.115.177139. | Intervention/Exposure
112 | Termannsen AD, Søndergaard CS, Færch K, et al. Effects of Plant-Based Diets on Markers of Insulin Sensitivity: A Systematic Review and Meta-Analysis of Randomised Controlled Trials. Nutrients. 2024;16:2110. doi:10.3390/nu16132110. | Intervention/Exposure
113 | Toh DWK, Koh ES, Kim JE. Incorporating healthy dietary changes in addition to an increase in fruit and vegetable intake further improves the status of cardiovascular disease risk factors: A systematic review, meta-regression, and meta-analysis of randomized controlled trials. Nutr Rev. 2020;78:532–545. doi:10.1093/nutrit/nuz104. | Intervention/Exposure
114 | Tsilidis KK, Cariolou M, Becerra-Tomás N, et al. Postdiagnosis body fatness, recreational physical activity, dietary factors and breast cancer prognosis: Global Cancer Update Programme (CUP Global) summary of evidence grading. Int J Cancer. 2023;152:635–644. doi:10.1002/ijc.34320. | Study Design
115 | Tsilidis KK, Markozannes G, Becerra-Tomás N, et al. Post-diagnosis adiposity, physical activity, sedentary behaviour, dietary factors, supplement use and colorectal cancer prognosis: Global Cancer Update Programme (CUP Global) summary of evidence grading. Int J Cancer. 2024;155:471–485. doi:10.1002/ijc.34904. | Study Design, Intervention/Exposure
116 | Utz-Melere M, Targa-Ferreira C, Lessa-Horta B, et al. Non-Alcoholic Fatty Liver Disease in Children and Adolescents: Lifestyle Change - a Systematic Review and Meta-Analysis. Ann Hepatol. 2018;17:345–354. doi:10.5604/01.3001.0011.7380. | Intervention/Exposure, Outcome
117 | Uusitupa M, Khan TA, Viguiliouk E, et al. Prevention of Type 2 Diabetes by Lifestyle Changes: A Systematic Review and Meta-Analysis. Nutrients. 2019;11:2611. doi:10.3390/nu11112611. | Intervention/Exposure, Comparator
118 | Viguiliouk E, Kendall CW, Kahleová H, et al. Effect of vegetarian dietary patterns on cardiometabolic risk factors in diabetes: A systematic review and meta-analysis of randomized controlled trials. Clin Nutr. 2019;38:1133–1145. doi:10.1016/j.clnu.2018.05.032. | Intervention/Exposure
119 | Wang F, Zheng J, Yang B, et al. Effects of Vegetarian Diets on Blood Lipids: A Systematic Review and Meta-Analysis of Randomized Controlled Trials. J Am Heart Assoc. 2015;4:e002408. doi:10.1161/jaha.115.002408. | Intervention/Exposure
120 | Wang M, Liu J, Zhang Z, et al. Effects of Dietary Intervention on Inflammatory Markers in Metabolic Syndrome: A Systematic Review and Meta-Analysis. Front Nutr. 2022;9:846591. doi:10.3389/fnut.2022.846591. | Intervention/Exposure
121 | Wang XJ, Zhang WS, Jiang CQ, et al. Low-carbohydrate diet score and the risk of stroke in older people: Guangzhou Biobank Cohort Study and meta-analysis of cohort studies. Nutrition. 2023;105:111844. doi:10.1016/j.nut.2022.111844. | Study Design
122 | Weigl J, Hauner H, Hauner D. Can Nutrition Lower the Risk of Recurrence in Breast Cancer?. Breast Care (Basel). 2018;13:86–91. doi:10.1159/000488718. | Study Design
123 | Wu L, Chu L, Pang Y, et al. Effects of dietary supplements, foods, and dietary patterns in Parkinson’s disease: meta-analysis and systematic review of randomized and crossover studies. Eur J Clin Nutr. 2024;78:365–375. doi:10.1038/s41430-024-01411-1. | Intervention/Exposure
124 | Wu PY, Chen KM, Tsai WC. The Mediterranean Dietary Pattern and Inflammation in Older Adults: A Systematic Review and Meta-analysis. Adv Nutr. 2021;12:363–373. doi:10.1093/advances/nmaa116. | Study Design in Meta-Analysis
125 | Xia X, Zhang J, Wang X, et al. Effects of vegetarian diets on blood lipids, blood glucose, and blood pressure: a systematic review and meta-analysis. Food Funct. 2024;15:11834–11846. doi:10.1039/d4fo03449j. | Intervention/Exposure
126 | Yamaoka K, Nemoto A, Tango T. Comparison of the Effectiveness of Lifestyle Modification with Other Treatments on the Incidence of Type 2 Diabetes in People at High Risk: A Network Meta-Analysis. Nutrients. 2019;11:1373. doi:10.3390/nu11061373. | Intervention/Exposure, Outcome
127 | Yang M, Duan Y, Liang W, et al. Effects of Face-to-Face and eHealth Blended Interventions on Physical Activity, Diet, and Weight-Related Outcomes among Adults: A Systematic Review and Meta-Analysis. Int J Environ Res Public Health. 2023;20:1560. doi:10.3390/ijerph20021560. | Intervention/Exposure, Outcome
128 | Yap HJ, Lim JJJ, Tan SD, et al. Effectiveness of digital health interventions on adherence and control of hypertension: a systematic review and meta-analysis. J Hypertens. 2024;42:1490–1504. doi:10.1097/hjh.0000000000003793. | Intervention/Exposure
129 | Yokoyama, Y, Levin, SM, Barnard, ND. Association between plant-based diets and plasma lipids: a systematic review and meta-analysis. Nutr Rev. 2017;75:683–698. doi:10.1093/nutrit/nux030 . | Intervention/Exposure
130 | Yoong SL, Lum M, Wolfenden L, et al. Healthy eating interventions delivered in early childhood education and care settings for improving the diet of children aged six months to six years. Cochrane Database Syst Rev. 2023;8:Cd013862. doi:10.1002/14651858.CD013862.pub3. | Intervention/Exposure, Outcome
131 | Zeb A, Sivarajan Froelicher E, Pienaar AJ, et al. Effectiveness of Community-based Obesity Intervention for Body Weight, Body Mass Index, and Waist Circumference: Meta-analysis. Iran J Nurs Midwifery Res. 2024;29:16–22. doi:10.4103/ijnmr.ijnmr_120_22. | Intervention/Exposure
132 | Zhang FF, Cudhea F, Shan Z, et al. Preventable Cancer Burden Associated With Poor Diet in the United States. JNCI Cancer Spectr. 2019;3:pkz034. doi:10.1093/jncics/pkz034. | Study Design
133 | Zhang J, He M, Yu Q, et al. The Effects of a Healthy Diet on Asthma and Wheezing in Children and Adolescents: A Systematic Review and Meta-Analysis. J Asthma Allergy. 2023;16:1007–1024. doi:10.2147/jaa.S423884. | Intervention/Exposure
134 | Zhang Y, Yang Y, Huang Q, et al. The effectiveness of lifestyle interventions for diabetes remission on patients with type 2 diabetes mellitus: A systematic review and meta-analysis. Worldviews Evid Based Nurs. 2023;20:64–78. doi:10.1111/wvn.12608. | Intervention/Exposure
135 | Zhang YB, Pan XF, Chen J, et al. Combined lifestyle factors, incident cancer, and cancer mortality: a systematic review and meta-analysis of prospective cohort studies. Br J Cancer. 2020;122:1085–1093. doi:10.1038/s41416-020-0741-x. | Intervention/Exposure
136 | Zhao XH, Zhang ZH. Risk factors for postpartum depression: An evidence-based systematic review of systematic reviews and meta-analyses. Asian J Psychiatr. 2020;53:102353. doi:10.1016/j.ajp.2020.102353. | Study Design, Intervention/Exposure
137 | Zou TT, Zhang C, Zhou YF, et al. Lifestyle interventions for patients with nonalcoholic fatty liver disease: a network meta-analysis. Eur J Gastroenterol Hepatol. 2018;30:747–755. doi:10.1097/meg.0000000000001135. | Intervention/Exposure, Comparator