# Appendix 1 Abbreviations

Table A 1 List of abbreviations
Abbreviation: Full name
AHEI: Alternative Healthy Eating Index
AMSTAR 2: A Measurement Tool to Assess systematic Reviews 2
DASH: Dietary Approaches to Stop Hypertension
HEI: Healthy Eating Index
KIDMED: Mediterranean Diet Quality Index for children and adolescents
MDS: Mediterranean Diet Score
MEDAS: Mediterranean Diet Adherence Screener
MOOSE: Meta-analyses Of Observational Studies in Epidemiology
NESR: Nutrition Evidence Systematic Review
NRCT: Non-randomized controlled trial
PCA: Principal component analysis
PCS: Prospective cohort study
PDI: Plant-based Dietary Index
PRISMA: Preferred Reporting Items for Systematic reviews and Meta-Analyses
RCS: Retrospective cohort study
RCT: Randomized controlled trial
RRR: Reduced rank regression
SUCRA: Surface under the cumulative ranking curve
USDA: United States Department of Agriculture