# List of abbreviations

Abbreviation: Full name
AMDR: Acceptable macronutrient distribution range
BMI: Body mass index
CNPP: Center for Nutrition Policy and Promotion
CVD: Cardiovascular disease
% E: % energy
EVOO: Extra virgin olive oil
FFMI: Fat-free mass index
FMI: Fat mass index
FNS: Food and nutrition service
f/u: Follow-up
HHS: Health and Human Services
mo: Month(s)
NESR: Nutrition Evidence Systematic Review team
ONGA: Office of Nutrition Guidance and Analysis
PCS: Prospective cohort study design
PREDIMED: Prevención con Dieta Mediterránea
RRR: Reduced rank regression
USDA: United States Department of Agriculture
wk: Week(s)
y: Year(s)