# WHAT IS THE RELATIONSHIP BETWEEN DIETARY PATTERNS CONSUMED AND GROWTH, SIZE, BODY COMPOSITION, AND/OR RISK OF OVERWEIGHT OR OBESITY?

## PLAIN LANGUAGE SUMMARY

### What is the question?

- The question is: What is the relationship between dietary patterns consumed and growth, size, body composition, and/or risk of overweight or obesity?

### What is the answer to the question?

Dietary patterns: Children

- Limited evidence suggests that dietary patterns consumed by children or adolescents that are lower in fruits, vegetables, whole grains, and low-fat dairy while being higher in added sugars, refined grains, fried potatoes, and processed meats are associated with higher fat-mass index and BMI later in adolescence.

Dietary patterns: Adults

- The 2020 Dietary Guidelines Advisory Committee reviewed recently published evidence using a systematic evidence scan and determined that the conclusion drawn by the 2015 Dietary Guidelines Advisory Committee generally reflects the current state of science: Moderate evidence indicates dietary patterns emphasizing vegetables, fruits, and whole grains; seafood and legumes; moderate in dairy products (particularly low and non-fat dairy) and alcohol; lower in meats (including red and processed meats), and low in sugar-sweetened foods and beverages, and refined grains are associated with favorable outcomes related to body weight, (including lower BMI, waist circumference, or percent body fat) or risk of obesity. Components of the dietary patterns associated with these favorable outcomes include higher intakes of unsaturated fats and lower intakes of saturated fats, cholesterol, and sodium.

Diets based on macronutrient distribution: Children

- No evidence is available to determine a relationship between diets based on macronutrient distribution consumed during childhood and growth, size, body composition, and risk of overweight/obesity.

Diets based on macronutrient distribution: Adults

- Insufficient evidence is available to determine the relationship between macronutrient distributions with proportions of energy falling outside of the AMDR for at least one macronutrient due to methodological limitations and inconsistent results.

### Why was this question asked?

- This important public health question was identified by the U.S. Departments of Agriculture (USDA) and Health and Human Services (HHS) to be examined by the 2020 Dietary Guidelines Advisory Committee.

### How was this question answered?

- The 2020 Dietary Guidelines Advisory Committee, Dietary Patterns Subcommittee conducted a systematic review and a systematic evidence scan to answer this question with support from the Nutrition Evidence Systematic Review (NESR) team.
- Dietary patterns were defined as the quantities, proportions, variety, or combination of different foods, drinks, and nutrients (when available) in diets, and the frequency with which they are habitually consumed.
- Diets based on macronutrient distribution were examined when at least one macronutrient proportion outside of the acceptable macronutrient distribution range (AMDR) for carbohydrate, fat, and/or protein, whether or not the foods/food groups consumed were provided.

### What is the population of interest?

- Children and adults, ages 2 years and older

### What evidence was found?

- This review identified 88 articles that met inclusion criteria.
- Twelve articles examined dietary patterns consumed by children or adolescents and growth, size, body composition, and/or risk of overweight or obesity.
  ○ Dietary patterns that were lower in fruits, vegetables, whole grains, and low-fat dairy, and higher in added sugars, refined grains, fried potatoes, and processed meat were related to higher body fat mass and body mass index (BMI).
  ○ The 2020 Committee determined the strength of this evidence was limited.
- Fifty-four articles examined dietary patterns consumed by adults and growth, size, body composition, and/or risk of overweight or obesity.
  ○ The 2020 Committee determined these articles were generally consistent with those from an existing NESR systematic review. Therefore, the 2020 Committee carried forward the conclusion from the 2015 Committee.
- No articles met inclusion criteria that examined diets based on macronutrient distribution consumed by children or adolescents and growth, size, body composition, and/or risk of overweight or obesity.
  ○ The 2020 Committee could not draw conclusions because there were no studies.
- Thirty-one articles examined diets based on macronutrient distribution consumed by adults and growth, size, body composition, and/or risk of overweight or obesity.
  ○ Many limitations in the study design and conduct of included articles were identified. This includes a lack of accounting for key confounders or possible changes in dietary intake over follow-up.
  ○ The 2020 Committee could not draw conclusions because the included studies had several limitations.

### How up-to-date is this systematic review?

- This review searched for studies from January, 2000 to October, 2019; and updated existing systematic reviews that included evidence from January 2000 to January 2014.

## FULL REVIEW

### Systematic review question

What is the relationship between dietary patterns consumed and growth, size, body composition, and/or risk of overweight or obesity?

### Conclusion statements and grades

#### Dietary patterns: Children

Limited evidence suggests that dietary patterns consumed by children or adolescents that are lower in fruits, vegetables, whole grains, and low-fat dairy while being higher in added sugars, refined grains, fried potatoes, and processed meats are associated with higher fat-mass index and BMI later in adolescence. (Grade: Limited)

#### Dietary patterns: Adults

The 2020 Dietary Guidelines Advisory Committee reviewed recently published evidence using a systematic evidence scan and determined that the conclusion drawn by the 2015 Dietary Guidelines Advisory Committee generally reflects the current state of science. Moderate evidence indicates dietary patterns emphasizing vegetables, fruits, and whole grains; seafood and legumes; moderate in dairy products (particularly low and non-fat dairy) and alcohol; lower in meats (including red and processed meats), and low in sugar-sweetened foods and beverages, and refined grains are associated with favorable outcomes related to body weight, (including lower BMI, waist circumference, or percent body fat) or risk of obesity. Components of the dietary patterns associated with these favorable outcomes include higher intakes of unsaturated fats and lower intakes of saturated fats, cholesterol, and sodium. (2015 Dietary Guidelines Advisory Committee Grade: Moderate)

#### Diets based on macronutrient distribution: Children

No evidence is available to determine a relationship between diets based on macronutrient distribution consumed by children or adolescents and growth, size, body composition, and risk of overweight/obesity. (Grade: Grade not assignable)

#### Diets based on macronutrient distribution: Adults

Insufficient evidence is available to determine the relationship between macronutrient distributions with proportions of energy falling outside of the AMDR for at least one macronutrient and growth, size, body composition, and/or risk of overweight or obesity, due to methodological limitations and inconsistent results. (Grade: Grade not assignable)

### Summary of the evidence

- Eighty-eight articles were identified that met inclusion criteria and examined the relationship between dietary patterns and/or diets based on macronutrient proportion and growth, size, body composition, and/or risk of overweight or obesity.
  ○ Dietary patterns were defined as the quantities, proportions, variety, or combination of different foods, drinks, and nutrients (when available) in diets, and the frequency with which they are habitually consumed.
  ○ Diets based on macronutrient distribution were considered to be those with at least one macronutrient proportion outside of the acceptable macronutrient distribution range (AMDR^ii^) for carbohydrate, fat, and/or protein, whether or not the foods/food groups consumed were provided.
    ■ When describing and categorizing studies included in this review, the Committee did not label the diets examined as “low” or “high,” because no universally accepted, standard definition is currently available, for example, for “low-carbohydrate” or “high-fat” diets. Instead, the Committee focused on whether, and the extent to which, the proportions of the macronutrients were below or above the AMDR.
  ○ Studies examining energy-restricted diets that induce weight loss or treat overweight and obesity for the purposes of treating additional or other medical conditions were excluded.

#### Dietary patterns: Children

- Twelve articles examined dietary patterns consumed by children and growth, size, body composition, and/or risk of overweight or obesity, met inclusion criteria, and were published between January 2013 and October 2019.^1–12^
  ○ All 12 articles were from prospective cohort studies.
  ○ Dietary patterns were assessed using a variety of methods including factor/cluster analysis, indices or scores, latent class analysis, and reduced rank regression
  ○ Outcome measures varied across studies and included incidence of overweight/obesity, fat mass, lean mass, body mass index (BMI), central adiposity, and weight/height.
  ○ Despite variability in methods, dietary patterns in childhood or adolescence that generally reflect poorer diet quality tended to associate with higher fat-mass index and BMI later in adolescence. However, the findings should be interpreted with caution due to several limitations.
    ■ Across the body of evidence, the direction of significant findings were mixed with relatively small and inconsistent magnitude.
    ■ Most of the studies assessed diet once at baseline with methods that were not necessarily validated, reliable, or applicable for children

#### Dietary patterns: Adults

- Fifty-four articles were identified by a systematic evidence scan examining dietary patterns consumed by adults and growth, size, body composition, and/or risk of overweight or obesity.^13–60,61,62–66^
  ○ These articles represent new evidence published since a review done by the 2015 Dietary Guidelines Advisory Committee.^iii^
  ○ A systematic evidence scan was conducted to identify and examine these articles, and determine whether a full systematic review update was warranted.
  ○ Based on results from the systematic evidence scan, the 2020 Committee determined that the newly published evidence was generally consistent with the body of evidence from the existing review, and a full systematic review update was not needed at this time. Therefore, the conclusion statement and grade from the existing review were carried forward.

#### Diets based on macronutrient distribution: Children

- No studies identified met inclusion criteria that examined diets based on macronutrient distribution consumed by children or adolescents and growth, size, body composition, and/or risk of overweight or obesity.

#### Diets based on macronutrient distribution: Adults

- Thirty-one articles examined diets based on macronutrient distribution consumed by adults and growth, size, body composition, and/or risk of overweight or obesity, met inclusion criteria, and were published between January 2000 and October 2019.^14,23,24,28,33,37,41,55,61,67–88^
  ○ Twenty-two articles came from randomized controlled trials (RCTs) and nine articles came from prospective cohort studies
  ○ Most of the articles examined distributions in which the proportion of energy from carbohydrate as below the AMDR; fat was above the AMDR; and protein was within the AMDR in at least one of the exposure groups compared.
  ○ Foods or food groups consumed as part of the diet were not reported consistently.
  ○ Results across studies were inconsistent, with the majority of studies reporting no significant association between diets based on macronutrient distribution and growth, size, body composition, and/or risk of overweight or obesity.
    ■ Some studies reported diets based on macronutrient distributions with proportions of energy from carbohydrate and/or fat within or close to AMDRs compared to those that were outside AMDRs significantly associated with favorable fat-mass, BMI, waist circumference, and/or change in weight. Notably, these results were closely linked to better quality of the diet, which typically consisted of vegetables, fruit, whole-grains, unsaturated vegetable oils, nuts, pulses, and/or lean meat or fish.
    ■ Numerous limitations that prevent adequate assessment across this body of evidence were identified:
      - Several studies did not directly test the difference in macronutrient proportions in the context of various dietary patterns during energy balance.
      - Although statistically significant relationships were reported, the gradient between macronutrient distributions was relatively narrow within studies (e.g., 45.3% vs. 43.8% carbohydrate) and between studies
      - Due to the variety of methods used to estimate macronutrient intake and adjust intake for total energy, the confidence in the reported proportions of energy falling outside the AMDR is low.
      - Several studies reported to be examining one particular macronutrient of interest, such as “high-protein” or “low-carbohydrate” intake, but the proportion for that nutrient was within the AMDR.

### Description of the evidence

#### Dietary patterns: Children

##### Population/participant characteristics

The 12 studies examining dietary patterns in children that are included in this systematic review were conducted in the following countries:

- Australia^3^
- Portugal^4^
- The Netherlands^8^
- United Kingdom^1,2,9,11^
- United States^6,7^

One multi-country study from Italy, Estonia, Cyprus, Belgium, Sweden, Hungary, Germany, and Spain was included in 3 articles.^5,10,12^ Multiple articles from the same study were included, but reported unique data on dietary patterns, outcomes, and ages of participants examined. Data from the following cohorts were represented in the evidence:

- Avon Longitudinal Study of Parents and Children (ALSPAC) cohort^2,11^
- Generation R Study^8^
- Generation XXI^4^
- Growing Up Today Study 2^7^
- Identification and prevention of Dietary- and lifestyle-induced health EFfects In Children and infantS (IDEFICS) study^5,12^
- Project EAT^6^
- Southampton Women’s Survey^9^
- Western Australian Pregnancy Cohort^3^

Sample size in the included articles ranged from 1,018 to 10,918 participants. Studies included participants who were healthy and/or at risk of chronic disease, or diagnosed with a chronic disease. Studies enrolled both boys and girls in relatively equal amounts. Participants with missing data were excluded from analyses in all studies, and those with diseases that influence diet were typically excluded.

##### Intervention/exposure

Dietary patterns were assessed at a mean age of participants, ranging from 2 to 15 years, using a variety of methods.

- Five studies examined adherence to dietary patterns using 5 different indices or scores,^3,6–8,12^ and
- Five studies used factor/cluster analysis^2,5,9–11^
- One study each used latent class analysis,^4^ or reduced rank regression.^1^

Dietary intake was assessed using a variety of methods in which the validity and reliability were inconsistent or unknown, or only validated in adults. Most studies assessed diet once at baseline. Three articles reported diet assessments at each age/timepoint examined.

##### Outcome assessment

Included studies examined outcomes over follow-up at a range of ages between 4y to 25y. Growth, size, body composition, and/or risk of overweight or obesity outcomes were reported as follows:

- Overweight/obesity incidence^10^
- Fat-mass, fat-mass index (FMI), FMI z-score (FMIz), or change in % fat mass^1,4,5,8,11,12^
- Lean mass or fat-free mass, including fat-free mass index (FFMI)^5,8,11^
- Body mass index (BMI) or BMI-z-score^2–10,12^
- Central adiposity or waist circumference^3–5,12^
- Absolute or change in (excess) weight and/or height^6,8^

#### Dietary patterns: Adults

Fifty-four articles met inclusion criteria, were published between January 2013 and October 2019, and examined dietary patterns in adults and growth, size, body composition, and/or risk of overweight or obesity.^13–60^ ^61^ ^62–66^

#### Diets based on macronutrient distribution: Children

No studies identified that met inclusion criteria examined diets based on macronutrient proportion in children.

#### Diets based on macronutrient distribution: Adults

##### Population/participant characteristics

Studies were conducted in populations from the following countries:

- Australia23,24,70,82
- China^81^
- Denmark^83^
- France75,80
- Korea^88^
- New Zealand^68,69^
- Spain14,76,84,86
- Sweden^28^
- United Kingdom^55,77^
- United States^33,37,41,61,67,71–73,85,87^
- Multiple countries within Europe,^74,78^ or Finland, Sweden, Denmark, and Iceland.^79^

Studies enrolled primarily healthy, adults or older adults. Primary results were included from the Prevención con Dieta Mediterránea (PREDIMED) randomized-controlled trial (RCT), which enrolled adults at high-risk for cardiovascular disease across multiple sites.^14,76^ Multiple articles reported results from the same established cohorts, e.g., Framingham Heart Study Offspring, and reported different macronutrient distributions, dietary patterns, and/or outcomes.

##### Intervention/exposure

Dietary intake was measured with various approaches including picture-plate waste, food records, 24-h recalls, validated FFQ, or diet history. Most of the included articles came from RCTs that confirmed dietary compliance with 3-4-day food records at baseline, and during follow-up. In the observational studies, diet assessment was primarily assessed once at baseline using validated methods or every 2y during follow-up.

Diets based on macronutrient distribution varied across studies, with some studies intentionally examining varied levels of specific macronutrient proportions while other studies focused on adherence to different dietary patterns such as a “Mediterranean” diet, published dietary guidelines, regional dietary patterns, or specific markers of diet quality. Twenty-two trials randomized participants to consume specific diets compared to control groups. Among the nine observational studies, several examined categories of total protein intake or adherence scores for a particular dietary pattern, where the macronutrient proportions of intake that were reported fell outside the AMDR.

Among the macronutrient distributions reported, the proportions of energy falling outside of the AMDR were as follows:

- Carbohydrate below the AMDR ranged between 25.3% and 44.9%
- Carbohydrate above the AMDR ranged between 66% and 77.5%
- Fat above the AMDR ranged between 35.2% and 47%
- Fat below the AMDR ranged between 9.9% and 19.3%
- Protein was above the AMDR in one study at 43.5%

The majority of studies examined macronutrient distributions in which the proportion of energy from carbohydrate was below the AMDR, and fat above the AMDR, in at least one of the exposure groups compared.^14,23,24,28,33,37,55,61,67–72,74–80,82–87^ Few studies examined macronutrient distributions in which the proportion of energy from carbohydrate was above the AMDR,^41,81,88^ with the proportion from fat either below, above, or within the AMDR. Only one study examined macronutrient distributions within the AMDR for carbohydrate and protein, and above the AMDR for fat only.^73^

##### Outcome assessment

Outcomes were measured using standardized methods by trained staff across most studies. Included studies primarily utilized dual-energy X-ray absorptiometry (DXA) and/or bio-electrical impedance analysis (BIA) to assess body composition, calibrated stadiometers to obtain height, calibrated scales to obtain weight, and tape to measure waist circumference. Few studies used self-reported anthropometric data^82,84,86^ or provided limited information on outcome assessment methods.^61,81,83^ Included studies examined outcomes over follow-up ranging in the RCT’s from 12wk to 2y, and in observational studies between 2y and 20y. The following growth, size, body composition, and/or risk of overweight or obesity outcomes were reported:

- Overweight and/or obesity incidence, range of follow-up 12wk to 7y^68,82,84–86^
- Fat-mass and/or lean or fat-free mass^14,23,33,41,67–72,75,78,88^
- Body mass index (BMI)^14,24,33,41,67–73,75,78,80,84,88^
- Central adiposity or waist circumference^14,33,37,55,67,69,70,72,73,75,76,78,81,83^
- Absolute or change in body weight^14,28,33,37,55,67,69–75,77–79,81,83,84,87,88^

### Evidence synthesis

Results reported in the studies included in this systematic review are summarized below by evidence that examined dietary patterns in children (Table 1), dietary patterns in adults, and diets based on macronutrient distributions in adults (Table 2).

#### Dietary patterns: Children

##### Summary of results

###### Index/score analysis

###### Mediterranean related indices/scores

Two studies reporting adherence to “Mediterranean” style indices in children were significantly associated with favorable outcomes.

- Martin-Calvo et al^7^ reported increased KidMed adherence scores were significantly associated with lower BMI after 7y follow-up.
- Tognon et al^12^ reported increased Mediterranean diet score adherence was significantly associated with lower gains in BMIz, waist-circumference, and waist-hip-ratio, and lower % fat-mass after 2y follow-up, but no significant association with absolute waist circumference.

###### Country-specific indices

Chan She Ping-Delfos et al^3^ reported increased adherence to the Australian Dietary Guideline Index for Children and Adolescents (DGI-CA) was significantly associated with higher BMI, but lower waist-hip-ratio at 17y follow-up.

###### Other indices/scores

Two studies examined the relationship between dietary patterns in children using diet quality indices.

- Hu et al^6^ reported increased a Priori Diet Quality Score (APDQS) adherence scores were significantly associated with lower BMI and reduced excess weight gain at age 25y.
- Nguyen et al^8^ reported that increased Diet Quality Score adherence scores at age 8y were significantly associated with higher fat-free mass, BMI, and absolute weight and height at 10y. In stratification analyses, results for BMI and weight/height were only significant in girls. No significant association was observed between Diet Quality Score adherence scores at age 8y and % body fat at age 10y.

###### Reduced rank regression

Ambrosini et al^1^ used reduced rank regression with predictor variables: % E from free sugars, %E from fat, dietary energy density (energy/g food consumed), dietary fiber density) to examine two dietary patterns at age 7y, “DP1” and “DP2”. Greater adherence to DP1 (higher in confectionery and chocolate, cakes and biscuits, sugar-sweetened beverages, low-fiber bread, and lower in fruit, vegetables, high-fiber bread, cereals) was significantly associated with higher FMIz, but not excess adiposity, at age 15y. No significant association was reported for adherence to DP2, which was higher in sugar-sweetened beverages, fruit juices, ready-to-eat breakfast cereals, and lower in whole milk, margarines and oils, cheese, crisps, and FMIz or excess adiposity at 15y.

###### Factor/cluster/latent class analysis

Pala et al^10^ examined the following dietary patterns identified by factor/cluster analysis: “Snacking” [characterized by street foods such as sandwiches, savory pastries, chocolate bars], “Sweet” [characterized by chocolate spreads, biscuits and sweets/candy, fried meat, soft drinks], “Vegetables and Wholemeal” [characterized by vegetables, fruits, wholemeal cereal products, unsweetened milk], or “Protein and Water” [characterized by fish, meat, eggs, water]. Increased adherence to the “Vegetables and Wholemeal” [characterized by vegetables, fruits, wholemeal cereal products, unsweetened milk] was significantly associated with reduced risk of overweight or obesity after 2y f/u (~age 4-12y). However, there was no significant association between any of the patterns and change in BMI after 2y f/u (~age 4-12y)

Okubo et al^9^ reported adherence to the “Prudent” dietary pattern score [characterized by fish and shellfish, vegetables (salad, green, root other), other fruits] was significantly associated with lower fat-mass at age 6y, but not significantly associated with BMI at age 6y.

Smith et al^11^ reported increased adherence to the “Health Aware” dietary pattern, characterized by fruits and vegetables, high-fiber bread, pasta, cheese, and fish, lower loadings for chips (French fries), crisps (potato and corn snacks), processed meat, fizzy (carbonated) drinks] was significantly associated with lower fat-mass and lean mass gain at 11y in girls (valid and under-reporting), and boys (under-reporting). Adherence to the “Packed Lunch” dietary pattern, with higher loadings for low-fiber bread, margarine, cheese, cold meats, salty flavorings such as yeast extract, diet squash (dilutable soft drink), was significantly associated with lower fat-mass and lean mass gain at 11y in girls (valid and under-reporting), and under-reporting boys.

Adherence to the “Traditional” dietary pattern, with higher loadings for meat, roast potatoes, vegetables, batter and pastry products, low energy-density sauces (e.g. gravy, desserts) was not significantly associated with fat-mass or lean mass.

Bull and Northstone^2^ reported that the “Processed” or the “Packed Lunch” vs. “Healthy” dietary patterns at age 7y were significantly associated with higher BMI at 17 y f/u. However, the “Traditional” vs. Healthy dietary patterns at age 7y were not significantly associated with BMI at 17 y f/u. None of the dietary patterns at age 10y or 13y were associated with BMI at 17y follow-up. Several key confounders were not adjusted for in analyses, including race/ethnicity, physical activity, and anthropometry.

Durao et al^4^ found that increased adherence to the energy-dense foods (EDF) pattern, characterized by sweets, soft drinks, salty pastry, processed meat, was significantly associated with higher FMI, BMIz, and waist-to-hip-ratio at 7y in girls, but associations were not significant in boys. There were no significant associations between consumption of either the “Snacking”, or “Healthier” dietary patterns and FMI, BMIz, or waist-hip-ratio at 7y in girls or boys.

Fernandez-Alvira et al^5^ reported that consistent consumption of the “Processed” dietary pattern (baseline to follow-up), or changing to a “Processed-Sweet” combination dietary pattern was significantly associated with higher FMI-z, BMIz, and waist-circumference z-score (WC-z) gain at 2y follow-up. Consumption of the “Processed” or “Sweet” compared to “Healthy” dietary pattern consumption at baseline was significantly associated with higher FMI-z, BMIz, and WC-z at follow-up. There were also many non-significant associations reported, such as those between “Processed” or “Sweet” compared to “Healthy” dietary pattern consumption at baseline and change in FFMIz at follow-up.

Overall, five studies reported increased adherence to indices or scores that emphasize vegetables, fruits, “high-fiber” or “wholegrain” bread, or wholemeal cereals were significantly associated with reduced risk of overweight/obesity^10^, lower BMI or reduced-gain in BMI,^6,7,12^ or lower fat mass.^9^ Associations with BMI were not significant in two of these studies.^6,9^ However, the studies also reported significantly lower gain in excess weight^6^, waist circumference, and waist-hip-ratio (WHR).^12^ Three studies reported dietary patterns characterized by sweets and refined grains (confectionary, biscuits, cakes, pastries), sugar-sweetened beverages, processed meats, and/or salty snacks were significantly associated with higher fat-mass index, BMIz, WHR and/or waist circumference-z-score.^1,4,5^ In Duaro et al,^4^ the results were sex-specific (significant in girls but not boys). Additional non-significant associations were reported in these studies when examining different dietary patterns (e.g., “Healthy” vs.”Processed”), or other outcomes (e.g., excess adiposity).

##### Assessment of the evidence^iv^

This systematic review update included 12 articles that examined dietary patterns in children and growth, size, body composition, and/or risk of overweight or obesity, met inclusion criteria, and were published between January 2014 and October 2019. Dietary patterns and outcome measures were assessed using a variety of approaches across studies. Despite variability in methods, dietary patterns in childhood or adolescence that generally reflect poorer diet quality tended to associate with higher fat-mass index and BMI later in adolescence. As outlined and described below, the body of evidence examining dietary patterns in children and growth, size, body composition, and/or risk of overweight or obesity was assessed for the following elements used when grading the strength of evidence.

- Risk of bias: There were a number of potential risks of bias, or limitations, across the body of evidence that make interpretation of results difficult (Table 4). Most studies adjusted for a number of potential confounders, but did not account for all key confounders, such as race/ethnicity. Note that alcohol and smoking are listed on the analytic framework but were not treated as key confounders in the evidence with children or adolescence. Diet assessment methods varied in validity and reliability. Most studies assessed dietary patterns once at baseline, though a few assessed at each age/time-point to account for change in dietary intake over follow-up. However, many used methods that were not necessarily valid, reliable, or applicable in children. Therefore, those studies are at higher risk of bias due to classification of exposure and departure from intended exposure
- Consistency: All 12 articles came from observational studies that used different approaches to assess dietary patterns, with about half each using indices/scores or factor analysis. Among those using indices/scores, each used a different indice/score to assess adherence to different dietary patterns. Multiple approaches to examine dietary patterns were used that varied between studies. Several studies examined dietary patterns that emphasize vegetables, fruits, “high-fiber” or “wholegrain” bread, or wholemeal cereals. Several of the dietary patterns emphasized intake of fish and shellfish, legumes and nuts, reduced-fat or low-fat dairy, and olive oil, but these elements were less consistent across the body of evidence. Whereas, other studies examined dietary patterns characterized by sweets and refined grains (confectionary, biscuits, cakes, pastries), sugar-sweetened beverages, processed meats, and/or salty snacks. Across the dietary patterns examined in children, there was also variation in the level of specificity within included components e.g., “unsweetened milk” vs. “dairy” vs. “reduced- or low-fat dairy”. Across the body of evidence, the direction of findings was relatively split depending on the dietary pattern examined or weight status/body composition outcome reported. Effect sizes were relatively small across the body of evidence (e.g., 0.04-SD increase in FMI, or −0.04 decrease in BMI).
- Directness: The populations, intervention, comparators, and outcomes of interest in the included studies are directly related to the systematic review question.
- Precision: Most of the studies did not report power analyses or sample size calculations, but had relatively large analytic sample sizes.
- Generalizability: The study participants, interventions and/or exposures, comparators, and outcomes examined in the body of evidence are applicable to the U.S. population.

#### Dietary patterns: Adults

The 2020 Dietary Guidelines Advisory Committee conducted a systematic evidence scan to identify and examine new evidence published since a review done by the 2015 Dietary Guidelines Advisory Committee.^v^

Results across the recently published body of evidence were generally consistent with the conclusion from the 2015 Committee, showing that dietary patterns of higher diet quality were typically associated with favorable weight status outcomes. Across the studies, the results for the Mediterranean and DASH dietary patterns showed the most consistent significant effects towards healthier weight status. Few studies showed no significant association, in particular those examining Nordic dietary patterns and weight status outcomes. The populations, intervention, comparators, and outcomes of interest are directly related to the systematic review question. The magnitude of effect across the body of evidence is relatively small for body weight, BMI, and waist circumference. The evidence is primarily from prospective cohort studies, and the number of RCTs within this newly published set of evidence is limited. Across these studies, there was insufficient evidence to determine a relationship between dietary patterns in adults and other measures of body composition and/or distribution, such as visceral adipose tissue, subcutaneous fat, and ectopic fat. The study participants, interventions and/or exposures, comparators, and outcomes examined in the body of evidence are applicable to the U.S. population.

The existing conclusion statement from the 2015 Committee noted that the included evidence reported favorable outcomes related to body weight with overall dietary patterns that may include moderate alcoholic beverage intake in adults. However, for the newly published evidence, inclusion of moderate alcohol intake within an overall dietary pattern may not necessarily be recommended, particularly with regards to prevention of co-morbid conditions that may be exacerbated with alcoholic beverage intake e.g. hypertension, cancer, etc. Studies that examine overall dietary patterns in adults often vary in how alcohol intake is measured, the thresholds applied for amounts of alcohol consumed, and scoring procedures of alcohol as a component (e.g., a positive component, positive in moderation, or negative component). Due to this inconsistency, the inclusion and specification of alcoholic beverages within dietary patterns warrants further investigation.

The 2020 Committee determined that the conclusion drawn by the 2015 Committee still reflects the current state of science on dietary patterns in adults and risk of type 2 diabetes. Therefore, a full systematic review was not conducted at this time, and the 2015 Committee’s conclusion statement and grade were carried forward. The 2015 Committee concluded that: Moderate evidence indicates dietary patterns emphasizing vegetables, fruits, and whole grains; seafood and legumes; moderate in dairy products (particularly low and non-fat dairy) and alcohol; lower in meats (including red and processed meats), and low in sugar-sweetened foods and beverages, and refined grains are associated with favorable outcomes related to body weight, including lower BMI, waist circumference, or percent body fat, or risk of obesity. Components of the dietary patterns associated with these favorable outcomes include higher intakes of unsaturated fats and lower intakes of saturated fats, cholesterol, and sodium.

#### Diets based on macronutrient distribution: Children

No studies identified that met inclusion criteria examined diets based on macronutrient proportion in children.

#### Diets based on macronutrient distribution: Adults

##### Summary of results

Thirty-one studies examined diets based on macronutrient distributions with proportions of energy falling outside of the AMDR for at least one macronutrient and growth, size, body composition, and/or risk of overweight or obesity outcomes. The 31 articles included 22 articles from RCTs (Table 2) and 9 articles from prospective cohort studies (Table 3).

Results across the body of evidence were mixed, depending on various factors including study design, the macronutrient distribution examined, and/or the outcome reported. Significant associations were reported in 14 of the 31 included articles.^23,28,41,55,61,72–75,81,83–85,87^ However, the majority of these studies also reported null, or mixed associations depending on the intervention/exposure group and/or specific outcome examined. No significant associations between diets based on macronutrient distribution and all outcomes were reported in 17 of the 31 included articles.^14,24,33,37,67–71,76–80,82,86,88^

###### Randomized controlled trials (RCTs)

Most of the RCTs did not show significantly meaningful differences between diet groups compared based on variations in macronutrient intakes and body size or composition outcomes. A number of these studies did report significant results, but the relationship between the macronutrient distribution and outcomes were indirect and limited by several methodological considerations.

Due et al^72^ examined the effects of a “low-fat” diet within AMDRs for all macronutrients (23.6% Fat) and a “high monounsaturated (MUFA) fat” diet consisting of carbohydrate below and fat above the AMDR with >20% from MUFA. Results supported significantly decreased fat mass in participants following either diet relative to a control diet at 32.1% fat.

Gardner et al^33^ tested ‘low-fat’ compared to ‘low-carbohydrate’ diets without energy restriction on weight change in participants with BMI between 28 and 40 kg/m^2^, reporting no clinically meaningful differences in % body fat, BMI, or waist circumference after 12mo.

Howard et al^73^ tested diets at varied levels of reduced fat intake within the AMDR compared to control diets with fat intake above the AMDR from the Women’s Health Initiative, reporting lower BMI, waist circumference and body weight after 1 year, but ultimately no significant differences between groups at the end of 6 y follow-up.

Kahleova et al^41^ examined the effect of a “low-fat vegan” diet based on different macronutrient distribution with fat below the AMDR at 17.5% energy, compared to fat intake within the AMDR. Participants consuming the “Low-fat vegan” diet had significantly lower lean mass, fat mass, and BMI at 16 weeks. Notably, the duration of follow-up in this study was relative short.

Turner-McGrievy et al^61^ tested the effects of plant-based based dietary patterns on weight loss without energy restriction and observed significant weight loss in all groups after 6mo. Those assigned to consume a “Vegan” diet lost the most weight compared to either “Semi-vegetarian”, “Pesco-vegetarian”, or “Omnivore” diets. It should be noted that the study was not powered to detect differences between the “Vegan” compared to “Vegetarian” groups.

Paineau et al^75^ compared reduced fat intake within the AMDR at 32.4% and reduced fat intake with reduced sugar intake to a control diet with fat intake above the AMDR at 35.6% fat. Reducing fat within the AMDR with reduced sugar intake was significantly associated with lower fat mass and BMI at 8mo follow-up, but no significant differences were observed in the group that only reduced fat within the AMDR compared to the control group. It should be noted that participants were parents, with their children concomitantly enrolled in the intervention to improve weight and other health outcomes in the family.

Wan et al^81^ assessed “low”, “moderate”, and “high” levels of fat and carbohydrate intake, with the proportion of fat above the AMDR at 40% in the “high-fat” distribution, and proportion of carbohydrate slightly above the AMDR at 66% of energy in the “high-carbohydrate”. All other proportions, including “low-fat” were within the AMDR. Lower-fat intake within the AMDR and carbohydrate near or within the AMDR at 66% or 56% energy were significantly associated with lower fat mass, BMI, waist circumference, or weight at 6 mo follow-up.

Larsen et al^74^ reported significant weight regain in previously weight-reduced participants assigned to the “low protein, high glycemic index” diet within AMDRs for all macronutrients. Individuals in the high protein groups, with either high or low glycemic index levels, had 0.93 kg less weight regain. In the “high-protein” groups’ mean intake from protein was within the AMDR at 21.7%-22.6% of energy and intake from carbohydrate was modestly below the AMDR at 43.0%-44.7% of energy.

Reidlinger et al^55^ reported smaller waist circumference and lower weight after 12 weeks in the “dietary guidelines” diet group compared to a control diet, which had a distribution with proportions of carbohydrate below the AMDR and Fat above the AMDR. While this trial had some small differences between intervention groups in all macronutrients, the overriding difference between arms could be the quality of intake with the “dietary guidelines” group consuming more whole grains and reducing sugar and salt intake.

Daly et al^23^ enrolled all older women engaged in resistance training to determine the effects of consuming lean red meat compared to pasta/rice, with carbohydrate intake below the AMDR in both intervention groups at 41% and 42%. Results showed a significant impact on lean mass in those consuming lean red meat.

All remaining RCTs included in the body of evidence reported no significant effects between diet groups and reported outcomes, including risk of overweight or obesity, lean mass, fat mass, BMI, waist circumference or waist-to-hip ratio, or body weight.^14,24,67–71,76–80^ Several of these studies specifically examined the effects of “Mediterranean” diets on weight and body composition outcomes.^14,24,76,80^ None of the studies examining “Mediterranean” diets reported significant effects between groups on weight, BMI, % body fat, fat-free mass, truncal fat-mass, waist circumference over follow-up ranging between 4mo and 3y. The macronutrient distribution for the “Mediterranean” patterns examined in those studies had proportions of carbohydrate slightly below and fat slightly above the AMDR, but because the trials were testing the different dietary patterns, there was often minor contrast between macronutrient distributions in the groups compared. In some cases, both intervention and control groups had proportions similarly outside of the AMDR in the same direction (e.g., 37.8% carbohydrate, 38.8% fat, 19.4% protein vs. 40.3% carbohydrate, 35.6% fat, 19.2% protein). In other studies, the contrast was substantial (e.g., 37.0% carbohydrate, 47.0% fat, 13.8% protein vs. 69.0% carbohydrate, 14.0% fat, 14.0% protein), yet there were no significant effects detected.

###### Observational studies

Five observational studies reported significant results and all examined proportions of carbohydrate below and fat above the AMDR. Beunza et al^84^ reported that high Mediterranean Diet Score (MDS), with proportions of carbohydrate and fat within the AMDR, were significantly associated with lower weight gain over follow-up (at 4y) compared to “low MDS” scores with carbohydrate slightly below and fat above the AMDR. Ericson et al^28^ reported that higher consumption of the “health-conscious” dietary pattern, with proportions of carbohydrate slightly below and fat above the AMDR, were significantly associated with greater weight change over 10 y in men, but when diet was examined continuously, results were not significant. There were no other significant associations in men or women when examining other dietary patterns. Quatromoni et al^87^ reported higher adherence to the diet quality index (DQI), with proportions of energy within compared to outside the AMDR, was significantly associated with reduced weight gain during 8 y follow-up in men or women. In the study by Ankarfeldt et al,^83^ results from the MONICA cohort reported a 5% substitution of protein for carbohydrate was associated with a small but statistically significant weight change of 123.4 g/year over 5 years. However, overall, substituting 5% of energy from protein for either carbohydrate or fat did not result in significant weight change. There were no significant associations reported in the other cohorts examined in that study. Bujnowski et al^85^ reported greater weight gain over 7 years in men with higher total- and animal-protein intake, but no significant association when examining macronutrient distribution based on vegetable-protein intake.

The remaining studies reported no significant associations between diets based on macronutrient distribution compared, with most examining intake of carbohydrate below the AMDR.^37,82,86,88^ In most, the lowest proportion of carbohydrate was associated with the poorest diet quality, if foods or food groups consumed in the diet were reported.

Determining the influence of macronutrient intake among these results is challenging. Although results show that macronutrient distributions of higher diet quality were generally associated with less weight gain over time, the range of carbohydrate intake was commonly not varied within or across studies, and the proximity to the AMDR limits were generally very close (e.g., 66% carbohydrate). For example, two of the studies reporting significant results compared diets with macronutrient distributions where all levels of carbohydrate intake compared were below the AMDR, and all levels of fat intake compared were above the AMDR. In addition, the primary focus was protein intake in several of the observational studies, but all proportions of protein were within the AMDR and carbohydrate and fat were varied outside the AMDR.^37,85,88^

##### Assessment of the evidence^vi^

This systematic review update included 31 articles that examined examined diets based on macronutrient distribution and growth, size, body composition, and/or risk of overweight or obesity, met inclusion criteria, and were published between January 2000 and October 2019.

Most of the articles examined macronutrient distributions in which the proportion of energy from carbohydrate was below the AMDR; Fat was above the AMDR; and protein was within the AMDR in at least one of the exposure groups compared. From a study design perspective, most of the clinical trials had control or comparator exposures that featured a different dietary pattern, either prescribed as a study intervention or as usual intake. The observational studies used derived food patterns or index scores as comparators, generally comparing poorer quality diets to higher quality alternatives. Therefore, across study designs, the comparisons were primarily of different dietary patterns and food groups that resulted in differing macronutrient proportions rather than comparing a different distribution of macronutrients within the same pattern of food intake. As a function of these study designs, the differences in macronutrient proportions between intervention arms were either limited in magnitude, of a similar direction relative to the AMDR (e.g., all below or above the AMDR), only modestly different from the AMDR, or only relevant for a limited subset of the study population. Several included articles were primary or secondary analyses from the PREDIMED trial, which was subject to randomization issues established after publication of the initial study. However, the republished results confirmed the initial findings, even after accounting for participants that were subject to protocol deviation.

Multiple databases were used to obtain publications from a large, comprehensive search. Although several studies were from large prospective cohorts, studies with smaller sample sizes were also included and reported both significant and non-significant results. Therefore, this risk of publication bias is low. As outlined and described below, the body of evidence examining diets based on macronutrient distribution and growth, size, body composition, and/or risk of overweight or obesity was assessed for the following elements used when grading the strength of evidence.

- Risk of bias: There were a number of potential risks of bias, or limitations, across the body of evidence that make interpretation of results difficult (Table 5 and Table 6). While studies adjusted for most potential confounders, they did not adjust for all key confounders, such as race/ethnicity, alcohol intake, and/or physical activity. Most of the observational studies and several RCT’s used self-reported methods that varied to obtain dietary intake, derive macronutrient intake, and/or assess diet adherence. Most studies selected participants that were free of chronic disease or other conditions at baseline, and are therefore at a higher risk of selection bias. It is likely that the reported results are reflective of generally healthier populations. Several studies did not assess the impact of missing data, either due to lost to follow-up or criteria used when selecting subjects into the analyses. Although several studies reported using standardized methods to collect or calculate anthropometric measures, several studies are at higher risk of bias due to the use of self-reported data or providing limited information on outcome assessment methods.
- Consistency: Study design varied in the body of evidence, with 22 articles from RCTs and 9 articles from prospective cohort studies. Results across studies were inconsistent in direction and magnitude. There was some evidence to suggest that diets based on macronutrient distributions within or closer to the AMDR compared to those that were outside the AMDR (below or above) are associated with favorable weight status outcomes, such as fat-mass, BMI, waist circumference, and/or change in weight, typically if the diet was reflective of higher quality. Among the macronutrient distributions within the AMDR that suggested favorable outcomes, several were comprised of vegetables, fruit, whole-grains, vegetable oils, nuts, pulses and/or lean meat or fish. However, the foods/food groups were inconsistently reported. Proportions of energy associated with these results varied for carbohydrate below the AMDR between 30.9% and 44.9%, for carbohydrate above the AMDR between 66% and 69.6%, and for fat above the AMDR between 35.6% and 41%. Although statistically significant relationships were reported, the gradient between macronutrient distributions was relatively narrow within studies and between studies (e.g., 45.3% vs. 43.8% carbohydrate). Several studies compared sufficiently distinct proportions between groups, whereas other proportions were much closer in proximity relative to one another, or to the actual AMDR cut-off (e.g., 44.9% vs. 45%). Studies varied in terms of the distribution of macronutrients that were examined and the methods used to estimate nutrient intakes, derive the proportion of energy from macronutrients, and/or apply substitution modelling (e.g., multivariate-nutrient density methods).
- Directness: Several studies reported the intent to directly examine different diets based on macronutrient distribution and the outcome of interest. However, for this review, an important limitation to highlight is that many of the studies were not designed to intentionally examine macronutrient proportions outside of the AMDR. Additionally, most of the studies assessed different dietary patterns as the primary comparators rather than using a common dietary pattern and adjusting macronutrient proportions within that dietary context. Due to the variety of methods used to estimate macronutrient intake and adjust intake for total energy, the confidence in the estimated proportions falling outside the AMDR is low. The gradient between proportions compared within macronutrients varied and in some cases, may not have been large enough to distinguish differences in the outcomes between intervention or exposure groups compared. Several studies reported to be examining “high” or “low” levels of one particular macronutrient of interest, but the proportion for that nutrient was typically within the AMDR. Due to these issues, directness across the body of evidence could not be adequately assessed.
- Precision: Of the 22 RCTs, all demonstrated adequate power but had generally smaller sample sizes and in some cases, a very small sample size (n=16). Two were insufficiently powered to detect differences either in the outcome of interest or between some exposure groups. The assessment of variance within these studies was relatively narrow, but several indicate wider variance in results. Observational studies did not report sample size or power calculations but did have large analytic sample sizes, ranging from n=1,107 to n=20,487.
- Generalizability: The study participants, interventions and/or exposures, comparators, and outcomes examined in the body of evidence are applicable to the U.S. population. Results across studies may be less generalizable due to differences between countries in terms of national recommendations and macronutrient distributions compared. For example, several of the macronutrient distributions compared were from populations that consume high amounts of rice with carbohydrate well above the AMDR and fat well below the AMDR, which is not typical of diets in the United States.

### Research recommendations

In order to better assess the relationship between dietary patterns and/or diets based on macronutrient distribution and growth, size, body composition, and/or risk of overweight or obesity, future research may:

1. Determine the impact that dietary patterns, independent of adiposity and/or weight-loss, may have on risk of type 2 diabetes, cardiovascular disease, and/or obesity.
2. Conduct well-designed, sufficiently powered, randomized controlled trials, including controlled feeding studies that examine the relationship between dietary patterns and growth, size, body composition, and risk of overweight or obesity; particularly lacking are studies that examine dietary patterns in children and adolescents.
3. Identify dietary patterns in childhood that may confer benefit to health outcomes including favorable growth and/or cardiometabolic health factors, over the lifecourse.
4. Develop a standardized definition for what constitutes a “very-low carbohydrate”, “low-carbohydrate”, “carbohydrate-restricted”, and/or “ketogenic diet” dietary pattern based on macronutrient distribution.
5. Examine the relationship between diets based on macronutrient distributions that test proportions of energy from carbohydrate below 25%, within the context of specific dietary patterns, to determine if and what relationship may exist between macronutrient-based dietary patterns and the prevention of obesity or avoidance of excess weight gain. These types of studies need to adequately control for the quality of food intake.
6. Examine additional body fat distribution outcomes and in particular, ectopic fat.
7. Explore the role that macronutrient quality may have in the relationship between “low-carbohydrate” diets and the prevention of obesity (i.e. effect modification), within the context of a constant dietary pattern.
8. Assess information regarding diet at more than one time-point, preferably during the course of follow-up and with more objective measures from improved technologies, to facilitate understanding the relationship between dietary patterns over time and risk of overweight/obesity.
9. Differentiate specific foods and food groups, in particular, the types and amounts, relevant biomarkers, and repeated measures to facilitate both preventive strategies and overall outcomes
10. Include continual updating of systematic reviews that examine the relationship between dietary patterns and growth, size, body composition, and risk of overweight/obesity to incorporate the rapidly emerging and overwhelming volume of literature on this topic, particularly in recent years.

### Included articles

1 Ambrosini GL, Johns DJ, Northstone K, Emmett PM, Jebb SA. Free sugars and total fat are important characteristics of a dietary pattern associated with adiposity across childhood and adolescence. J Nutr. 2016;146(4):778–784. doi:10.3945/jn.115.224659.
2 Bull CJ, Northstone K. Childhood dietary patterns and cardiovascular risk factors in adolescence: results from the Avon Longitudinal Study of Parents and Children (ALSPAC) cohort. Public Health Nutr. 2016;19(18):3369–3377. doi:10.1017/s1368980016001592.27339189
3 Chan She Ping-Delfos WL, Beilin LJ, Oddy WH, Burrows S, Mori TA. Use of the Dietary Guideline Index to assess cardiometabolic risk in adolescents. Br J Nutr. 2015;113(11):1741–1752. doi:10.1017/s0007114515001026.25873301
4 Durao C, Severo M, Oliveira A, . Association between dietary patterns and adiposity from 4 to 7 years of age. Public Health Nutr. 2017;20(11):1973–1982. doi:10.1017/s1368980017000854.28534458
5 Fernandez-Alvira JM, Bammann K, Eiben G, . Prospective associations between dietary patterns and body composition changes in European children: the IDEFICS study. Public Health Nutr. 2017;20(18):3257–3265. doi:10.1017/s1368980017002361.28879834
6 Hu T, Jacobs DR, Jr., Larson NI, Cutler GJ, Laska MN, Neumark-Sztainer D. Higher diet quality in adolescence and dietary improvements are related to less weight gain during the transition from adolescence to adulthood. J Pediatr. 2016;178:188–193.e183. doi:10.1016/j.jpeds.2016.08.026.27640354
7 Martin-Calvo N, Chavarro JE, Falbe J, Hu FB, Field AE. Adherence to the Mediterranean dietary pattern and BMI change among US adolescents. Int J Obes 2016;40(7):1103–1108. doi:10.1038/ijo.2016.59.
8 Nguyen AN, Jen V, Jaddoe VWV, . Diet quality in early and mid-childhood in relation to trajectories of growth and body composition. Clin Nutr. 2020;39(3):845–852. doi:10.1016/j.clnu.2019.03.017.30967308
9 Okubo H, Crozier SR, Harvey NC, . Diet quality across early childhood and adiposity at 6 years: the Southampton Women’s Survey. Int J Obes. 2015;39(10):1456–1462. doi:10.1038/ijo.2015.97.
10 Pala V, Lissner L, Hebestreit A, . Dietary patterns and longitudinal change in body mass in European children: a follow-up study on the IDEFICS multicenter cohort. Eur J Clin Nutr. 2013;67(10):1042–1049. doi:10.1038/ejcn.2013.145.23942180
11 Smith AD, Emmett PM, Newby PK, Northstone K. Dietary patterns and changes in body composition in children between 9 and 11 years. Food Nutr Res. 2014;58. doi:10.3402/fnr.v58.22769.
12 Tognon G, Hebestreit A, Lanfer A, . Mediterranean diet, overweight and body composition in children from eight European countries: cross-sectional and prospective results from the IDEFICS study. Nutr Metab Cardiovasc Dis. 2014;24(2):205–213. doi:10.1016/j.numecd.2013.04.013.23870847
13 Agnoli C, Sieri S, Ricceri F, . Adherence to a Mediterranean diet and long-term changes in weight and waist circumference in the EPIC-Italy cohort. Nutr Diabetes. 2018;8(1):22. doi:10.1038/s41387-018-0023-3.29695712
14 Alvarez-Perez J, Sanchez-Villegas A, Diaz-Benitez EM, . Influence of a Mediterranean dietary pattern on body fat distribution: results of the PREDIMED-Canarias intervention randomized trial. J Am Coll Nutr. 2016;35(6):568–580. doi:10.1080/07315724.2015.1102102.27314172
15 Arabshahi S, Ibiebele TI, Hughes MCB, Lahmann PH, Williams GM, van der Pols JC. Dietary patterns and weight change: 15-year longitudinal study in Australian adults. Eur J Nutr. 2017;56(4):1455–1465. doi:10.1007/s00394-016-1191-3.26919993
16 Babio N, Toledo E, Estruch R, . Mediterranean diets and metabolic syndromestatus in the PREDIMED randomized trial. CMAJ. 2014;186(17):E649–657. doi:10.1503/cmaj.140764.25316904
17 Canhada SL, Luft VC, Giatti L, . Ultra-processed foods, incident overweight andobesity, and longitudinal changes in weight and waist circumference: the Brazilian Longitudinal Study of Adult Health (ELSA-Brasil). Public Health Nutr. 2020;23(6):1076–1086. doi:10.1017/s1368980019002854.31619309
18 Casas R, Sacanella E, Urpi-Sarda M, . The effects of the Mediterranean diet on biomarkers of vascular wall inflammation and plaque vulnerability in subjects with high risk for cardiovascular disease. A randomized trial. PLoS One. 2014;9(6):e100084. doi:10.1371/journal.pone.0100084.24925270
19 Casas R, Sacanella E, Urpi-Sarda M, . Long-term immunomodulatory effects of a Mediterranean diet in adults at high risk of cardiovascular disease in the PREvencion con DIeta MEDiterranea (PREDIMED) randomized controlled trial. J Nutr. 2016;146(9):1684–1693. doi:10.3945/jn.115.229476.27440261
20 Cespedes Feliciano EM, Tinker L, Manson JE, . Change in dietary patterns and change in waist circumference and DXA trunk fat among postmenopausal women. Obesity. 2016;24(10):2176–2184. doi:10.1002/oby.21589.27548405
21 Chen Z, Schoufour JD, Rivadeneira F, . Plant-based diet and adiposity overtime in a middle-aged and elderly population: the Rotterdam Study. Epidemiology. 2019;30(2):303–310. doi:10.1097/ede.0000000000000961.30507650
22 Czekajlo A, Rozanska D, Zatonska K, Szuba A, Regulska-Ilow B. Association between dietary patterns and metabolic syndrome in the selected population of Polish adults-results of the PURE Poland Study. Eur J Public Health. 2019;29(2):335–340. doi:10.1093/eurpub/cky207.30285088
23 Daly RM, O’Connell SL, Mundell NL, Grimes CA, Dunstan DW, Nowson CA. Protein-enriched diet, with the use of lean red meat, combined with progressive resistance training enhances lean tissue mass and muscle strength and reduces circulating IL-6 concentrations in elderly women: a cluster randomized controlled trial. Am J Clin Nutr. 2014;99(4):899–910. doi:10.3945/ajcn.113.064154.24477043
24 Davis CR, Bryan J, Hodgson JM, Woodman R, Murphy KJ. A Mediterranean diet reduces F2-isoprostanes and triglycerides among older Australian men and women after 6 months. J Nutr. 2017;147(7):1348–1355. doi:10.3945/jn.117.248419.28566524
25 Davis CR, Hodgson JM, Woodman R, Bryan J, Wilson C, Murphy KJ. AMediterranean diet lowers blood pressure and improves endothelial function: results from the MedLey randomized intervention trial. Am J Clin Nutr. 2017;105(6):1305–1313. doi:10.3945/ajcn.116.146803.28424187
26 Eguaras S, Toledo E, Buil-Cosiales P, . Does the Mediterranean diet counteract the adverse effects of abdominal adiposity? Nutr Metab Cardiovasc Dis. 2015;25(6):569–574. doi:10.1016/j.numecd.2015.03.001.25921850
27 Eguaras S, Toledo E, Hernandez-Hernandez A, Cervantes S, Martinez-Gonzalez MA. Better adherence to the Mediterranean diet could mitigate the adverse consequences of obesity on cardiovascular disease: the SUN Prospective Cohort. Nutrients. 2015;7(11):9154–9162. doi:10.3390/nu7115457.26556370
28 Ericson U, Brunkwall L, Alves Dias J, . Food patterns in relation to weight change and incidence of type 2 diabetes, coronary events and stroke in the Malmo Diet and Cancer cohort. Eur J Nutr. 2019;58(5):1801–1814. doi:10.1007/s00394-018-1727-9.29855685
29 Estruch R, Martinez-Gonzalez MA, Corella D, . Effect of a high-fat Mediterranean diet on bodyweight and waist circumference: a prespecified secondary outcomes analysis of the PREDIMED randomised controlled trial. Lancet Diabetes Endocrinol. 2019;7(5):e6–e17. doi:10.1016/s2213-8587(19)30074-9.31003626
30 Ford C, Chang S, Vitolins MZ, . Evaluation of diet pattern and weight gain in postmenopausal women enrolled in the Women’s Health Initiative Observational Study. Br J Nutr. 2017;117(8):1189–1197. doi:10.1017/s0007114517000952.28509665
31 Fung TT, Pan A, Hou T, . Long-term change in diet quality Is associated with body weight change in men and women. J Nutr. 2015;145(8):1850–1856. doi:10.3945/jn.114.208785.26084363
32 Funtikova AN, Benitez-Arciniega AA, Gomez SF, Fito M, Elosua R, Schroder H. Mediterranean diet impact on changes in abdominal fat and 10-year incidence of abdominal obesity in a Spanish population. Br J Nutr. 2014;111(8):1481–1487. doi:10.1017/s0007114513003966.24382017
33 Gardner CD, Trepanowski JF, Del Gobbo LC, . Effect of low-fat vs low-carbohydrate diet on 12-month weight loss in overweight adults and the association with genotype pattern or insulin secretion: the DIETFITS randomized clinical trial. JAMA. 2018;319(7):667–679. doi:10.1001/jama.2018.0245.29466592
34 Gomez-Donoso C, Martinez-Gonzalez MA, Gea A, Murphy KJ, Parletta N, Bes-Rastrollo M. A food-based score and incidence of overweight/obesity: The Dietary Obesity-Prevention Score (DOS). Clin Nutr. 2019;38(6):2607–2615. doi:10.1016/j.clnu.2018.11.003.30522848
35 Gomez-Donoso C, Martinez-Gonzalez MA, Martinez JA, . A provegetarian food pattern emphasizing preference for healthy plant-derived foods reduces the risk of overweight/obesity in the SUN Cohort. Nutrients. 2019;11(7). doi:10.3390/nu11071553.
36 Hennein R, Liu C, McKeown NM, . Increased Diet Quality is Associated with Long-Term Reduction of Abdominal and Pericardial Fat. Obesity. 2019;27(4):670–677. doi:10.1002/oby.22427.30825267
37 Hruby A, Jacques PF. Dietary protein and changes in markers of cardiometabolic health across 20 years of follow-up in middle-aged Americans. Public Health Nutr. 2018;21(16):2998–3010. doi:10.1017/s1368980018001854.30115136
38 Jenkins DJA, Boucher BA, Ashbury FD, . Effect of current dietary recommendations on weight loss and cardiovascular risk factors. J Am Coll Cardiol. 2017;69(9):1103–1112. doi:10.1016/j.jacc.2016.10.089.28254171
39 Johns DJ, Lindroos AK, Jebb SA, Sjostrom L, Carlsson LM, Ambrosini GL. Dietary patterns, cardiometabolic risk factors, and the incidence of cardiovascular disease in severe obesity. Obesity 2015;23(5):1063–1070. doi:10.1002/oby.20920.25865622
40 Kafeshani M, Janghorbani M, Salehi R, Kazemi M, Entezari MH. Dietary Approaches to Stop Hypertension influence on insulin receptor substrate-1gene expression: a randomized controlled clinical trial. J Res Med Sci. 2015;20(9):832–837. doi:10.4103/1735-1995.170596.26759568
41 Kahleova H, Dort S, Holubkov R, Barnard ND. A plant-based high-carbohydrate, low-fat diet in overweight individuals in a 16-week randomized clinical trial: the role of carbohydrates. Nutrients. 2018;10(9). doi:10.3390/nu10091302.
42 Kanerva N, Harald K, Mannisto S, . Adherence to the healthy Nordic diet is associated with weight change during 7 years of follow-up. Br J Nutr. 2018;120(1):101–110. doi:10.1017/s0007114518001344.29936927
43 Konieczna J, Yanez A, Monino M, . Longitudinal changes in Mediterranean diet and transition between different obesity phenotypes. Clin Nutr. 2020;39(3):966–975. doi:10.1016/j.clnu.2019.04.002.31053509
44 Leon-Munoz LM, Garcia-Esquinas E, Lopez-Garcia E, Banegas JR, Rodriguez-Artalejo F. Major dietary patterns and risk of frailty in older adults: a prospective cohort study. BMC Med. 2015;13:11. doi:10.1186/s12916-014-0255-6.25601152
45 Li Y, Roswall N, Strom P, Sandin S, Adami HO, Weiderpass E. Mediterranean and Nordic diet scores and long-term changes in body weight and waist circumference: results from a large cohort study. Br J Nutr. 2015;114(12):2093–2102. doi:10.1017/s0007114515003840.26458747
46 Li P, Zhang M, Zhu Y, . Dietary patterns and changes in cardiovascular risk factors in apparently healthy Chinese women: a longitudinal study. J Clin Biochem Nutr. 2016;58(3):232–239. doi:10.3164/jcbn.15-78.27257349
47 Lima ST, da Silva Nalin de Souza B, Franca AK, Salgado Filho N, Sichieri R. Dietary approach to hypertension based on low glycaemic index and principles of DASH (Dietary Approaches to Stop Hypertension): a randomised trial in a primary care service. Br J Nutr. 2013;110(8):1472–1479. doi:10.1017/s0007114513000718.23632203
48 Maskarinec G, Lim U, Jacobs S, . Diet quality in midadulthood predicts visceral adiposity and liver fatness in older ages: the Multiethnic Cohort Study. Obesity. 2017;25(8):1442–1450. doi:10.1002/oby.21868.28745024
49 Mattei J, Sotos-Prieto M, Bigornia SJ, Noel SE, Tucker KL. The Mediterranean diet score is more strongly associated with favorable cardiometabolic risk factors over 2 years than other diet quality indexes in Puerto Rican adults. J Nutr. 2017;147(4):661–669. doi:10.3945/jn.116.245431.28275099
50 Mendonca RD, Pimenta AM, Gea A, . Ultraprocessed food consumption and risk of overweight and obesity: the University of Navarra Follow-Up (SUN) cohort study. Am J Clin Nutr. 2016;104(5):1433–1440. doi:10.3945/ajcn.116.135004.27733404
51 Mirmiran P, Moslehi N, Mahmoudof H, Sadeghi M, Azizi F. A longitudinal study of adherence to the Mediterranean dietary pattern and metabolic syndrome in a non-Mediterranean population. Int J Endocrinol Metab. 2015;13(3):e26128. doi:10.5812/ijem.26128v2.26425127
52 Olstad DL, Lamb KE, Thornton LE, . Prospective associations between diet quality and body mass index in disadvantaged women: the Resilience for Eating and Activity Despite Inequality (READI) study. Int J Epidemiol. 2017;46(5):1433–1443. doi:10.1093/ije/dyx040.28398554
53 Perala MM, von Bonsdorff MB, Mannisto S, . The healthy Nordic diet predicts muscle strength 10 years later in old women, but not old men. Age Ageing. 2017;46(4):588–594. doi:10.1093/ageing/afx034.28338859
54 Poulsen SK, Crone C, Astrup A, Larsen TM. Long-term adherence to the New Nordic Diet and the effects on body weight, anthropometry and blood pressure: a 12-month follow-up study. Eur J Nutr. 2015;54(1):67–76. doi:10.1007/s00394-014-0686-z.24664189
55 Reidlinger DP, Darzi J, Hall WL, Seed PT, Chowienczyk PJ, Sanders TA. How effective are current dietary guidelines for cardiovascular disease prevention in healthy middle-aged and older men and women? A randomized controlled trial. Am J Clin Nutr. 2015;101(5):922–930. doi:10.3945/ajcn.114.097352.25787998
56 San-Cristobal R, Navas-Carretero S, Livingstone KM, . Mediterranean diet adherence and genetic background roles within a web-based nutritional intervention: the Food4Me Study. Nutrients. 2017;9(10). doi:10.3390/nu9101107.
57 Shakeri Z, Mirmiran P, Khalili-Moghadam S, Hosseini-Esfahani F, Ataie-Jafari A, Azizi F. Empirical dietary inflammatory pattern and risk of metabolic syndrome and its components: Tehran Lipid and Glucose Study. Diabetol Metab Syndr. 2019;11:16. doi:10.1186/s13098-019-0411-4.30805034
58 Sidahmed E, Cornellier ML, Ren J, . Development of exchange lists for Mediterranean and Healthy Eating diets: implementation in an intervention trial. J Hum Nutr Diet. 2014;27(5):413–425. doi:10.1111/jhn.12158.24112099
59 Steffen LM, Van Horn L, Daviglus ML, . A modified Mediterranean diet score is associated with a lower risk of incident metabolic syndrome over 25 years among young adults: the CARDIA (Coronary Artery Risk Development in Young Adults) study. Br J Nutr. 2014;112(10):1654–1661. doi:10.1017/s0007114514002633.25234439
60 Tabung FK, Satija A, Fung TT, Clinton SK, Giovannucci EL. Long-term change in both dietary insulinemic and inflammatory potential is associated with weight gain in adult women and men. J Nutr. 2019;149(5):804–815. doi:10.1093/jn/nxy319.31004153
61 Turner-McGrievy GM, Davidson CR, Wingard EE, Wilcox S, Frongillo EA. Comparative effectiveness of plant-based diets for weight loss: a randomized controlled trial of five different diets. Nutrition. 2015;31(2):350–358. doi:10.1016/j.nut.2014.09.002.25592014
62 Satija A, Malik V, Rimm EB, Sacks F, Willett W, Hu FB. Changes in intake of plant-based diets and weight change: results from 3 prospective cohort studies. Am J Clin Nutr. 2019;110(3):574–582. doi:10.1093/ajcn/nqz049.31127828
63 Roswall N, Angquist L, Ahluwalia TS, . Association between Mediterranean and Nordic diet scores and changes in weight and waist circumference: influence of FTO and TCF7L2 loci. Am J Clin Nutr. 2014;100(4):1188–1197. doi:10.3945/ajcn.114.089706.25099543
64 Tobias DK, Zhang C, Chavarro J, . Healthful dietary patterns and long-term weight change among women with a history of gestational diabetes mellitus. Int J Obes 2016;40(11):1748–1753. doi:10.1038/ijo.2016.156.
65 Wang T, Heianza Y, Sun D, . Improving adherence to healthy dietary patterns, genetic risk, and long term weight gain: gene-diet interaction analysis in two prospective cohort studies. BMJ. 2018;360:j5644. doi:10.1136/bmj.j5644.29321156
66 Winkvist A, Klingberg S, Nilsson LM, . Longitudinal 10-year changes in dietary intake and associations with cardio-metabolic risk factors in the Northern Sweden Health and Disease Study. Nutr J. 2017;16(1):20. doi:10.1186/s12937-017-0241-x.28351404
67 Arciero PJ, Gentile CL, Pressman R, . Moderate protein intake improves total and regional body composition and insulin sensitivity in overweight adults. Metabolism. 2008;57(6):757–765. doi:10.1016/j.metabol.2008.01.015.18502257
68 Brown RC, Cox CM, Goulding A. High-carbohydrate versus high-fat diets: effect on body composition in trained cyclists. Med Sci Sports Exerc. 2000;32(3):690–694. doi:10.1097/00005768-200003000-00021.10731014
69 Dale KS, McAuley KA, Taylor RW, . Determining optimal approaches for weight maintenance: a randomized controlled trial. Cmaj. 2009;180(10):E39–46. doi:10.1503/cmaj.080974.19433812
70 Delbridge EA, Prendergast LA, Pritchard JE, Proietto J. One-year weight maintenance after significant weight loss in healthy overweight and obese subjects: does diet composition matter? Am J Clin Nutr. 2009;90(5):1203–1214. doi:10.3945/ajcn.2008.27209.19793858
71 Donnelly JE, Sullivan DK, Smith BK, . Alteration of dietary fat intake to prevent weight gain: Jayhawk Observed Eating Trial. Obesity. 2008;16(1):107–112. doi:10.1038/oby.2007.33.18223621
72 Due A, Larsen TM, Mu H, Hermansen K, Stender S, Astrup A. Comparison of 3 ad libitum diets for weight-loss maintenance, risk of cardiovascular disease, and diabetes: a 6-mo randomized, controlled trial. Am J Clin Nutr. 2008;88(5):1232–1241. doi:10.3945/ajcn.2007.25695.18996857
73 Howard BV, Curb JD, Eaton CB, . Low-fat dietary pattern and lipoprotein risk factors: the Women’s Health Initiative Dietary Modification Trial. Am J Clin Nutr. 2010;91(4):860–874. doi:10.3945/ajcn.2009.28034.20164311
74 Larsen TM, Dalskov SM, van Baak M, . Diets with high or low protein content and glycemic index for weight-loss maintenance. N Engl J Med. 2010;363(22):2102–2113. doi:10.1056/NEJMoa1007137.21105792
75 Paineau DL, Beaufils F, Boulier A, . Family dietary coaching to improve nutritional intakes and body weight control: a randomized controlled trial. Arch Pediatr Adolesc Med. 2008;162(1):34–43. doi:10.1001/archpediatrics.2007.2.18180410
76 Razquin C, Martinez JA, Martinez-Gonzalez MA, Mitjavila MT, Estruch R, Marti A. A 3 years follow-up of a Mediterranean diet rich in virgin olive oil is associated with high plasma antioxidant capacity and reduced body weight gain. Eur J Clin Nutr. 2009;63(12):1387–1393. doi:10.1038/ejcn.2009.106.19707219
77 Sanders TA, Lewis FJ, Goff LM, Chowienczyk PJ. SFAs do not impair endothelial function and arterial stiffness. Am J Clin Nutr. 2013;98(3):677–683. doi:10.3945/ajcn.113.063644.23964054
78 Tierney AC, McMonagle J, Shaw DI, . Effects of dietary fat modification on insulin sensitivity and on other risk factors of the metabolic syndrome--LIPGENE: a European randomized dietary intervention study. Int J Obes. 2011;35(6):800–809. doi:10.1038/ijo.2010.209.
79 Uusitupa M, Hermansen K, Savolainen MJ, . Effects of an isocaloric healthy Nordic diet on insulin sensitivity, lipid profile and inflammation markers in metabolic syndrome -- a randomized study (SYSDIET). J Intern Med. 2013;274(1):52–66. doi:10.1111/joim.12044.23398528
80 Vincent-Baudry S, Defoort C, Gerber M, . The Medi-RIVAGE study: reduction of cardiovascular disease risk factors after a 3-mo intervention with a Mediterranean-type diet or a low-fat diet. Am J Clin Nutr. 2005;82(5):964–971. doi:10.1093/ajcn/82.5.964.16280426
81 Wan Y, Wang F, Yuan J, . Effects of macronutrient distribution on weight and related cardiometabolic profile in healthy non-obese Chinese: a 6-month, randomized controlled-feeding trial. EBioMedicine. 2017;22:200–207. doi:10.1016/j.ebiom.2017.06.017.28655596
82 Aljadani HM, Patterson AJ, Sibbritt D, Collins CE. Diet quality and six-year risk of overweight and obesity among mid-age Australian women who were initially in the healthy weight range. Health Promot J Austr. 2016;27(1):29–35. doi:10.1071/he14070.26568282
83 Ankarfeldt MZ, Larsen SC, Angquist L, . Interaction between genetic predisposition to adiposity and dietary protein in relation to subsequent change in body weight and waist circumference. PLoS One. 2014;9(10):e110890. doi:10.1371/journal.pone.0110890.25350854
84 Beunza JJ, Toledo E, Hu FB, . Adherence to the Mediterranean diet, long-term weight change, and incident overweight or obesity: the Seguimiento Universidad de Navarra (SUN) cohort. Am J Clin Nutr. 2010;92(6):1484–1493. doi:10.3945/ajcn.2010.29764.20962161
85 Bujnowski D, Xun P, Daviglus ML, Van Horn L, He K, Stamler J. Longitudinal association between animal and vegetable protein intake and obesity among men in the United States: the Chicago Western Electric Study. J Am Diet Assoc. 2011;111(8):1150–1155.e1151. doi:10.1016/j.jada.2011.05.002.21802560
86 de la Fuente-Arrillaga C, Martinez-Gonzalez MA, Zazpe I, Vazquez-Ruiz Z, Benito-Corchon S, Bes-Rastrollo M. Glycemic load, glycemic index, bread and incidence of overweight/obesity in a Mediterranean cohort: the SUN project. BMC Public Health. 2014;14:1091. doi:10.1186/1471-2458-14-1091.25335643
87 Quatromoni PA, Pencina M, Cobain MR, Jacques PF, D’Agostino RB. Dietary quality predicts adult weight gain: findings from the Framingham Offspring Study. Obesity 2006;14(8):1383–1391. doi:10.1038/oby.2006.157.16988081
88 So E, Choi SK, Joung H. Impact of dietary protein intake and obesity on lean mass in middle-aged individuals after a 12-year follow-up: the Korean Genome and Epidemiology Study (KoGES). Br J Nutr. 2019;122(3):322–330. doi:10.1017/s000711451900117x.31177993

Table 1 Studies that examined the relationship between dietary patterns in children and growth size, body composition, and risk of overweight or obesity^vii^

Study and Participant Characteristics^viii^ | Intervention/Exposure | Results^ix^ | Methodological Considerations
Ambrosini, 2016 ^1^; United Kingdom, Avon Longitudinal Study of Parents and Children (ALSPAC) cohort; Prospective Cohort Study; N=4729; ~56% female; Excluded those with missing data; other reasons NR | [underlined: Reduced rank regression] (predictor variables: %E from free sugars, %E from fat, dietary energy density (energy/g food consumed), dietary fiber density):; - “DP1” (categorical, quintiles, Q1, ref) at age 7y: Higher in confectionery and chocolate, cakes and biscuits, SSBs, low-fiber bread, and lower in fruit, vegetables, high-fiber bread, cereals; - “DP2” (categorical, quintiles, Q1, ref) at age 7y: Higher in sugar-sweetened beverages (SSBs), fruit juices, ready-to-eat breakfast cereals, and lower in whole milk, margarines and oils, cheese, crisps | DP1: ↑ FMIz, ᴓ excess adiposiy at 15y; DP2: ᴓ FMIz, excess adiposiy at 15y | - Did not account for: Race/ethnicity; - Diet assessed via paren-report at age 7y, then parent-assisted child at older ages; - Did not describe or fully account for selection into analyses or missing data; Funding: The United Kingdom Medical Research Council; Wellcome Trust; University of Bristol
Bull, 2016 ^2^; United Kingdom, Avon Longitudinal Study of Parents and Children (ALSPAC) cohort; Prospective Cohort Study; N=2311; 56% female; Excluded those with missing data on CVD measures, dietary patterns info at all time points, and covariable data | [underlined: Factor/cluster analysis:]; Three dietary patterns identified at ages 7, 10, and 13y:; - “Healthy”, ref.: Non-white bread, reduced-fat milk, cheese, yoghurt and fromage frais, butter, breakfast cereal, rice, pasta, eggs, fish, vegetable and vegetarian dishes, soup, salad, legumes, fruit, crackers and crispbreads, high-energy-density sauces (e.g. mayonnaise), fruit juice, water; - “Processed”: Processed meat, pies and pasties, coated and fried chicken and white fish, pizza, chips, baked beans and tinned pasta, chocolate, sweets, sugar, diet and regular fizzy drinks; - “Traditional”: Red meat, poultry, potatoes, vegetables, starch-based products, low-energy-density sauces, puddings, tea, coffee; - Packed Lunch: White bread, margarine, ham and bacon, sweet spreads, salty flavourings, crisps, biscuits, diet squash, tea, coffee | Dietary patterns at 7y:; “Healthy”, ref; - Processed: ↑ BMI at 17 y f/u; - Traditional: ᴓ, BMI at 17 y f/u, NSA; - Packed lunch: ↑ BMI at 17 y f/u; Dietary patterns at 10y:; “Packed Lunch”, “Traditional”, and “Processed” vs. “Healthy”: ᴓ BMI at 17 y f/u; Dietary patterns at 13y:; Packed Lunch, Traditional, and Processed vs. Healthy: ᴓ BMI at 17 y f/u | - Did not account for: Race/ethnicity, Physical activity, Anthropometry; - Diet assessed once each age time point; - Unclear if diet assessment methods were valid/reliable; Funding: The United Kingdom Medical Research Council; Wellcome Trust; University of Bristol
Chan She Ping-Delfos, 2015 ^3^; Australia, Western Australian Pregnancy Cohort; Prospective Cohort Study; N=1419; 53% female; Excluded those with missing data, implausible energy intake | [underlined: Index/score:] Dietary Guideline Index for Children and Adolescents (DGI-CA) score (continuous) at age 14y; DGI-CA components: Fruit/100% fruit juice, vegetables and legumes, breads and cereals, wholegrain bread relative to total, meat and alternatives (excluding processed meat); dairy products: reduced- or low-fat dairy, water as a beverage, healthy fats: total fats, <3/d ‘extra foods’ | ↑ BMI at 17y f/u; ᴓ WC at 17 y f/u; ↓ Waist:Hip Ratio at 17 y f/u | - Did not account for: Race/ethnicity; - Diet assessed once at baseline; - Diet assessment record validated in adults only; Funding: University of Western Australia; the Faculty of Medicine, Dentistry and Health Sciences at the University of Western Australia; the Telethon Kids Institute; the Women and Infants Research Foundation; Curtin University; and the Raine Medical Research Foundation; National Health and Medical Research Council; Telstra Research Fund; National Health and Medical Research Council
Durao, 2017 ^4^; Portugal, Generation XXI; Prospective Cohort Study; N=3473; 50% female; Excluded those with diseases that influence diet, missing data | [underlined: Latent class analysis:]; Three patterns (continuous) at age 4y; - “Energy Dense Foods” (EDF): Sweets, soft drinks, salty pastry, processed meat; - “Snacking”: Snack foods, lower in fish, meat, eggs, rice, pasta, potatoes, vegetables; - “Healthier”: Higher in vegetables, fish, and lower in energy dense foods | In girls,; - EDF:; ○ ↑ FMI at 7y, but ᴓ FM%; ○ ↑ BMIz at 7y; ○ ↑ waist-to-hip ratio (WHR) at 7y; - Snacking, Healthier:; ○ ᴓ FMI%, FMI at 7y; ○ ᴓ WHR at 7y; ○ ᴓ BMIz at 7y; In boys,; - EDF, Snacking, Healthier:; ○ ᴓ WHR at 7y; ○ ᴓ FMI%, FMI at 7y; ○ ᴓ BMIz at 7y | - Did not account for: Race/ethnicity; - Diet assessed once at baseline; - Diet assessment record validated in adults only; Funding: Programa Operacional de Saúde (Regional Department of Ministry of Health); Portuguese Foundation for Science and Technology (FCT) and by the Calouste Gulbenkian Foundation; EDER from the Operational Programme Factors of Competitiveness—COMPETE and through national funding from the FCT (Portuguese Ministry of Education and Science)
Fernandez-Alvira, 2017 ^5^; Italy, Estonia, Cyprus, Belgium, Sweden, Hungary, Germany, Spain, Identification and prevention of Dietary- and lifestyle-induced health EFfects In Children and infantS (IDEFICS) study; Prospective Cohort Study; N=8341; 50% female; Excluded those with missing data | [underlined: Factor/cluster analysis:]; Four patterns examined (continuous; and change from baseline to f/u) at age 2-9y; - “Processed”: Higher takeaway and high-fat foods, such as savoury pastries, fritters, pizza as main dish, fried potatoes, hamburger, hot dog, kebab and wraps, and lowest scores for products such as wholemeal bread, cooked vegetables, raw vegetables, and fresh fruits without added sugar; - “Sweet”: Higher sugar-rich products, like chocolate- or nut-based spread, sweetened drinks, fruit juices, diet drinks, candies, loose candies, marshmallows, and biscuits, packaged cakes, pastries and puddings, with the lowest scores for water, porridge, oatmeal, gruel, unsweetened cereals, muesli, raw vegetables, plain unsweetened milk and plain unsweetened yoghurt; - “Healthy”: Higher low-fat foods, foods rich in vitamins and wholegrain foods, e.g. raw vegetables, fresh fruits without added sugar, porridge, oatmeal, gruel, unsweetened cereals, muesli and plain unsweetened milk, and the lowest values for high-fat, high-sugar products, such as fried potatoes, sweetened drinks, sweetened milk, mayonnaise and mayonnaise-based products, chocolate- or nut-based spread, crisps, corn crisps, popcorn, and biscuits, packaged cakes, pastries and puddings | “Processed” vs. “Healthy”:; - ↑ FMIz at f/u (age 4-11y); - ᴓ FFMIz at f/u (age 4-11y); - ↑ BMIz at f/u (age 4-11y); - ᴓ WCz at f/u (age 4-11y); “Sweet” vs. “Healthy”:; - ↑ FMIz at f/u (age 4-11y); - ᴓ FFMIz at f/u (age 4-11y); - ↑ BMIz at f/u (age 4-11y); - ↑ WCz at f/u (age 4-11y); “Processed-Processed” (baseline-f/u) and “Processed-Sweet” vs. “Healthy-“Healthy”:; - ↑ FMIz at f/u (age 4-11y); - ↑ BMIz at f/u (age 4-11y); “Processed-Processed” vs. “Healthy-Healthy”:; - ↑ WC at f/u (age 4-11y); “Processed-Sweet” vs. “Healthy-Healthy”:; - ↑ WC at f/u (age 4-11y); “Sweet-Sweet” vs. “Healthy-“Healthy”:; - ↑ WC at f/u (age 4-11y) | - Did not account for: Race/ethnicity; - Did not account for missing data; Funding: European Community’s Sixth RTD Framework Programme
Hu, 2016 ^6^; United States, Project EAT; Prospective Cohort Study; N=2656; ~50% female; Excluded those with missing data | [underlined: Index/score:] A Priori Diet Quality Score (APDQS, continuous) at age 15y; - Positively rated foods, serving/d: Beans, Chocolate, Coffee, Fish, Fruit, Green vegetables, Low-fat dairy, Nuts, Poultry, Tea, Tomato, Whole grain, Yellow vegetables; - Neutral foods, serving/d: Diet soft drink, Eggs, Fruit juice, Margarine, Other vegetables, Potatoes, Refined grains, Seafood, Soup, Beer, Liquor, Wine; - Negatively rated foods, serving/d: Butter, Fried foods, Fried potato, Grain dessert, Organ meat, Processed meat, Red meat, Salty snacks, Sauces, Soft drinks, Sweet bread, Whole fat dairy | ↓ BMI at 25y; ↓ weight, excess weight gain at 25y | - Diet assessed once at baseline; - Self-reported outcome data; - Did not account for missing data; Funding: National Heart, Lung, and Blood Institute; National Institute on Aging; NIH
Martin-Calvo, 2016 ^7^; United States, Growing Up Today Study 2; Prospective Cohort Study; N=10,918; 55% female; Excluded those with missing data | [underlined: Index/score:] modified KidMed Index (categorical, quartiles of 2y change, Q1, ref; continuously per-2-pt increase) at age 8-15y; - Positive components: Fruit or fruit juice, vegetables, fish, legumes, modified cereals/bread, nuts, olive oil, reduced- or low-fat dairy, yogurt/cheese; specified frequency/amounts per day or wk.; - Negative components: fast food >1/wk, skipping breakfast, commercial bakery as breakfast, candies/sweets ≥ 1/d | ↓ gain in BMI after 7y f/u | - Did not account for: Race/ethnicity; - Self-reported outcome data; - Did not account for missing data; Funding: Breast Cancer Research Foundation; NIH
Nguyen, 2019 ^8^; The Netherlands, Generation R Study; Prospective Cohort Study; N=3950; 51% female; Excluded those with missing data | [underlined: Index/score:] Diet Quality Score (based on age-specific dietary guidelines), continuous at age 8y; - Positive components: intake of fruit (150 g/d); vegetables (150 g/d); whole grains (90 g/d); fish (60 g/w); legumes (84 g/w); nuts (15 g/d); dairy (300 g/d); oils and fats (30 g/d);; - Negative components: sugar-containing beverages (150 g/d); and meat (250 g/w) | Diet Quality Score at 8y:; - ↑ FFMI at 10y; - ᴓ FMI % body fat at 10y (results were similar when stratified by sex); - ↑ BMI at 10y (when stratified by sex, results were only significant in girls); - ↑ weight, height at 10y (when stratified by sex, results were only significant in girls) | - N/A; Funding: Errasmus Medical Center, Rotterdam, Erasmus University Rotterdam, and the Netherlands Organization for Health Research and Development ‘Geestkracht’ program; Netherlands Organization for Health Research and Development
Okubo, 2015 ^9^; United Kingdom, Southampton Women’s Survey; Prospective Cohort Study; N=1018; ~48% female; Excluded those with missing data | [underlined: Factor/cluster analysis:]; “Prudent” dietary pattern score (categorical, tertiles, T3, ref; continuous per 1unit increase) at age 3y; “Prudent” dietary pattern characterized by fish and shellfish, vegetables (salad, green, root other), other fruits | ↓ FM at 6y; ᴓ BMI at 6y | - Did not account for: Race/ethnicity; - Diet measured at 4 time points; - Did not account for missing data; Funding: Medical Research Council, the British Heart Foundation, Arthritis Research United Kingdom, the National Osteoporosis Society, the International Osteoporosis Foundation, the Cohen Trust, the National Institute for Health Research Southampton Biomedical Research Centre, University of Southampton and University Hospital Southampton National Health Service Foundation Trust, and the National Institute for Health Research Musculoskeletal Biomedical Research Unit, University of Oxford.
Pala, 2013 ^10^; Italy, Estonia, Cyprus, Belgium, Sweden, Hungary, Germany, Spain, Identification and prevention of Dietary- and lifestyle-induced health EFfects In Children and infantS (IDEFICS) study; Prospective Cohort Study; N=9427; 49% female; Excluded those with missing data | [underlined: Factor/cluster analysis:]; “Snacking” (categorical, tertiles, T1, ref; continuous per 1-unit increase) at age 2-10y: Street foods (e.g., sandwiches), savory pastries, chocolate bars; “Sweet” (categorical, tertiles, T1, ref; continuous per 1-unit increase) at age 2-10y: Chocolate spreads, biscuits and sweets/candy, fried meat, soft drinks; “Vegetables and Wholemeal” (categorical, tertiles, T1, ref; continuous per 1-unit increase): Vegetables, fruits, wholemeal cereal products, unsweetened milk; “Protein and Water”: Fish, meat, eggs, water | Vegetables and Wholemeal: ↓ overweight/obesity after 2y f/u; “Snacking”, “Sweet”, “Protein and Water”: ᴓ overweight/obesity after 2y f/u; “Snacking”, “Sweet”, “Vegetables and Wholemeal”, “Protein and Water”: ᴓ change in BMI after 2y f/u | - Did not account for: Race/ethnicity; - Diet measured once at baseline; - Water intake was imputed; - Limited generalizability of sample tested; Funding: European Community’s Sixth RTD Framework Programme
Smith, 2014 ^11^; United Kingdom, Avon Longitudinal Study of Parents and Children (ALSPAC) cohort; Prospective Cohort Study; N=3911; ~56% female; Excluded those with missing data; other reasons NR | [underlined: Factor/cluster analysis:]; - “Health Aware” (continuous, per 1 SD increase) at 9y: Higher loadings for fruits and vegetables, high-fiber bread, pasta, cheese, and fish, lower loadings for chips (French fries), crisps (potato and corn snacks), processed meat, fizzy (carbonated) drinks; - “Traditional” (continuous, per 1 SD increase) at 9y: Higher loadings for meat, roast potatoes, vegetables, batter and pastry products, low energy-density sauces (e.g. gravy, desserts); - “Packed Lunch” (continuous, per 1 SD increase) at 9y: Higher loadings for low-fiber bread, margarine, cheese, cold meats, salty flavorings such as yeast extract, diet squash (dilutable soft drink) | “Health Aware”: ↓ FM and lean mass gain at 11y in girls (valid and under-reporting), and under-reporting boys; “Traditional”: ᴓ M gain at 11y in girls and boys (valid- and under-reporting); “Packed Lunch”: ↓ FM gain at 11y in “valid-reporting” girls, ↓ lean mas | - Did not account for: Race/ethnicity; - Diet assessed once each age time point; unclear timing of diet measurement in relation to outcomes; - Unclear if diet assessment methods were valid/reliable; - Did not account for missing data; Funding: The UK Medical Research Council, the Wellcome Trust and the University of Bristol; World Cancer Research Fund
Tognon, 2014 ^12^; Italy, Estonia, Cyprus, Belgium, Sweden, Hungary, Germany, Spain, Identification and prevention of Dietary- and lifestyle-induced health EFfects In Children and infantS (IDEFICS) study; Prospective Cohort Study; N=9114; 49% female; Excluded those with missing data | [underlined: Index/score:]; Mediterranean diet score, (high adherence levels, >3pts, vs. low) at 2-9y; - Points for intake higher than median for: vegetables and legumes, fruit and nuts (fruit added or not with sugar, nuts, seeds, dried fruit), cereals (breakfast cereals, white and wholemeal bread, rolls and crispbread, pasta, noodles and rice), fish (fresh or frozen fish, and fried fish and fish fingers); - Points for intake below median for: dairy (milk, yoghurt, cheese including spreadable cheese), and meat products (fried and non-fried meat, hamburgers, falafel, kebab, etc.) | ↓ change in %FM after 2y f/u (p=0.06); ↓ change in BMIz after 2y f/u; ↓ change in waist circumference, WHR after 2y f/u | - Did not account for: Race/ethnicity; - Diet comparison groups not clearly described; - Diet measured once at baseline; - Did not account for missing data; Funding: European Union within the Sixth RTD Framework Program; Swedish Council on Working Life and Social Research (FAS) EpiLife Center and the Swedish Research Council

Table 2 Randomized controlled trials that examined diets based on macronutrient proportion and risk of growth size, body composition, and risk of overweight or obesity^x^

Study and Participant Characteristics^xi^ | Diet Exposure^xii^ | Macronutrient Distribution, % Energy | | | Results^xiii^ | Methodological Considerations
Study and Participant Characteristics^xi^ | Diet Exposure^xii^ | Carbohlydrate | Fat | Protein | Results^xiii^ | Methodological Considerations
Alvarez-Perez, 2016 ^14^; Spain, PREDIMED-Canarias, RCT; N=351; All type 2 diabetes or >3 CVD risk factors | Mediterranean diet with EVOO | 45.0% | 38.9% | 17.4% | ᴓ % body fat, FM, FFM, truncal FM at 1y; ᴓ BMI at 1y; ᴓ WC at 1 y; ᴓ Wt at 1y | Concerns with randomization; Funding: Instituto de Salud Carlos III, Spanish Government, Fondo de Investigaciones Sanitarias, Ministerio de Sanidad y Consumo, Centro de Investigacion Biomedica en Red de Fisiopatologia de la Obesidad y Nutricion, Agencia Canaria de Investigacion, Innovacion y Sociedad de la Informacion, Gobierno de Canarias, European Research Council
Alvarez-Perez, 2016 ^14^; Spain, PREDIMED-Canarias, RCT; N=351; All type 2 diabetes or >3 CVD risk factors | Mediterranean diet with nuts | 44.4% | 39.0% | 14.9% | ᴓ % body fat, FM, FFM, truncal FM at 1y; ᴓ BMI at 1y; ᴓ WC at 1 y; ᴓ Wt at 1y
Alvarez-Perez, 2016 ^14^; Spain, PREDIMED-Canarias, RCT; N=351; All type 2 diabetes or >3 CVD risk factors | Control group | 50.1% | 32.6% | 20.3% | ᴓ % body fat, FM, FFM, truncal FM at 1y; ᴓ BMI at 1y; ᴓ WC at 1 y; ᴓ Wt at 1y
Arciero, 2008 ^67^; United States, RCT; N=16; All overweight or obese | % E in “high-protein” (HP) diet | 25.3% | 31.3% | 43.5% | ᴓ body fat %, FM, LM, or LM/Wt % at 3mo; ᴓ BMI at 3mo; ᴓ WC, abdominal fat (%, kg) at 3mo; ᴓ Wt at 3mo | Funding: Abbott Laboratories, EAS division
Arciero, 2008 ^67^; United States, RCT; N=16; All overweight or obese | % E in “moderate-protein” diet | 41.9% | 28.8% | 26.9% | ᴓ body fat %, FM, LM, or LM/Wt % at 3mo; ᴓ BMI at 3mo; ᴓ WC, abdominal fat (%, kg) at 3mo; ᴓ Wt at 3mo | Funding: Abbott Laboratories, EAS division
Brown, 2000 ^68^; New Zealand, RCT; N=32; All competitive cyclists in good health | “High Fat” diet | 37.0% | 47.0% | 13.8% | ᴓ Wt status at 12wk; ᴓ LM, FM, % body fat at 12wk; ᴓ BMI at 12wk | Funding: Kiwi Co-operative Dairies, New Zealand
Brown, 2000 ^68^; New Zealand, RCT; N=32; All competitive cyclists in good health | “High Carbohydrate” diet | 69.0% | 14.0% | 14.0% | ᴓ Wt status at 12wk; ᴓ LM, FM, % body fat at 12wk; ᴓ BMI at 12wk | Funding: Kiwi Co-operative Dairies, New Zealand
Dale, 2009 ^69^; New Zealand, RCT; N=174; All women, without chronic disease | “High Monounsatured Fat” (MUFA) Diet, year 1, year 2 | 43%, 50% | 30%, 24% | 23%, 21% | ᴓ FFM, FM at 1y, 2y; ᴓ BMI at 1y, 2y; ᴓ WC at 1y, 2y; ᴓ Wt at 1y, 2y | Funding: Health Research Council of New Zealand
Dale, 2009 ^69^; New Zealand, RCT; N=174; All women, without chronic disease | “High Carbohydrate” Diet, year 1, year 2 | 43%, 47% | 31%, 27% | 22%, 22% | ᴓ FFM, FM at 1y, 2y; ᴓ BMI at 1y, 2y; ᴓ WC at 1y, 2y; ᴓ Wt at 1y, 2y | Funding: Health Research Council of New Zealand
Daly, 2014 ^23^; Australia, RCT; N=91; All women, 60-90yo, w/o acute or terminal illness, hx of fracture, type 1 diabetes, kidney disease | Lean meat group | 41% | 30% | 24% | ↑ LM at 16wk; ᴓ FM, % body fat at 16wk | Ran 2 sessions of the intervention within each village, 1 yr apart; Funding: Meat and Livestock Australia Ltd, a National Health and Medical Research Council Career Development Award; an Australian Research Council Future Fellowship
Daly, 2014 ^23^; Australia, RCT; N=91; All women, 60-90yo, w/o acute or terminal illness, hx of fracture, type 1 diabetes, kidney disease | Rice/pasta group | 42% | 33% | 18% | ↑ LM at 16wk; ᴓ FM, % body fat at 16wk
Davis, 2017; Australia, RCT; N=166; All non-smoker, w/o chronic disease and major psychological illnesses | “Traditional” Diet | 37.8% | 38.8% | 19.4% | ᴓ BMI at 3mo, 6mo; ᴓ Wt at 3mo, 6mo | Funding: National Health and Medical Research Council (Australian government)
Davis, 2017; Australia, RCT; N=166; All non-smoker, w/o chronic disease and major psychological illnesses | “Habitual” Diet | 40.3% | 35.6% | 19.2% | ᴓ BMI at 3mo, 6mo; ᴓ Wt at 3mo, 6mo | Funding: National Health and Medical Research Council (Australian government)
Delbridge, 2009 ^70^; Australia, RCT; N=141; All overweight or obese | “High Carbohydrate” diet | 55% | 30% | 15% | ᴓ FM, FFM at 12mo; ᴓ BMI at 12mo; ᴓ WC, WHR at 12mo; ᴓ Weight at 12mo | Funding: Meat and Livestock Australia
Delbridge, 2009 ^70^; Australia, RCT; N=141; All overweight or obese | “High Protein” diet | 40% | 30% | 30% | ᴓ FM, FFM at 12mo; ᴓ BMI at 12mo; ᴓ WC, WHR at 12mo; ᴓ Weight at 12mo | Funding: Meat and Livestock Australia
Donnelly, 2008 ^71^; United States, Jayhawk Observed Eating Trial, RCT; N=305; All weight stable, w/o chronic disease | “Low Fat” Diet | 64.7% | 20.4% | 14.9% | ᴓ % Body fat at 12wk; ᴓ BMI at 12wk; ᴓ Wt at 12wk, after accounting for energy intake | Funding: Health Management Resources; National Institute of Diabetes and Digestive and Kidney Diseases; Clinical Research Center of the University of Colorado Health Sciences Center
Donnelly, 2008 ^71^; United States, Jayhawk Observed Eating Trial, RCT; N=305; All weight stable, w/o chronic disease | “Moderate Fat” Diet | 54.3% | 30.7% | 15.0% | ᴓ % Body fat at 12wk; ᴓ BMI at 12wk; ᴓ Wt at 12wk, after accounting for energy intake | Funding: Health Management Resources; National Institute of Diabetes and Digestive and Kidney Diseases; Clinical Research Center of the University of Colorado Health Sciences Center
Donnelly, 2008 ^71^; United States, Jayhawk Observed Eating Trial, RCT; N=305; All weight stable, w/o chronic disease | “High Fat” Diet | 44.2% | 40.3% | 15.5% | ᴓ % Body fat at 12wk; ᴓ BMI at 12wk; ᴓ Wt at 12wk, after accounting for energy intake | Funding: Health Management Resources; National Institute of Diabetes and Digestive and Kidney Diseases; Clinical Research Center of the University of Colorado Health Sciences Center
Due, 2008 ^72^; United States, RCT; N=125; All lost >8% Wt after pre-intervention phase | “MUFA” diet: Guidance to consume vegetables, fruit, whole-meal cereals, vegetable oils, nuts, pulses, fish, poultry, eggs; restrictred meat, butter, dairy, white rice, plain pasta, white bread, potatoes, sweets, soft drinks | 43.3% | 38.4% | 15.3% | ↓ FM at 6mo, MUFA vs. Control; ᴓ LM at 6mo MUFA vs. Control; ᴓ BMI at 6mo MUFA vs. Control; ᴓ WC at 6mo MUFA vs. Control; ᴓ Wt at 6mo MUFA vs. Control; ↓ FM at 6mo, LF vs. Control; ᴓ LM at 6mo LF vs. Control; ᴓ BMI at 6mo LF vs. Control; ᴓ WC at 6mo LF vs. Control; ᴓ Wt at 6mo LF vs. Control | Funding: H.A. Foundation, The Danish Heart Association, The Danish Diabetes Association, the Centre for Advanced Food Research, the State Research Councils, The Danish Pork Council foundations, associations, and research councils
Due, 2008 ^72^; United States, RCT; N=125; All lost >8% Wt after pre-intervention phase | “Low-Fat” (LF) diet: Guidance to consume vegetables, fruit, whole-meal cereals, vegetable oils, nuts, pulses, fish, poultry, eggs; restrictred meat, butter, dairy, white rice, plain pasta, white bread, potatoes, sweets, soft drinks | 57.6% | 23.6% | 15.8%
Due, 2008 ^72^; United States, RCT; N=125; All lost >8% Wt after pre-intervention phase | Control: Guidance to consume dairy, cheese, red meat; less fish, poultry, eggs, rice/pasta, bread, sweets, soft drinks, fruit, vegetables, pulses, nuts, oils | 49.8% | 32.1% | 15.9%
Gardner, 2018 ^33^; United States, DIETFITS, RCT; N=609; All overweight or obese | “Healthy Low Fat” diet: Guidance to consume oils, fatty meats, whole-fat dairy, nuts | 48.4% | 28.7% | 20.6% | ᴓ % Body fat at 12mo; ᴓ BMI at 12mo; ᴓ WC at 12mo; ᴓ Wt at 12mo | Study did not restrict energy but intended for participants to lose weight; Funding: National Institute of Diabetes and Digestive and Kidney Diseases; Nutrition Science Initiative; National Heart, Lung, and Blood Institute, and the Stanford Clinical and Translational Science Award
Gardner, 2018 ^33^; United States, DIETFITS, RCT; N=609; All overweight or obese | “Healthy Low Carbohydrate” diet: Guidance to consume cereals, grains, rice, starchy vegetables, legumes | 29.8% | 44.6% | 22.9% | ᴓ % Body fat at 12mo; ᴓ BMI at 12mo; ᴓ WC at 12mo; ᴓ Wt at 12mo
Howard, 2010 ^73^; United States, Women’s Health Initiative Dietary Modification Trial, RCT; N=2730; All postmenopausal women, w/o hx of cancer, >32%E fat intake | “Low Fat Diet” year 1; year 3; year 6; Guidance to reduce fat from ~35%E to 20%E of energy, 5 servings/d fruits and vegetables, 6 serving/d grains | 58.0%,; 56.4%,; 53.9% | 25.3%,; 26.5%,; 29.3% | 17.5%,; 17.6%,; 17.7% | Low Fat vs. Control:; ↓ BMI at 1y,; ᴓ BMI at 3y, 6y; ↓ WC at 1y, 3y; ᴓ WC at 6y; ↓ Wt at 1y; ᴓ Wt at 3y, 6y | Some missing outcome data not accounted for; Funding: National Heart, Lung, and Blood Institute, NIH, US Department of Health and Human Services
Howard, 2010 ^73^; United States, Women’s Health Initiative Dietary Modification Trial, RCT; N=2730; All postmenopausal women, w/o hx of cancer, >32%E fat intake | Control Diet, year 1; year 3; year 6; Received print-only materials | 47.9%,; 47.0%,; 46.3% | 35.7%,; 36.0%,; 37% | 16.5%,; 17%,; 17% | Low Fat vs. Control:; ↓ BMI at 1y,; ᴓ BMI at 3y, 6y; ↓ WC at 1y, 3y; ᴓ WC at 6y; ↓ Wt at 1y; ᴓ Wt at 3y, 6y | Some missing outcome data not accounted for; Funding: National Heart, Lung, and Blood Institute, NIH, US Department of Health and Human Services
Kahleova, 2018 ^41^; United States, RCT; N=75; All overweight or obese, w/o hx of diabetes, smoking, alcohol/ drug abuse, pregnancy/ lactation, or current use of vegan diet | “Low Fat, Vegan” Diet: Guidance to consume vegetables, grains, legumes, and fruits, and avoid animal products and added fats | 69.6% | 17.5% | 12.3% | ↓ LM, FM, visceral FM at 16wk; ↓ BMI at 16wk | Adherence not fully described; No information about foods and beverages consumed; Funding: Physicians Committee for Responsible Medicine
Kahleova, 2018 ^41^; United States, RCT; N=75; All overweight or obese, w/o hx of diabetes, smoking, alcohol/ drug abuse, pregnancy/ lactation, or current use of vegan diet | Control Diet | 46.6% | 35.0% | 17.0% | ↓ LM, FM, visceral FM at 16wk; ↓ BMI at 16wk | Adherence not fully described; No information about foods and beverages consumed; Funding: Physicians Committee for Responsible Medicine
Larsen, 2010 ^74^; Europe - Multiple Countries, RCT; N=773; All lost wt during the initial 8wk weight loss pre-intervention phase | “Low Protein-Low Glycemic Index” Diet | 50.8% | 29.8% | 18.2% | ↑ Wt regain at 26wk in Low-Protein - High Glycemic Index diet vs. other groups (completers); ↑ Wt regain at 26wk in Low protein and High glycemic index groups (ITT, completers) | Funding: European Commission Food Quality and Safety Priority of the Sixth Framework Program
Larsen, 2010 ^74^; Europe - Multiple Countries, RCT; N=773; All lost wt during the initial 8wk weight loss pre-intervention phase | “Low Protein-High Glycemic Index” Diet | 50.9% | 30.9% | 16.7% | ↑ Wt regain at 26wk in Low-Protein - High Glycemic Index diet vs. other groups (completers); ↑ Wt regain at 26wk in Low protein and High glycemic index groups (ITT, completers) | Funding: European Commission Food Quality and Safety Priority of the Sixth Framework Program
Larsen, 2010 ^74^; Europe - Multiple Countries, RCT; N=773; All lost wt during the initial 8wk weight loss pre-intervention phase | “High Protein-Low Glycemic Index” Diet | 43.0% | 32.0% | 21.7% | ↑ Wt regain at 26wk in Low-Protein - High Glycemic Index diet vs. other groups (completers); ↑ Wt regain at 26wk in Low protein and High glycemic index groups (ITT, completers) | Funding: European Commission Food Quality and Safety Priority of the Sixth Framework Program
Larsen, 2010 ^74^; Europe - Multiple Countries, RCT; N=773; All lost wt during the initial 8wk weight loss pre-intervention phase | “High Protein-High Glycemic Index” Diet | 44.7% | 31.2% | 22.6% | ↑ Wt regain at 26wk in Low-Protein - High Glycemic Index diet vs. other groups (completers); ↑ Wt regain at 26wk in Low protein and High glycemic index groups (ITT, completers) | Funding: European Commission Food Quality and Safety Priority of the Sixth Framework Program
Larsen, 2010 ^74^; Europe - Multiple Countries, RCT; N=773; All lost wt during the initial 8wk weight loss pre-intervention phase | Control Diet | 46.4% | 33.4% | 18.7% | ↑ Wt regain at 26wk in Low-Protein - High Glycemic Index diet vs. other groups (completers); ↑ Wt regain at 26wk in Low protein and High glycemic index groups (ITT, completers) | Funding: European Commission Food Quality and Safety Priority of the Sixth Framework Program
Paineau, 2008 ^75^; France, RCT; N=1013; All parents with children (family intervention) | Reduce Fat, Increase Complex Carbohydrate diet | 46.4% | 32.4% | 18.8% | Reduce Fat vs. Control:; ᴓ FM, FFM at 8mo; ᴓ BMI at 8mo; ᴓ WC at 8mo; ᴓ Wt at 8mo; Reduce Fat/Sugar vs. Control:; ↓ FM at 8 mo; ᴓ FFM at 8mo; ↓ BMI at 8 mo | Funding: French Ministry of Research; ELPAS study’s private partners
Paineau, 2008 ^75^; France, RCT; N=1013; All parents with children (family intervention) | Reduce Fat/Sugar, Increase Complex Carbohydrate diet | 45.3% | 33.0% | 19.3% | Reduce Fat vs. Control:; ᴓ FM, FFM at 8mo; ᴓ BMI at 8mo; ᴓ WC at 8mo; ᴓ Wt at 8mo; Reduce Fat/Sugar vs. Control:; ↓ FM at 8 mo; ᴓ FFM at 8mo; ↓ BMI at 8 mo | Funding: French Ministry of Research; ELPAS study’s private partners
Paineau, 2008 ^75^; France, RCT; N=1013; All parents with children (family intervention) | Control | 43.8% | 35.6% | 18.0% | Reduce Fat vs. Control:; ᴓ FM, FFM at 8mo; ᴓ BMI at 8mo; ᴓ WC at 8mo; ᴓ Wt at 8mo; Reduce Fat/Sugar vs. Control:; ↓ FM at 8 mo; ᴓ FFM at 8mo; ↓ BMI at 8 mo | Funding: French Ministry of Research; ELPAS study’s private partners
Razquin, 2009 ^76^; Spain, PREDIMED, RCT; N=187; All w/ T2D or ≥3 risk factors for metabolic syndrome | “Mediterranean diet” with EVOO | 43.7% | 38.2% | 16.5% | ᴓ WC at 3y; ᴓ Wt at 3y | Funding: Department of Health of the Navarra Government, Linea Especial of the University of Navarra, Instituto de Salud Carlos III of the Spanish Government and CIBERobn
Razquin, 2009 ^76^; Spain, PREDIMED, RCT; N=187; All w/ T2D or ≥3 risk factors for metabolic syndrome | “Dietary Guidelines” diet | 40.3% | 41.8% | 15.3% | ᴓ WC at 3y; ᴓ Wt at 3y | Funding: Department of Health of the Navarra Government, Linea Especial of the University of Navarra, Instituto de Salud Carlos III of the Spanish Government and CIBERobn
Razquin, 2009 ^76^; Spain, PREDIMED, RCT; N=187; All w/ T2D or ≥3 risk factors for metabolic syndrome | Control diet | 37.8% | 43.7% | 15.4% | ᴓ WC at 3y; ᴓ Wt at 3y | Funding: Department of Health of the Navarra Government, Linea Especial of the University of Navarra, Instituto de Salud Carlos III of the Spanish Government and CIBERobn
Reidlinger, 2015 ^55^; United Kingdom, CRESSIDA, RCT; N=162; All w/CVD or <20% 10y CVD risk | Dietary Guidelines Diet | 45.2% | 33.1% | 17.7% | ↓ WC at 12wk; ↓ Wt at 12wk | Funding: United Kingdom Food Standards Agency and Department of Health and by the National Institute for Health Research (NIHR) Clinical Research Facility at Guy’s and St Thomas’ NHS Foundation Trust and NIHR Biomedical Research Centre based at Guy’s and St Thomas’ NHS Foundation Trust and King’s College London.
Reidlinger, 2015 ^55^; United Kingdom, CRESSIDA, RCT; N=162; All w/CVD or <20% 10y CVD risk | Control Diet | 43.1% | 37.8% | 15.7% | ↓ WC at 12wk; ↓ Wt at 12wk
Sanders, 2013 ^77^; United Kingdom, RISCK, RCT; N=108; All at risk for metabolic syndrome | “High Saturated Fat” diet: Guidance to use full-fat milk and cheese | 42.8% | 35.7% | 17.8% | ᴓ Wt at 24wk | Funding: National Institute for Health Research (NIHR) Clinical Research Facility at Guy’s and St Thomas’ National Health Service (NHS) Foundation Trust and NIHR Biomedical Research Centre based at Guy’s and St Thomas’ NHS Foundation Trust and King’s College London
Sanders, 2013 ^77^; United Kingdom, RISCK, RCT; N=108; All at risk for metabolic syndrome | “High MUFA” diet: Guidance to replace full-fat milk with skimmed and full-fat cheese with half-fat cheese; snack foods provided (nuts and potato crisps) | 47.2% | 34.4% | 16.2% | ᴓ Wt at 24wk
Sanders, 2013 ^77^; United Kingdom, RISCK, RCT; N=108; All at risk for metabolic syndrome | “High Carbohydrate” diet: Guidance to replace full-fat milk with skimmed and full-fat cheese with half-fat cheese; advised to consume additional portions of bread, potatoes, and rice | 53.1% | 26.1% | 17.8% | ᴓ Wt at 24wk
Tierney, 2011 ^78^; Europe - Multiple Countries, LIPGENE, RCT; N=417; All with metabolic syndrome | “High-Fat, High-Saturated Fat” diet | 41.2% | 39.8% | 17.4% | ᴓ Abdominal obesity at 12wk; ᴓ BMI at 12wk; ᴓ WC at 12wk; ᴓ Wt at 12wk | Intent for weight-loss without energy-restriction; Funding: EU 6 Framework Food Safety & Quality Programme; Norwegian Foundation for Health and Rehabilitation, South-Eastern Norway Regional Health Authority, the Johan Throne Holst Foundation for Nutrition Research and the Freia Medical Research Foundation
Tierney, 2011 ^78^; Europe - Multiple Countries, LIPGENE, RCT; N=417; All with metabolic syndrome | “High-Fat, High-MUFA” diet | 42.1% | 38.9% | 16.9% | ᴓ Abdominal obesity at 12wk; ᴓ BMI at 12wk; ᴓ WC at 12wk; ᴓ Wt at 12wk
Tierney, 2011 ^78^; Europe - Multiple Countries, LIPGENE, RCT; N=417; All with metabolic syndrome | “Low-Fat, High-Complex-Carbohydrate” diet + sunflower oil supplement | 49.4% | 29.6% | 19.2% | ᴓ Abdominal obesity at 12wk; ᴓ BMI at 12wk; ᴓ WC at 12wk; ᴓ Wt at 12wk
Tierney, 2011 ^78^; Europe - Multiple Countries, LIPGENE, RCT; N=417; All with metabolic syndrome | “Low-Fat, High-Complex-Carbohydrate diet + n-3 PUFA supplement | 50.2% | 29.1% | 18.3% | ᴓ Abdominal obesity at 12wk; ᴓ BMI at 12wk; ᴓ WC at 12wk; ᴓ Wt at 12wk
Turner-McGrievy, 2015 ^61^; United States, RCT; N=62; All overweight, obese, w/stable medical condition | Vegan Diet, %E, Δ baseline to 2mo | 55.9% | 28.9% | 13.7% | All groups: ↓ Wt at 2mo, 6mo; Vegan group lost more Wt than all others; Omnivore lost less wt than the other groups at 2mo; Omnivore, semi-veg, and pesco-veg lost less Wt than vegetarian and vegan at 6mo | Not powered to detect diffreences between Vegan and Vegetarian groups; Funding: NR
Turner-McGrievy, 2015 ^61^; United States, RCT; N=62; All overweight, obese, w/stable medical condition | Vegan Diet, %E, Δ baseline to 6mo | 53.6% | 30.8% | 14.8% | | Not powered to detect diffreences between Vegan and Vegetarian groups; Funding: NR
Turner-McGrievy, 2015 ^61^; United States, RCT; N=62; All overweight, obese, w/stable medical condition | Vegetarian Diet, %E, Δ baseline to 2mo | 49.0% | 36.3% | 13.4% | | Not powered to detect diffreences between Vegan and Vegetarian groups; Funding: NR
Turner-McGrievy, 2015 ^61^; United States, RCT; N=62; All overweight, obese, w/stable medical condition | Vegetarian Diet, %E, Δ baseline to 6mo | 51.9% | 33.4% | 14.2% | | Not powered to detect diffreences between Vegan and Vegetarian groups; Funding: NR
Turner-McGrievy, 2015 ^61^; United States, RCT; N=62; All overweight, obese, w/stable medical condition | Pesco-Vegetarian Diet, %E, Δ baseline to 2mo | 48.3% | 30.4% | 18.6% | | Not powered to detect diffreences between Vegan and Vegetarian groups; Funding: NR
Turner-McGrievy, 2015 ^61^; United States, RCT; N=62; All overweight, obese, w/stable medical condition | Pesco-Vegetarian Diet, %E, Δ baseline to 6mo | 49.2% | 32.5% | 16.3% | | Not powered to detect diffreences between Vegan and Vegetarian groups; Funding: NR
Turner-McGrievy, 2015 ^61^; United States, RCT; N=62; All overweight, obese, w/stable medical condition | Semi-Vegetarian Diet, %E, Δ baseline to 2mo | 45.7% | 33.4% | 17.6% | | Not powered to detect diffreences between Vegan and Vegetarian groups; Funding: NR
Turner-McGrievy, 2015 ^61^; United States, RCT; N=62; All overweight, obese, w/stable medical condition | Semi-Vegetarian Diet, %E, Δ baseline to 6mo | 43.1% | 36.6% | 17.3% | | Not powered to detect diffreences between Vegan and Vegetarian groups; Funding: NR
Turner-McGrievy, 2015 ^61^; United States, RCT; N=62; All overweight, obese, w/stable medical condition | Omnivorous Diet, %E, Δ baseline to 2mo | 42.6% | 39.5% | 19.4% | | Not powered to detect diffreences between Vegan and Vegetarian groups; Funding: NR
Uusitupa, 2013 ^79^; Finland, Sweden, Denmark, Iceland, SYSDIET, RCT; N=166; All with features of metabolic syndrome | Healthy Nordic Diet | 46.1% | 32.9% | 16.9% | ᴓ Wt at 18/24wk | Funding: NordForsk; Academy of Finland, Finnish Diabetes Research Foundation^xiv^
Uusitupa, 2013 ^79^; Finland, Sweden, Denmark, Iceland, SYSDIET, RCT; N=166; All with features of metabolic syndrome | Control Diet | 44.6% | 35.2% | 16.2% | ᴓ Wt at 18/24wk | Funding: NordForsk; Academy of Finland, Finnish Diabetes Research Foundation^xiv^
Vincent-Baudry, 2005 ^80^; France, Medi-RIVAGE, RCT; N=212; All at high CVD risk | “Mediterranean” diet: Consume nuts, whole-meal bread, cereals, fruit, vegetables, legumes, olive oil; fish 4/wk, red meat 1/wk; sheep, poultry; oat-brain enriched pasta, tomato sauce, olive oil provided | 45.9% | 34.6% | 19.6% | ᴓ BMI at 3mo | Funding: French Research Ministry; INSERM ^xv^
Vincent-Baudry, 2005 ^80^; France, Medi-RIVAGE, RCT; N=212; All at high CVD risk | “Low-Fat” diet: Consume more poultry than mammal meat, avoid offal and saturated-fat-rich animal products, fish 2-3x/wk; fruit, vegetables, low-fat dairy products, vegetable oils | 44.8% | 33.9% | 21.3% | ᴓ BMI at 3mo | Funding: French Research Ministry; INSERM ^xv^
Wan, 2017 ^81^; China, RCT; N=307; All BMI <28 kg/m2 | “Low-Fat, High-Carbohydrate” (LF-HC) | 66.0% | 20.0% | 14.0% | ↓ WC at 6mo in LF-HC vs. MF-MC, HF-LC; ᴓ WC at 6mo in HF-LC vs. MF-MC; ↓ Wt at 6mo in LF-HC vs. MF-MC, HF-LC; ᴓ Wt at 6mo in HF-LC vs. MF-MC | Funding: National Basic Research Program of China
Wan, 2017 ^81^; China, RCT; N=307; All BMI <28 kg/m2 | “Moderate-Fat, Moderate-Carbohydrate” (MF-MC) | 56.0% | 30.0% | 14.0% | ↓ WC at 6mo in LF-HC vs. MF-MC, HF-LC; ᴓ WC at 6mo in HF-LC vs. MF-MC; ↓ Wt at 6mo in LF-HC vs. MF-MC, HF-LC; ᴓ Wt at 6mo in HF-LC vs. MF-MC | Funding: National Basic Research Program of China
Wan, 2017 ^81^; China, RCT; N=307; All BMI <28 kg/m2 | “High-Fat, Low-Carbohydrate” (HF-LC) | 46.0% | 40.0% | 14.0% | ↓ WC at 6mo in LF-HC vs. MF-MC, HF-LC; ᴓ WC at 6mo in HF-LC vs. MF-MC; ↓ Wt at 6mo in LF-HC vs. MF-MC, HF-LC; ᴓ Wt at 6mo in HF-LC vs. MF-MC | Funding: National Basic Research Program of China

Table 3 Observational studies that examined diets based on macronutrient proportion and risk of growth size, body composition, and risk of overweight or obesity^xvi^

Study and Participant Characteristics^xvii^ | Diet Exposure^xviii^ | Group | Macronutrient Distribution, % Energy | | | Results^xix^ | Methodological Considerations
Study and Participant Characteristics^xvii^ | Diet Exposure^xviii^ | Group | Carbohydrate | Fat | Protein | Results^xix^ | Methodological Considerations
Aljadani, 2016 ^82^; Australia, Australian Longitudinal Study of Women’s Health; PCS; N=1107; All women, normalweight, w/o chronic disease at f/u | Normal weight, maintained | | 40.5% | 33.8% | 19.2% | ᴓ Wt. status at 6y | Did not account or adjust for: Sex, Age, Race/ethnicity, Alcohol, Physical activity, Anthropometry, Smoking; Reported results were descriptive; Wt self-reported; Did not account for missing data; Funding: NR
Aljadani, 2016 ^82^; Australia, Australian Longitudinal Study of Women’s Health; PCS; N=1107; All women, normalweight, w/o chronic disease at f/u | Normal weight to overweight or obese | | 39.8% | 33.6% | 19.5% | ᴓ Wt. status at 6y
Ankarfeldt, 2014 ^83^; Denmark, PCS; MONICA, N=1257; All w/o cancer, CVD, and diabetes; DCH Study, N=2167; All w/o cancer, CVD, and diabetes, stable smoking habits or weight; Inter99, N=3630; All w/o cancer, CVD, diabetes | 5%E Protein replacing Carbohydrate, MONICA | | 35.9% | 44.2% | 14.0% | ↑ Wt after 5y | Did not account or adjust for: Race/ethnicity, Alcohol; Funding: Danish Council for Strategic Research
| 5%E Protein replacing Fat, MONICA | | 35.9% | 44.2% | 14.0% | ᴓ Wt after 5y | Did not account or adjust for: Race/ethnicity, Alcohol; Funding: Danish Council for Strategic Research
| 5%E Protein replacing Carbohydrate, DCH | | 41.6% | 34.2% | 17.7% | ᴓ WC after 5y; ᴓ Wt after 5y | Did not account or adjust for: Race/ethnicity, Alcohol; Funding: Danish Council for Strategic Research
| 5%E Protein replacing Fat, DCH | | 41.6% | 34.2% | 17.7% | ᴓ WC after 5y; ᴓ Wt after 5y | Did not account or adjust for: Race/ethnicity, Alcohol; Funding: Danish Council for Strategic Research
| 5%E Protein replacing Carbohydrate, Inter99 | | 47.5% | 32.4% | 14.8% | ᴓ WC after 5y; ᴓ Wt after 5y | Did not account or adjust for: Race/ethnicity, Alcohol; Funding: Danish Council for Strategic Research
| 5%E Protein replacing Fat, Inter99 | | 47.5% | 32.4% | 14.8% | ᴓ WC after 5y; ᴓ Wt after 5y | Did not account or adjust for: Race/ethnicity, Alcohol; Funding: Danish Council for Strategic Research
Beunza, 2010 ^84^; Spain, SUN Cohort; PCS; N=10,376 | Mediterranean Diet Score (Trichopoulou, 2003) | MDS 0-3 | 41% | 39% | 18% | ᴓ Overweight or Obesity at 2y or 4y; no interaction with previous weight gain in 5y pre-baseline; ᴓ BMI after 2y; ↓ absolute Wt gain after 2y or 4y of ≥3 or 5 kg and ↓ averge Wt gain of ≥3 kg in those with MDS 6-9 vs. MDS 0-3 | Did not account or adjust for: Race/ethnicity; Funding: Spanish Government (Instituto de Salud Carlos III, Fondo de Investigaciones Sanitarias), Navarra Regional Government, University of Navarra, La Caixa Foundation
Beunza, 2010 ^84^; Spain, SUN Cohort; PCS; N=10,376 | Mediterranean Diet Score (Trichopoulou, 2003) | MDS 4-6 | 44% | 36% | 18%
Beunza, 2010 ^84^; Spain, SUN Cohort; PCS; N=10,376 | Mediterranean Diet Score (Trichopoulou, 2003) | MDS, 7-9 | 46% | 33% | 18%
Bujnowski, 2011 ^85^; United States, Chicago Western Electric Study; PCS; N=1730; All men | %E, Total protein | Q1 | 40.6% | 41.6% | 12.8% | ↑ Overweight, Obesity after 7y, Q4 vs. Q1 for Total and Animal protein | Did not account or adjust for Race/ethnicity, physical activity; Funding: NIH
Bujnowski, 2011 ^85^; United States, Chicago Western Electric Study; PCS; N=1730; All men | %E, Total protein | Q4 | 35.4% | 43.4% | 17.5% | ↑ Overweight, Obesity after 7y, Q4 vs. Q1 for Total and Animal protein | Did not account or adjust for Race/ethnicity, physical activity; Funding: NIH
Bujnowski, 2011 ^85^; United States, Chicago Western Electric Study; PCS; N=1730; All men | %E, Animal protein | Q1 | 40.8% | 41.3% | 12.9% | ↑ Overweight, Obesity after 7y, Q4 vs. Q1 for Total and Animal protein | Did not account or adjust for Race/ethnicity, physical activity; Funding: NIH
Bujnowski, 2011 ^85^; United States, Chicago Western Electric Study; PCS; N=1730; All men | %E, Animal protein | Q4 | 35.0% | 44.0% | 17.3% | ↑ Overweight, Obesity after 7y, Q4 vs. Q1 for Total and Animal protein | Did not account or adjust for Race/ethnicity, physical activity; Funding: NIH
Bujnowski, 2011 ^85^; United States, Chicago Western Electric Study; PCS; N=1730; All men | %E, Vegetable protein | Q1 | 35.8% | 44.9% | 15.6% | ᴓ Overweight, Obesity after 7 y, Q4 vs. Q1 for Vegetable protein | Did not account or adjust for Race/ethnicity, physical activity; Funding: NIH
Bujnowski, 2011 ^85^; United States, Chicago Western Electric Study; PCS; N=1730; All men | %E, Vegetable protein | Q4 | 39.5% | 41.0% | 14.8% | ᴓ Overweight, Obesity after 7 y, Q4 vs. Q1 for Vegetable protein | Did not account or adjust for Race/ethnicity, physical activity; Funding: NIH
de la Fuente-Arrillaga, 2014 ^86^; Spain, SUN Project; PCS; N=9267; All w/o chronic disease or following a special diet | Glycemic Index | Q1 | 39.0% | 38.0% | 20.0% | ᴓ Overweight and obesity after 5y | Did not account or adjust for: Race/ethnicity, Alcohol; Diet assessed once; Funding: Spanish Government; the Navarra Regional Government; the University of Navarra
de la Fuente-Arrillaga, 2014 ^86^; Spain, SUN Project; PCS; N=9267; All w/o chronic disease or following a special diet | Glycemic Index | Q2 | 42.0% | 37.0% | 18.0% | ᴓ Overweight and obesity after 5y | Did not account or adjust for: Race/ethnicity, Alcohol; Diet assessed once; Funding: Spanish Government; the Navarra Regional Government; the University of Navarra
de la Fuente-Arrillaga, 2014 ^86^; Spain, SUN Project; PCS; N=9267; All w/o chronic disease or following a special diet | Glycemic Index | Q3 | 43.0% | 37.0% | 17.0% | ᴓ Overweight and obesity after 5y | Did not account or adjust for: Race/ethnicity, Alcohol; Diet assessed once; Funding: Spanish Government; the Navarra Regional Government; the University of Navarra
de la Fuente-Arrillaga, 2014 ^86^; Spain, SUN Project; PCS; N=9267; All w/o chronic disease or following a special diet | Glycemic Index | Q4 | 44.0% | 36.0% | 16.0% | ᴓ Overweight and obesity after 5y | Did not account or adjust for: Race/ethnicity, Alcohol; Diet assessed once; Funding: Spanish Government; the Navarra Regional Government; the University of Navarra
de la Fuente-Arrillaga, 2014 ^86^; Spain, SUN Project; PCS; N=9267; All w/o chronic disease or following a special diet | Glycemic Index | Q5 | 47.0% | 33.0% | 16.0% | ᴓ Overweight and obesity after 5y | Did not account or adjust for: Race/ethnicity, Alcohol; Diet assessed once; Funding: Spanish Government; the Navarra Regional Government; the University of Navarra
de la Fuente-Arrillaga, 2014 ^86^; Spain, SUN Project; PCS; N=9267; All w/o chronic disease or following a special diet | Glycemic Load | Q1 | 37.0% | 39.0% | 20.0% | ᴓ Overweight and obesity after 5y | Did not account or adjust for: Race/ethnicity, Alcohol; Diet assessed once; Funding: Spanish Government; the Navarra Regional Government; the University of Navarra
de la Fuente-Arrillaga, 2014 ^86^; Spain, SUN Project; PCS; N=9267; All w/o chronic disease or following a special diet | Glycemic Load | Q2 | 41.0% | 37.0% | 18.0% | ᴓ Overweight and obesity after 5y | Did not account or adjust for: Race/ethnicity, Alcohol; Diet assessed once; Funding: Spanish Government; the Navarra Regional Government; the University of Navarra
de la Fuente-Arrillaga, 2014 ^86^; Spain, SUN Project; PCS; N=9267; All w/o chronic disease or following a special diet | Glycemic Load | Q3 | 43.0% | 36.0% | 17.0% | ᴓ Overweight and obesity after 5y | Did not account or adjust for: Race/ethnicity, Alcohol; Diet assessed once; Funding: Spanish Government; the Navarra Regional Government; the University of Navarra
de la Fuente-Arrillaga, 2014 ^86^; Spain, SUN Project; PCS; N=9267; All w/o chronic disease or following a special diet | Glycemic Load | Q4 | 45.0% | 35.0% | 17.0% | ᴓ Overweight and obesity after 5y | Did not account or adjust for: Race/ethnicity, Alcohol; Diet assessed once; Funding: Spanish Government; the Navarra Regional Government; the University of Navarra
de la Fuente-Arrillaga, 2014 ^86^; Spain, SUN Project; PCS; N=9267; All w/o chronic disease or following a special diet | Glycemic Load | Q5 | 49.0% | 32.0% | 15.0% | ᴓ Overweight and obesity after 5y | Did not account or adjust for: Race/ethnicity, Alcohol; Diet assessed once; Funding: Spanish Government; the Navarra Regional Government; the University of Navarra
Ericson, 2019 ^28^; Sweden, Malmo" Diet and Cancer cohort; PCS; N=20,487 | %E in women for “Health-Conscious” Dietary Pattern; Higher loadings for cottage cheese, fibre-rich bread, fruits, vegetables, breakfast cereals, fish and low-fat yoghurt; lower loadings for low-fibre bread, red and processed meat, sugar-sweetened beverages | Q1 | 44.9% | 40.2% | 14.9% | ᴓ Wt change after 10y | Did not account or adjust for: Race/ethnicity; Measured diet once at baseline using breakfast cereals, fish and low-fat yoghurt; lower loadings for low-fibre bread, red and processed meat, sugar-sweetened beverages validated diet history methods; Note: Macronutrient distributions were NR for three additional patterns, “traditional meal”, “tea-breakfast”, and “sugar-rich”, which showed NS results; Funding: The Swedish Research Council, Region Skane, Skane University Hospital, Novo Nordic Foundation, Albert Pahlsson Research Foundation
Ericson, 2019 ^28^; Sweden, Malmo" Diet and Cancer cohort; PCS; N=20,487 | | Q2 | 45.6% | 39.2% | 15.2% | ᴓ Wt change after 10y
Ericson, 2019 ^28^; Sweden, Malmo" Diet and Cancer cohort; PCS; N=20,487 | | Q3 | 45.8% | 38.8% | 14.4% | ᴓ Wt change after 10y
Ericson, 2019 ^28^; Sweden, Malmo" Diet and Cancer cohort; PCS; N=20,487 | | Q4 | 46.6% | 37.7% | 15.6% | ᴓ Wt change after 10y
Ericson, 2019 ^28^; Sweden, Malmo" Diet and Cancer cohort; PCS; N=20,487 | | Q5 | 47.7% | 36.1% | 16.2% | ᴓ Wt change after 10y
Ericson, 2019 ^28^; Sweden, Malmo" Diet and Cancer cohort; PCS; N=20,487 | %E in women for “Low-Fat Products” Dietary Pattern; Higher loadings for low-fat margarines, low-fat milk, low-fat yoghurt; lower loadings for butter | Q1 | 43.3% | 42.3% | 14.4% | ᴓ Wt change after 10y
Ericson, 2019 ^28^; Sweden, Malmo" Diet and Cancer cohort; PCS; N=20,487 | %E in women for “Low-Fat Products” Dietary Pattern; Higher loadings for low-fat margarines, low-fat milk, low-fat yoghurt; lower loadings for butter | Q2 | 45.3% | 39.4% | 15.3% | ᴓ Wt change after 10y
Ericson, 2019 ^28^; Sweden, Malmo" Diet and Cancer cohort; PCS; N=20,487 | %E in women for “Low-Fat Products” Dietary Pattern; Higher loadings for low-fat margarines, low-fat milk, low-fat yoghurt; lower loadings for butter | Q3 | 46.6% | 37.8% | 15.6% | ᴓ Wt change after 10y
Ericson, 2019 ^28^; Sweden, Malmo" Diet and Cancer cohort; PCS; N=20,487 | %E in women for “Low-Fat Products” Dietary Pattern; Higher loadings for low-fat margarines, low-fat milk, low-fat yoghurt; lower loadings for butter | Q4 | 47.1% | 37.1% | 15.8% | ᴓ Wt change after 10y
Ericson, 2019 ^28^; Sweden, Malmo" Diet and Cancer cohort; PCS; N=20,487 | %E in women for “Low-Fat Products” Dietary Pattern; Higher loadings for low-fat margarines, low-fat milk, low-fat yoghurt; lower loadings for butter | Q5 | 48.3% | 35.4% | 16.2% | ᴓ Wt change after 10y
Ericson, 2019 ^28^; Sweden, Malmo" Diet and Cancer cohort; PCS; N=20,487 | %E in women for “Dressing-Vegetables” Dietary Pattern; Higher loadings for dressing/oils, vegetables, poultry, salty snacks, rice/pasta, fried potatoes, cheese; lower loadings for boiled potatoes, jam/sugar | Q1 | 47.4% | 37.4% | 15.2% | ᴓ Wt change after 10y
Ericson, 2019 ^28^; Sweden, Malmo" Diet and Cancer cohort; PCS; N=20,487 | | Q2 | 46.8% | 37.9% | 15.2% | ᴓ Wt change after 10y
Ericson, 2019 ^28^; Sweden, Malmo" Diet and Cancer cohort; PCS; N=20,487 | | Q3 | 46.1% | 38.5% | 15.4% | ᴓ Wt change after 10y
Ericson, 2019 ^28^; Sweden, Malmo" Diet and Cancer cohort; PCS; N=20,487 | | Q4 | 45.3% | 39.1% | 15.6% | ᴓ Wt change after 10y
Ericson, 2019 ^28^; Sweden, Malmo" Diet and Cancer cohort; PCS; N=20,487 | | Q5 | 44.9% | 39.1% | 16.0% | ᴓ Wt change after 10y
Ericson, 2019 ^28^; Sweden, Malmo" Diet and Cancer cohort; PCS; N=20,487 | %E in men for “Health-Conscious” Dietary Pattern; Higher loadings for cream, fibre-rich bread, fruits, vegetables, breakfast cereals, fish, low-fat yoghurt; lower loadings for low-fibre bread, red and processed meat, sugar-sweetened beverages | Q1 | 44.9% | 40.5% | 14.6% | ↓ Wt change after 10-y, categorical; ᴓ continuous
Ericson, 2019 ^28^; Sweden, Malmo" Diet and Cancer cohort; PCS; N=20,487 | | Q2 | 44.5% | 40.7% | 14.8% | ↓ Wt change after 10-y, categorical; ᴓ continuous
Ericson, 2019 ^28^; Sweden, Malmo" Diet and Cancer cohort; PCS; N=20,487 | | Q3 | 45.0% | 40.1% | 14.9% | ↓ Wt change after 10-y, categorical; ᴓ continuous
Ericson, 2019 ^28^; Sweden, Malmo" Diet and Cancer cohort; PCS; N=20,487 | | Q4 | 45.4% | 39.4% | 15.2% | ↓ Wt change after 10-y, categorical; ᴓ continuous
Ericson, 2019 ^28^; Sweden, Malmo" Diet and Cancer cohort; PCS; N=20,487 | | Q5 | 46.2% | 38.0% | 15.7% | ↓ Wt change after 10-y, categorical; ᴓ continuous
Ericson, 2019 ^28^; Sweden, Malmo" Diet and Cancer cohort; PCS; N=20,487 | %E in men for “Low-Fat Products” Dietary Pattern, Q1; Higher loadings for low-fat margarines, low-fat milk, low-fat yoghurt; lower loadings for butter | Q1 | 42.2% | 43.8% | 14.0% | ᴓ Wt change after 10y
Ericson, 2019 ^28^; Sweden, Malmo" Diet and Cancer cohort; PCS; N=20,487 | %E in men for “Low-Fat Products” Dietary Pattern, Q1; Higher loadings for low-fat margarines, low-fat milk, low-fat yoghurt; lower loadings for butter | Q2 | 44.2% | 41.0% | 14.8% | ᴓ Wt change after 10y
Ericson, 2019 ^28^; Sweden, Malmo" Diet and Cancer cohort; PCS; N=20,487 | %E in men for “Low-Fat Products” Dietary Pattern, Q1; Higher loadings for low-fat margarines, low-fat milk, low-fat yoghurt; lower loadings for butter | Q3 | 45.7% | 39.1% | 15.2% | ᴓ Wt change after 10y
Ericson, 2019 ^28^; Sweden, Malmo" Diet and Cancer cohort; PCS; N=20,487 | %E in men for “Low-Fat Products” Dietary Pattern, Q1; Higher loadings for low-fat margarines, low-fat milk, low-fat yoghurt; lower loadings for butter | Q4 | 46.3% | 38.3% | 15.3% | ᴓ Wt change after 10y
Ericson, 2019 ^28^; Sweden, Malmo" Diet and Cancer cohort; PCS; N=20,487 | %E in men for “Low-Fat Products” Dietary Pattern, Q1; Higher loadings for low-fat margarines, low-fat milk, low-fat yoghurt; lower loadings for butter | Q5 | 47.6% | 36.6% | 15.8% | ᴓ Wt change after 10y
Ericson, 2019 ^28^; Sweden, Malmo" Diet and Cancer cohort; PCS; N=20,487 | %E in men for “Dressing-Vegetables” Dietary Pattern, Q1; Higher loadings for dressing/oils, vegetables, poultry, salty snacks, rice/pasta, fried potatoes, cheese; lower loadings for boiled potatoes, jam/sugar | Q1 | 46.6% | 38.9% | 14.5% | ᴓ Wt change after 10y
Ericson, 2019 ^28^; Sweden, Malmo" Diet and Cancer cohort; PCS; N=20,487 | | Q2 | 45.7% | 39.5% | 14.8% | ᴓ Wt change after 10y
Ericson, 2019 ^28^; Sweden, Malmo" Diet and Cancer cohort; PCS; N=20,487 | | Q3 | 45.0% | 39.9% | 15.1% | ᴓ Wt change after 10y
Ericson, 2019 ^28^; Sweden, Malmo" Diet and Cancer cohort; PCS; N=20,487 | | Q4 | 44.6% | 40.2% | 15.2% | ᴓ Wt change after 10y
Ericson, 2019 ^28^; Sweden, Malmo" Diet and Cancer cohort; PCS; N=20,487 | | Q5 | 44.1% | 40.3% | 15.6% | ᴓ Wt change after 10y
Hruby, 2018 ^37^; United States, Framingham Heart Study Offspring cohort; PCS; N=3066 | %E Protein (g/d) | Q1 | 52.2% | 27.7% | 13.1% | ᴓ WC after 20y; ᴓ Wt after 20y | Did not account or adjust for: Race/ethnicity, Physical activity; Diet assessed once at baseline; Did not account for missing data; Funding: USDA – Agricultural Research Service; North American Branch of the International Life Sciences Institute; NHLBI; Boston University School of Medicine
Hruby, 2018 ^37^; United States, Framingham Heart Study Offspring cohort; PCS; N=3066 | %E Protein (g/d) | Q2 | 55.0% | 32.1% | 15.9% | ᴓ WC after 20y; ᴓ Wt after 20y
Hruby, 2018 ^37^; United States, Framingham Heart Study Offspring cohort; PCS; N=3066 | %E Protein (g/d) | Q3 | 52.6% | 32.4% | 18.1% | ᴓ WC after 20y; ᴓ Wt after 20y
Hruby, 2018 ^37^; United States, Framingham Heart Study Offspring cohort; PCS; N=3066 | %E Protein (g/d) | Q4 | 43.1% | 28.8% | 21.0% | ᴓ WC after 20y; ᴓ Wt after 20y
Quatromoni, 2006 ^87^; United States, Framingham Offspring Study; PCS; N=2245; All w/o Hx of cancer | Diet Quality Index (DQI) score, in men | 0 | 40.2% | 39.7% | 16.7% | ↓ Wt gain after 8y | Did not account or adjust for: Race/ethnicity; Funding: NHLBI; USDA; Unilever Research (Colworth, United Kingdom)
Quatromoni, 2006 ^87^; United States, Framingham Offspring Study; PCS; N=2245; All w/o Hx of cancer | Diet Quality Index (DQI) score, in men | 1 | 42.7% | 37.7% | 16.5% | ↓ Wt gain after 8y | Did not account or adjust for: Race/ethnicity; Funding: NHLBI; USDA; Unilever Research (Colworth, United Kingdom)
Quatromoni, 2006 ^87^; United States, Framingham Offspring Study; PCS; N=2245; All w/o Hx of cancer | Diet Quality Index (DQI) score, in men | 2 | 45.2% | 34.0% | 16.6% | ↓ Wt gain after 8y | Did not account or adjust for: Race/ethnicity; Funding: NHLBI; USDA; Unilever Research (Colworth, United Kingdom)
Quatromoni, 2006 ^87^; United States, Framingham Offspring Study; PCS; N=2245; All w/o Hx of cancer | Diet Quality Index (DQI) score, in men | 3 | 50.0% | 28.8% | 16.9% | ↓ Wt gain after 8y | Did not account or adjust for: Race/ethnicity; Funding: NHLBI; USDA; Unilever Research (Colworth, United Kingdom)
Quatromoni, 2006 ^87^; United States, Framingham Offspring Study; PCS; N=2245; All w/o Hx of cancer | Diet Quality Index (DQI) score, in men | 4 | 56.5% | 25.0% | 16.9% | ↓ Wt gain after 8y | Did not account or adjust for: Race/ethnicity; Funding: NHLBI; USDA; Unilever Research (Colworth, United Kingdom)
Quatromoni, 2006 ^87^; United States, Framingham Offspring Study; PCS; N=2245; All w/o Hx of cancer | Diet Quality Index (DQI) score, in men | 5 | 59.5% | 23.1% | 17.3% | ↓ Wt gain after 8y | Did not account or adjust for: Race/ethnicity; Funding: NHLBI; USDA; Unilever Research (Colworth, United Kingdom)
Quatromoni, 2006 ^87^; United States, Framingham Offspring Study; PCS; N=2245; All w/o Hx of cancer | DQI score, in women | 0 | 40.3% | 41.0% | 17.1% | ↓ Wt gain after 8y | Did not account or adjust for: Race/ethnicity; Funding: NHLBI; USDA; Unilever Research (Colworth, United Kingdom)
Quatromoni, 2006 ^87^; United States, Framingham Offspring Study; PCS; N=2245; All w/o Hx of cancer | DQI score, in women | 1 | 42.5% | 38.9% | 17.1% | ↓ Wt gain after 8y | Did not account or adjust for: Race/ethnicity; Funding: NHLBI; USDA; Unilever Research (Colworth, United Kingdom)
Quatromoni, 2006 ^87^; United States, Framingham Offspring Study; PCS; N=2245; All w/o Hx of cancer | DQI score, in women | 2 | 44.6% | 36.6% | 17.3% | ↓ Wt gain after 8y | Did not account or adjust for: Race/ethnicity; Funding: NHLBI; USDA; Unilever Research (Colworth, United Kingdom)
Quatromoni, 2006 ^87^; United States, Framingham Offspring Study; PCS; N=2245; All w/o Hx of cancer | DQI score, in women | 3 | 50.1% | 31.5% | 17.0% | ↓ Wt gain after 8y | Did not account or adjust for: Race/ethnicity; Funding: NHLBI; USDA; Unilever Research (Colworth, United Kingdom)
Quatromoni, 2006 ^87^; United States, Framingham Offspring Study; PCS; N=2245; All w/o Hx of cancer | DQI score, in women | 4 | 55.3% | 26.2% | 18.0% | ↓ Wt gain after 8y | Did not account or adjust for: Race/ethnicity; Funding: NHLBI; USDA; Unilever Research (Colworth, United Kingdom)
Quatromoni, 2006 ^87^; United States, Framingham Offspring Study; PCS; N=2245; All w/o Hx of cancer | DQI score, in women | 5 | 59.6% | 23.1% | 18.3% | ↓ Wt gain after 8y | Did not account or adjust for: Race/ethnicity; Funding: NHLBI; USDA; Unilever Research (Colworth, United Kingdom)
So, 2019 ^88^; Korea, KoGES; PCS; N=4412; Excluded those with low skeletal muscle mass | %E Protein, in men | T1 | 75.4% | 11.8% | 11.3% | ᴓ LM after 12y; ᴓ BMI after 12y; ᴓ Wt after 12y | Did not account or adjust for: Race/ethnicity; Funding: None
So, 2019 ^88^; Korea, KoGES; PCS; N=4412; Excluded those with low skeletal muscle mass | %E Protein, in men | T2 | 69.9% | 15.5% | 13.5% | ᴓ LM after 12y; ᴓ BMI after 12y; ᴓ Wt after 12y | Did not account or adjust for: Race/ethnicity; Funding: None
So, 2019 ^88^; Korea, KoGES; PCS; N=4412; Excluded those with low skeletal muscle mass | %E Protein, in men | T3 | 63.7% | 19.3% | 16.0% | ᴓ LM after 12y; ᴓ BMI after 12y; ᴓ Wt after 12y | Did not account or adjust for: Race/ethnicity; Funding: None
So, 2019 ^88^; Korea, KoGES; PCS; N=4412; Excluded those with low skeletal muscle mass | %E Protein, in women | T1 | 77.5% | 9.9% | 11.2% | ᴓ LM after 12y; ᴓ BMI after 12y; ᴓ Wt after 12y | Did not account or adjust for: Race/ethnicity; Funding: None
So, 2019 ^88^; Korea, KoGES; PCS; N=4412; Excluded those with low skeletal muscle mass | %E Protein, in women | T2 | 71.8% | 13.9% | 13.4% | ᴓ LM after 12y; ᴓ BMI after 12y; ᴓ Wt after 12y | Did not account or adjust for: Race/ethnicity; Funding: None
So, 2019 ^88^; Korea, KoGES; PCS; N=4412; Excluded those with low skeletal muscle mass | %E Protein, in women | T3 | 65.2% | 18.2% | 15.9% | ᴓ LM after 12y; ᴓ BMI after 12y; ᴓ Wt after 12y | Did not account or adjust for: Race/ethnicity; Funding: None

Table 4 Risk of bias for observational studies examining dietary patterns in children and growth size, body composition, and risk of overweight or obesity^xx^

Article | Confounding | Selection of participants | Classification of exposures | Deviations from intended exposures | Missing data | Outcome measurement | Selection of the reported result
Ambrosini, 2016 ^1^ | Serious | Moderate | Moderate | Serious | Serious | Low | Moderate
Bull, 2016 ^2^ | Serious | Low | Moderate | Serious | Serious | Low | Serious
Chan She Ping-Delfos, 2015 ^3^ | Serious | Low | Low | Serious | Moderate | Low | Moderate
Durao, 2017 ^4^ | Serious | Moderate | Low | Moderate | Serious | Low | Moderate
Fernandez-Alvira, 2017 ^5^ | Serious | Low | Low | Moderate | Serious | Low | Moderate
Hu, 2016 ^6^ | Moderate | Low | Low | Serious | Serious | Serious | Moderate
Martin-Calvo, 2016 ^7^ | Serious | Low | Low | Low | Moderate | Serious | Moderate
Nguyen, 2019 ^8^ | Moderate | Low | Low | Moderate | Serious | Low | Moderate
Okubo, 2015 ^9^ | Serious | Low | Low | Moderate | Serious | Low | Moderate
Pala, 2013 ^10^ | Serious | Low | Low | Serious | Serious | Low | Moderate
Smith, 2014 ^11^ | Serious | Moderate | Moderate | Moderate | Serious | Low | Moderate
Tognon, 2014 ^12^ | Serious | Low | Moderate | Serious | Serious | Low | Moderate

Table 5 Risk of bias for randomized controlled trials examining diets based on macronutrient distribution and growth size, body composition, and risk of overweight or obesity^xxi^

Article | Randomization | Deviations from intended interventions - effect assignment | Deviations from intended interventions - per protocol | Missing outcome data | Outcome measurement | Selection of the reported result
Alvarez-Perez, 2016 ^14^ | Some concerns | Low | Low | High | Low | Low
Arciero, 2008 ^67^ | Low | Low | Low | Low | Low | High
Brown, 2000 ^68^ | Some concerns | Low | Low | Low | Low | Low
Dale, 2009 ^69^ | Low | Low | Low | Low | Low | Low
Daly, 2014 ^23^ | Low | Some concerns | Low | Low | Low | Some concerns
Davis, 2017 J Nutr ^24^ | Low | Low | Low | Low | Low | Some concerns
Delbridge, 2009 ^70^ | Low | Low | Some concerns | Low | Low | Some concerns
Donnelly, 2008 ^71^ | Low | Low | Low | Low | Low | Low
Due, 2008 ^72^ | Some concerns | Some concerns | Some concerns | Low | Low | Low
Garnder, 2018 ^33^ | Low | Low | Low | Low | Low | High
Howard, 2010 ^73^ | Low | Low | Some concerns | Some concerns | Low | Low
Kahleova, 2018 ^41^ | Low | Low | Low | Low | Low | Low
Larsen, 2010 ^74^ | Low | Low | Some concerns | High | Low | Some concerns
Paineau, 2008 ^75^ | Some concerns | Low | Low | Some concerns | Low | Low
Razquin, 2009 ^76^ | Some concerns | Low | Low | Low | Low | High
Reidlinger, 2015 ^55^ | Low | Low | Low | Low | Low | Low
Sanders, 2013 ^77^ | Low | Low | Some concerns | Some concerns | Low | Some concerns
Tierney, 2011 ^78^ | Low | Low | Not Applicable | Some concerns | Low | High
Turner-McGrievy, 2015 ^61^ | Some concerns | Not Applicable | Low | Low | Low | Low
Uusitupa, 2013 ^79^ | Low | Low | Some concerns | High | Low | Some concerns
Vincent-Baudry, 2005 ^80^ | Some concerns | Low | Low | Low | Low | Low
Wan, 2017 ^81^ | Low | Low | Low | Low | Low | Low

Table 6 Risk of bias in observational studies examining diets based on macronutrient distribution and growth size, body composition, and risk of overweight or obesity^xxii^

Article | Confounding | Selection of participants | Classification of exposures | Deviations from intended exposures | Missing data | Outcome measurement | Selection of the reported result
Aljadani, 2016 ^82^ | Critical | Serious | Moderate | Serious | Serious | Serious | Serious
Ankarfeldt, 2014 ^83^ | Serious | Serious | Moderate | Serious | Serious | Moderate | Moderate
Beunza, 2010 ^84^ | Serious | Serious | Moderate | Moderate | Moderate | Moderate | Serious
Bujnowski, 2011 ^85^ | Serious | Moderate | Moderate | Serious | Serious | Low | Moderate
de la Fuente-Arrillaga, 2014 ^86^ | Serious | Serious | Low | Serious | Moderate | Serious | Moderate
Ericson, 2019 ^28^ | Serious | Serious | Low | Serious | Serious | Moderate | Serious
Hruby, 2018 ^37^ | Serious | Low | Moderate | Serious | Serious | Low | Moderate
Quatromoni, 2006 ^87^ | Serious | Moderate | Low | Moderate | Moderate | Low | Moderate
So, 2019 ^88^ | Serious | Serious | Low | Serious | Moderate | Low | Moderate

ii Briefly, the AMDR in adults are as follows: Carbohydrate: 45 to 65% of energy; Fat: 25 to 35% of energy; Protein: 10 to 35% of energy. The AMDR for children are as follows: Carbohydrate: 45 to 65% of energy; Protein, ages 1-3y: 5 to 20% of energy, ages 4-18y: 10 to 30% of energy; Fat, ages 1-3y: 30 to 40% of energy, ages 4-18y: 25 to 35% of energy. Source: Institute of Medicine. Dietary Reference Intakes for Energy, Carbohydrate, Fiber, Fat, Fatty Acids, Cholesterol, Protein, and Amino Acids. Washington (DC): The National Academies Press; 2002 . For more details on the AMDR, see the Intervention/Exposure Inclusion and Exclusion criteria.

iii Dietary Guidelines Advisory Committee. Scientific Report of the 2015 Dietary Guidelines Advisory Committee: Advisory Report to the Secretary of Health and Human Services and the Secretary of Agriculture. US Department of Agriculture, Agricultural Research Service. https://health.gov/our-work/food-nutrition/2015-2020-dietary-guidelines/advisory-report. Published 2015. Accessed April 30, 2020 .

iv A detailed description of the methodology used for grading the strength of the evidence is available on the NESR website: https://nesr.usda.gov/2020-dietary-guidelines-advisory-committee-systematic-reviews and in Part C of the following reference: Dietary Guidelines Advisory Committee. 2020. Scientific Report of the 2020 Dietary Guidelines Advisory Committee: Advisory Report to the Secretary of Agriculture and the Secretary of Health and Human Services. U.S. Department of Agriculture, Agricultural Research Service, Washington, DC .

v Dietary Guidelines Advisory Committee. Scientific Report of the 2015 Dietary Guidelines Advisory Committee: Advisory Report to the Secretary of Health and Human Services and the Secretary of Agriculture. US Department of Agriculture, Agricultural Research Service. https://health.gov/our-work/food-nutrition/2015-2020-dietary-guidelines/advisory-report. Published 2015. Accessed April 30, 2020 .

vi A detailed description of the methodology used for grading the strength of the evidence is available on the NESR website: https://nesr.usda.gov/2020-dietary-guidelines-advisory-committee-systematicreviews and in Part C of the following reference: Dietary Guidelines Advisory Committee. 2020. Scientific Report of the 2020 Dietary Guidelines Advisory Committee: Advisory Report to the Secretary of Agriculture and the Secretary of Health and Human Services. U.S. Department of Agriculture, Agricultural Research Service, Washington, DC .

vii Abbreviations: BMI, body mass index; BMIz, body mass index z-score; CVD, cardiovascular disease; FM, Fat mass; FFM, Fat-free mass; FFMI, Fat-free mass index; FMI, Fat mass index; FMIz, Fat mass index z-score; LM, Lean mass; N/A, Not applicable; NR, Not reported; SSB, sugar-sweetened beverage; WC, waist circumference; wk, week(s); WHR, waist-to-hip ratio; Wt, body weight; y, year(s)

viii Includes last name of first author, publication year, country, analytic sample size, and select participant characteristics.

ix Results use the following symbols:

- ↑, Significant (positive) association between higher adherence to diet and higher incidence/risk/absolute outcomes;
- ᴓ, Aassociation or difference between diet groups and outcome reported;
- ↓, Significant (inverse) association between higher adherence to diet and lower incidence/risk/absolute outcomes

x Abbreviations: % E, Percent energy; BMI, body mass index; BMIz, body mass index z-score; CVD, cardiovascular disease; EVOO, extra virgin olive oil; FM, Fat mass; FFM, Fat-free mass; FFMI, Fat-free mass index; FMI, Fat mass index; FMIz, Fat mass index z-score; f/u, follow-up; LM, Lean mass; Med, Mediterranean; MUFA, monounsaturated fat/fatty acid; N/A, Not applicable; NIH, National Institutes of Health; NR, Not reported; PUFA, polyunsaturated fat/fatty acids; RCT, randomized controlled trial; WC, waist circumference; wk, week(s); WHR, waist-to-hip ratio; Wt, body weight; y, year(s)

xi Includes last name of first author, publication year, country, analytic sample size, and select participant characteristics.

xii Unless otherwise noted, the first category listed was used as the referent group.

xiii Relevant results for the systematic review question are summarized using the following symbols:

- ↑, Significant (positive) association between higher adherence to diet and higher incidence/risk/absolute outcomes;
- ᴓ, Association or difference between diet groups and outcome was not statistically signficant;
- ↓, Significant (inverse) association between higher adherence to diet and lower incidence/risk/absolute outcomes

xiv Additional funding sources reported in Uusitupa, 2013 were: Finnish Foundation for Cardiovascular Research, The Sigfrid Juselius Foundation, Kuopio University Hospital; the Druvan Foundation, ESPEN, Skane County Council Research and Development Foundation, The Heart-Lung Foundation, Diabetesfonden and Foundation Cerealia; The Danish Obesity Research Centre, The Danish Council for Strategic Research, The Agricultural Productivity Fund, The Research Fund of the University of Iceland.

xv Additional funding sources reported in Vincent-Baudry, 2005 were: the Provence-Alpes-Côte d’Azur Regional Council, the Bouches du Rhône General Council, the CRITT-PACA; Rivoire & Carret Lustucru, Jean Martin, Le Cabanon, Boulangerie Coagulation Surgelés, Distplack Mariani, and Minoterie Giraud.

xvi Abbreviations: % E, Percent energy; BMI, body mass index; BMIz, body mass index z-score; CVD, cardiovascular disease; EVOO, extra virgin olive oil; FM, Fat mass; FFM, Fat-free mass; FFMI, Fat-free mass index; FMI, Fat mass index; f/u, follow-up; LM, Lean mass; Med, Mediterranean; N/A, Not applicable; NHLBI, National Heart, Lung, and Blood Institute; NIH, National Institutes of Health; NR, Not reported; PCS, Prospective cohort study; USDA, US Department of Agriculture; WC, waist circumference; wk, week(s); WHR, waist-to-hip ratio; Wt, body weight; y, year(s)

xvii Includes last name of first author, publication year, country, analytic sample size, and select participant characteristics.

xviii Unless otherwise noted, the first category listed was used as the referent group.

xix Relevant results for the systematic review question are summarized using the following symbols:

- ↑, Significant (positive) association between higher adherence to diet and higher incidence/risk/absolute outcomes;
- ᴓ, Association or difference between diet groups and outcome was not statistically signficant;
- ↓, Significant (inverse) association between higher adherence to diet and lower incidence/risk/absolute outcomes

xx A detailed description of the methodology used for assessing risk of bias is available on the NESR website: https://nesr.usda.gov/2020-dietary-guidelines-advisory-committee-systematic-reviews and in Part C of the following reference: Dietary Guidelines Advisory Committee. 2020. Scientific Report of the 2020 Dietary Guidelines Advisory Committee: Advisory Report to the Secretary of Agriculture and the Secretary of Health and Human Services. U.S. Department of Agriculture, Agricultural Research Service, Washington, DC .

Possible ratings of low, moderate, serious, critical, or no information determined using the “Risk of Bias for Nutrition Observational Studies” tool (RoB-NObs) ( Dietary Guidelines Advisory Committee. 2020. Scientific Report of the 2020 Dietary Guidelines Advisory Committee: Advisory Report to the Secretary of Agriculture and the Secretary of Health and Human Services. U.S. Department of Agriculture, Agricultural Research Service, Washington, DC .)

xxi Possible ratings of low, some concerns, or high determined using the “Cochrane Risk-of-bias 2.0” (RoB 2.0) (August 2016 version)” ( Higgins JPT, Sterne JAC, Savović J, Page MJ, Hróbjartsson A, Boutron I, Reeves B, Eldridge S. A revised tool for assessing risk of bias in randomized trials In: Chandler J, McKenzie J, Boutron I, Welch V (editors). Cochrane Methods. Cochrane Database of Systematic Reviews 2016, Issue 10 (Suppl 1). 10.1002/14651858.CD201601 .)

xxii Possible ratings of low, moderate, serious, critical, or no information determined using the “Risk of Bias for Nutrition Observational Studies” tool (RoB-NObs) ( Dietary Guidelines Advisory Committee. 2020. Scientific Report of the 2020 Dietary Guidelines Advisory Committee: Advisory Report to the Secretary of Agriculture and the Secretary of Health and Human Services. U.S. Department of Agriculture, Agricultural Research Service, Washington, DC .)