# ACKNOWLEDGEMENTS

Pregnancy Technical Expert Collaborative (TEC) members:

- Barbara Abrams, DrPH, RD, University of California, Berkeley School of Public Health
- Anne Bartholomew, MS, RD, USDA
- Lisa M. Bodnar, PhD, MPH, RD, University of Pittsburgh School of Public Health
- Alison Gernand, PhD, MPH, RD The Pennsylvania State University
- Kathleen Rasmussen, ScD, RD, Cornell University
- Anna Maria Siega-Riz, PhD, University of Virginia School of Nursing
- Jamie S. Stang, PhD, MPH, RDN, University of Minnesota School of Public Health

Nutrition Evidence Systematic Review (NESR) team:

- Ramkripa Raghavan^i^, DrPH, MPH, MSc, Panum Group, Lead analyst
- Carol Dreibelbis^i^, MPH, Panum Group, Analyst
- Brittany James Kingshipp^i^, PhD, Panum Group, Analyst (01/2017-Present)
- Yat Ping Wong, MLS, MPH, USDA, Librarian
- Nancy Terry, MS, MLS, HHS, Librarian

Project Leads:

- Eve Stoody, PhD, USDA
- Joanne M. Spahn, MS, RDN, USDA
- Kellie O. Casavale, PhD, RD, HHS

Federal Expert Group (FEG)-Technical Expert Collaborative (TEC) Liaisons:

- Anne Bartholomew, MS, RD, USDA

All TEC and NESR team members, Project leads, and FEG-TEC liaisons participated in establishing the research questions, analytic framework, and study inclusion and exclusion criteria. RR, CD, and YPW developed and conducted the literature search. RR, CD, and BLK screened search results, identified studies for inclusion, extracted data, and assessed risk of bias for included studies. BA, AB, LMB, AG, KR, AMSR, JSS, EES, JMS, and KOC reviewed and provided substantive feedback on all systematic review materials, including the synthesis of the body of evidence, conclusion statement, and grade of the strength of the evidence. RR prepared this report and EES, JMS, and KOC provided oversight. All authors critically reviewed and approved the final report. The authors declare no conflicts of interest.

i Under contract with the Food and Nutrition Service, United States Department of Agriculture.