# References for all three evidence scan chapters

### Chapter 1 High dietary protein intake (including amino acid intake) and acute adverse health effects references

1 Jager R, Kerksick CM, Campbell BI, . International Society of Sports Nutrition Position Stand: protein and exercise. J Int Soc Sports Nutr. 2017;14:20 doi: 10.1186/s12970-017-0177-8.28642676
2 Wolfe RR, Cifelli AM, Kostas G, Kim IY. Optimizing Protein Intake in Adults: Interpretation and Application of the Recommended Dietary Allowance Compared with the Acceptable Macronutrient Distribution Range. Adv Nutr. 2017;8(2):266–275 doi: 10.3945/an.116.013821.28298271
3 Wu G. Dietary protein intake and human health. Food Funct. 2016;7(3):1251–1265 doi: 10.1039/c5fo01530h.26797090
4 Van Elswyk ME, Weatherford CA, McNeill SH. A Systematic Review of Renal Health in Healthy Individuals Associated with Protein Intake above the US Recommended Daily Allowance in Randomized Controlled Trials and Observational Studies. Adv Nutr. 2018;9(4):404–418 doi: 10.1093/advances/nmy026.30032227
5 Vasconcelos Q, Bachur TPR, Aragao GF. Whey protein supplementation and its potentially adverse effects on health: a systematic review. Appl Physiol Nutr Metab. 2021;46(1):27–33 doi: 10.1139/apnm-2020-0370.32702243
6 Ben-Harchache S, Roche HM, Corish CA, Horner KM. The Impact of Protein Supplementation on Appetite and Energy Intake in Healthy Older Adults: A Systematic Review with Meta-Analysis. Adv Nutr. 2021;12(2):490–502 doi: 10.1093/advances/nmaa115.33037427
7 Borack MS, Volpi E. Efficacy and Safety of Leucine Supplementation in the Elderly. J Nutr. 2016;146(12):2625S–2629S doi: 10.3945/jn.116.230771.27934654
8 Cynober L, Bier DM, Kadowaki M, Morris SM, Jr., Elango R, Smriga M. Proposals for Upper Limits of Safe Intake for Arginine and Tryptophan in Young Adults and an Upper Limit of Safe Intake for Leucine in the Elderly. J Nutr. 2016;146(12):2652S–2654S doi: 10.3945/jn.115.228478.27934658
9 Davani-Davari D, Karimzadeh I, Sagheb MM, Khalili H. The Renal Safety of L-Carnitine, L-Arginine, and Glutamine in Athletes and Bodybuilders. J Ren Nutr. 2019;29(3):221–234 doi: 10.1053/j.jrn.2018.08.014.30341034
10 Durante W. The Emerging Role of l-Glutamine in Cardiovascular Health and Disease. Nutrients. 2019;11(9) doi: 10.3390/nu11092092.
11 Elango R, Rasmussen B, Madden K. Safety and Tolerability of Leucine Supplementation in Elderly Men. J Nutr. 2016;146(12):2630S–2634S doi: 10.3945/jn.116.234930.27934655
12 Fernstrom JD. A Perspective on the Safety of Supplemental Tryptophan Based on Its Metabolic Fates. J Nutr. 2016;146(12):2601S–2608S doi: 10.3945/jn.115.228643.27934651
13 Holecek M. Histidine in Health and Disease: Metabolism, Physiological Importance, and Use as a Supplement. Nutrients. 2020;12(3) doi: 10.3390/nu12030848.
14 Ligthart-Melis GC, Engelen M, Simbo SY, . Metabolic Consequences of Supplemented Methionine in a Clinical Context. J Nutr. 2020;150(Suppl 1):2538S–2547S doi: 10.1093/jn/nxaa254.33000166
15 McNeal CJ, Meininger CJ, Reddy D, Wilborn CD, Wu G. Safety and Effectiveness of Arginine in Adults. J Nutr. 2016;146(12):2587S–2593S doi: 10.3945/jn.116.234740.27934649
16 Oketch-Rabah HA, Roe AL, Gurley BJ, Griffiths JC, Giancaspro GI. The Importance of Quality Specifications in Safety Assessments of Amino Acids: The Cases of l-Tryptophan and l-Citrulline. J Nutr. 2016;146(12):2643S–2651S doi: 10.3945/jn.115.227280.27934657
17 Roberts A. The Safety and Regulatory Process for Amino Acids in Europe and the United States. J Nutr. 2016;146(12):2635S–2642S doi: 10.3945/jn.116.234591.27934656
18 Smriga M. International Regulations on Amino Acid Use in Foods and Supplements and Recommendations to Control Their Safety Based on Purity and Quality. J Nutr. 2020;150(Suppl 1):2602S–2605S doi: 10.1093/jn/nxaa093.33000158
19 Thalacker-Mercer AE, Gheller ME. Benefits and Adverse Effects of Histidine Supplementation. J Nutr. 2020;150(Suppl 1):2588S–2592S doi: 10.1093/jn/nxaa229.33000165
20 Hayamizu K, Oshima I, Fukuda Z, . Safety assessment of L-lysine oral intake: a systematic review. Amino Acids. 2019;51(4):647–659 doi: 10.1007/s00726-019-02697-3.30661148
21 Hayamizu K, Oshima I, Nakano M. Comprehensive Safety Assessment of l-Lysine Supplementation from Clinical Studies: A Systematic Review. J Nutr. 2020;150(Suppl 1):2561S–2569S doi: 10.1093/jn/nxaa218.33000161
22 Rhim HC, Kim MS, Park YJ, . The Potential Role of Arginine Supplements on Erectile Dysfunction: A Systemic Review and Meta-Analysis. J Sex Med. 2019;16(2):223–234 doi: 10.1016/j.jsxm.2018.12.002.30770070

### Chapter 2 Protein intake and chronic disease risk references

23 Chen Z, Glisic M, Song M, . Dietary protein intake and all-cause and cause-specific mortality: results from the Rotterdam Study and a meta-analysis of prospective cohort studies. Eur J Epidemiol. 2020;35(5):411–429 doi: 10.1007/s10654-020-00607-6.32076944
24 Naghshi S, Sadeghi O, Willett WC, Esmaillzadeh A. Dietary intake of total, animal, and plant proteins and risk of all cause, cardiovascular, and cancer mortality: systematic review and dose-response meta-analysis of prospective cohort studies. Bmj-Brit Med J. 2020;370 doi: ARTN m241210.1136/bmj.m2412.
25 Qi XX, Shen P. Associations of dietary protein intake with all-cause, cardiovascular disease, and cancer mortality: A systematic review and meta-analysis of cohort studies. Nutr Metab Cardiovasc Dis. 2020;30(7):1094–1105 doi: 10.1016/j.numecd.2020.03.008.32451273
26 Curneen JMG, Casey M, Laird E. The relationship between protein quantity, BMD and fractures in older adults. Irish J Med Sci. 2018;187(1):111–121 doi: 10.1007/s11845-017-1642-8.28674746
27 Darling AL, Manders RJF, Sahni S, . Dietary protein and bone health across the life-course: an updated systematic review and meta-analysis over 40 years. Osteoporos Int. 2019;30(4):741–761 doi: 10.1007/s00198-019-04933-8.30903209
28 Groenendijk I, den Boeft L, van Loon LJC, de Groot L. High Versus low Dietary Protein Intake and Bone Health in Older Adults: a Systematic Review and Meta-Analysis. Comput Struct Biotechnol J. 2019;17:1101–1112 doi: 10.1016/j.csbj.2019.07.005.31462966
29 Shams-White MM, Chung M, Du M, . Dietary protein and bone health: a systematic review and meta-analysis from the National Osteoporosis Foundation. Am J Clin Nutr. 2017;105(6):1528–1543 doi: 10.3945/ajcn.116.145110.28404575
30 Tsagari A. Dietary protein intake and bone health. J Frailty Sarcopenia Falls. 2020;5(1):1–5 doi: 10.22540/JFSF-05-001.32300728
31 Wallace TC, Frankenfeld CL. Dietary Protein Intake above the Current RDA and Bone Health: A Systematic Review and Meta-Analysis. J Am Coll Nutr. 2017;36(6):481–496 doi: 10.1080/07315724.2017.1322924.28686536
32 Wright CS, Li J, Campbell WW. Effects of Dietary Protein Quantity on Bone Quantity following Weight Loss: A Systematic Review and Meta-analysis. Adv Nutr. 2019;10(6):1089–1107 doi: 10.1093/advances/nmz058.31301138
33 Dinu M, Pagliai G, Angelino D, . Effects of Popular Diets on Anthropometric and Cardiometabolic Parameters: An Umbrella Review of Meta-Analyses of Randomized Controlled Trials. Adv Nutr. 2020;11(4):815–833 doi: 10.1093/advances/nmaa006.32059053
34 Schwingshackl L, Chaimani A, Schwedhelm C, . Comparative effects of different dietary approaches on blood pressure in hypertensive and pre-hypertensive patients: A systematic review and network meta-analysis. Crit Rev Food Sci Nutr. 2019;59(16):2674–2687 doi: 10.1080/10408398.2018.1463967.29718689
35 Van Elswyk ME, Weatherford CA, McNeill SH. A Systematic Review of Renal Health in Healthy Individuals Associated with Protein Intake above the US Recommended Daily Allowance in Randomized Controlled Trials and Observational Studies. Adv Nutr. 2018;9(4):404–418 doi: 10.1093/advances/nmy026.30032227
36 Zhang XW, Yang Z, Li M, Li K, Deng YQ, Tang ZY. Association between dietary protein intake and risk of stroke: A meta-analysis of prospective studies. Int J Cardiol. 2016;223:548–551 doi: 10.1016/j.ijcard.2016.08.106.27552579
37 van Elten TM, Karsten MDA, van Poppel MNM, . Diet and physical activity in pregnancy and offspring’s cardiovascular health: a systematic review. J Dev Orig Health Dis. 2019;10(3):286–298 doi: 10.1017/S204017441800082X.30419991
38 Mousavi SM, Jayedi A, Jalilpiran Y, Hajishafiee M, Aminianfar A, Esmaillzadeh A. Dietary intake of total, animal and plant proteins and the risk of coronary heart disease and hypertension: a systematic review and dose-response meta-analysis of prospective cohort studies. Crit Rev Food Sci Nutr. 2022;62(5):1336–1349 doi: 10.1080/10408398.2020.1841730.33131293
39 Sukhato K, Akksilp K, Dellow A, Vathesatogkit P, Anothaisintawee T. Efficacy of different dietary patterns on lowering of blood pressure level: an umbrella review. Am J Clin Nutr. 2020;112(6):1584–1598 doi: 10.1093/ajcn/nqaa252.33022695
40 Coelho-Junior HJ, Calvani R, Landi F, Picca A, Marzetti E. Protein Intake and Cognitive Function in Older Adults: A Systematic Review and Meta-Analysis. Nutr Metab Insights. 2021;14:11786388211022373 doi: 10.1177/11786388211022373.34158801
41 Muth AK, Park SQ. The impact of dietary macronutrient intake on cognitive function and the brain. Clin Nutr. 2021;40(6):3999–4010 doi: 10.1016/j.clnu.2021.04.043.34139473
42 Fan M, Li Y, Wang C, . Dietary Protein Consumption and the Risk of Type 2 Diabetes: ADose-Response Meta-Analysis of Prospective Studies. Nutrients. 2019;11(11) doi: 10.3390/nu11112783.
43 Shang X, Scott D, Hodge AM, . Dietary protein intake and risk of type 2 diabetes: results from the Melbourne Collaborative Cohort Study and a meta-analysis of prospective studies. Am J Clin Nutr. 2016;104(5):1352–1365 doi: 10.3945/ajcn.116.140954.27629053
44 Tian S, Xu Q, Jiang R, Han T, Sun C, Na L. Dietary Protein Consumption and the Risk of Type 2 Diabetes: A Systematic Review and Meta-Analysis of Cohort Studies. Nutrients. 2017;9(9) doi: 10.3390/nu9090982.
45 Ye J, Yu Q, Mai W, Liang P, Liu X, Wang Y. Dietary protein intake and subsequent risk of type 2 diabetes: a dose-response meta-analysis of prospective cohort studies. Acta Diabetol. 2019;56(8):851–870 doi: 10.1007/s00592-019-01320-x.30929078
46 Zhao LG, Zhang QL, Liu XL, Wu H, Zheng JL, Xiang YB. Dietary protein intake and risk of type 2 diabetes: a dose-response meta-analysis of prospective studies. Eur J Nutr. 2019;58(4):1351–1367 doi: 10.1007/s00394-018-1737-7.29858629
47 Bergia RE, 3rd, Hudson JL, Campbell WW. Effect of whey protein supplementation on body composition changes in women: a systematic review and meta-analysis. Nutr Rev. 2018;76(7):539–551 doi: 10.1093/nutrit/nuy017.29688559
48 Ferre N, Luque V, Closa-Monasterolo R, . Association of Protein Intake during the Second Year of Life with Weight Gain-Related Outcomes in Childhood: A Systematic Review. Nutrients. 2021;13(2) doi: 10.3390/nu13020583.
49 Hansen TT, Astrup A, Sjodin A. Are Dietary Proteins the Key to Successful Body Weight Management? A Systematic Review and Meta-Analysis of Studies Assessing Body Weight Outcomes after Interventions with Increased Dietary Protein. Nutrients. 2021;13(9) doi: 10.3390/nu13093193.
50 Hsu KJ, Liao CD, Tsai MW, Chen CN. Effects of Exercise and Nutritional Intervention on Body Composition, Metabolic Health, and Physical Performance in Adults with Sarcopenic Obesity: A Meta-Analysis. Nutrients. 2019;11(9) doi: 10.3390/nu11092163.
51 Hudson JL, Wang Y, Bergia RE, Campbell WW. Protein Intake Greater than the RDA Differentially Influences Whole-Body Lean Mass Responses to Purposeful Catabolic and Anabolic Stressors: A Systematic Review and Meta-analysis. Advances in Nutrition. 2020;11(3):548–558 doi: 10.1093/advances/nmz106.31794597
52 Kim JE, O’Connor LE, Sands LP, Slebodnik MB, Campbell WW. Effects of dietary protein intake on body composition changes after weight loss in older adults: a systematic review and meta-analysis. Nutr Rev. 2016;74(3):210–224 doi: 10.1093/nutrit/nuv065.26883880
53 Lin YN, Tseng TT, Knuiman P, . Protein supplementation increases adaptations to endurance training: A systematic review and meta-analysis. Clin Nutr. 2021;40(5):3123–3132 doi: 10.1016/j.clnu.2020.12.012.33358231
54 Patro-Golab B, Zalewski BM, Kouwenhoven SMP, . Protein Concentration in Milk Formula, Growth, and Later Risk of Obesity: A Systematic Review. Journal of Nutrition. 2016;146(3):551–564 doi: 10.3945/jn.115.223651.26865649
55 Stokes A, Campbell KJ, Yu HJ, . Protein Intake from Birth to 2 Years and Obesity Outcomes in Later Childhood and Adolescence: A Systematic Review of Prospective Cohort Studies. Adv Nutr. 2021;12(5):1863–1876 doi: 10.1093/advances/nmab034.33903896
56 Tagawa R, Watanabe D, Ito K, . Dose-response relationship between protein intake and muscle mass increase: a systematic review and meta-analysis of randomized controlled trials. Nutrition Reviews. 2021;79(1):66–75 doi: 10.1093/nutrit/nuaa104.
57 Tielemans MJ, Garcia AH, Peralta Santos A, . Macronutrient composition and gestational weight gain: a systematic review. Am J Clin Nutr. 2016;103(1):83–99 doi: 10.3945/ajcn.115.110742.26675773
58 Valenzuela PL, Mata F, Morales JS, Castillo-Garcia A, Lucia A. Does Beef Protein Supplementation Improve Body Composition and Exercise Performance? A Systematic Review and Meta-Analysis of Randomized Controlled Trials. Nutrients. 2019;11(6) doi: ARTN 142910.3390/nu11061429.
59 van Baak MA, Mariman ECM. Dietary Strategies for Weight Loss Maintenance. Nutrients. 2019;11(8) doi: 10.3390/nu11081916.
60 Yin YH, Liu JYW, Valimaki M. Effectiveness of non-pharmacological interventions on the management of sarcopenic obesity: A systematic review and meta-analysis. Exp Gerontol. 2020;135:110937 doi: 10.1016/j.exger.2020.110937.32240820
61 Zhang Y, Chen X, Allison DB, Xun P. Efficacy and safety of a specific commercial high-protein meal-replacement product line in weight management: meta-analysis of randomized controlled trials. Crit Rev Food Sci Nutr. 2022;62(3):798–809 doi: 10.1080/10408398.2020.1829539.33938779
62 Patro-Golab B, Zalewski BM, Kolodziej M, . Nutritional interventions or exposures in infants and children aged up to 3 years and their effects on subsequent risk of overweight, obesity and body fat: a systematic review of systematic reviews. Obes Rev. 2016;17(12):1245–1257 doi: 10.1111/obr.12476.27749991
63 Devries MC, Sithamparapillai A, Brimble KS, Banfield L, Morton RW, Phillips SM. Changes in Kidney Function Do Not Differ between Healthy Adults Consuming Higher Compared with Lower-or Normal-Protein Diets: A Systematic Review and Meta-Analysis. Journal of Nutrition. 2018;148(11):1760–1775 doi: 10.1093/jn/nxy197.30383278
64 Coelho-Junior HJ, Milano-Teixeira L, Rodrigues B, Bacurau R, Marzetti E, Uchida M. Relative Protein Intake and Physical Function in Older Adults: A Systematic Review and Meta-Analysis of Observational Studies. Nutrients. 2018;10(9) doi: 10.3390/nu10091330.
65 Yaegashi A, Kimura T, Hirata T, Tamakoshi A. Association of dietary protein intake with skeletal muscle mass in older adults: A systematic review. Geriatr Gerontol Int. 2021;21(12):1077–1083 doi: 10.1111/ggi.14291.34643981
66 Naseeb MA, Volpe SL. Protein and exercise in the prevention of sarcopenia and aging. Nutr Res. 2017;40:1–20 doi: 10.1016/j.nutres.2017.01.001.28473056
67 Kirwan RP, Mazidi M, Garcia CR, . Protein interventions augment the effect of resistance exercise on appendicular lean mass and handgrip strength in older adults: a systematic review and meta-analysis of randomized controlled trials. Am J Clin Nutr. 2021 doi: 10.1093/ajcn/nqab355.
68 Ben-Harchache S, Roche HM, Corish CA, Horner KM. The Impact of Protein Supplementation on Appetite and Energy Intake in Healthy Older Adults: A Systematic Review with Meta-Analysis. Adv Nutr. 2021;12(2):490–502 doi: 10.1093/advances/nmaa115.33037427
69 de Carvalho KMB, Pizato N, Botelho PB, Dutra ES, Goncalves VSS. Dietary protein and appetite sensations in individuals with overweight and obesity: a systematic review. Eur J Nutr. 2020;59(6):2317–2332 doi: 10.1007/s00394-020-02321-1.32648023
70 Kohanmoo A, Faghih S, Akhlaghi M. Effect of short- and long-term protein consumption on appetite and appetite-regulating gastrointestinal hormones, a systematic review and meta-analysis of randomized controlled trials. Physiol Behav. 2020;226:113123 doi: 10.1016/j.physbeh.2020.113123.32768415
71 Zhao X, Han Q, Gang X, . The Role of Gut Hormones in Diet-Induced Weight Change: A Systematic Review. Horm Metab Res. 2017;49(11):816–825 doi: 10.1055/s-0043-115646.28934819

### Chapter 3 Average daily dietary protein intake (including amino acid intake) requirement

72 Campbell WW, Johnson CA, McCabe GP, Carnell NS. Dietary protein requirements of younger and older adults. American Journal of Clinical Nutrition. 2008;88(5):1322–1329. https://www.scopus.com/inward/record.uri?eid=2-s2.0-55849098062&doi=10.3945%2fajcn.2008.26072&partnerID=40&md5=9e5736fe5bbb8a223365a4dd325a9059.18996869
73 Elango R, Humayun MA, Ball RO, Pencharz PB. Protein requirement of healthy school-age children determined by the indicator amino acid oxidation method. American Journal of Clinical Nutrition. 2011;94(6):1545–1552. https://www.scopus.com/inward/record.uri?eid=2-s2.0-82355190947&doi=10.3945%2fajcn.111.012815&partnerID=40&md5=f5a8f4699bd36a22bde835555da38ab1.22049165
74 Humayun MA, Elango R, Ball RO, Pencharz PB. Reevaluation of the protein requirement in young men with the indicator amino acid oxidation technique. American Journal of Clinical Nutrition. 2007;86(4):995–1002. https://www.scopus.com/inward/record.uri?eid=2-s2.0-35148889011&doi=10.1093%2fajcn%2f86.4.995&partnerID=40&md5=1fa9185dfc0318ba74784bacbd273640.17921376
75 Morse MH, Haub MD, Evans WJ, Campbell WW. Protein requirement of elderly women: Nitrogen balance responses to three levels of protein intake. Journals of Gerontology - Series A Biological Sciences and Medical Sciences. 2001;56(11):M724–M730. https://www.scopus.com/inward/record.uri?eid=2-s2.0-0034767178&doi=10.1093%2fgerona%2f56.11.M724&partnerID=40&md5=dc7092ff87829b14c2a3d17c20ac5efa.11682582
76 Pedersen AN, Cederholm T. Health effects of protein intake in healthy elderly populations: A systematic literature review. Food and Nutrition Research. 2014;58. https://www.scopus.com/inward/record.uri?eid=2-s2.0-84894454891&doi=10.3402%2ffnr.v58.23364&partnerID=40&md5=934386f95bb440c35ad0eb372a53ad33.
77 Rafii M, Chapman K, Elango R, . Dietary protein requirement of men > 65 years old determined by the indicator amino acid oxidation technique is higher than the current estimated average requirement. Journal of Nutrition. 2016;146(4):681–687. https://www.scopus.com/inward/record.uri?eid=2-s2.0-84963830996&doi=10.3945%2fjn.115.225631&partnerID=40&md5=843e328da36bae4a9827b7f5914be7ce.
78 Rand WM, Pellett PL, Young VR. Meta-analysis of nitrogen balance studies for estimating protein requirements in healthy adults. American Journal of Clinical Nutrition. 2003;77(1):109–127. https://www.scopus.com/inward/record.uri?eid=2-s2.0-0037215371&doi=10.1093%2fajcn%2f77.1.109&partnerID=40&md5=aecb7ee191bc05ab8456777eed5af7f7.12499330
79 Richter M, Baerlocher K, Bauer JM, . Revised Reference Values for the Intake of Protein. Annals of Nutrition and Metabolism. 2019;74(3):242–250. https://www.scopus.com/inward/record.uri?eid=2-s2.0-85063567061&doi=10.1159%2f000499374&partnerID=40&md5=281ebce4b6f149386d389ba4308dbc79.30904906
80 Tang M, McCabe GP, Elango R, Pencharz PB, Ball RO, Campbell WW. Assessment of protein requirement in octogenarian women with use of the indicator amino acid oxidation technique. American Journal of Clinical Nutrition. 2014;99(4):891–898. https://www.scopus.com/inward/record.uri?eid=2-s2.0-84896932676&doi=10.3945%2fajcn.112.042325&partnerID=40&md5=2fa8395a341ed28b437bddc16d6c8551.24429540
81 Tian Y, Liu J, Zhang Y, . Examination of chinese habitual dietary protein requirements of chinese young female adults by an indicator amino acid method. Asia Pacific Journal of Clinical Nutrition. 2011;20(3):390–396. https://www.scopus.com/inward/record.uri?eid=2-s2.0-80053631972&partnerID=40&md5=8b8d4adf46398f19ef546783f5dc4c18.21859657
82 Borgonha S, Regan MM, Oh SH, Condon M, Young VR. Threonine requirement of healthy adults, derived with a 24-h indicator amino acid balance technique. American Journal of Clinical Nutrition. 2002;75(4):698–704.11916756
83 El-Khoury AE, Pereira PCM, Borgonha S, . Twenty-four-hour oral tracer studies with L-[1-C-13]lysine at a low (15 mg center dot kg(-1)center dot d(-1)) and intermediate (29 mg-kg(-1)center dot d(-1)) lysine intake in healthy adults. American Journal of Clinical Nutrition. 2000;72(1):122–130.10871570
84 Kriengsinyos W, Wykes LJ, Goonewardene LA, Ball RO, Pencharz PB. Phase of menstrual cycle affects lysine requirement in healthy women. Am J Physiol-Endocrinol Metab. 2004;287(3):E489–E496.15308475
85 Kurpad AV, Raj T, El-Khoury A, . Lysine requirements of healthy adult Indian subjects, measured by an indicator amino acid balance technique. American Journal of Clinical Nutrition. 2001;73(5):900–907. https://www.scopus.com/inward/record.uri?eid=2-s2.0-0035043306&doi=10.1093%2fajcn%2f73.5.900&partnerID=40&md5=7924c2ff6c14ba349b42100f2a8d8786.11333843
86 Kurpad AV, Raj T, El-Khoury A, . Daily requirement for and splanchnic uptake of leucine in healthy adult Indians. American Journal of Clinical Nutrition. 2001;74(6):747–755.11722955
87 Kurpad AV, Regan MM, Raj T, . Lysine requirements of healthy adult Indian subjects receiving long-term feeding, measured with a 24-h indicator amino acid oxidation and balance technique. American Journal of Clinical Nutrition. 2002;76(2):404–412.12145014
88 Kurpad AV, Raj T, Regan MM, . Threonine requirements of healthy Indian men, measured by a 24-h indicator amino acid oxidation and balance technique. American Journal of Clinical Nutrition. 2002;76(4):789–797.12324292
89 Kurpad AV, Regan MM, Varalakshmi S, . Daily methionine requirements of healthy Indian men, measured by a 24-h indicator amino acid oxidation and balance technique. American Journal of Clinical Nutrition. 2003;77(5):1198–1205. https://www.scopus.com/inward/record.uri?eid=2-s2.0-0038811791&doi=10.1093%2fajcn%2f77.5.1198&partnerID=40&md5=2f5002d13312023aa34bcbdaaebaf863.12716672
90 Kurpad AV, Regan MM, Varalakshmi S, Gnanou J, Lingappa A, Young VR. Effect of cystine on the methionine requirement of healthy Indian men determined by using the 24-h indicator amino acid balance approach. American Journal of Clinical Nutrition. 2004;80(6):1526–1535.15585764
91 Kurpad AV, Regan MM, Raj TDS, Gnanou JV, Rao VN, Young VR. The daily valine requirement of healthy adult Indians determined by the 24-h indicator amino acid balance approach. American Journal of Clinical Nutrition. 2005;82(2):373–379.16087981
92 Riazi R, Rafii M, Wykes LJ, Ball RO, Pencharz PB. Valine may be the first limiting branched-chain amino acid in egg protein in men. Journal of Nutrition. 2003;133(11):3533–3539.14608070
93 Riazi R, Wykes LJ, Ball RO, Pencharz PB. The total branched-chain amino acid requirement in young healthy adult men determined by indicator amino acid okidation by use of L-[1-C-13] phenylalanine. Journal of Nutrition. 2003;133(5):1383–1389.12730426