# Project methods

This section provides an overview of the methodology utilized to conduct this series of evidence scans. Detailed methodology for each evidence scan can be found in each of the three specific methods sections below.

An evidence scan is a systematic and exploratory process used to describe the volume and characteristics of research available on a topic or question and to identify evidence gaps. They are characterized by the following:

- Providing objective data to support topic and question development, refinement, and prioritization, and inform protocol development
- [underlined: Not] answering the research question, but giving a description of available evidence
- [underlined: Not] involving risk of bias assessment, synthesis, or grading the strength of the evidence

## Develop a protocol

For each evidence scan, the NESR team collaborated with the Working Group to develop a protocol. An evidence scan protocol is a plan for how a specific review or scan will be conducted. The protocol includes:

- Analytic framework
- Literature search and screening plan
  ○ Inclusion and exclusion criteria
  ○ Electronic databases and search terms

The evidence scan protocols were established up-front, and designed to capture the most appropriate, relevant, and direct body of evidence related to the topic or question of interest. Specific methods and any variations to protocols that occurred during the course of the evidence scans are documented in the three chapters of this report.

A description of NESR’s methodology for developing an analytic framework is below. NESR’s methodology for developing inclusion and exclusion criteria and the search strategy, as well as processes related to screening and selecting studies for inclusion in the evidence scan, is described, below, in “Search for, screen, and select literature.”

### Develop analytic frameworks

Analytic frameworks were developed for each evidence scan question. An analytic framework defines the core elements of the scan question, includes definitions for key terms, and helps to ensure that important contributing elements in the causal chain will be considered. The analytic framework serves as the foundation for the rest of the evidence scan process and informs the inclusion/exclusion criteria, literature search strategy, and data extraction.

A standard framework, called the PICO framework, was used to define core elements of each evidence scan question. The elements of the PICO framework are the Population (for both the intervention/exposure and for the outcome), Intervention and/or exposure, Comparator (i.e., the alternative being compared to the intervention or exposure), and Outcomes. Key terms, key confounders, and other factors to be considered (i.e., mediators, moderators, covariates) were also identified and included in the analytic framework where appropriate.

### Search for, screen, and select literature

Systematic searching, screening, and selecting the scientific literature is a process through which NESR sought to identify the most complete and relevant body of evidence related to the evidence scan questions. The process started with defining inclusion and exclusion criteria a priori, followed by developing and implementing literature search strategies, and finally screening and identifying search results. The entire process was documented, including a complete list of articles that met criteria for inclusion in each scan, and a list of excluded articles, with the rationale for exclusion.

#### Define inclusion and exclusion criteria

Inclusion and exclusion criteria provide an objective, consistent, and transparent framework for determining which articles to include in each evidence scan. These criteria were developed to guide selection of the most relevant and appropriate body of evidence for each evidence scan. Additionally, these criteria were framed to increase the utility of the scans for the upcoming protein DRI process. Any revisions to the criteria that occurred during the evidence scan are documented in the individual chapters in this report.

NESR analysts collaborated with the Working Group to establish inclusion and exclusion criteria that were tailored to the specific scan question addressed.

### Developing and implementing the literature search strategy

Once the inclusion and exclusion criteria were set, the NESR librarian used the analytic framework and inclusion/exclusion criteria to guide development of a comprehensive literature search strategy. The librarian worked in collaboration with NESR staff to construct a preliminary search strategy using PubMed operators and search terms. This was used to conduct a test search, preview the results, and correct any syntax, spelling, or grammatical errors. Each search strategy underwent multiple revisions to refine and adjust the search before it was finalized for use. The search strategies are included in this report for all evidence scans completed (Chapters 1-3).

#### Identify bibliographic databases

In Chapters 1 and 2, the librarian searched PubMed alone. In Chapter 3, the librarian used Scopus and Web of Science to map citations.

#### Develop search terms and apply search filters

NESR analysts helped identify initial key terms and/or relevant articles to ensure that the NESR librarian understood the scope and intent of the evidence scan question. The librarian was responsible for drafting the search and incorporating feedback from NESR analysts in finalizing the search.

Individual evidence scan search strategies are detailed in the report chapters below.

## Screen and select studies

The screening of search results was facilitated by the use of a web-based tool (i.e., DistillerSR) and screening forms that were developed based on the inclusion and exclusion criteria identified for each evidence scan. All search results were dual screened by two NESR analysts. The goal of screening was to review the search results and exclude those that did not meet the inclusion criteria. Screening was completed at three levels. The first level of screening was completed using only the title of each article. If an article was not excluded at this level, it moved forward to the second level, where the abstract was screened. Finally, if an article passed the first two levels, it moved to the third level, where the full text of the article was screened. Any disagreements between analysts were reconciled between the two screenings. If necessary, a third analyst was consulted to resolve differences. Any deviations from this screening process are noted in each chapter of this report.

### Document the search results

After the electronic searches were completed, NESR analysts and the librarian documented the literature search and screening results by compiling lists of the included and excluded citations, along with the rationale for exclusion at the full-text level.

### Extract data

NESR analysts extracted and summarized data from each included article to objectively describe the body of evidence available for each evidence scan. To expedite data extraction, only the most essential data for answering the question were extracted. Specific elements extracted for each evidence scan are detailed in subsequent chapters.

Once the types of data to be extracted were determined, an electronic data extraction form was developed and used to facilitate accurate, consistent, and efficient data extraction. This form ensured that the same information from each article was formatted consistently, which made the content easier to compare and contrast during synthesis. NESR analysts used DistillerSR to extract data.

One NESR analyst extracted data from each included article using the data extraction form. In some cases, the required data were not reported in the article. In those situations, the data were recorded as “not reported.” Next, a second analyst reviewed only the extracted results for completeness, accuracy, and consistent presentation and formatting. Evidence tables were created by NESR analysts using the extracted data.

### Description of the evidence

NESR analysts described the volume and characteristics of the evidence identified using text and tables considerations were noted that could potentially be useful for future DRI systematic reviews.

## Identifying considerations for future DRI work

Points that could be of note to the Working Group were summarized as considerations for their future work and future contributions to the macronutrient DRI process. These noted considerations were completed after describing the volume and characteristics of the evidence, and they were based on the gaps and limitations observed during data extraction.