# Introduction

The Joint Canada-US Dietary Reference Intakes Working Group has launched an effort to update the Dietary Reference Intakes (DRIs) for macronutrients in the coming years, including protein. The USDA Nutrition Evidence Systematic Review team is supporting this effort by conducting a series of evidence scans related to total dietary protein intake. These evidence scans will inform potential future systematic reviews (SRs) that will be conducted to update the macronutrient (including protein) DRIs.

Current DRIs^a^ for dietary protein include Estimated Average Requirements (EAR) and Recommended Dietary Allowance (RDA) values for apparently healthy children age 7 months to 18 years and apparently healthy adults age 19 years and older, based on a meta-analysis of nitrogen balance studies. Adequate Intake (AI) values for apparently healthy infants 0 to 6 months, are based on the average consumption of protein from human milk. There was not enough information to establish specific Tolerable Upper Intake levels (UL) for dietary protein or the indispensable amino acids.

a Institute of Medicine 2005. Dietary Reference Intakes for Energy, Carbohydrate, Fiber, Fat, Fatty Acids, Cholesterol, Protein, and Amino Acids. Washington, DC: The National Academies Press. 10.17226/10490.

Acceptable Macronutrient Distribution Ranges (AMDR), defined as “a range of intakes for a particular energy source that is associated with reduced risk of chronic diseases while providing adequate intakes of essential nutrients,” are set for protein and the other macronutrients.^a^ Protein requirements (expressed as a percentage of total energy intake) are not independent of other energy sources or the total energy requirement of the individual. However, the upper range for total protein intake from diet as a percent of total energy intake was set at no more than 35% in adults to decrease risk of chronic disease. In 2005, there was insufficient evidence to support a recommendation for total protein intake or to suggest an upper limit for an AMDR for protein intake based on chronic disease risk specifically. It was acknowledged, however, that high total protein intake or high animal protein intake is implicated in the following health conditions: osteoporosis, renal stones, renal insufficiency, coronary artery disease, and obesity.

Since the 2005 DRIs for macronutrients and energy were published, further research has been completed on the relationship between protein intake and health, including adverse health effects, chronic disease risk, and protein intake requirements overall. To address the update to the evidence base around protein intake and to aid in informing future work on the DRIs, the following evidence scans were completed:

The first evidence scan (Chapter 1) addresses the following questions:

- What is the relationship between high dietary protein intake and acute adverse health effects?
- What is the relationship between high amino acid intake and acute adverse health effects?

The second evidence scan (Chapter 2) addresses the following question:

- What is the relationship between dietary protein intake and risk of chronic disease^b^?
  b i.e., bone outcomes; sarcopenia; renal outcomes; cardiovascular disease risk; diabetes risk; growth, size, and body composition; developmental milestones; dementia/cognitive decline; all-cause moratlity

The third evidence scan (Chapter 3) addresses the following questions:

- What is the average daily dietary protein intake requirement^c^ of apparently healthy individuals by life stage and sex?
  c Requirement: lowest daily intake value for a nutrient that will meet the need as defined by a specified indicator or criterion of adequacy, of apparently healthy individuals
- What is the average daily intake requirement for individual indispensable amino acids of apparently healthy individuals by life stage and sex?