# Chapter 3 Average daily dietary protein intake (including amino acid intake) requirement

## Specific methods to conduct this evidence scan

### Develop a protocol

The research questions, “What is the average daily dietary protein intake requirement of apparently healthy individuals by life stage and sex”? and “What is the average daily intake requirement for individual indispensable amino acids of apparently healthy individuals by life stage and sex”? are explored with this evidence scan.

In order to answer the research questions, a protocol was written to clarify the areas of interest and structure the questions in more detail.

The analytic framework for the evidence scan examining protein intake requirements is presented in Figure 3-a. The analytic framework visually represents the overall scope of the evidence scan question and depicts the contributing elements that were considered. The intervention or exposure of interest was total daily protein intake level or total daily intake of indispensable amino acids (AAs; histidine, isoleucine, leucine, lysine, methionine, phenylalanine, threonine, tryptophan, and valine). The comparator was a different levels of total daily protein intake level or a different total daily intake of indispensable AAs. The outcomes were: total protein requirement as defined by the following indicators or criteria of adequacy – nitrogen balance method, factorial method, indicator amino acid method, mean protein intake of infants fed principally human milk [0-6 months], mean protein content of human milk [0-6 months]; indispensable AA requirement as defined by the following indicators or criteria of adequacy – plasma AA response method, direct AA oxidation method, 24-hour AA balance method, indicator AA oxidation method, mean AA intake of infants fed principally human milk [0-6 months], mean AA content of human milk [0-6 months]. There were no key confounders noted due to the limited data extraction completed in evidence scans.

Figure 3-a Analytic framework for protein intake requirements

Analytic Framework diagram Analytic framework for the protein intake requirements review examining the relationship between total daily protein intake level and total daily intake of indispensable amino acids (Histidine, Isoleucine, Leucine, Lysine, Methionine, Phenylalanine, Threonine, Tryptophan, Valine) compared to different total daily intake of protein or amino acids as defined by indicators or criterion of adequacy. For total protein, the following indicators of adequacy were outcomes of interest: Nitrogen balance method, factorial method, indicator AA method, mean protein intake of infants fed principally human milk (0-6 mo), and mean protein content of human milk (0-6 mo). For indispensable amino acids, the following indicators of adequacy were outcomes of interest: Plasma AA response method, direct AA oxidation method, 24-hour AA balance method, indicator AA oxidation method, mean AA intake of infants fed principally human milk (0-6 mo), and mean AA content of human milk (0-6 mo).

Figure 3-b Literature search and screen flowchart for protein intake requirements

Literature search and screen flowchart Citation mining for the protein requirements evidence scan yielded 1,600 search results (730 from backward and 1,710 from forward mining) after the removal of duplicates and assessment of relevance. Dual-screening resulted in the exclusion of 1,455 abstracts, and 123 full-text articles. The body of evidence included 22 articles: 10 articles on total protein requirements, 12 articles on indispensable AA requirements.

### Search for and select studies

NESR analysts worked jointly with the Working Group to establish the final inclusion and exclusion criteria and literature search strategy, which are detailed in Table 3-a and Appendix 3-a, respectively.

In this evidence scan, initial searches had low precision, leading the team to choose to identify articles through citation mining, rather than a systematic search.

The librarian identified a set of six relevant reports and systematic reviews on protein intake.^a^ Then, using Scopus and Web of Science, the librarian extracted all of the articles cited in those six papers (one level of backward citation mining) and all of those articles which cited those papers (one level of forward citation mining). These extracted articles were checked for relevance (those which mentioned dietary, macronutrient, energy, protein, or amino acid intake or interventions); date (published after 2000); and publication type (proceedings and conference abstracts excluded).

a Deutz, N. E., Bauer, J. M., Barazzoni, R., Biolo, G., Boirie, Y., Bosy-Westphal, A., … & Calder, P. C. (2014). Protein intake and exercise for optimal muscle function with aging: recommendations from the ESPEN Expert Group. Clinical nutrition, 33(6), 929–936. Guidelines: https://www.espen.org/guidelines-home/espen-guidelines 24814383

Bauer, J., Biolo, G., Cederholm, T., Cesari, M., Cruz-Jentoft, A. J., Morley, J. E., … & Boirie, Y. (2013). Evidence-based recommendations for optimal dietary protein intake in older people: a position paper from the PROT-AGE Study Group. Journal of the American Medical Directors association, 14(8), 542–559.23867520

Hörnell, A., Lagström, H., Lande, B., & Thorsdottir, I. (2013). Protein intake from 0 to 18 years of age and its relation to health: a systematic literature review for the 5th Nordic Nutrition Recommendations. Food & nutrition research, 57(1), 21083. Guidelines: http://norden.diva-portal.org/smash/get/diva2:704251/FULLTEXT01.pdf

Joint FAO/WHO/UNU Expert Consultation on Protein and Amino Acid Requirements in Human Nutrition (2002 : Geneva, Switzerland), Food and Agriculture Organization of the United Nations, World Health Organization & United Nations University. (2007). Protein and amino acid requirements in human nutrition: report of a joint FAO/WHO/UNU expert consultation. World Health Organization. https://apps.who.int/iris/handle/10665/43411

Pedersen A, Cederholm T. Health effects of protein intake in healthy elderly populations: a systematic literature review. Food Nutr Res 2014;58:23364. 10.3402/fnr.v58.23364.

EFSA Panel on Dietetic Products, Nutrition and Allergies (NDA), 2012. Scientific Opinion on Dietary Reference Values for protein. EFSA Journal;10(2). https://efsa.onlinelibrary.wiley.com/doi/abs/10.2903/j.efsa.2012.2557

Using this method, the librarian identified 372 articles in the backward citation mining and 1,228 articles in the forward citation mining after de-duplication.

Citation mining, while a useful strategy for mapping evidence in a subject area, searches within a small, contained sample, and is not an exhaustive search method.

### Extract data

NESR analysts extracted data from each included review to objectively describe the body of evidence. Data extraction was completed in DistillerSR by two analysts for each article. Any conflicts between analysts were reconciled between the two screeners. If necessary, a third analyst was consulted to resolve differences. The following data elements were extracted from each included article:

- Publication author and publication year
- Study design
- Population studied (life stage/age group)
- Outcome assessment method
- Outcome assessed (total protein or select AAs)

No results were extracted from the included articles and no quality assessments were completed.

### Describe the evidence

NESR analysts summarized the volume and characteristics of included studies to inform the following question:

- What is the average daily dietary protein intake requirement of apparently healthy individuals by life stage and sex?
- What is the average daily intake requirement for individual indispensable amino acids of apparently healthy individuals by life stage and sex?

The extracted data were summarized in written form, as well as presented visually in a table. The extracted information helped analysts and the Working Group understand the following:

- The volume and characteristics of research examining protein intake requirements
- The volume and characteristics of research examining indispensable AA intake requirements

### Considerations for future DRI work

Considerations for future systematic reviews completed to inform the DRI process were were included in this evidence scan.

## Results

### Literature search and screening results

Citation mining for the protein requirements evidence scan yielded 1,600 search results after the removal of duplicates and assessment of relevance (see Figure 3-b). Dual-screening resulted in the exclusion of 1,455 abstracts, and 123 full-text articles. Reasons for full-text exclusion are in Appendix 3-b. The body of evidence included 22 articles:

- 10 articles on total protein requirements
- 12 articles on indispensable AA requirements

### Description of evidence

#### Total protein requirement

Ten articles examined total protein requirements.^72–81^ Of these, one article^78^ was found to have been cited in the 2005 IOM report on protein^a^. The evidence on total protein requirements is organized by age of the participants. Table 3-b shows the full extraction table with citation, protein requirement(s) assessed, outcome assessment method(s), population(s) examined, and study design(s) for articles reporting on total protein requirements.

a Institute of Medicine 2005. Dietary Reference Intakes for Energy, Carbohydrate, Fiber, Fat, Fatty Acids, Cholesterol, Protein, and Amino Acids. Washington, DC: The National Academies Press. 10.17226/10490.

##### Children (2-12 years)

One RCT examined total protein requirements in children (2-12 years).^73^ Total protein requirements in this study were assessed using the indicator AA oxidation (IAAO) method.

##### Adults (19-59 years)

Two RCTs examined total protein requirements in adults (19-59 years).^74,81^ One RCT was conducted with female participants only,^81^ whereas one was conducted with male participants only.^74^ Both studies utilized the IAAO method to assess total protein requirements. Additionally, one of the RCTs included a MA of 29 studies that utilized the nitrogen balance method to assess total protein requirements.^74^

##### Adults (19-59 years) and older adults (60+ years)

Two studies, one RCT^72^ and one SR with MA,^78^ examined total protein requirements in a combined population of adults (19-59 years) and older adults (60+ years). Both studies utilized the nitrogen balance method to assess total protein requirements. As previously noted, the SR with MA, which included 27 studies in the SR and 19 studies in the MA, was cited in the 2005 IOM report.^78^

##### Older adults (60+ years)

Four studies, three RCTs^75,77,80^ and one SR,^76^ examined total protein requirements in older adults (60+ years). Among the RCTs, two were conducted with female participants,^75,80^ whereas one was conducted with male participants.^77^ Further, two RCTs utilized the IAAO method to determine total protein requirements,^77,80^ whereas one utilized the nitrogen balance method.^75^ The SR assessed studies that determined total protein requirements using the nitrogen balance and included one MA and 4 additional individual studies.

##### All age groups

One SR reported on total protein requirements across all age groups from infancy to older adulthood.^79^ The number of included studies in the SR was not reported. Methods used to determine protein requirements that were summarized by the SR included the mean protein content of human milk, the factorial method, and the nitrogen balance method.

#### Indispensable AA requirements

Twelve articles examined indispensable AA requirements.^82–93^ Of these, six articles^82,83,85–88^ were found to have been cited in the 2005 IOM report on protein^b^. The evidence on indispensable AA requirements is organized by the type of AA. Table 3-c shows the full extraction table with citation, population, intervention/exposure, and outcome data for articles reporting on indispensable AA requirements.

b Institute of Medicine 2005. Dietary Reference Intakes for Energy, Carbohydrate, Fiber, Fat, Fatty Acids, Cholesterol, Protein, and Amino Acids. Washington, DC: The National Academies Press. 10.17226/10490.

##### Leucine

One RCT examined leucine requirements in adult (19-59 years) males.^86^ This RCT used the 24-hour AA balance method, the direct AA oxidation method, and the nitrogen balance method to determine leucine requirements. This RCT was cited in the 2005 IOM report on protein.

##### Lysine

Four studies, three RCTs^84,85,87^ and 1 NRCT,^83^ examined lysine requirements in adults (19-59 years). One RCT had not been previously cited in the 2005 IOM report on protein.^84^ In this study, lysine requirements were assessed using the IAAO method and participants were limited to females.^84^ Of the three studies that had been cited in the 2005 IOM report on protein, two were conducted with male participants and utilized the IAAO and 24-hour indicator AA balance methods to determine lysine requirements, whereas one was conducted with both male and female participants and utilized the 24-hour AA balance and direct AA oxidation methods to determine lysine requirements.

##### Methionine

Two RCTs examined methionine requirements in adult (19-59 years) males.^89,90^ Both RCTs utilized the IAAO and 24-hour AA balance methods to determine methionine requirements. Neither study was cited in the 2005 IOM report on protein.

##### Threonine

Two RCTs examined threonine requirements in adults (19-59 years),^82,88^ both of which were cited in the 2005 IOM report. Both RCTs utilized the IAAO and 24-hour indicator AA balance methods to determine threonine requirements. One RCT was conducted with male participants,^88^ whereas one RCT included both male and female participants.^82^

##### Valine

One RCT examined valine requirements in adult (19-59 years) males.^91^ This RCT utilized the IAAO and 24-hour indicator AA balance methods to determine valine requirements. This RCT was cited in the 2005 IOM report on protein.

##### Total branched-chain AAs (BCAAs)

Two RCTs examined the total requirement for BCAAs (isoleucine, leucine, valine) in adult (19-59 years) males.^92,93^ Both RCTs utilized the IAAO method to determine BCAA requirements. Neither study was cited in the 2005 IOM report on protein.

### Considerations for future DRI work

As the DRI process moves forward at the guidance of the Working Group, the following may be important to consider as a result of this completed evidence scan:

1. Relatively few studies or systematic reviews have been published on the topic of total protein or individual indispensable AA requirements since the completion of the 2005 IOM report on protein DRIs. Most new evidence was focused on total protein requirements and assessed adults (19-59 years) and older adults (60+ years). Fewer new studies were available on individual indispensable AA requirements (6 RCTs) or in children (2-12 years; 1 RCT). No new evidence was identified for adolescents, toddlers, or infants except as part of a systematic review on total protein requirements across the lifespan.
2. Citation mining, while a useful strategy for mapping evidence in a subject area, searches within a small, contained sample, and is not an exhaustive search method. Therefore, it is possible that there are additional, relevant studies that have been published since the completion of the 2005 IOM report on protein DRIs that were not captured by this evidence scan.
3. A full systematic review to fully explore this topic may be beneficial to inform future DRI work. The information found through citation mining was thorough but was part of an abbreviated evidence scan procedure. A systematic review would potentially provide a stronger body of evidence on protein requirements.