# Chapter 2 Protein intake and chronic disease risk

## Specific methods to conduct this evidence scan

### Develop a protocol

The research question, “What is the relationship between protein intake and chronic disease risk?”, was explored using an evidence scan.

The analytic framework for the evidence scan examining the relationship between dietary protein intake and risk of chronic disease is presented in Figure 2-a. The analytic framework visually represents the overall scope of the evidence scan question and depicts the contributing elements that were considered. The intervention or exposure of interest was total protein intake from foods, beverages, and dietary supplements. The comparator was consumption of different levels of total protein intake or no comparator. The outcomes were chronic disease outcomes, including: bone outcomes, sarcopenia, renal outcomes, risk of cardiovascular disease (CVD), risk of diabetes, growth/size/body composition, neurocognitive development, dementia/cognitive decline, and all-cause mortality (ACM). General outcomes were listed in the analytic framework but were not limited to this list. There were no key confounders noted due to the limited data extraction completed in evidence scans.

### Search for and select studies

NESR analysts worked with the Working Group to finalize the inclusion and exclusion criteria and the literature search strategy, which are detailed in Table 2-a and Appendix 2-a, respectively. The study designs of interest for this specific scan included SRs, MAs, scoping reviews and umbrella reviews in order to streamline the literature search. Supplemental searches were completed to evaluate protein intake and length of sleep (search strategy detailed in Appendix 2-b), as well as protein intake and appetite/satiety (search strategy detailed in Appendix 2-c). Articles were screened by two NESR analysts independently for inclusion based on these pre-determined criteria and disagreements were reconciled by a third analyst. The DRI Protein WG desired information on the number articles that evaluated animal and/or protein intake. A bibliography of articles that evaluated protein intake from animal or plant sources but were excluded because analysis did not include an assessment of total protein intake is found in Appendix 2-d.

### Extract data

NESR analysts extracted data from each included review to objectively describe the body of evidence available in the last 5 years about protein intake and risk of chronic disease. Data extraction was completed in DistillerSR by one analyst for each review and a second analyst checked the extracted data for accuracy. The following data elements were extracted from each included review:

- Publication author and publication year
- Study design
- Purpose of review or research question answered by the review
- Population studied (life stage/age group)
- Intervention/exposure and comparator
- Outcomes examined in the review
- Direction of the relationship between the intervention/exposure and outcome (inverse, positive, null)

No effect estimates or measures of statistical validity were extracted from the included reviews.

### Describe the evidence

NESR analysts summarized the volume and characteristics of included studies to inform the following question:

- What is the relationship between dietary protein intake and risk of chronic disease?

The extracted data were summarized in written form, as well as presented visually in a table. The extracted information helped analysts and the Working Group understand the following:

- The volume and characteristics of research examining the levels of protein intake (total protein and amino acids) associated with increased chronic disease risk
- Which chronic disease outcomes occur as a result of total protein intake

### Quality and duplication assessment

The Working Group reviewed results from the evidence scans conducted as described above and identified the following outcomes as warranting further investigation: ACM, bone health, CVD, diabetes, renal health and sarcopenia. For each identified study within these topic areas, NESR analysts conducted a formal assessment to evaluate the methodological quality of the review, noted the source of funding, and conducted a duplication assessment to identify the number of unique studies within the body of evidence. The following topics were excluded from further evaluation due to insufficient evidence (dementia/cognitive decline; neurocognitive development) or were considered beyond the scope of chronic disease (growth, size, and body composition). Below is a brief description of each assessment.

#### AMSTAR 2 assessment and documentation of funding source

NESR analysts conducted a dual, independent assessment for each review using AMSTAR 2 (A MeaSurement Tool to Assess systematic Reviews),^a^ a 16-item critical appraisal tool for assessing the quality of SRs that include randomized and/or non-randomized studies. Critical domains were defined a priori based on the needs of the Working Group. Responses were compared, and any disagreements were discussed and reconciled. To address the potential for conflict of interest and bias, NESR analysts also noted the funding source of each included review.

a Shea BJ, Reeves BC, Wells G, . AMSTAR 2: a critical appraisal tool for systematic reviews that include randomised or nonrandomised studies of healthcare interventions, or both. BMJ. 2017;358:j4008. Published 2017 Sep 21. doi:10.1136/bmj.j4008 28935701

#### Duplication assessment

NESR analysts identified the component studies within each review that addressed specific outcomes, constructing tables to illustrate citation overlap across the body of evidence and identified the number of unique studies included within the identified reviews for each topic area.

### Considerations for future DRI work

Considerations for future SRs completed to inform the DRI process across chronic disease outcomes were were included in this evidence scan.

## Results

### Literature search and screening results

The chronic disease risk literature search yielded 3,850 search results (see Figure 2-b). Dual-screening resulted in the exclusion of 3,397 titles, 270 abstracts, and 138 full-text articles. Reasons for full-text exclusion are in Appendix 2-e. The body of evidence included 45 reviews and meta-analyses:

- 3 reviews provided evidence on ACM
- 7 reviews provided evidence on bone health
- 10 reviews provided evidence on CVD risk
- 2 reviews provided evidence on dementia/cognitive decline (adults)
- 6 reviews provided evidence on diabetes risk
- 17 reviews provided evidence on growth, size, and body composition
- 0 reviews provided evidence on neurocognitive development (children)
- 2 reviews provided evidence on renal health
- 5 reviews provided evidence on sarcopenia

Separate literature searches were conducted for sleep duration and appetite/satiety. The sleep duration literature search yielded 74 search results and dual-screening resulted in the exclusion of 64 titles, 3 abstract and 7 full-text; no reviews met inclusion criteria for sleep duration (see Figure 2-c). Reasons for full-text exclusion are in Appendix 2-f. The appetite and satiety literature search identified 87 search results (see Figure 2-d) and dual-screening resulted in exclusion of 41 titles, 28 abstracts and 14 full-text articles; four SRs met inclusion criteria for appetite and satiety. Reasons for full-text exclusion are in Appendix 2-g.

### Description of the evidence

#### All-cause mortality

Three SRs examined the relationship between protein intake and ACM risk.^23–25^ Table 2-b shows the full extraction table with population, intervention/exposure, and outcome data for SRs reporting on the all-cause mortality outcome.

##### Review and population characteristics

All three SRs on ACM risk were conducted with MA. The number of included studies within each SR ranged from 8^23^ to 29 studies.^24^ All three articles included only prospective cohort studies (PCSs). There was considerable overlap of included studies between the three reviews with 31 unique studies (Appendix 2-i). Adults were studied in the three articles, with two reviews also including older adults.^23,25^ The AMSTAR 2 ratings for the included SRs were moderate^23,25^ and low^24^ (Appendix 2-h).

##### Intervention/exposure characteristics

All the included studies in the three reviews evaluated habitual protein intake as the exposure (one continuously,^25^ one categorically,^23^ and one with both^24^). Follow-up varied across these observational studies ranging from 3.4 years to 27 years.

##### Outcome characteristics and trends

All three reviews and meta-analyses evaluated ACM as an outcome alongside other cause-specific outcomes. For ACM, effect estimates were broken down according to the following exposures: total protein intake, plant protein intake, and animal protein intake. There were mixed results (inconsistent) found for the relationship between total protein intake and ACM risk. Two reviews found null associations between animal protein intake and ACM risk^24,25^ and one with a positive relationship.^23^ All three reviews found an inverse relationship between plant protein intake and ACM (increased intake of plant protein was associated with lower ACM risk).

#### Bone health

Seven SRs examined the relationship between protein intake and bone outcomes.^26–32^ Table 2-c shows the full extraction table with population, intervention/exposure, and outcome data for systematic reviews reporting on bone outcomes.

##### Review and population characteristics

Of the seven SRs on bone outcomes, five were conducted with MA^27–29,31,32^ and two were conducted without MA.^26,30^ The number of included studies within each SR primarily ranged from 13 studies with relevant outcomes^28^ to 34 studies with relevant outcomes.^32^ However, one review included 103 studies with relevant outcomes (many of which were cross-sectional studies).^27^ Most reviews had considerable overlap in studies that provided data on relevant outcomes, with 149 unique articles represented in total (Appendix 2-j). Of these, 124 reported on bone mass (bone mineral density [BMD] and/or bone mineral content [BMC]), 25 reported on fracture, and 6 reported on osteoporosis/osteopenia. Older adults were studied in all seven SRs and adults were studied in six SRs.^27–32^ Children and adolescents, 2 to 18 years old, were studied in one SR.^27^ The population of one SR focused on participants with overweight or obesity.^32^ The AMSTAR 2 ratings for the included SRs were moderate,^28^ low,^27,29,32^ and critically low^26,30,31^ (Appendix 2-h).

##### Intervention/exposure characteristics

All reviews on bone health included interventions that altered protein intake and six reviews included studies that assessed habitual protein intake (reported continuously and categorically).^26–31^ The included studies of one SR also had a primary focus on interventions designed to induce weight loss and interventions that were multi-component (but isolated the effect of total protein).^32^ The duration of interventions varied across the studies in the reviews, ranging from 4 days to 2 years. Similarly, the duration of follow-up for included observational studies varied across the reviews, ranging from no follow-up (cross-sectional studies) to 32 years.

##### Outcome characteristics and trends

All seven SRs examined outcomes related to bone mass, specifically BMD and BMC. The relationship between protein intake and bone mass varied across the reviews and by site examined, with positive, mixed, and null results reported. A variety of sites were examined within and across the reviews, such as hip, femoral neck, lumbar spine, and total body.

Five SRs examined fractures as an outcome.^26–29,31^ The review conclusions tended towards null and inverse (higher protein, lower risk) for hip fracture. For other fracture sites, such as the spine and the forearm, the review conclusions tended to be null, mixed, or inconclusive.

Finally, one SR assessed osteoporosis as an outcome, reporting mixed results.^27^

#### Cardiovascular disease risk

Ten SRs examined the relationship between protein intake and CVD outcomes.^23–25,33–39^ Table 2-d shows the full extraction table with population, intervention/exposure, and outcome data for SRs reporting on CVD outcomes.

##### Review and population characteristics

Of the 10 included reviews, two were umbrella reviews^33,39^ and 8 were SRs, 5 of which were conducted with MA.^23–25,34,36^ Four reviews included only RCTs^33–35,39^ and the other six included only PCSs.^23–25,36–38^ The 2 umbrella reviews each had 6 meta-analyses of RCTs with 8 relevant unique studies due to considerable overlap, and the 8 SRs had 71 relevant unique studies with minimal overlap by outcome. (Appendix 2-k) One review included individuals during pregnancy,^37^ one review included adults (age 19-59 years of age),^33^ and the remaining reviews included adults and older adults.^23–25,34–36,38,39^ The AMSTAR 2 ratings for the included SRs were high,^33,37,39^ moderate,^23,25,34,38^ low,^24,35^ and critically low.^36^ (Appendix 2-h)

##### Intervention/exposure characteristics

Of the four reviews evaluating trials, all evaluated interventions that altered protein intake.^33–35,39^ Of the six reviews evaluating observational studies (PCS in all), the studies were evaluating habitual protein intake, both categorical and continuous.^23–25,36–38^

The four reviews containing only RCTs ranged in intervention duration from 0.8 months to 52 months in those studies that reported intervention duration.^33,34^ Of the reviews including only PCSs, follow-up duration ranged from 2.3 years to 32 years in those reviews that reported follow-up duration.^23–25,36,38^

##### Outcome characteristics and trends

There were 4 categories of CVD outcomes within the 10 included reviews evaluating total protein intake and CVD risk. Five reviews evaluated blood pressure, including hypertension^33–35,38,39^; one review evaluated the protein intake of pregnant persons and the blood pressure of their offspring.^37^ Cardiovascular disease mortality was detailed in three reviews.^23–25^ One review evaluated stroke mortality^23^ and one review evaluated stroke risk.^36^ Finally, one review focused on protein intake and coronary heart disease risk.^38^

Of the five total reviews evaluating protein intake and blood pressure, results were mixed, including null and inverse results. In the review evaluating protein intake in pregnancy, there was a null association with offspring blood pressure. Total protein intake was not consistently associated with cardiovascular disease mortality. Null and positive associations with total protein and animal protein was observed with CVD mortality; null and inverse associations were observed with plant protein. Both reviews evaluating stroke related outcomes found null associations, as did the review evaluating coronary heart disease risk.

#### Dementia/cognitive decline (adults)

Two SRs examined the relationship between protein intake and dementia/cognitive decline outcomes.^40,41^ Table 2-e shows the full extraction table with population, intervention/exposure, and outcome data for SRs reporting on dementia/cognitive decline outcomes.

##### Review and population characteristics

Both SRs on dementia and cognitive decline outcomes were conducted without MA and primarily included cross-sectional studies: one review included eight cross-sectional studies and one PCS,^40^ while the other review included five cross-sectional studies and two RCTs.^41^ There was minimal overlap in studies included across the two reviews. The populations studied included adults and older adults in one review^41^ and older adults alone in the other review.^40^

##### Intervention/exposure characteristics

Both reviews on dementia and cognitive decline outcomes assessed habitual intake or protein (reported continuously and categorically).^40,41^ The observational studies that assessed habitual intake of protein were predominantly cross-sectional, but the one included PCS reported a follow-up duration of 8.5 months.^40^ One SR assessed an intervention (3 weeks in duration) that altered protein intake.^41^

##### Outcome characteristics and trends

A variety of cognitive outcomes were assessed across the two reviews including: abstract reasoning, digit subtraction, fluid intelligence, global cognition/cognitive function, immediate and delayed learning ability, inhibition control, memory, nonverbal learning, problem-solving ability, processing speed, reaction time, risk of mild cognitive impairment, short-term memory, sustained attention, verbal fluency, verbal and nonverbal memory, and working memory.^40,41^ Few studies within each review assessed the same aspect of cognition. One review reported predominantly null associations between protein intake and cognitive decline,^40^ while the other review reported mixed results with some positive associations.^41^

#### Diabetes risk

Five SRs with MA,^42–46^ and one umbrella review of MAs^33^ examined the relationship between protein intake and risk of type 2 diabetes. Table 2-f shows the full extraction with population, intervention/exposure, outcome data and AMSTAR 2 rating for systematic and umbrella reviews reporting on diabetes outcomes.

##### Review and population characteristics

The 5 SRs with MA each included 6 to 9 PCSs, but there was significant overlap among included studies, with 12 unique studies in total across the reviews (see Appendix 2-l). The umbrella review included six meta-analyses of RCTs. All the SRs included adults and older adults, while the umbrella review reported subject age as greater than or equal to 18 years. The AMSTAR 2 ratings for the included SRs were high,^33^ moderate,^42,43,45,46^ and critically low^44^ (Appendix 2-h).

##### Intervention/exposure characteristics

All SRs included interventions that assessed higher verses lower habitual intake reported categorically, and four also examined a continuous measure of habitual protein intake.^42,43,45,46^ The one umbrella review examined meta-analyses which examined interventions that altered the quantity of protein intake.^33^

##### Outcome characteristics and trends

Five SRs with MA found total protein intake and animal protein intake was positively associated with type 2 diabetes. Results for plant protein intake and type 2 diabetes were inconsistent, with studies reporting null,^43^ inverse,^42^ or U-shaped curve associations^46^ or results which differed by gender^44^ or level of protein intake.^45^

The umbrella review which included six meta-analyses found higher compared to lower protein intake had a weak or null effect on Hemoglobin A1c (HbA1c).^33^

#### Growth, size, and body composition

Fifteen systematic reviews^47–61^ and two umbrella reviews^33,62^ examined the relationship between protein intake and outcomes related to growth, size, and body composition. Table 2-g summarizes the population, intervention/exposure, and outcome data for reviews reporting on protein intake and growth, size, and body composition.

##### Review and population characteristics

Of the 15 SRs, 11 were conducted with MA^47,49–53,56,58–61^ and 4 were conducted without MA.^48,54,55,57^ Most SRs included only RCTs,^47,49–53,56,58–61^ two only included PCSs,^55,57^ one included RCTs and PCSs,^48^ and one included RCTs and non-randomized controlled trials (NRCTs).^54^ The number of included studies within the systematic reviews ranged from two^60^ to 66.^56^ Of the two umbrella reviews, one included two systematic reviews^62^ and one included seven meta-analyses.^33^ Four reviews studied infant populations,^48,54,55,62^ two of which also included toddlers 12-23 months and/or children 2-12 years.^48,55^ Thirteen reviews studied adult populations,^33,47,49–53,56–61^ 10 of which also included older adults.^33,47,50–53,56,58–60^

##### Intervention/exposure characteristics

Fifteen reviews included interventions that altered protein intake,^33,47–54,56–62^ nine of which also included interventions designed to induce weight loss.^47,49–52,56,59–61^ Two reviews included interventions with supplements designed to enhance athletic performance.^53,58^ Three reviews assessed habitual intake (reported continuously and/or categorically).^48,55,57^

##### Outcome characteristics

Six reviews examined outcomes related to growth,^48,54,55,57,59,62^ including weight gain,^48,54^ gestational weight gain,^57^ incidence or prevalence of overweight and/or obesity,^48,54,55,62^ and weight loss maintenance.^59^ The relationship between protein intake during the first 2 years of life and risk of overweight and/or obesity later in childhood was a mix of positive and null results.

Seven reviews examined outcomes related to size,^33,48,49,54,55,61^ including weight/weight z-score,^33,49,54,61^ length,^54^ BMI/BMI z-score,^33,48,49,54,55,61,62^ head circumference,^54^ and waist circumference.^49,61^ For protein intake and BMI/BMI z-score, reviews tended to show a positive relationship for infants and an inverse relationship in adults.

Thirteen reviews examined outcomes related to body composition,^47–56,58,60,61^ including muscle mass,^50^ muscle thickness,^58^ lean mass,^47,51–53,56,58^ fat-free mass or fat-free mass index,^54,55,60,61^ fat mass or fat mass index,^47–50,52–55,58,61^ body mass,^47^ and body fat percentage.^55^ For fat mass, reviews tended to be a mix of positive and null results for infants, and a mix of inverse and null results for adults. For fat-free mass, reviews tended to report null results in both infants and adults. For lean mass, reviews tended to be a mix of positive and null results for adults.

#### Neurocognitive development (children)

No reviews were found that met the inclusion/exclusion criteria for this outcome.

#### Renal health

Two SRs examined the relationship between protein intake and renal outcomes.^35,63^ Table 2-h shows the full extraction table with population, intervention/exposure, and outcome data for SRs reporting on renal outcomes.

##### Review and population characteristics

Of the two SRs on renal outcomes, one was conducted with MA^63^ while one was conducted without MA.^35^ The SR with MA included 28 RCTs.^63^ The SR without MA included 13 RCTs, 5 cross-sectional studies, and 2 PCSs with data relevant to the evidence scan’s included outcomes.^35^ There was some overlap in the included studies between the 2 reviews, with 41 unique articles with relevant outcome data represented in total (Appendix 2-m). The populations studied in both SRs were adults and older adults (19 years old and older). The AMSTAR 2 rating was moderate for one SR^63^ and low for the other SR^35^ (Appendix 2-h).

##### Intervention/exposure characteristics

Both SRs on renal outcomes assessed interventions that altered protein intake.^35,63^ The SR that included observational studies also examined habitual intake of protein (measured and reported continuously and in categories).^35^ The duration of included trials across reviews ranged from 1 day to 104 weeks,^35,63^ while the time to follow-up of included observational studies ranged from no follow-up (cross-sectional studies) to 21 years.^35^

##### Outcome characteristics and trends

Both SRs examined glomerular filtration rate (GFR) or estimated GFR (eGFR).^35,63^ While mixed results were reported, there was a tendency toward positive relationships between protein intake and GFR. One SR reported on kidney disease incidence and the reported association with protein intake was null; however, this outcome was assessed in only one of the review’s included studies.^35^

#### Sarcopenia

Five SRs examined the relationship between protein intake and sarcopenia outcomes.^53,64–67^ Table 2-h shows the full extraction table with population, intervention/exposure, and outcome data for SRs reporting on sarcopenia outcomes.

##### Review and population characteristics

Of the five SRs on total protein intake and sarcopenia outcomes, three were conducted with MA.^53,64,67^ The majority of studies included in the five reviews are PCSs and RCTs, though a few cross-sectional, case-control, and NRCTs were included as well. Between the 3 outcome categories (muscle strength, muscle mass, and sarcopenia) there were 100 relevant articles found in each of the reviews with no overlap present (Appendix 2-n). All five reviews included studies with older adult participants with one review that also included adults age 19 to 59 years of age.^53^ The AMSTAR 2 ratings for the included SRs were low^53,67^ and critically low^64–66^ (Appendix 2-h).

##### Intervention/exposure characteristics

Three reviews included studies assessing habitual intake (reported continuously and categorically),^64–66^ three reviews included interventions that altered protein intake,^53,66,67^ and one included multi-component interventions that isolated the effect of total protein.^53^ Two reviews evaluating trials had intervention durations of 4.5 to 24 weeks^53^ and 10 to 104 weeks.^67^ The third review evaluating trials did not report intervention duration.^66^ One review that evaluated observational studies had a follow-up range of up to 6 years.^65^ The other two reviews that included observational studies did not report follow-up duration.^64,66^

##### Outcome characteristics and trends

For this evidence scan, sarcopenia itself was included as an outcome, as well as muscle mass and muscle strength outcomes that make up the definition of sarcopenia. Four reviews evaluated muscle strength outcomes,^64,66,67^ four reviews evaluated muscle mass outcomes,^53,65–67^ and one review evaluated sarcopenia overall.^66^ There were all null results across reviews for upper-limb and lower-limb muscle strength^53,64,66,67^ aside from a positive relationship in one review for handgrip strength (but only when combined with exercise in frail/sarcopenic populations).^67^ Two reviews had trends towards a positive relationship for lean muscle mass gain and for skeletal muscle mass^53,65^ and the other two muscle mass reviews found only null relationships.^66,67^ The review evaluating protein intake and sarcopenia overall found inconclusive/mixed results.^66^

#### Supplemental scans

##### Sleep duration

No reviews were found that met the inclusion/exclusion criteria for this supplemental scan.

##### Appetite and satiety

Four SRs examined the relationship between protein intake and appetite and satiety outcomes.^68–71^ Table 2-j shows the full extraction table with population, intervention/exposure, and outcome data for SRs reporting on appetite and satiety outcomes.

###### Review and population characteristics

Of the four SRs on appetite and satiety outcomes, two were conducted with MA^68,70^ and two were conducted without MA.^69,71^ All of the reviews predominantly included RCTs, with the number of relevant included studies ranging from 2^71^ to approximately 41.^70^ The populations studied included adults and older adults in three reviews^69–71^ and older adults alone in one review.^68^ Two reviews focused on studies where 100 percent of participants were with overweight or obesity.^69–71^

###### Intervention/exposure characteristics

All reviews predominantly assessed interventions that altered protein intake.^68–71^ The two reviews focusing on individuals with overweight or obesity included interventions that were designed to induce weight loss.^69–71^ Two of the SRs assessed studies with acute intervention durations, ranging from immediate assessment of appetite and satiety following protein intake to approximately 3 hours following protein intake.^68,70^ All four SRs reported on longer-term interventions with durations ranging from 2 days to 34 months.

###### Outcome characteristics and trends

A variety of appetite and satiety related outcomes were assessed, including hunger, fullness, desire to eat, prospective food consumption, thoughts about food, satiety, and composite appetite score.^68–71^ For acute studies, the reviews reported mixed findings but there was a tendency towards higher protein intake increasing satiety and decreasing appetite.^68,70^ For longer-term studies, the reviews reported mixed findings – primarily null or a positive effect of protein on satiety.

### Considerations for future DRI work

As the DRI process moves forward at the guidance of the Working Group, the following may be important to consider as a result of this completed evidence scan:

1. This evidence scan describes a broad range of evidence related to total dietary protein intake and chronic disease risk. It is difficult to know how pivotal the role of protein intake is to these relationships and it is challenging to isolate the effect of protein from the effect of other macronutrients, micronutrients, and bioactive substances.
2. Evidence was derived from existing systematic reviews, meta-analyses, and umbrella reviews identified by a literature search in PubMed. Use of a broader range of bibliographic databases may have identified additional reviews.
3. Completing duplication assessment of the relevant studies included in each review according to the reported outcome provided a rough estimate of the potentially included unique primary research articles. However, future systematic reviews would need to consider differences in intervention/exposure, database coverage, and assess the full inclusion/exclusion criteria used to identify and evaluate primary evidence.
4. Modifying the inclusion and exclusion criteria for each outcome would influence the strength and size of the reviews. This includes modifications to the following criteria: date range; study design; health status of the participants; characteristics or scope of the intervention/exposure (e.g., weight loss interventions, expanding scope to include protein source, duration of intervention, study/sample size); range of validated intermediate and health outcomes; and potential sources of confounding (e.g., studies that assess percent AMDR or describe full macronutrient distribution of the diet).