# Chapter 1 High dietary protein intake (including amino acid intake) and acute adverse health effects

## Specific methods to conduct this evidence scan

### Develop a protocol

The research questions, “What is the relationship between high dietary protein intake and acute adverse health effects?” and “What is the relationship between high amino acid intake and acute adverse health effects?”, were explored with an evidence scan. The following section describes the protocol developed for this evidence scan.

The analytic framework for the evidence scan examining the relationships between total protein intake and amino acid intake and acute adverse health effects is presented in Figure 1-a. The analytic framework visually represents the overall scope of the evidence scan question and depicts the contributing elements that were considered. The first intervention or exposure of interest was any level of total protein intake defined as elevated or high, or compared to a lower level of protein intake. The comparator was a lower protein intake or no comparator. The next intervention or exposure of interest was any level of amino acid intake defined as elevated or high, or compared to a lower level of amino acid intake. The comparator was a lower amino acid intake or no comparator. The included amino acids were as follows: histidine, isoleucine, leucine, lysine, methionine, cysteine, phenylalanine, tyrosine, threonine, tryptophan, valine, arginine, and glutamine. The comparator was a lower level of amino acid intake or no comparator. For both intervention/exposures, the outcomes were any acute adverse health effects, especially those with a focus on toxicity. General outcomes were listed in the analytic framework but were not limited to this list. There were no key confounders noted due to the limited data extraction completed in evidence scans.

Figure 1-a Analytic framework for high protein intake and acute adverse health effects

Analytic framework figure The analytic framework visually displays the interventions and exposures, comparators and the acute adverse health effects considered in this review. The first intervention or exposure of interest was any level of total protein intake defined as elevated or high, relative to a lower level of protein intake or based on % AMDR. The comparator was a lower protein intake or no comparator. The next intervention or exposure of interest was any level of amino acid intake defined as elevated or high, or relative to a lower level of amino acid intake. The comparator was a lower amino acid intake or no comparator. For both intervention and exposures, the outcomes were any acute adverse health effects including but not limited to: Diarrhea/constipation/change in bowel habits, change in appetite, gastrointestinal (GI) discomfort, nausea/vomiting, change in weight, change in mood, and headache.

Figure 1-b Literature search and screen flowchart for high protein intake and acute adverse health effects

Literature search and screen flowchart The literature search in PubMed retrieved 2,375 records after removing duplicates. Dual-screening resulted in the exclusion of 2,240 titles, 44 abstracts, and 70 full-text articles. One additional review was identified from the manual search. The body of evidence included 22 reviews, 6 reviews on total dietary protein and 16 reviews on amino acids.

### Search for and select studies

NESR analysts worked with the Working Group to finalize the inclusion and exclusion criteria and the literature search strategy, which are detailed in Table 1-a and Appendix 1-a, respectively. The study designs of interest for this specific scan included SRs, meta-analyses (MAs) and narrative reviews in order to streamline the literature search.

Table 1-a Inclusion and exclusion criteria for high protein intake and acute adverse health effects

Category | Inclusion Criteria | Exclusion Criteria
Study design | - Systematic reviews; - Meta-analyses; - Narrative reviews | - Primary literature including:; ○ Randomized controlled trials; ○ Non-randomized controlled trials (including quasi-experimental and controlled before and after studies); ○ Prospective cohort studies; ○ Retrospective cohort studies; ○ Nested case-control studies; ○ Case-control studies; ○ Case studies; ○ Brief reports; ○ Uncontrolled trials; ○ Cross-sectional studies; ○ Uncontrolled before and after studies
Intervention/exposure | - High dietary total protein intake from food, beverages, and protein supplements; ○ RDA value as a cut off (145 mg N/kg/d); ○ Relative to a lower protein intake; ○ Based upon percentage of energy intake (AMDR); - High amino acid (AA) intake (Histidine, isoleucine, leucine, lysine, methionine, cysteine, phenylalanine, tyrosine, threonine, tryptophan, valine, arginineError! Bookmark not defined., glutamine*); ○ RDA and EAR values as a cut off; ○ Relative to lower AA intake | - Studies that only assess protein intake via infusions (rather than the GI track)
Comparator | - Consumption of different levels of total dietary protein; - Consumption of different levels of amino acids; - No comparator | - Co-exposures (i.e., same protein intake level but varying supplementation or physical activity)
Outcomes | Acute adverse health effects (toxicological outcomes), including but not limited to:; - Diarrhea/constipation/change in bowel habits; - Change in appetite; - GI discomfort; - Nausea/vomiting; - Change in weight; - Change in mood; - Headache | - Chronic disease outcomes related to protein intake (renal disease, bone health outcomes, diabetes, etc.)
Study duration | - Observational studies: Any duration; - Trials: Up to 8 weeks | - Trials: >8 weeks
Publication date | - Review Papers; ○ 2016 to October 2021 | - Review Papers; ○ Prior to 2016
Publication status | - Articles published in peer-reviewed journals | - Articles that have not been peer reviewed and are not published in peer-reviewed journals (e.g., unpublished data, manuscripts, pre-prints, reports, abstracts, conference proceedings)
Language | - Articles published in English | - Articles published in languages other than English
Country | - Studies conducted in any country
Study participants | - Human participants; ○ Males; ○ Females | - Non-human participants (e.g., animal studies, in-vitro models)
Age of study participants | - Age at intervention or exposure:; ○ Infants, children, and adolescents (0-18 years); ○ Adults (19-64 years); ○ Older adults (65 years and older) | N/A
Health status of study participants | - Studies that enroll participants who are healthy and/or at risk for chronic disease, including those with obesity; - Studies that enroll some participants diagnosed with a disease or hospitalized with and illness or injury; - Studies that enroll some participants diagnosed with a disease or with the health outcome of interest; - Studies which exclusively recruit athletes and/or highly active individuals | - Studies that exclusively enroll participants diagnosed with a disease or hospitalized with an illness or injury (for this criterion, studies that exclusively enroll participants with obesity will not be excluded); - Studies that exclusively enroll undernourished participants; - Studies that exclusively enroll participants with a baseline diet deficient in protein; - Studies that exclusively enroll pre-term infants.

Table 1-b Evidence examining the relationship between high protein intake and acute adverse health effects^a^

Author, Year and Review Type | Purpose of review or research question | Life Stage (Population studied) | High protein intake without adverse effects | Adverse effects noted as a result of high protein intake
Ben-Harchache, 2021^6^; Systematic review and meta-analysis | Aimed to determine the effects of protein supplementation on appetite and/or energy intake in healthy older adults. | Older adults, 60+ y | N/A | - Appetite change (In acute studies (n = 8), appetite ratings were suppressed in 7 out of 24 protein arms); - Intervention varied and duration/dosing were not specified)
Jager, 2017^1^; Narrative review | An updated position stand addressing the most important dietary protein categories that affect physically active individuals across domains such as exercise performance, body composition, protein timing, recommended intakes, protein sources and quality, and the preparation methods of various proteins. | Adults, 19-59 y | - No harmful effects at ~3.4–4.4 g/kg/day (duration NR); - No harmful effects at 4.4 g/kg/day over 8 weeks in healthy resistance trained individuals; - No changes in any assessed blood parameters at 3.4 g/kg/day over 8 weeks while following a prescribed resistance training program; - No clinical side effects or body composition changes at >3.0 g/kg/day over 8 weeks. | N/A
Van Elswyk, 2018^4^; Systematic review | To examine published literature investigating the relation of protein intake and indicators of kidney function in healthy adults, with the purpose of understanding if levels of intake above the currently established US RDA of 0.8 g/kg body weight, but within the AMDR, are consistent with normal kidney health and function | Adults, 19-59 y; Older adults, 60+ y | - Evidence reported suggests that protein intake above the US RDA has no adverse effect on blood pressure.; - In studies with protein intake of up to 1.8–2.5 g/kg daily, no pattern of abnormality among blood variables, suggestive of adverse effects of increased protein intake, was observed.; - One exception was in a study of 5 young men participating in a 12-week crossover study comparing “low” (0.8 g/kg), “moderate” (1.8 g/kg), and “high” (3.6 g/kg) protein intake. In this study, protein intake of 3.6 g/kg significantly increased blood urea nitrogen concentrations beyond the UL of the normal range.; - A one week crossover study with “high-protein" diet in healthy young men induces significant changes in the GFR, the filtration fraction, albuminuria, serum uric acid, and urinary pH values, whereas other indicators of renal function remained unchanged.; - The clinical significance of these findings is unclear and all studies in this review had protein intake of under 35% total energy intake. | N/A
Vasconcelos, 2021^5^; Systematic Review | To find documents dealing with harmful and/or adverse and/or deleterious effects of whey protein supplementation on animals and/or humans (only human studies were extracted) | Adults, 19-59 y; Older adults, 60+ y | N/A | - Change in biomarkers (27 g/d of whey protein alone for 3 days); - Exacerbation of acne lesions (dose not specified, high protein intake for 60 days)
Wolfe, 2017^2^; Narrative Review | The discussion in this review describes limitations to the derivation and practical application of the RDA compared with the use of the AMDR to help maximize health benefits associated with higher protein intake by using flexible calories inherent in different dietary patterns. | Adults, 19-59 y; Older adults, 60+ y | - To the knowledge of the review authors, there has never been a study in which the RDA for protein intake was compared with a higher level of protein intake, and the RDA was found to be superior in terms of any endpoint; - In contrast to the scenario of increasing either the fat or carbohydrate portion of the diet to satisfy the total requirement for energy intake, consumption of dietary protein in excess of the RDA but within the AMDR guidelines is not known to cause adverse responses. There have been no reported adverse effects of protein intake above the RDA | N/A
Wu, 2016^3^; Narrative review | To highlight historic studies of dietary protein intake by humans and recent issues concerning the effects of protein nutrition on health, particularly the preservation of skeletal-muscle mass and function in adults. | NR/Unclear | N/A | - This review provided a general list of potential adverse effects of protein intake (duration of exposure not provided); - Intestinal discomfort, hyperaminoacidemia, hyperammonemia, hyperinsulinemia, dehydration, irritation, nausea, diarrhea, liver and kidney injuries, fatigue, headache, seizures, high risk of cardiovascular disease, or even death

a Abbreviations: AMDR: Acceptable Macronutrient Distribution Range; g; gram(s); GFR: glomerular filtration rate; kg: kilogram(s); N/A: not applicable or not available; NR: not reported; RDA: Recommended Dietary Allowance; UL: Tolerable Upper Limit; y: year(s)

Table 1-c Evidence examining the relationship between high amino acid intake and acute adverse health effects^a^

Author, Year and Review Type | Amino Acid(s) studied | Purpose of review | Life Stage (Population studied) | High amino acid intake without adverse effects | Adverse effects noted as a result of high amino acid intake
Borack, 2016^7^; Narrative Review | Leucine | To describe the efficacy and safety of leucine supplementation in the elderly. | Adults, 19-59 y | N/A | - Nausea/Vomiting/GI discomfort (Varying dosages, duration NR); - Change in biomarkers (Varying dosages, duration NR); - Note - although focus on review was the elderly, evidence in humans regarding acute effects was in healthy young men)
Cynober, 2016^8^; Narrative Review | Leucine; Tryptophan; Arginine | This conference workshop supplement paper proposes a no observed adverse effect level for diet-added arginine (30 g/day) and diet-added tryptophan (4.5 g/day) in young adults and an upper limit of safe intake for total dietary leucine (500 mg/kg/day) in elderly adults. | Adults, 19-59 y; Older adults, 60+ y | N/A | Change in biomarkers (dose of amino acids and duration varied)
Davani-Davari, 2019^9^; Narrative Review | Glutamine | To review the available experimental and clinical data on the renal safety of several amino acids (carnitine, arginine, glutamine) used by athletes and bodybuilders. | Adults, 19-59 y; Older adults, 60+ y | N/A | Change in biomarkers (0.5 g/kg/day over 14 days)
Durante, 2019^10^; Narrative Review | Glutamine | This review describes the metabolism and function of glutamine in cardiovascular physiology and pathology, and highlights potential therapeutic approaches targeting glutamine in cardiovascular disease. | NR/Unclear | N/A | Change in biomarkers (dose of amino acids and duration varied)
Elango, 2016^11^; Narrative Review | Leucine | To describe 2 current studies to determine the UL for leucine in young and elderly men | Adults, 19-59 y; Older adults, 60+ y | N/A | Biomarkers change (varied doses of 50, 150, 250, 500, 750, 1000, 1250 mg per kg per day/single day)
Fernstrom, 2016^12^; Narrative Review | Tryptophan | To examine pathways of tryptophan metabolism and their effects on target body functions. | Adults, 19-59 y; Older adults, 60+ y | - No effects of acute/chronic intake of tryptophan in doses of 1-15 g on GI pain/discomfort, diarrhea, or constipation; - The relatively modest increase in melatonin production and secretion that accompanies tryptophan supplementation would also be expected to be safe as a result of high oral doses of melatonin supplementation that has been shown to be safe.; - Serotonin-related effects on gut function appear to be minor or absent after tryptophan ingestion, at doses that can be quite high in relation to normal daily tryptophan ingestion in dietary protein | Nausea/vomiting/GI discomfort (at above 7.5 g tryptophan/dose, duration not reported)
Hayamizu, 2019^20^; Meta-analysis | Lysine | To evaluate the safety of oral ingestion of lysine | Adolescents, 13-18 y; Adults, 19-59 y; Older adults, 60+ y | N/A | Change in bowel habits and nausea/vomiting/GI discomfort (varied doses and durations across studies)
Hayamizu, 2020^21^; Meta-analysis | Lysine | To assess clinical safety of lysine supplementation. | Adolescents, 13-18 y; Adults, 19-59 y; Older adults, 60+ y | N/A | - Bowel habits change and nausea/vomiting/GI discomfort (dosage and duration varied); - Change in biomarkers (6 g lysine/d/14d); - Skin rash, dizziness, headache (4.8 g lysine/day/56 days)
Holecek, 2020^13^; Narrative Review | Histidine | To review histidine metabolism and the results of studies examining the benefits and therapeutic potential of histidine. | Adults, 19-59 y | N/A | - Change in biomarkers (dosing of histidine supplementation and duration NR); - Although some adverse effects appear to be reported, paper states that there are no reports of signs of toxicity or mutagenic activity in subjects treated with histidine.
Ligthart-Melis, 2020^14^; Narrative Review | Methionine | This narrative review discusses the importance and potentially harmful effects of Methionine supplementation from clinical studies performed in humans over the past 20 years. | Adults, 19-59 y; Older adults, 60+ y | No signs of intolerance or changes in body composition at lowest observed adverse effect level in healthy older adults after consuming varied doses of Met supplements; dosages were 9.2, 22.5, 46.3, and 91 mg; Met/kg/day for two weeks with 2-week washout periods between intakes (Deutz). | Change in biomarkers (Dosage and duration varied)
McNeal, 2016^15^; Narrative Review | Arginine | The purpose of this review is to summarize the current knowledge with regard to the safety of Arg, especially noting data from recent studies in animals and humans pertinent to the effects of Arg on adipose tissue and the metabolic derangements associated with adiposity. | Adults, 19-59 y; Older adults, 60+ y | - Doses of Arg range from 3-42 g/day; - In a previous review, studies included had some populations exclusively with chronic conditions, but no adverse effects were noted overall (Shao and Hathcock). There is an absence of any pattern in the adverse effects that are attributable to Arg, and therefore the literature demonstrates a substantial level of safety for supplemental Arg.; - The current review did evaluate adverse effects in other studies, but those 8 weeks or shorter had only participants with chronic conditions (T2D, eclampsia) | N/A
Oketch-Rabah, 2016^16^; Narrative Review | Tryptophan | Examines 2 amino acids that have been associated with in-market adverse events to show how quality specifications might have helped prevent the adverse clinical outcomes. | NR/Unclear | N/A | Mentioned incident in 1989 involving tryptophan and eosinophilia-myalgia syndrome
Rhim, 2019^22^; Meta-analysis | Arginine | To evaluate the potential role of arginine/citrulline alone or arginine combined with other supplements in erectile dysfunction of mild to moderate severity. | Adults, 19-59 y; Older adults, 60+ y | N/A | The adverse effects included headache, itching, and insomnia, and no severe adverse effect was observed. However, these arginine supplements were in some cases given in combination with other supplements. (1500 mg/day/17 days; 5000 mg/day/4 weeks; 5000 mg/day/6 weeks) Arginine alone had even fewer adverse effects
Roberts, 2016^17^; Narrative Review | Leucine; Lysine; Tryptophan; Arginine; Glutamine | This conference workshop supplement paper discusses the safety and regulatory process of long-term amino acid supplementation in Europe and the United States; it highlights the need for human studies as opposed to classical animal toxicological studies. | NR/Unclear | Review mentions several clinical studies that were submitted to FDA for GRAS determination showing a lack of adverse effects. | Review mentioned one article that found “adverse events” resulting from consumption of Ltryptophan contaminated with 1,1′-ethylene-bis (tryptophan) but did not discuss duration.
Smriga, 2020^18^; Narrative Review | Amino acids | In International regulation of AAs argue that controlling the standards of purity and ingredient quality are the key safety issues | NR/Unclear | While there have been adverse effects triggered by contaminated amino acid supplements, no peer-reviewed literature documents severe adverse reactions to an amino acid supplement overdose, even in subgroups suspected of frequently consuming dietary supplements | N/A
Thalacker-Mercer, 2020^19^; Narrative Review | Histidine | To examine existing research on the benefits of histidine intake, adverse effects of excess histidine, and upper tolerance level for histidine. | Adults, 19-59 y | N/A | - Appetite change, GI discomfort/nausea/vomiting, mood changes, headache, weakness, drowsiness, painful eyes, visual acuity, mental confusion, poor memory (24-64 g histidine/day for 4 wks); - Smell/taste change (65 g histidine/day for 24 days); - Change in biomarkers (varied doses 4-16 g histidine/day for 4 wks)

a Abbreviations: AA: Amino acid; Arg: Arginine; FDA: Food and Drug Administration; g: gram(s); GI: Gastrointestinal; GRAS: Generally recognized as safe; kg: kilogram(s); mg: milligram(s); N/A: not available or not applicable; NR: Not reported; T2D: Type 2 Diabetes; UL: Tolerable Upper Limit; wks: weeks; y: year(s)

The final search terms and number of search results are included in Appendix 1-a.

Standard screening and selection processes were utilized for this scan, however handsearching was completed in addition to the electronic database search. Handsearching of the citations from each included review was completed in order to verify the comprehensiveness of the literature search for this evidence scan.

The included citations for each evidence scan can be found in References for all three evidence scan chapters.

### Extract data

NESR analysts extracted data from each included review to objectively describe the body of evidence available in the last 5 years about high protein and high amino acid intake. Data extraction was completed in DistillerSR by one analyst for each review and a second analyst checked the extracted data for accuracy. The following data elements were extracted from each included review:

- Publication author and publication year
- Study design
- Purpose of review or research question answered by the review
- Population studied (life stage/age group)
- Adverse health effects discussed or outlined in the review
  ○ Dosage of high protein and/or high amino acid intake (if noted)
  ○ Duration of high protein and/or high amino acid intake (if noted)
- If study noted no adverse health effects
  ○ Dosage of high protein and/or high amino acid intake (if noted)
  ○ Duration of high protein and/or high amino acid intake (if noted)

No effect estimates or measures of statistical validity were extracted from the included reviews and no quality assessments were completed.

### Describe the evidence

NESR analysts summarized the volume and characteristics of included studies to inform the following two questions:

1. What is the relationship between high dietary protein intake and acute adverse health effects?
2. What is the relationship between high amino acid intake and acute adverse health effects?

The extracted data were summarized in written form, as well as presented visually in a table. The extracted information helped analysts and the Working Group understand the following:

- The volume and characteristics of research examining the levels of protein intake (total protein and amino acids) at which acute adverse health outcomes do or do not occur
- Which acute adverse health outcomes occur as a result of high protein or amino acid intake and how they are defined
- How ‘high protein intake’ and ‘high/excess amino acid intake’ are defined in the literature

### Considerations for future DRI work

Considerations for future SRs completed to inform the DRI process across acute adverse health effects were included in this evidence scan.

## Results

### Literature search and screening results

The literature search yielded 2,375 search results after the removal of duplicates (see Figure 2). Dual-screening resulted in the exclusion of 2,240 titles, 44 abstracts, and 70 full-text articles. Reasons for full-text exclusion are in Appendix 1-b. One additional review was identified from the manual search. The body of evidence included 22 reviews:

- 6 reviews provided evidence on total dietary protein
- 16 reviews provided evidence on amino acids

Figure 2-a Analytic framework for protein intake and chronic disease risk

Analytic framework figure The analytic framework visually represents the overall scope of the evidence scan question and depicts the contributing elements that were considered. The intervention or exposure of interest was total protein intake from foods, beverages, and dietary supplements. The comparator was consumption of different levels of total protein intake or no comparator. The outcomes were chronic disease outcomes, including: bone outcomes, sarcopenia, renal outcomes, risk of cardiovascular disease, risk of diabetes, growth/size/body composition, neurocognitive development, dementia/cognitive decline, and all-cause mortality (ACM). The population included individuals from birth to older adults who are healthy and/or at risk for chronic disease.

Figure 2-b Literature search and screen flowchart for total dietary protein intake and chronic disease risk

Literature search and screen flowchart The literature search in PubMed retrieved 3,850 records after removing duplicates. Dual-screening resulted in the exclusion of 3,397 titles, 270 abstracts, and 138 full-text articles. The body of evidence included 45 reviews and meta-analyses including: 3 reviews on ACM, 7 reviews on bone health, 10 reviews on CVD risk, 2 reviews on dementia/cognitive decline (adults), 6 reviews on diabetes risk, 17 reviews on growth, size, and body composition, 0 reviews on neurocognitive development (children), 2 reviews on renal health, and 5 reviews on sarcopenia.

Figure 2-c Literature search and screen flowchart for protein intake and sleep duration

Literature search and screen flowchart The literature search in PubMed retrieved 74 records after removing duplicates. 64 titles, 3 abstracts, and 7 full texts were excluded. 0 articles were included in the systematic review.

Figure 2-d Literature search and screen flowchart for protein intake and appetite/satiety

Literature search and screen flowchart The literature search in PubMed retrieved 87 records after removing duplicates. 41 titles, 28 abstracts, and 14 full-texts were excluded. 4 articles were included in the systematic review.

### Description of the evidence

This evidence scan included 22 reviews.

- Six reviews included some information regarding high dietary protein intake and acute adverse health effects (three narrative reviews,^1–3^ two SRs,^4,5^ and one SR with MA^6^).
- Sixteen reviews included some information regarding high dietary amino acid intake and acute adverse health effects (13 narrative reviews^7–19^ and 3 SRs with MAs^20–22^).

#### Population characteristics

##### Total Protein Reviews

The populations studied for adverse effects in all included reviews were adults, aside from one review where age was not reported.^3^ Three of the six protein reviews included studies with adult and older adult participants,^2,4,5^ one focused on adults,^1^ and one focused on older adults.^6^

Table 2 shows the full extraction table with population, intervention/exposure, and outcome data of the total protein reviews.

Table 2-a Inclusion and exclusion criteria for protein intake and chronic disease risk

Category | Inclusion Criteria | Exclusion Criteria
Study design | - Systematic reviews; - Meta-analyses; - Scoping reviews; - Umbrella reviews | - Narrative reviews; - Systematic reviews or meta-analyses that exclusively include cross-sectional and/or uncontrolled studies; - All other study designs
Intervention/exposure | - Total dietary protein intake from food, beverages, and dietary supplements | - Studies that do not specify the amount of protein intake (e.g., studies that only report type of protein or source of protein); - Studies that assess %AMDR, but do not describe the entire macronutrient distribution of the diet (i.e., studies that only examine a single macronutrient in relation to outcomes); - Studies that only assess protein intake via infusions (rather than the GI tract); - Studies that examine food products or dietary supplements not widely available to U.S. consumers; - Multi-component interventions that do not isolate the effect or association of protein (including protein and exercise combinations)
Comparator | - Consumption of different levels of total dietary protein intake; - No comparator | - Co-exposures (i.e., same protein intake level or source, but varying supplementation or physical activity)
Chronic Disease Risk Outcomes | - Bone outcomes:; ○ Osteoporosis; ○ Osteopenia; ○ Fracture; ○ Bone mass including bone mineral density, bone mineral content; - Sarcopenia; - Renal outcomes:; ○ Incidence of kidney stones or ureteral stones; ○ Incidence of chronic kidney disease, renal insufficiency; - Incidence of cardiovascular disease; ○ Blood pressure; ○ Hypertension; - Diabetes; ○ Incidence of type 2 diabetes; ○ Incidence of gestational diabetes; ○ HbA1C, glucose tolerance (not post-prandial measures); - Growth, size, and body composition; ○ Weight, weight-for-age, weight-for-gestational age; ○ Length or height, length/stature-for-age; ○ BMI, BMI z-score, weight-for-length; ○ Body circumferences (e.g., head, arm, waist, thigh, neck); ○ Body composition and distribution (e.g., % fat mass, fat-free mass, skinfold thickness, DEXA, BEI, MRI); ○ Gestational weight change, postpartum weight change; ○ Incidence and prevalence of:; ▪ Underweight, failure to thrive, stunting, and wasting; ▪ Healthy weight; ▪ Rapid infant weight gain; ▪ Infant macrosomia; ▪ Overweight; ▪ Obesity; - Developmental milestones, including neurocognitive development (i.e., examined via milestone achievement and/or scales/indices) in children; - Dementia/cognitive decline in adults; - All-cause mortality; - Additional factors considered; - Appetite and satiety; - Sleep duration | - Incidence of type 1 diabetes, prediabetes, insulin levels, post-prandial assessments
Publication date | - Review Papers; ○ 2016 to December 2021; - Primary Research (only if no relevant review papers are identified); ○ 2002 to December 2021 | - Review Papers; ○ Prior to 2016; - Primary Research; ○ Prior to 2002
Publication status | - Articles published in peer-reviewed journals | - Articles that have not been peer reviewed and are not published in peer-reviewed journals (e.g., unpublished data, manuscripts, pre-prints, reports, abstracts, conference proceedings)
Language | - Articles published in English | - Articles published in languages other than English
Country^a^ | - Studies conducted in high or very high human development countries | - Studies conducted in low or medium human development countries
Study participants | - Human participants; ○ Males; ○ Females | - Non-human participants (e.g., animal studies, in-vitro models)
Age of study participants | - Age at intervention or exposure:; ○ Infants, children, and adolescents (0-18 years); ○ Adults (19-64 years); ○ Older adults (65 years and older) | N/A
Health status of study participants | - Studies that enroll participants who are healthy and/or at risk for chronic disease, including those with obesity and/or sarcopenia; - Studies that enroll some participants diagnosed with a disease or hospitalized or in a long-term care facility with an illness or injury; - Studies that enroll some participants diagnosed with a disease or with the health outcome of interest; - Studies that exclusively recruit athletes and/or highly active individuals | - Studies that exclusively enroll participants diagnosed with a disease or hospitalized or in a long-term care facility with an illness or injury (for this criterion, studies that exclusively enroll participants with obesity will not be excluded); - Studies that aim to treat participants who have already been diagnosed with theoutcome of interest (except weight loss interventions in overweight or obese subjects and studies in subjects with sarcopenia); - Studies that exclusively enroll undernourished participants; - Studies that exclusively enroll participants with a baseline diet deficient in protein; - Studies that exclusively enroll pre-term infants.; - Studies that exclusively enroll post-bariatric surgery subjects

a The Human Development classification was based on the Human Development Index (HDI) ranking from the year the study intervention occurred or data were collected. If the study did not report the year in which the intervention occurred or data were collected, the HDI classification for the year of publication was applied. HDI values are available from 1980, and then from 1990 to present. If a study was conducted prior to 1990, the HDI classification from 1990 was applied. When a country was not included in the HDI ranking, the current country classification from the World Bank is used instead.

Table 2-b Evidence examining the relatonship between protein intake and all-cause mortality^a^

Author, Year; Included Relevant Studies; and Review Date Range | Purpose of the review | Populations and/or Life-Stages | Study duration; Intervention/Exposure and comparator | Outcomes Examined and Brief Results (Directly from source article)
Chen, 2020^23^; Systematic Review and Meta-analysis; 8 PCS; Date range: Through 2019 | To further clarify the current evidence from previous studies, researchers systematically reviewed and metaanalyzed their findings with those from previous prospective studies to evaluate the association of dietary protein intake with mortality. | Adults, 19-59 y; Adults, 60+ y | Duration:; Trials: NA; Observational: 9.4 y to 27 y; Intervention/Exposure:; Higher vs Lower habitual intake (Categories) | All-cause Mortality:; Total Protein: Positive (Higher total protein intake was associated with higher risk of all-cause mortality); Animal Protein: Positive; Plant Protein: Inverse
Naghshi, 2020^24^; Systematic Review and Meta-analysis; 29 PCS; Date range: Through 2019 | To examine and quantify the potential dose-response relation between intake of total, animal, and plant protein and the risk of mortality from all causes, cardiovascular disease, and cancer. | Adults, 19-59 y | Duration:; Trials: NA; Observational: 3.4 y to 22 y; Intervention/Exposure:; Higher vs Lower habitual intake (Categories); Habitual intake (Continuous) | All-cause Mortality:; Total Protein: Inverse (lower risk associated with higher total protein intake); Plant Protein: Inverse; Animal protein: Null
Qi, 2020^25^; Systematic Review and Meta-analysis; 10 PCS; Date range: Through 2020 | To summarize the evidence of the relationships between dietary protein intake and risk of all-cause, cardiovascular disease, and cancer mortality. | Adults, 19-59 y; Adults, 60+ y | Duration:; Trials: NA; Observational: 4.8 y to 27 y; Intervention/Exposure:; Habitual intake (Continuous) | All-cause Mortality:; Total Protein: Null; Animal protein: Null; Plant protein: Inverse

a Abbreviations: NA, not applicable; PCS, prospective cohort study; y, years

Table 2-c Evidence examining the relatonship between protein intake and bone health^a^

Author, Year; Included Relevant Studies; and Review Date Range | Purpose of the review | Populations and/or Life-Stages | Study duration; Intervention/Exposure | Outcomes Examined and Brief Results (Directly from source article)
Curneen, 2018 ^26^; Systematic Review; 20 studies (study designs not reported consistently); Date range: Through 2018 | To review the evidence of a relationship between BMD and protein quantity in animal subjects and individuals >50 years of age. To assess the association between the concentration of protein consumed in the diet and bone fracture (hip fracture). | Adults, 60+ y | Duration:; Trials: Unclear; Observational: Unclear; Intervention/Exposure: Higher vs Lower habitual intake (Categories); Habitual intake (Continuous); Interventions that alter protein intake | Fracture:; Total fracture and hip fracture: primarily inverse (decreased fracture) but some null; Bone Mass:; Femoral neck BMD, lumbar spine BMD, total hip BMD, total body BmD: primarily positive but some null
Darling, 2019 ^27^; Systematic Review and Meta-analysis; 13 RCT, 22 PCS, 62 CS, and 13 CC (some overlap in studies across designs); Date range: 1976 to 2016 | To perform a systematic review and meta-analysis of evidence published the past 40 years on dietary protein intake and all indices of bone health across the life-course. | Children, 2-12 y; Adolescents, 13-18 y; Adults, 19-59 y; Adults, 60+ y | Duration:; Trials: 4 d to 9 mo; Observational: 0 y (CS) to 22 y; Intervention/Exposure: Higher vs Lower habitual intake (Categories); Habitual intake (Continuous); Interventions that alter protein intake | Osteoporosis: Mixed; Fracture:; Osteoporotic Fractures: Null (for total, animal and plant protein); Low trauma Fractures: Null; Bone Mass:; Lumbar Spine BMD: Null; Femoral Neck BMD: Null
Groenendijk, 2019 ^28^; Systematic Review and Meta-analysis; 1 RCT and 12 PCS; Date Range: Through 2018 | To assess the impact of dietary protein intake above the RDA (0.8 g/kg/d) on BMD/BMC, bone turnover markers, and fracture risk in older adults compared to a lower dietary protein intake. | Adults, 60+ y | Duration:; Trials: 2 y; Observational: 1 y to 32 y; Intervention/Exposure: Higher vs Lower habitual intake (Categories); Habitual intake (Continuous); Interventions that alter protein intake | Fracture:; Hip fractures: Inverse (decreased fracture); Total fractures: Null; Spine fractures: Null; Bone Mass:; Total hip BMD: Primarily positive but mixed; Femoral neck BMD: Primarily positive but mixed; Total body BMD: Mixed; Lumbar spine BMD: Mixed; Total body BMC: Mixed
Shams-White, 2017 ^29^; Systematic Review and Meta-analysis; 11 RCT and 18 PCS; Date range: Through 2016 | To clarify the impact of dietary protein and dietary protein and calcium with or without vitamin D on bone health outcomes in healthy adults. | Adults, 19-59 y; Adults, 60+ y | Duration:; Trials: 6 mo to 24 mo; Observational: 1 y to 17 y; Intervention/Exposure: Habitual intake (continuous and categorical); Interventions altering protein intake | Fracture:; Hip fractures: Null; Spine, forearm, and overall: Insufficient or inconsistent data; Bone Mass:; Lumbar spine BMD: Positive (small effect); Total hip BMD, femoral neck BMD: Null; Total body BMD, total body BMC: Inconclusive data
Tsagari, 2020 ^30^; Systematic Review; 11 RCT and 7 PCS; Date range: Through 2019 | To clarify the impact of dietary protein on bone health outcomes (BMD, bone biomarkers, fractures) in healthy adults. | Adults, 19-59 y; Adults, 60+ y | Duration:; Trials: 12 mo to 24 mo; Observational: 2.5 y to 5 y; Intervention/Exposure: Higher vs Lower habitual intake (Categories); Habitual intake (Continuous); Interventions that alter protein intake | Bone Mass:; Lumbar spine BMD: Trends towards positive (RCTs); Femoral neck BmD: Null; Total hip BMD: Null; Total body BMD: Null, but trends towards positive (PCS)
Wallace, 2017 ^31^; Systematic Review and Meta-analysis; 5 RCT and 15 PCS; Date range: Through 2017 | To assess whether there is an independent relationship between dietary protein intake above the current RDA (0.8 g/kg/d) and fractures, BMD/BMC, or markers of bone turnover. | Adults, 19-59 y; Adults, 60+ y | Duration:; Trials: 0.6 wk to 104 wk; Observational: 1 y to 32 y; Intervention/Exposure: Higher vs Lower habitual intake (Categories); Habitual intake (Continuous); Interventions that alter protein intake | Fracture:; Hip fractures: Primarily inverse (higher protein, fewer fractures); Total fractures: Mixed; Spine fractures: Null; Forearm fractures: Inverse (only 1 study); Bone Mass:; BMC, Cortical bone BMD, trabecular bone BMD, femoral neck BMD, hip/total hip BMD, intertrochanter/trochanter BmD, spine/lumbar spine BMD, proximal femur BMD, radius and radial shaft/midshaft BMD, total body BMD, Ward’s area BMD, tibia/total tibia BmD, total body BMD: Tendency toward positive relationships in PCS, mixed results in RCTs
Wright, 2019 ^32^; Systematic Review and Meta-analysis; 27 RCT, 6 ‘longitudinal intervention’ studies, 1 CC; Date range: Through 2019 | To conduct a systematic review and meta-analysis assessing the effect of dietary protein quantity (high protein vs normal protein) on energy-restriction-induced changes in BMD and BMC in healthy adults. | Adults, 19-59 y; Adults, 60+ y; 100% of participants were overweight or obese | Duration:; Trials: 3 mo to 2 y; Observational: NA; Intervention/Exposure: Interventions that alter protein intake; Interventions designed to induce weight loss; Multi-component interventions (isolates effect of total protein) | Bone Mass:; Total BMD and Lumbar spine BMD: Tendency toward positive relationship but clinical significance questionable Femoral neck BMD, Hip BMD: results NR Total BMC, Lumbar spine BMC, Femoral neck BMC, Hip BMC: Mixed with tendency toward null

a Abbreviations: BMC, bone mineral content; BMD, bone mineral density; CC, case-control study; CS, cross-sectional study; d, days; g, grams; kg, kilograms; mo, months; NA, not applicable; NR, not reported; PCS, prospective cohort study; RCT, randomized controlled trial; RDA, recommended daily allowance; wk, weeks; y, years

Table 2-d Evidence examining the relatonship between protein intake and cardiovascular disease risk^a^

Author, Year; Included Relevant Studies; and Review Date Range | Purpose of the review | Populations and/or Study Life-Stages | Study duration; Intervention/Exposure and comparator | Outcomes Examined and Brief Results (Directly from source article)
Chen, 2020 ^23^; Systematic Review and meta-analysis; 5 PCS (3 additional studies that looked at plant or animal protein only); Date Range: Through Aug 27, 2019 | To examine associations of dietary protein from different sources with all-cause and cause-specific mortality. | Adults, 19-59 y; Adults, 60+ y | Duration:; Observational: median ~13 y; Intervention/Exposure:; Higher vs Lower habitual intake (Categories) | CVD mortality, and non-stroke CVD mortality: Total protein and animal protein intake associated with higher risk; null association with plant protein; Stroke mortality: Null association with protein intake or animal protein intake (found as part of primary research done for systematic review, not the MA)
Dinu, 2020 ^33^; Umbrella Review; 6 meta-analyses of RCTs; Date range: Through April 2019 | To describe and critically evaluate the impact of different diets and/or dietary patterns on human health, by considering their effects on anthropometric parameters and cardiometabolic risk factors. | Adults, 19-59 y | Duration: 0.8 mo to 52 mo; Intervention/Exposure:; Interventions that alter protein intake | Blood pressure: Weak or no evidence with high protein diet
Mousavi, 2020 ^38^; Systematic Review; 13 PCS (8 on CHD; 5 on HTN); Date Range: Through April 2020 | To summarize previous investigations on the association between total, animal and plant proteins intake and the risk of coronary heart disease and hypertension in adults. | Adults, 19-59 y; Adults, 60+ y | Duration:; Observational: 2.3 y to 22 y; Intervention/Exposure:; Higher vs Lower habitual intake (Categories); Habitual intake (Continuous) | CHD: No significant relationship with protein intake; HTN: No significant relationship with protein intake
Naghshi, 2020 ^24^; Systematic Review and Meta-analysis; 14 PCS (10 in meta-analysis); Date range: Through Dec 2019 | To examine and quantify the potential dose-response relation between intake of total, animal, and plant protein and the risk of mortality from all causes, cardiovascular disease, and cancer. | Adults, 19-59 y; Adults, 60+ y | Duration: Observational: 5 y to 32 y; Intervention/Exposure:; Higher vs Lower habitual intake (Categories); Habitual intake (Continuous) | CVD mortality: Null association with total protein and animal protein; lower risk associated with plant protein
Qi, 2020 ^25^; Systematic Review and Meta-analysis; 8 PCS; Date range: Through Feb 2020 | To assess the relationships between total, animal, and plant protein intakes and risk of all-cause, CVD, and cancer mortality in the general population. | Adults, 19-59 y; Adults, 60+ y | Duration:; Observational: 4.8 y to 27 y; Intervention/Exposure:; Higher vs Lower habitual intake (Categories); Habitual intake (Continuous) | CVD mortality: Null association with total protein; animal protein associated with higher risk; plant protein associated with lower risk
Schwingshackl, 2019 ^34^; Systematic Review and Meta-analysis; 12 high-protein RCTs; Date range: Through June 2017 | To establish a clinically meaningful hierarchy of different dietary approaches on blood pressure in hypertensive and pre-hypertensive patients in a systematic review through the synthesis of available evidence from randomized trials. | Adults, 19-59 y; Adults, 60+ y | Duration:; Trials: 3 mo to 15 mo; Intervention/Exposure:; Interventions that alter protein intake | Blood pressure: High protein diets were more effective in reducing SBP and DBP compared to control diets; the effects compared to low fat diets were not statistically significant
Sukhato, 2020 ^39^; Umbrella Review; 6 MAs of RCTs (high protein diet); Date Range: Through June 2020 | To provide an update on the available evidence for the efficacy of different dietary patterns on blood pressure lowering. | Adults, 19-59 y; Adults, 60+ y | Duration:; Trials: NR; Intervention/Exposure:; Habitual intake (Continuous) | Blood Pressure: Small beneficial effect of high protein diets on lowering blood pressure.; DBP: Small beneficial effect of high protein diets lowering DBP.; SBP: SBP in the high-protein diet groups was significantly lower than SBP in the low-protein diet groups
Van Elswyk, 2018 ^35^; Systematic Review; 9 RCT; Date range: Through 2017 | To examine published literature investigating the relation of protein intake and indicators of kidney function in healthy adults with the purpose of understanding whether levels of intake above the currently established US RDA of 0.8 g/kg body weight, but within the AMDR, are consistent with normal kidney health and function. | Adults, 19-59 y; Adults, 60+ y | Duration:; Trials: NR; Intervention/Exposure:; Interventions that alter protein intake | Blood pressure: Null association with total protein intake
van Elten, 2019 ^37^; Systematic Review; 8 PCS; Date Range: Through June 30, 2017 | To synthesize evidence examining the association of maternal diet and physical activity before and during pregnancy with offspring’s blood pressure and vascular health. | Pregnancy | Duration:; Trials: NR; Observational: NR; Intervention/Exposure:; Higher vs Lower habitual intake (Categories); Habitual intake (Continuous); Interventions that alter protein intake | Offspring blood pressure: Predominately null association
Zhang, 2016 ^36^; Systematic Review and meta-analysis; 12 PCS; Date Range: Through June 27, 2016 | To quantitatively estimate dietary protein intake and risk of stroke, using the most recent data. | Adults, 19-59 y; Adults, 60+ y | Duration:; Observational: 5 y to 26 y; Intervention/Exposure:; Higher vs Lower habitual intake (Categories); Habitual intake (Continuous) | Stroke risk: Null association between protein intake and stroke risk (both total risk and individual stroke types)

a Abbreviations: AMDR, acceptable macronutrient distribution range; CHD, coronary heart disease; CVD, cardiovascular disease; DBP, diastolic blood pressure; g, grams; HTN, hypertension; kg, kilograms; Ma, meta-analysis; NR, not reported; PCS, prospective cohort study; RCT, randomized controlled trial; RDA, recommended daily allowance; SBP, systolic blood pressure; US, United States; y, years;

Table 2-e Evidence examining the relatonship between protein intake and dementia/cognitive decline (adults)^a^

Author, Year; Included Relevant Studies; and Review Date Range | Purpose of the review | Populations and/or Life-Stages | Study duration; Intervention/Exposure | Outcomes Examined and Brief Results (Directly from source article)
Coelho-Júnior, 2021 ^40^; Systematic Review; 8 CS, 1 PCS; Date range: 1983 to 2020 | To investigate the available evidence on the association between protein intake and cognitive function in older adults | Adults, 60+ y | Trials: NA; Observational: 0 mo (CS) to 8.5 mo; Intervention/Exposure: Habitual intake (Continuous) | Dementia/Cognitive Decline (adults): Global cognitive function, immediate and delayed learning ability, nonverbal learning, verbal and nonverbal memory, short-term memory, working memory, verbal fluency, processing speed, problem-solving ability, sustained attention, abstract reasoning: Predominantly null
Muth, 2021 ^41^; Systematic Review; 2 RCT, 5 CS; Date range: ~1998 to 2018 | To synthesize previous research addressing the effects of macronutrients from acute, intervention, and long-term whole meal studies on cognitive functioning in healthy young and old adults. | Adults, 19-59 y; Adults, 60+ y | Duration:; Trials: 3 wk; Observational: All CS; Intervention/Exposure: Higher vs Lower habitual intake (Categories); Habitual intake (Continuous); Interventions that alter protein intake | Dementia/Cognitive Decline (adults): Inhibition control, reaction time, fluid intelligence, working memory, memory, global cognition, digit subtraction, risk of mild cognitive impairment: Mixed but some positive associations

a Abbreviations: CS, cross-sectional study; mo, months; NA, not applicable; PCS, prospective cohort study; RCT, randomized controlled trial; wk, weeks; y, years

Table 2-f Evidence examining the relatonship between protein intake and diabetes risk^a^

Author, Year; Included Relevant Studies; and Review Date Range | Purpose of the review | Populations and/or Life-Stages | Study duration; Intervention/Exposure and Comparator | Outcomes Examined and Brief Results (Directly from source article)
Dinu, 2020 ^33^; Umbrella review of meta-analyses; 6 MA; Date range: Through 2019 | The aim was to describe and critically evaluate the impact of different diets and/or dietary patterns on human health, by considering their effects on anthropometric parameters and cardiometabolic risk factors. | Adults, 19-59 y; Adults, 60+ y; 3 of 6 included meta-analyses examined participants with T2D | Duration:; Trials: 1 mo to 52 mo; Observational: NA; Intervention/Exposure: Interventions that alter protein intake | HbA1c: Weak or null
Fan, 2019 ^42^; Systematic Review and Meta-analysis; 6 PCS; Date range: Through 2019 | To explore the relations between dietary protein consumption and the risk of T2D | Adults, 19-59 y; Adults, 60+ y | Duration:; Trials: NA; Observational: 7.2 y to 20 y; Intervention/Exposure: Higher vs Lower habitual intake (Categories); Habitual intake (Continuous) | Type 2 Diabetes:; Total Protein: Positive; Animal Protein: Positive; Plant Protein: Inverse; Meta-analyses showed the same results.
Shang, 2016 ^43^; Systematic Review and Meta-analysis; 9 PCS; Date range: Through 2016 | Prospectively examined the relations of total, animal and plant protein intakes with incidence of T2D. | Adults, 19-59 y; Adults, 60+ y | Duration:; Trials: NA; Observational: 5 y- 24 y; Intervention/Exposure: Higher vs Lower habitual intake (Categories); Habitual intake (Continuous) | Type 2 Diabetes:; Total Protein: Positive; Animal Protein: Positive; Plant Protein: Null
Tian, 2017 ^44^; Systematic Review and Meta-analysis; 9 PCS; Date range: Through 2017 | To clarify the association of protein consumption with risk of T2DM. | Adults, 19-59 y; Adults, 60+ y | Duration:; Trials: NA; Observational: 5 y to 24 y; Intervention/Exposure: Higher vs Lower habitual intake (Categories) | Type 2 Diabetes:; Total Protein: Positive (high protein intake, high risk of T2D); Animal Protein: Positive; Plant Protein: Mixed (Null in males, negative in females)
Ye, 2019 ^45^; Systematic Review and Meta-analysis; 8 PCS; Date range: Until 2018 | To evaluate the association between dietary proteins and the risk of T2DM. | Adults, 19-59 y; Adults, 60+ y | Duration:; Trials: NA; Observational: 5 y to 24 y; Intervention/Exposure: Higher vs Lower habitual intake (Categories); Habitual intake (Continuous) | Type 2 Diabetes:; High total protein: Positive; Moderate total protein: Null; High animal protein: Positive; Moderate animal protein: Null; High plant protein: Null; Moderate plant protein: Inverse
Zhao, 2019 ^46^; Systematic Review and Meta-analysis; 8 PCS; Date range: Through 2018 | To quantitatively assess whether dietary total, animal, and plant protein would be associated with type 2 diabetes risk. | Adults, 19-59 y; Adults, 60+ y | Duration:; Trials: NA; Observational: 5 y to 24 y; Intervention/Exposure: Higher vs Lower habitual intake (Categories); Habitual intake (Continuous) | Type 2 Diabetes:; Total protein: Positive; Animal protein: Positive; Plant Protein: U-shaped curve indicating protective effect

a Abbreviations: HbA1c, hemoglobin A1c; MA, meta-analysis; mo, months; NA, not applicable; PCS, prospective cohort study; T2D, type 2 diabetes; y, years

Table 2-g Evidence examining the relatonship between protein intake and growth, size, and body composition^a^

Author, Year; Included Relevant Studies; and Review Date Range | Purpose of the review | Populations and/or Life-Stages | Study duration; Intervention/Exposure | Outcomes Examined and Brief Results (Directly from source article)
Bergia, 2018 ^47^; Systematic Review and Meta-analysis; 8 RCT; Date range: Through 2017 | To assess effects of whey protein supplementation with or without energy restriction and resistance training on changes in body mass, lean mass, and fat mass in women. | Adults, 19-59 y; Adults, 60+ y | Duration:; Trials: 6 wk to 12 mo; Observational: NA; Intervention/Exposure: Interventions that alter protein intake; Interventions with supplements; Interventions designed to induce weight loss | Body composition:; Lean mass: Positive; Fat mass: Null; Body mass: Null
Dinu, 2020 ^33^; Umbrella review of meta-analyses; 7 meta-analyses (7 on Weight; 2 on BMI); Date range: Through 2019 | The aim was to describe and critically evaluate the impact of different diets and/or dietary patterns on human health, by considering their effects on anthropometric parameters and cardiometabolic risk factors. | Adults, 19-59 y; Adults, 60+ y (NR) | Duration:; Trials: 1 mo to 52 mo; Observational: NA; Intervention/Exposure: Interventions that alter protein intake | Size:; Weight: Weak or null; BMI: Weak or null
Ferré, 2021 ^48^; Systematic Review; 8 PCS and 1 RCT; Date range: Through 2020 | To evaluate the effects of protein intake during the second year of life on weight and fat mass gain and the subsequent risk of obesity development later in childhood. | Infants, <12 mo; Toddlers, 12-23 mo | Duration:; Trials: 1 y; Observational: 1 mo to 11 y; Intervention/Exposure: Interventions that alter protein intake; Higher vs Lower habitual intake (Categories); Habitual intake (Continuous) | Growth:; Risk of overweight or obesity: Null; Rapid weight gain: Mixed; Size:; BMI z-score: Positive and null; Body composition:; Fat mass: Positive
Hansen, 2021 ^49^; Systematic Review and Meta-analysis; 37 RCT; Date range: Through 2021 | To summarize the current evidence investigating if dietary interventions rich in protein lead to improved body weight management in adults with excessive body weight. | Adults, 19-59 y | Duration:; Trials: 8 wk to 104 wk; Observational: NA; Intervention/Exposure: Interventions that alter protein intake; Interventions designed to induce weight loss | Size:; Weight: Inverse; BMI: Inverse; Waist circumference: Null; Body composition:; Fat mass: Inverse
Hsu, 2019 ^50^; Systematic Review and Meta-analysis; 2 RCT; Date range: Through 2019 | To investigate the effects of exercise or nutrition on body composition, metabolic health, and physical performance in individuals with sarcopenic obesity and (2) to determine if exercise combined with nutrition provides additional benefits for body composition, metabolic health, and physical performance, compared to exercise or nutrition alone, in individuals with sarcopenic obesity. | Adults, 19-59 y; Adults, 60+ y | Duration:; Trials: 12 wk and 16 wk; Intervention/Exposure: Interventions that alter protein intake; Interventions designed to induce weight loss | Body composition:; Fat mass: Inverse; Muscle mass: Null
Hudson, 2020 ^51^; Systematic Review and Meta-analysis; 18 RCT (15 without resistance training); Date range: Through 2018 | To conduct a systematic review and meta-analysis to assess the effects of protein intakes greater than the RDA, compared with at the RDA, on changes in whole-body lean mass. | Adults, 19-59 y; Adults, 60+ y | Duration:; Trials: 8 wk to 52 wk; Observational: NA; Intervention/Exposure: Interventions that alter protein intake; Interventions designed to induce weight loss | Body composition:; Lean mass: Null
Kim, 2016 ^52^; Systematic Review and Meta-analysis; 20 RCT; Date range: Through 2015 | To assess the effects of protein intake on energy restriction-induced changes in body mass, lean mass, and fat mass in adults older than 50 years. | Adults, 19-59 y; Adults, 60+ y | Duration:; Trials: 8 wk to 104 wk; Observational: NA; Intervention/Exposure: Interventions that alter protein intake; Interventions designed to induce weight loss; Multi-component interventions (isolates effect of total protein) | Body composition:; Lean mass: Positive; Fat mass: Inverse
Lin, 2021 ^53^; Systematic Review and Meta-analysis; 11 RCT; Date range: Through 2020 | To determine the impact of protein supplementation during endurance training on aerobic capacity, body composition, and exercise performance in healthy and clinical populations. | Adults, 19-59 y; Adults, 60+ y | Duration:; Trials: 4.5 wk to 24 wk; Observational: NA; Intervention/Exposure: Interventions that alter protein intake; Interventions with supplements; Interventions designed to enhance athletic performance | Body composition:; Lean mass gain: Positive; Fat mass: Null
Patro-Gołąb, 2016 ^54^; Systematic Review; 10 RCT and 2 NRCT; Date range: Through 2014 | To investigate current evidence on the effects of infant formulas and follow-on formulas with different protein concentrations on infants ‘and children’s growth, body composition, and later risk of overweight and obesity. | Infants, <12 mo | Duration:; Trials: 3 mo to 12 mo; Observational: NA; Intervention/Exposure: Interventions that alter protein intake | Growth:; Weight gain: Null; Risk of obesity: Positive; Size:; Weight/Weight z-score: Positive at age ~6-12mo, Null at later ages; BMI/BMI z-score: Positive; Length: Null; Head circumference: Null; Body composition:; Fat mass: Null; Fat-free mass: Null
Patro-Gołąb, 2016 ^62^; Umbrella Review; 2 systematic reviews; Date range: Through 2015 | To provide a systematic review of systematic reviews on the effects of nutritional interventions or exposures in children (up to three years of age) on the subsequent risk of obesity, overweight, and adiposity. | Infants, <12 mo | Duration:; Trials: NR; Observational: NA; Intervention/Exposure: Interventions that alter protein intake (Infant formula) | Growth:; Obesity prevalence: Positive; Size:; BMI: Positive
Stokes, 2021 ^55^; Systematic Review; 8 PCS; Date range: Through 2020 | To review and appraise studies that explored the long-term associations between intakes of total protein and protein from different sources during the first 2 y of life and subsequent obesity outcomes in childhood and adolescence. | Infants, < 12 mo; Toddlers, 12-23 mo; Children, 2-12 y | Duration:; Trials: NA; Observational: 5 y to 11 y; Intervention/Exposure: Habitual intake (Continuous) | Growth:; Risk of overweight: Positive and null; Size:; BMI/BMI z-score: Positive; mixed results by protein source; Body composition:; % Body Fat: Positive; mixed results by protein source; Fat mass index: Positive; mixed results by protein source; Fat-free mass index: Null
Tagawa, 2020 ^56^; Systematic Review and Meta-analysis; 105 RCT (66 without resistance training); Date range: Through 2019 | To evaluate the dose-response relationship of the effects of protein intake on lean body mass. | Adults, 19-59 y; Adults, 60+ y | Duration:; Trials: 2 wk to 18 mo; Observational: NA; Intervention/Exposure: Interventions that alter protein intake; Interventions designed to induce weight loss | Body composition:; Lean mass: Positive
Tielemans, 2016 ^57^; Systematic Review; 19 PCS; Date range: Through 2015 | To evaluate the effects of energy intake and macronutrient intake on gestational weight gain. | Adults, 19-59 y | Duration:; Trials: NA; Observational: Through 3rd trimester; Intervention/Exposure: Habitual intake (Continuous) | Growth:; Gestational weight gain: Mixed (total and by protein source)
Valenzuela, 2019 ^58^; Systematic Review and Meta-analysis; 7 RCT; Date range: Through 2019 | To compare the effects of beef protein, whey protein, or no protein supplementation combined with exercise training on body composition and exercise performance. | Adults, 19-59 y; Adults, 60+ y | Duration:; Trials: 8 wk to 16 wk; Observational: NA; Intervention/Exposure: Interventions that alter protein intake; Interventions with supplements; Interventions designed to enhance athletic performance; Multi-component interventions (isolates effect of total protein) | Body composition:; Lean mass: Positive; Fat mass: Null; Muscle thickness: Mixed
van Baak, 2019 ^59^; Systematic Review and Meta-analysis; 3 RCT; Date range: NR (but included studies ranged from 1997-2017) | To review what is currently known about dietary strategies for weight loss maintenance, focusing on nutrient composition. | Adults, 19-59 y; Adults, 60+ y | Duration:; Trials: 26 wk and 12 mo; Intervention/Exposure: Interventions that alter protein intake; Interventions designed to induce weight loss | Growth; Weight loss maintenance: Positive
Yin, 2020 ^60^; Systematic Review and Meta-analysis; 2 RCT; Date range: Through 2019 | To describe the criteria used to identify people with sarcopenic obesity and the components of the non-pharmacological interventions used to manage it, and to evaluate the effectiveness of those interventions. | Adults, 19-59 y; Adults, 60+ y | Duration:; Trials: 3 mo and 4 mo; Observational: NA; Intervention/Exposure: Interventions that alter protein intake; Interventions designed to induce weight loss | Body composition:; Fat-free mass: Null
Zhang, 2020 ^61^; Systematic Review and Meta-analysis; 9 RCT; Date range: Through 2019 | To quantitatively estimate dietary protein intake and risk of stroke, using the most recent data. | Adults, 19-59 y | Duration:; Trials: 12 wk to 12 mo; Observational: NA; Intervention/Exposure: Interventions that alter protein intake; Interventions designed to induce weight loss | Size:; Weight: Inverse; BMI: Inverse; Waist circumference: Null; Body composition:; Fat mass: Inverse; Fat-free mass: Null

a Abbreviations: BMI, body mass index; mo, months; NA, not applicable; NR, not reported; NRCT, non-randomized controlled trial; PCS, prospective cohort study; RCT, randomized controlled trial; wk, weeks; y, years; %, percent

Table 2-h Evidence examining the relatonship between protein intake and renal health^a^

Author, Year; Relevant Included Studies; and Review Date Range | Purpose of the review | Populations and/or Life-Stages | Study duration; Intervention/Exposure | Outcomes Examined and Brief Results (Directly from source article)
Devries, 2018 ^63^; Systematic Review and Meta-analysis; 28 RCT; Date range: Through 2017 | To examine whether GFR increase to a greater extent after a high protein diet as compared with a normal or lower protein diet in individuals without CKD. | Adults, 19-59 y; Adults, 60+ y | Duration:; Trials: 4 d to 104 wk; Observational: NA; Intervention/Exposure: Interventions that alter protein intake | Renal Insufficiency:; GFR post-intervention: Positive (increased protein, increased GFR); GFR change: Null
Van Elswyk, 2018 ^35^; Systematic Review; 13 RCT, 5 CS, 2 PCS; Date range: Through 2017 | To examine published literature investigating the relation of protein intake and indicators of kidney function in healthy adults with the purpose of understanding whether levels of intake above the currently established US RDA of 0.8 g/kg body weight, but within the AMDR, are consistent with normal kidney health and function. | Adults, 19-59 y; Adults, 60+ y | Duration:; Trials: 1 d to 4 mo; Observational: 0 y (CS) to 21 y; Intervention/Exposure: Higher vs Lower habitual intake (Categories); Habitual intake (Continuous); Interventions that alter protein intake | Renal Insufficiency:; GFR and eGFR: Primarily positive but mixed; Kidney disease incidence: Null

a Abbreviations: AMDR, acceptable macronutrient distribution range; CKD, chronic kidney disease; CS, cross-sectional study; d, days; eGFR, estimated glomerular filtration rate; g, grams; GFR, glomerular filtration rate; kg, kilograms; mo, months; NA, not applicable; PCS, prospective cohort study; RCT, randomized controlled trial; RDA, recommended daily allowance; US, United States; wk, weeks; y, years

Table 2-i Evidence examining the relatonship between protein intake and sarcopenia^a^

Author, Year; Included Relevant Studies; and Review Date Range | Purpose of the review | Populations and/or Life-Stages | Study duration; Intervention/Exposure and comparator | Outcomes Examined and Brief Results (Directly from source article)
Coelho-Júnior, 2018 ^64^; Systematic Review and Meta-analysis; 4 PCS, 2 CS, 1 CC; Date range: Through 2018 | To conduct a systematic review and meta-analysis of observational studies investigating the association of relative protein intake and physical function in older adults. | Adults, 60+ y | Duration:; Trials: NA; Observational: NR; Intervention/Exposure: Higher vs Lower habitual intake (Categories) | Upper-limb muscle strength (isometric handgrip): Null for high vs low protein intake; Lower-limb muscle strength (chair-rise, knee extensor strength): Null for high vs low protein intake
Kirwan, 2021 ^67^; Systematic Review and Meta-analysis; 28 RCT Total (9 without resistance exercise); Date range: 1990 to 2021 | To complete a systematic review and meta-analysis of RCTs assessing the effect of protein supplementation or higher-protein diets, without the use of essential amino acids or supplements known to to stimulate hypertrophy, with or without concomitant resistance exercise interventions on lean body mass, appendicular lean mass, and strength in older adults. | Adults, 60+ y | Duration:; Trials: 10 wk to 104 wk; Observational: NA; Intervention/Exposure: Interventions that alter protein intake | Appendicular lean mass: Null; positive relationship when combined with exercise in frail/sarcopenic populations; Handgrip strength: Null; positive relationship when combined with exercise in frail/sarcopenic populations; Total lean body mass: Null; Knee extension strength: Null
Lin, 2021 ^53^; Systematic Review and Meta-analysis; 14 RCT and 1 NRCT; Date range: Through 2020 | To determine the impact of protein supplementation during endurance training on aerobic capacity, body composition, and exercise performance in healthy and clinical populations. | Adults, 19-59 y; Adults, 60+ y | Duration:; Trials: 4.5 wk to 24 wk; Observational: NA; Intervention/Exposure: Interventions that alter protein intake; Interventions with supplements; Interventions designed to enhance athletic performance; Multi-component interventions (isolates effect of total protein) | Lean muscle mass gain: Trended toward Positive; Muscle strength: Null
Naseeb, 2017 ^66^; Systematic Review; 2 CS, 7 RCT and 1 PCS; Date range: 2010 to 2015 | To discuss the role of protein and exercise in slowing the progression of sarcopenia. | Adults, 60+ y | Duration:; Trials: NR; Observational: NR; Intervention/Exposure: Higher vs Lower habitual intake (Categories); Habitual intake (Continuous); Interventions that alter protein intake | Muscle mass: Null; Muscular strength: Null; Sarcopenia: Only one study, results inconclusive
Yaegashi, 2021 ^65^; Systematic Review; 6 PCS and 11 CS; Date range: Through 2021 | To investigate the association of dietary protein intake with skeletal muscle mass in older adults. | Adults, 60+ y | Duration:; Trials: NA; Observational: 0 y (cross-sectional) to 6 y; Intervention/Exposure: Higher vs Lower habitual intake (Categories); Habitual intake (Continuous) | Appendicular skeletal muscle mass and whole skeletal muscle mass: 70% of studies had a positive association but the other studies contained null and inverse associations

a Abbreviations: CC, case-control; CS, cross-sectional; NA, not applicable; NR, not reported; PCS, prospective cohort study; RCT, randomized controlled trial; wk, weeks; y, years; %, percent

Table 2-j Evidence examining the relatonship between protein intake and appetite/satiety^a^

Author, Year; Relevant Included Studies; and Review Date Range | Purpose of the review | Populations and/or Life-Stages | Study duration; Intervention/Exposure | Outcomes Examined and Brief Results (Directly from source article)
Ben-Harchache, 2021 ^68^; Systematic Review and Meta-analysis; 10 RCT (8 acute and 2 longer-term); Date range: Through 2020 | To determine the effects of protein supplementation (supplements or whole foods) on appetite and energy intake in healthy older adults. | Adults, 60+ y | Duration:; Trials (acute): 0 h (immediately after protein intake) to 3 h; Trials (longer-term): 18 d to 11 wk; Observational: NA; Intervention/Exposure: Interventions that alter protein intake | Appetite and Satiety:; [underlined: Acute]; Composite appetite score, hunger, fullness, desire to eat, prospective food consumption: Mixed, some positive (higher protein, greater satiety), some null; [underlined: Longer-term]; Hunger, desire to eat: Mixed
de Carvalho, 2020 ^69^; Systematic Review; 9 RCT, 1 NRCT (all longer-term); Date range: Through 2019 | To synthesize the best available evidence on effect of high protein diets (longer than 7 days) on appetite among individuals with overweight or obesity. | Adults, 19-59 y; Adults, 60+ y; 100% of participants with overweight or obesity | Duration:; Trials (longer-term): 7 d to 34 mo; Observational: NA; Intervention/Exposure: Interventions that alter protein intake; Interventions designed to induce weight loss | Appetite and Satiety:; [underlined: Longer-term]; Hunger, desire to eat, thoughts about food, fullness, fullness after meals, satiety, prospective food consumption: Mixed, some positive (higher protein, greater satiety), some null
Kohanmoo, 2020 ^70^; Systematic Review and Meta-analysis; ~41 RCT (~28 acute and ~ 13 longer-term; individual studies not reported clearly); Date range: Through 2019 | To evaluate the effect of protein intake on appetite and gastrointestinal hormones involved in appetite regulation, and to assess if the effect of protein on these outcomes differs between acute and longer-term intake. | Adults, 19-59 y; Adults, 60+ y | Duration:; Trials (acute): ~3 h (time varied but range NR); Trials (longer-term) 3 d to 9 mo; Observational: NA; Intervention/Exposure: Interventions that alter protein intake | Appetite and Satiety:; [underlined: Acute]; Hunger, fullness, satiety, desire to eat, prospective food consumption: Positive (higher protein, greater satiety) based on meta-analysis; [underlined: Longer-term]; Hunger, fullness, satiety, desire to eat, prospective food consumption: Null based on meta-analysis
Zhao, 2017 ^71^; Systematic Review; 2 RCT (both longer-term); Date range: Through 2016 | To assess evidence exploring alterations of gut hormones during diet-induced weight changes. | Adults, 19-59 y; Adults, 60+ y; 100% of participants with overweight or obesity | Duration:; Trials (longer-term): 5 wk to 12 wk; Observational: NA; Intervention/Exposure: Interventions that alter protein intake; Interventions designed to induce weight loss | Appetite and Satiety:; [underlined: Longer-term]; Hunger, desire to eat, fullness: Positive (higher protein, greater satiety)

a Abbreviations: d, days; h, hours; mo, months; NA, not applicable; NRCT, non-randomize controlled trial; RCT, randomized controlled trial; wk, weeks; y, years, %, percent

##### Amino Acid Reviews

The populations studied for adverse effects in the amino acid reviews ranged from adolescents to older adults, aside from the four reviews in which age was not reported or unclear.^10,16–18^ Two reviews included adolescent, adult, and older adult populations,^20,21^ three reviews focused on adults only,^7,13,19^ and seven reviews focused on adults and older adults.^8,9,11,12,14,15,22^

Table 3 shows the full extraction table with population, intervention/exposure, and outcome data of the amino acid reviews.

Table 3-a Inclusion and exclusion criteria for protein intake requirements

Category | Inclusion Criteria | Exclusion Criteria
Study design | - Systematic reviews; - Meta-analyses; - Scoping reviews; - Umbrella reviews; - Randomized controlled trials; - Non-randomized controlled trials, including quasi-experimental and controlled before-and-after studies; - Prospective cohort studies; - Retrospective cohort studies; - Nested case-control studies | - International and government reports; - Narrative reviews; - Systematic reviews or meta-analyses that exclusively include cross-sectional and/or uncontrolled studies; - Uncontrolled trials; - Case-control studies; - Uncontrolled before-and-after studies
Intervention/exposure | - Total daily protein intake level; - Total daily intake of indispensable AAs (Histidine, Isoleucine, Leucine, Lysine, Methionine, Phenylalanine, Threonine, Tryptophan, Valine) | - Studies that only assess protein intake via infusions (rather than the GI tract); - Studies that examine food products or dietary supplements not widely available to U.S. consumers; - Multi-component interventions that do not isolate the effect or association of protein (including protein and exercise combinations)
Comparator | - Different total daily protein intake level; - Different total daily intake of indispensable AAs | - No comparator
Protein requirement outcome | Total protein requirement* as defined by the following indicators or criterion of adequacy:; - Nitrogen balance method; - Factorial method; - Indicator AA oxidation method; - Mean protein intake of infants fed principally human milk (0-6 mo); - Mean protein content of human milk (0-6 mo); Indispensable AA requirement* as defined by the following indicators or criterion of adequacy:; - Plasma AA response method; - Direct AA oxidation method; - 24-hour AA balance method; - Indicator AA oxidation method; - Mean AA intake of infants fed principally human milk (0-6 mo); - Mean protein content of human milk (0-6 mo) | N/A
Publication date | - 2000 to January 2022 | - Prior to 2000
Publication status | - Reports published by international and government entities; - Articles published in peer-reviewed journals | - Articles that have not been peer reviewed and are not published in peer-reviewed journals (e.g., unpublished data, manuscripts, pre-prints, reports, abstracts, conference proceedings)
Language | - Articles and reports published in English | - Articles and reports published in languages other than English
Country | - Studies conducted in any country
Study participants | - Human participants; - Subjects who are pregnant | - Non-human participants (e.g., animal studies, in-vitro models)
Age of study participants | - Age at intervention or exposure:; ○ Infants, children, and adolescents (0-18 years); ○ Adults (19-64 years); ○ Older adults (65 years and older) | N/A
Health status of study participants | - Studies that enroll participants who are healthy and/or at risk for chronic disease, including those with obesity; - Studies that enroll some participants diagnosed with a disease or hospitalized or in a long-term care facility with an illness or injury; - Studies that enroll some participants diagnosed with a disease or with the health outcome of interest; - Studies that exclusively recruit athletes and/or highly active individuals | - Studies that exclusively enroll participants diagnosed with a disease or hospitalized or in a long-term care facility with an illness or injury (for this criterion, studies that exclusively enroll participants with obesity will not be excluded); - Studies that aim to treat participants who have already been diagnosed with the outcome of interest (except weight loss interventions in overweight or obese subjects); - Studies that exclusively enroll undernourished participants; - Studies that exclusively enroll participants with a baseline diet deficient in protein; - Studies that exclusively enroll pre-term infants; - Studies that exclusively enroll post-bariatric surgery subjects

Table 3-b Protein requirements bibliography with study characteristics: total protein^a^

Citation | Protein Requirement(s) Assessed | Outcome Assessment Method(s) | Population(s) Examined | Study Design(s)
Children (2-12 y)
Elango, R, Humayun, MA, Ball, RO, Pencharz, PB. Protein requirement of healthy school-age children determined by the indicator amino acid oxidation method. American Journal of Clinical Nutrition. 2011. 94(6):1545-1552. doi:10.3945/ajcn.111.012815.^73^ | Total Protein | Indicator AA oxidation method | Children (2-12 y) | RCT
Adults (19-59 y)
Humayun, MA, Elango, R, Ball, RO, Pencharz, PB. Reevaluation of the protein requirement in young men with the indicator amino acid oxidation technique. American Journal of Clinical Nutrition. 2007. 86(4):995-1002. doi:10.1093/ajcn/86.4.995.^74^ | Total Protein | Indicator AA oxidation method,; Nitrogen balance method | Adults (19-59 y), Males Alone | RCT, Meta-Analysis (29 studies)
Tian, Y, Liu, J, Zhang, Y, Piao, J, Gou, L, Tian, Y, Li, M, Ji, Y, Yang, X. Examination of chinese habitual dietary protein requirements of chinese young female adults by an indicator amino acid method. Asia Pacific Journal of Clinical Nutrition. 2011. 20(3):390-396. https://apjcn.nhri.org.tw/server/APJCN/20/3/390.pdf. Accessed February 9, 2022.^81^ | Total Protein | Indicator AA oxidation method | Adults (19-59 y), Females Alone | RCT
Adults (19-59 y) and Older Adults (60+ y)
Campbell, WW, Johnson, CA, McCabe, GP, Carnell, NS. Dietary protein requirements of younger and older adults. American Journal of Clinical Nutrition. 2008. 88(5):1322-1329. doi:10.3945/ajcn.2008.26072.^72^ | Total Protein | Nitrogen balance method | Adults (19-59 y), Older Adults (60+ y) | RCT
^b^Rand, WM, Pellett, PL, Young, VR. Meta-analysis of nitrogen balance studies for estimating protein requirements in healthy adults. American Journal of Clinical Nutrition. 2003. 77(1):109-127. doi:10.1093/ajcn/77.1.109.^78^ | Total Protein | Nitrogen balance method | Adults (19-59 y), Older Adults (60+ y) | Systematic Review (27 studies), Meta-Analysis (19 studies)
Older Adults (60+ y)
Morse, MH, Haub, MD, Evans, WJ, Campbell, WW. Protein requirement of elderly women: Nitrogen balance responses to three levels of protein intake. Journals of Gerontology - Series A Biological Sciences and Medical Sciences. 2001. 56(11):M724-M730. doi:10.1093/gerona/56.11.M724.^75^ | Total Protein | Nitrogen balance method | Older Adults (60+ y), Females Alone | RCT
Pedersen, AN, Cederholm, T. Health effects of protein intake in healthy elderly populations: A systematic literature review. Food and Nutrition Research. 2014. 58. doi:10.3402/fnr.v58.23364.^76^ | Total Protein | Nitrogen balance method | Older Adults (60+ y) | Systematic Review (1 meta-analysis [Rand 2003] with 19 included studies, 4 studies)
Rafii, M, Chapman, K, Elango, R, Campbell, WW, Ball, RO, Pencharz, PB, Courtney-Martin, G. Dietary protein requirement of men > 65 years old determined by the indicator amino acid oxidation technique is higher than the current estimated average requirement. Journal of Nutrition. 2016. 146(4):681-687. doi:10.3945/jn.115.225631.^77^ | Total Protein | Indicator AA oxidation method | Older Adults (60+ y), Males Alone | RCT
Tang, M, McCabe, GP, Elango, R, Pencharz, PB, Ball, RO, Campbell, WW. Assessment of protein requirement in octogenarian women with use of the indicator amino acid oxidation technique. American Journal of Clinical Nutrition. 2014. 99(4):891-898. doi:10.3945/ajcn.112.042325.^80^ | Total Protein | Indicator AA oxidation method | Older Adults (60+ y), Females Alone | RCT
All Age Groups
Richter, M, Baerlocher, K, Bauer, JM, Elmadfa, I, Heseker, H, Leschik-Bonnet, E, Stangl, G, Volkert, D, Stehle, P. Revised Reference Values for the Intake of Protein. Annals of Nutrition and Metabolism. 2019. 74(3):242-250. doi:10.1159/000499374.^79^ | Total Protein | Factorial method,; Mean protein content of human milk,; Nitrogen balance method | Infants (0-6 mo), Infants (7-11 mo), Toddlers (12-23 mo), Children (2-12 y), Adolescents (13-18 y), Adults (19-59 y), Older Adults (60+ y) | Systematic Review (number of included studies NR)

a Abbreviations: AA, amino acid; BCAA, branched-chain amino acid; NRCT, non-randomized controlled trial; RCT, randomized controlled trial; y, year

b Included in: Institute of Medicine 2005. Dietary Reference Intakes for Energy, Carbohydrate, Fiber, Fat, Fatty Acids, Cholesterol, Protein, and Amino Acids. Washington, DC: The National Academies Press. 10.17226/10490.

Table 3-c Protein requirements bibliography with study characteristics: individual amino acids^a^

Citation | Protein Requirement(s) Assessed | Outcome Assessment Method(s) | Population(s) Examined | Study Design(s)
Leucine
^b^Kurpad, AV, Raj, T, El-Khoury, A, Kuriyan, R, Maruthy, K, Borgonha, S, Chandukudlu, D, Regan, MM, Young, VR. Daily requirement for and splanchnic uptake of leucine in healthy adult Indians. American Journal of Clinical Nutrition. 2001. 74(6):747-755. doi:10.1093/ajcn/74.6.747.^86^ | Leucine | 24-hour AA balance method,; Direct AA oxidation method,; Nitrogen balance method | Adults (19-59 y), Males Alone | RCT
Lysine
^b^El-Khoury, AE, Pereira, PCM, Borgonha, S, Basile, A, Beaumier, L, Wang, SY, Metges, CC, Ajami, AM, Young, VR. Twenty-four-hour oral tracer studies with L-[1-C-13]lysine at a low (15 mg center dot kg(-1)center dot d(-1)) and intermediate (29 mg-kg(-1)center dot d(-1)) lysine intake in healthy adults. American Journal of Clinical Nutrition. 2000. 72(1):122-130. doi:10.1093/ajcn/72.1.122.^83^ | Lysine | 24-hour AA balance method,; Direct AA oxidation method | Adults (19-59 y) | NRCT
Kriengsinyos, W, Wykes, LJ, Goonewardene, LA, Ball, RO, Pencharz, PB. Phase of menstrual cycle affects lysine requirement in healthy women. American Journal of Physiology-Endocrinology and Metabolism. 2004. 287(3):E489-E496. doi:10.1152/ajpendo.00262.2003.^84^ | Lysine | Indicator AA oxidation method | Adults (19-59 y), Females Alone | RCT
^b^Kurpad, AV, Raj, T, El-Khoury, A, Beaumier, L, Kuriyan, R, Srivatsa, A, Borgonha, S, Selvaraj, A, Regan, MM, Young, VR. Lysine requirements of healthy adult Indian subjects, measured by an indicator amino acid balance technique. American Journal of Clinical Nutrition. 2001. 73(5):900-907. doi:10.1093/ajcn/73.5.900.^85^ | Lysine | Indicator AA oxidation method,; 24-hour indicator AA balance method | Adults (19-59 y), Males Alone | RCT
^b^Kurpad, AV, Regan, MM, Raj, T, El-Khoury, A, Kuriyan, R, Vaz, M, Chandakudlu, D, Venkataswamy, VG, Borgonha, S, Young, VR. Lysine requirements of healthy adult Indian subjects receiving long-term feeding, measured with a 24-h indicator amino acid oxidation and balance technique. American Journal of Clinical Nutrition. 2002. 76(2):404-412. doi:10.1093/ajcn/76.2.404.^87^ | Lysine | Indicator AA oxidation method,; 24-hour indicator AA balance method | Adults (19-59 y), Males Alone | RCT
Methionine
Kurpad, AV, Regan, MM, Varalakshmi, S, Gnanou, J, Lingappa, A, Young, VR. Effect of cystine on the methionine requirement of healthy Indian men determined by using the 24-h indicator amino acid balance approach. American Journal of Clinical Nutrition. 2004. 80(6):1526-1535. doi:10.1093/ajcn/80.6.1526.^90^ | Methionine | Indicator AA oxidation method,; 24-hour indicator AA balance method | Adults (19-59 y), Males Alone | RCT
Kurpad, AV, Regan, MM, Varalakshmi, S, Vasudevan, J, Gnanou, J, Raj, T, Young, VR. Daily methionine requirements of healthy Indian men, measured by a 24-h indicator amino acid oxidation and balance technique. American Journal of Clinical Nutrition. 2003. 77(5):1198-1205. doi:10.1093/ajcn/77.5.1198.^89^ | Methionine | Indicator AA oxidation method,; 24-hour indicator AA balance method | Adults (19-59 y), Males Alone | RCT
Threonine
^b^Borgonha, S, Regan, MM, Oh, SH, Condon, M, Young, VR. Threonine requirement of healthy adults, derived with a 24-h indicator amino acid balance technique. American Journal of Clinical Nutrition. 2002. 75(4):698-704. doi:10.1093/ajcn/75.4.698.^82^ | Threonine | Indicator AA oxidation method,; 24-h indicator AA balance method | Adults (19-59 y) | RCT
^b^Kurpad, AV, Raj, T, Regan, MM, Vasudevan, J, Caszo, B, Nazareth, D, Gnanou, J, Young, VR. Threonine requirements of healthy Indian men, measured by a 24-h indicator amino acid oxidation and balance technique. American Journal of Clinical Nutrition. 2002. 76(4):789-797. doi:10.1093/ajcn/76.4.789.^88^ | Threonine | Indicator AA oxidation method,; 24-hour indicator AA balance method | Adults (19-59 y), Males Alone | RCT
Valine
Kurpad, AV, Regan, MM, Raj, TDS, Gnanou, JV, Rao, VN, Young, VR. The daily valine requirement of healthy adult Indians determined by the 24-h indicator amino acid balance approach. American Journal of Clinical Nutrition. 2005. 82(2):373-379. doi:10.1093/ajcn/82.2.373.^91^ | Valine | Indicator AA oxidation method,; 24-hour indicator AA balance method | Adults (19-59 y), Males Alone | RCT
Total BCAAs
Riazi, R, Rafii, M, Wykes, LJ, Ball, RO, Pencharz, PB. Valine may be the first limiting branched-chain amino acid in egg protein in men. Journal of Nutrition. 2003. 133(11):3533-3539. doi:10.1093/jn/133.11.3533.^92^ | Isoleucine, Leucine, Valine (Assessed together as BCAAs) | Indicator AA oxidation method | Adults (19-59 y), Males Alone | RCT
Riazi, R, Wykes, LJ, Ball, RO, Pencharz, PB. The total branched-chain amino acid requirement in young healthy adult men determined by indicator amino acid oxidation by use of L-[1-C-13]phenylalanine. Journal of Nutrition. 2003. 133(5):1383-1389. doi:10.1093/jn/133.5.1383.^93^ | Isoleucine, Leucine, Valine (Assessed together as BCAAs) | Indicator AA oxidation method | Adults (19-59 y), Males Alone | RCT

a Abbreviations: AA, amino acid; BCAA, branched-chain amino acid; NRCT, non-randomized controlled trial; RCT, randomized controlled trial; y, year

b Included in: Institute of Medicine 2005. Dietary Reference Intakes for Energy, Carbohydrate, Fiber, Fat, Fatty Acids, Cholesterol, Protein, and A National Academies Press. 10.17226/10490.

#### Intervention/exposure characteristics

##### Total Protein Reviews

While six reviews were found total, three were narrative reviews describing the landscape of evidence available regarding high protein intake, and none of the included SRs were designed specifically to review evidence on protein toxicity. The extracted data from the reviews demonstrates gaps in the evidence available to determine specific and generalizable UL values.

##### Amino Acid Reviews

The 16 reviews identified that met the inclusion/exclusion criteria provided information about 7 amino acids. Multiple reviews suggested methods for establishing UL values in the future as more evidence becomes available. While most reviews evaluated the safety of amino acid supplementation, noted adverse effects from high amino acid intake were supported by only a few studies with limited data. The dosage and duration of amino acid intake/supplementation were not clearly defined or were not reported.

One review evaluated amino acids generally,^18^ four reviews evaluated arginine,^8,15,17,22^ three reviews evaluated glutamine,^9,10,17^ two reviews evaluated histidine,^13,19^ four reviews evaluated leucine,^7,8,11,17^ three reviews evaluated lysine,^17,20,21^ one review evaluated methionine,^14^ and four reviews evaluated tryptophan.^8,12,16,17^ Two reviews had information about multiple amino acids.^8,17^

#### Outcome assessment

##### Total Protein Reviews

Three reviews mentioned or discussed acute adverse effects occurring as a result of high protein intake and three reviews discussed instances of high protein intake without adverse effects.

###### Adverse effects

1. One SR reported suppressed appetite with high protein intake (dosage/duration of intervention not reported).^6^
2. Another SR reported changes in urinary biomarkers (increased urinary calcium and decreased urinary pH) with 27 g per day of whey protein for 3 days.^5^
3. The same SR reported exacerbation of acne lesions when consuming a high level of protein for 60 days.^5^
4. A narrative review provided a general list of possible adverse effects of high protein intake (no duration or dosage information provided): intestinal discomfort, hyperaminoacidemia, hyperammonemia, hyperinsulinemia, dehydration, irritation, nausea, diarrhea, liver and kidney injuries, fatigue, headache, seizures, high risk of cardiovascular disease, or even death.^3^

###### No adverse effects

1. One narrative review reported no harmful effects (including changes in blood parameters and clinical side effects) with protein intake of 3.0-4.4 g/kg/d over 8 weeks in healthy resistance-trained adults.^1^
2. Another narrative review noted that there have been no previously reported adverse effects of protein intake above the RDA (within the AMDR).^2^
3. One SR reported no pattern of abnormality among blood variables or blood pressure in studies with protein intake under 35% of total energy intake.^4^ One study compared intake of 0.8 g/kg to 3.6 g/kg in a 12-week crossover and found significantly increased blood urea nitrogen concentrations. Another study found changes in a number of renal lab values with 1 week of high protein, but the clinical significance was unclear and not viewed as ‘adverse’.

##### Amino Acid Reviews

Fourteen reviews mentioned or discussed acute adverse effects occurring as a result of high amino acid intake and 3 reviews discussed instances of high protein intake without adverse effects. Some reviews discussed both instances of adverse effects and instances without any serious effects.

###### Adverse effects

1. Nausea/vomiting/GI discomfort
  - Varying high doses of leucine in an unspecified duration^7^
  - At above 7.5 g of tryptophan in an unspecified duration^12^
  - Varying high doses of lysine in an unspecified duration^20,21^
  - At 24-64 g of histidine per day for 4 weeks^19^
2. Change in biomarkers (e.g., markers of liver function, blood ammonia, serum urea nitrogen)
  - Varying high doses of leucine in an unspecified duration^7^
  - Varied high doses of leucine per day (single day)^11^
  - Varying high doses of leucine, tryptophan, and arginine in an unspecified duration^8^
  - At 0.5g/kg/day of glutamine over 14 days^9^
  - Varying high doses of glutamine in an unspecified duration^10^
  - At 6 g/d of lysine for 14 days^21^
  - Varying high doses of histidine in an unspecified duration^13^
  - At 4-16 g histidine per day for 4 weeks^19^
  - Varying high doses of methionine in an unspecified duration^14^
3. Headache
  - At 4-16 g histidine per day for 4 weeks^19^
  - At 4.8 g lysine per day for 56 days^21^
  - At 1,500 mg of arginine per day for 17 days to 5,000 mg of arginine per day for 6 weeks^22^
4. Skin rash, dizziness
  - At 4.8 g lysine per day for 56 days^21^
5. Itching, insomnia
  - At 1,500 mg of arginine per day for 17 days to 5,000 mg of arginine per day for 6 weeks^22^
6. Appetite change, mood changes, weakness, drowsiness, painful eyes, visual acuity, mental confusion, poor memory
  - At 24-64 g of histidine per day for 4 weeks^19^
7. Smell/taste change
  - At 65 mg of histidine per day for 24 days^19^
8. Eosinophilia-myalgia syndrome
  - 1989 incident involving high dose tryptophan^16^

###### No adverse effects

1. Acute or chronic doses of tryptophan ranging from 1-15 g per day had no effects of GI pain/discomfort, diarrhea, or constipation^12^
2. No reports of signs of toxicity or mutagenic activity in subjects treated with histidine (dose and duration not specified)^13^
3. Varying dosages of methionine in a crossover study (9.2-91 mg/kg/day for 2 weeks with 2-week washout) showed no signs of intolerance or changes in body composition at lowest observed adverse effect level^14^
4. In doses of arginine ranging from 3-42 g per day, no adverse effects were noted overall^15^
5. Several clinical studies were submitted to FDA for GRAS determination showing a lack of adverse effects^17^
6. Contaminated amino acid supplements have been shown to cause adverse effects but no peer-reviewed literature documents severe adverse reactions to an amino acid overdose, even in subgroups suspected of frequently consuming dietary supplements^17,18^

### Considerations for future DRI work

As the DRI process moves forward at the guidance of the Working Group, the following may be important to consider as a result of this completed evidence scan:

1. This evidence scan found little evidence to support a systematic review on the acute adverse health effects resulting from high dietary protein intake. There were no reviews focused specifically on protein and adverse health effects, only a few select sentences or cited studies within the reviews.
2. A large proportion of the data extracted in this evidence scan came from narrative reviews. Although narrative reviews can help provide an overview of potentially relevant evidence, they involve less rigorous methodology compared to systematic reviews (including those with meta-analyses), which are considered the gold standard of evidence synthesis.
3. Since the previous edition of DRIs were published, more research has been completed on amino acid intake. However, much of this research was conducted in animals or was focused on chronic health outcomes. Further exploration of amino acid intake, especially supplementation of high doses, is needed to inform potential future UL values.