# Acknowledgments and funding

Joint Canada-US Dietary Reference Intakes Working Group members:

- Samantha Adas, MS, RDN (National Institutes of Health (NIH)), Gisela Butera, MLIS (NIH), Kong Chen, PhD, MSCI (NIH), Cindy Davis, PhD (U.S. Department of Agriculture (USDA) – Agricultural Research Service (ARS)), Janet de Jesus, MS, RD (Health and Human Services (HHS) – Office of Disease Prevention and Health Promotion (ODPHP), Dana Desilva, PhD, RD (HHS-ODPHP), Krista Esslinger, MSc, RD (Health Canada), Karl Friedl, PhD (Department of Defense), Sarah Gebauer, PhD (Food and Drug Administration (FDA)), Linda Greene-Finestone, PhD, RD (Health Canada), Donna Johnson-Bailey, MPH, RD (USDA – Food and Nutrition Service), Christopher Lynch, PhD (NIH), Amanda MacFarlane, PhD (Health Canada), Matthew Parrott, PhD (Health Canada), Karen Regan, MS, RD (NIH), Jenna Seymour, PhD (Centers for Disease Control and Prevention), Pamela Starke Reed, PhD (USDA-ARS), Eve Stoody, PhD (USDA – Center for Nutrition Policy and Promotion), and Essie Yamini, PhD, RD (FDA)

The NESR team members were involved in: establishing all aspects of the protocol, which presented the plan for how they would examine the scientific evidence, including the inclusion and exclusion criteria; reviewing all studies that met the criteria they set; and describing the body of evidence for each question. The NESR team facilitated, executed, and documented the work necessary to ensure the evidence scan was completed in accordance with NESR methodology.

The NESR team was supported by the Joint Canada-US Dietary Reference Intakes Working Group, who provided input on the evidence scan question and protocol.