# Appendix 3-b Excluded articles for the protein requirements evidence scan

The following table lists the articles excluded after full-text screening for this evidence scan. At least one reason for exclusion is provided for each article, though this may not reflect all possible reasons. Information about articles excluded after title and abstract screening is available upon request.

# | Citation | Exclusion reason #1 | Exclusion reason #2
1 | Agergaard, J, Hansen, ET, van Hall, G, Holm, L. Postprandial amino acid availability after intake of intact or hydrolyzed meat protein in a mixed meal in healthy elderly subjects: a randomized, single blind crossover trial. Amino Acids. 2021. 53:951-959. doi:10.1007/s00726-021-03000-z | Intervention/exposure | -
2 | Agostoni, C, Scaglioni, S, Ghisleni, D, Verduci, E, Giovannini, M, Riva, E. How much protein is safe?. INTERNATIONAL JOURNAL OF OBESITY. 2005. 29:S8-S13. doi:10.1038/sj.ijo.0803095 | Study design | -
3 | Al-Nimr, RI. Optimal Protein Intake during Weight Loss Interventions in Older Adults with Obesity. Journal of Nutrition in Gerontology and Geriatrics. 2019. 38:50-68. doi:10.1080/21551197.2018.1544533 | Outcome | -
4 | Arnal, MA, Mosoni, L, Boirie, Y, Houlier, ML, Morin, L, Verdier, E, Ritz, P, Antoine, JM, Prugnaud, J, Beaufrère, B, Patureau Mirand, P. Protein feeding pattern does not affect protein retention in young women. Journal of Nutrition. 2000. 130:1700-1704. doi:10.1093/jn/130.7.1700 | Comparator | Outcome
5 | Bauer, J, Biolo, G, Cederholm, T, Cesari, M, Cruz-Jentoft, AJ, Morley, JE, Phillips, S, Sieber, C, Stehle, P, Teta, D, Visvanathan, R, Volpi, E, Boirie, Y. Evidence-based recommendations for optimal dietary protein intake in older people: A position paper from the prot-age study group. Journal of the American Medical Directors Association. 2013. 14:542-559. doi:10.1016/j.jamda.2013.05.021 | Study design | -
6 | Bauer, JM, Diekmann, R. Protein and Older Persons. Clinics in Geriatric Medicine. 2015. 31:327-338. doi:10.1016/j.cger.2015.04.002 | Study design | -
7 | Beasley, JM, Wertheim, BC, Lacroix, AZ, Prentice, RL, Neuhouser, ML, Tinker, LF, Kritchevsky, S, Shikany, JM, Eaton, C, Chen, Z, Thomson, CA. Biomarker-calibrated protein intake and physical function in the women’s health initiative. Journal of the American Geriatrics Society. 2013. 61:1863-1871. doi:10.1111/jgs.12503 | Outcome | -
8 | Berryman, CE, Lieberman, HR, Fulgoni, VL, III, Pasiakos, SM. Protein intake trends and conformity with the Dietary Reference Intakes in the United States: Analysis of the National Health and Nutrition Examination Survey, 2001-2014. American Journal of Clinical Nutrition. 2018. 108:405-413. doi:10.1093/ajcn/nqy088 | Outcome | -
9 | Bonnefoy, M, Gilbert, T. Frailty and nutrition — the current state of play and outlook for the future. Cahiers de l’Annee Gerontologique. 2015. 7:8-12. doi:10.1007/s12612-015-0445-7 | Pub. language | -
10 | Brestenský, M, Nitrayová, S, Patráš, P, Nitray, J. Dietary requirements for proteins and amino acids in human nutrition. Current Nutrition and Food Science. 2019. 15:638-645. doi:10.2174/1573401314666180507123506 | Study design | -
11 | Campbell, WW, Leidy, HJ. Dietary Protein and Resistance Training Effects on Muscle and Body Composition in Older Persons. Journal of the American College of Nutrition. 2007. 26:696S-703S. doi:10.1080/07315724.2007.10719650 | Study design | -
12 | Campbell, WW, Trappe, TA, Jozsi, AC, Kruskall, LJ, Wolfe, RR, Evans, WJ. Dietary protein adequacy and lower body versus whole body resistive training in older humans. Journal of Physiology. 2002. 542:631-642. doi:10.1113/jphysiol.2002.020685 | Intervention/exposure | Comparator
13 | Campbell, WW, Trappe, TA, Wolfe, RR, Evans, WJ. The recommended dietary allowance for protein may not be adequate for older people to maintain skeletal muscle. Journals of Gerontology - Series A Biological Sciences and Medical Sciences. 2001. 56:M373-M380. doi:10.1093/gerona/56.6.M373 | Comparator | -
14 | Chevalier, S, Gougeon, R, Nayar, K, Morais, JA. Frailty amplifies the effects of aging on protein metabolism: Role of protein intake. American Journal of Clinical Nutrition. 2003. 78:422-429. doi:10.1093/ajcn/78.3.422 | Intervention/exposure | Outcome
15 | Chew, STH, Kayambu, G, Lew, CCH, Ng, TP, Ong, F, Tan, J, Tan, NC, Tham, SL. Singapore multidisciplinary consensus recommendations on muscle health in older adults: assessment and multimodal targeted intervention across the continuum of care. BMC Geriatrics. 2021. 21:#pages#. doi:10.1186/s12877-021-02240-8 | Study design | Outcome
16 | Chouraqui, JP, Tavoularis, G, Simeoni, U, Ferry, C, Turck, D. Food, water, energy, and macronutrient intake of non-breastfed infants and young children (0-3 years). European Journal of Nutrition. 2020. 59:67-80. doi:10.1007/s00394-018-1883-y | Intervention/exposure | Outcome
17 | Dangin, M, Boirie, Y, Garcia-Rodenas, C, Gachon, P, Fauquant, J, Callier, P, Ballèvre, O, Beaufrère, B. The digestion rate of protein is an independent regulating factor of postprandial protein retention. American Journal of Physiology - Endocrinology and Metabolism. 2001. 280:E340-E348. doi:10.1152/ajpendo.2001.280.2.e340 | Intervention/exposure | Outcome
18 | Dangin, M, Guillet, C, Garcia-Rodenas, C, Gachon, P, Bouteloup-Demange, C, Reiffers-Magnani, K, Fauquant, J, Ballèvre, O, Beaufrère, B. The rate of protein digestion affects protein gain differently during aging in humans. Journal of Physiology. 2003. 549:635-644. doi:10.1113/jphysiol.2002.036897 | Intervention/exposure | Outcome
19 | Dardevet, D, Mosoni, L, Savary-Auzeloux, I, Peyron, MA, Polakof, S, Rémond, D. Important determinants to take into account to optimize protein nutrition in the elderly: Solutions to a complex equation. Cahiers de Nutrition et de Dietetique. 2021. 56:333-349. doi:10.1016/j.cnd.2021.10.002 | Study design | -
20 | Dato, S, Hoxha, E, Crocco, P, Iannone, F, Passarino, G, Rose, G. Amino acids and amino acid sensing: implication for aging and diseases. Biogerontology. 2019. 20:17-31. doi:10.1007/s10522-018-9770-8 | Study design | -
21 | De Vries-Ten Have, J, Owolabi, A, Steijns, J, Kudla, U, Melse-Boonstra, A. Protein intake adequacy among Nigerian infants, children, adolescents and women and protein quality of commonly consumed foods. Nutrition Research Reviews. 2020. 33:102-120. doi:10.1017/S0954422419000222 | Outcome | -
22 | Deer, RR, Volpi, E. Protein intake and muscle function in older adults. Current Opinion in Clinical Nutrition and Metabolic Care. 2015. 18:248-253. doi:10.1097/MCO.0000000000000162 | Study design | -
23 | Deutz, NEP, Bauer, JM, Barazzoni, R, Biolo, G, Boirie, Y, Bosy-Westphal, A, Cederholm, T, Cruz-Jentoft, A, Krznariç, Z, Nair, KS, Singer, P, Teta, D, Tipton, K, Calder, PC. Protein intake and exercise for optimal muscle function with aging: Recommendations from the ESPEN Expert Group. Clinical Nutrition. 2014. 33:929-936. doi:10.1016/j.clnu.2014.04.007 | Study design | -
24 | Dickinson, JM, Volpi, E, Rasmussen, BB. Exercise and nutrition to target protein synthesis impairments in aging skeletal muscle. Exercise and Sport Sciences Reviews. 2013. 41:216-223. doi:10.1097/JES.0b013e3182a4e699 | Study design | -
25 | Dideriksen, K, Reitelseder, S, Holm, L. Influence of amino acids, dietary protein, and physical activity on muscle mass development in humans. Nutrients. 2013. 5:852-876. doi:10.3390/nu5030852 | Study design | -
26 | Diekmann, R, Bauer, JM. Protein requirements of elderly people. Deutsche Medizinische Wochenschrift. 2014. 139:239-242. doi:10.1055/s-0033-1359989 | Pub. language | -
27 | Drummond, MJ. A practical dietary strategy to maximize the anabolic response to protein in aging muscle. Journals of Gerontology - Series A Biological Sciences and Medical Sciences. 2015. 70:55-56. doi:10.1093/gerona/glu157 | Study design | -
28 | Efsa Panel on Dietetic Products, Nutrition, Allergies, . Scientific Opinion on nutrient requirements and dietary intakes of infants and young children in the European Union. EFSA Journal. 2013. 11:#pages#. doi:10.2903/j.efsa.2013.3408 | Study design | -
29 | Elango, R, Ball, RO, Pencharz, PB. Individual amino acid requirements in humans: An update. Current Opinion in Clinical Nutrition and Metabolic Care. 2008. 11:34-39. doi:10.1097/MCO.0b013e3282f2a5a4 | Study design | -
30 | Emery, PW. Protein requirements in nutrition support. Advanced Nutrition and Dietetics in Nutrition Support. 2018. #volume#:127-134. doi:10.1002/9781118993880 | Study design | -
31 | Evans, WJ. Protein Nutrition, Exercise and Aging. Journal of the American College of Nutrition. 2004. 23:601S-609S. doi:10.1080/07315724.2004.10719430 | Study design | -
32 | Franz, K, Müller-Werdan, U, Norman, K. Nutrition and malnutrition in old age: Interdisciplinary measures for the optimization of nutrition. Klinikarzt. 2017. 46:620-623. doi:10.1055/s-0043-122588 | Pub. language | -
33 | Franzke, B, Neubauer, O, Cameron-Smith, D, Wagner, KH. Dietary protein, muscle and physical function in the very old. Nutrients. 2018. 10:#pages#. doi:10.3390/nu10070935 | Study design | -
34 | Gaffney-Stomberg, E, Insogna, KL, Rodriguez, NR, Kerstetter, JE. Increasing dietary protein requirements in elderly people for optimal muscle and bone health. Journal of the American Geriatrics Society. 2009. 57:1073-1079. doi:10.1111/j.1532-5415.2009.02285.x | Study design | -
35 | Gaillard, C, Alix, E, Boirie, Y, Berrut, G, Ritz, P. Are elderly hospitalized patients getting enough protein?. Journal of the American Geriatrics Society. 2008. 56:1045-1049. doi:10.1111/j.1532-5415.2008.01721.x | Health status | -
36 | Gaspareto, N, Previdelli, ÁN, Laurentino, GC, de Aquino, RC. Protein Consumption: Inadequacy in Amount, Food Sources, and Mealtime Distribution in Community-Dwelling Older Adults. Ageing International. 2021. #volume#:#pages#. doi:10.1007/s12126-021-09465-3 | Outcome | -
37 | Grote, V, Von Kries, R, Closa-Monasterolo, R, Scaglioni, S, Gruszfeld, D, Sengier, A, Langhendries, JP, Koletzko, B. Protein intake and growth in the first 24 months of life. Journal of Pediatric Gastroenterology and Nutrition. 2010. 51:S117-S118. doi:10.1097/MPG.0b013e3181f96064 | Outcome | -
38 | Han, JH, Kang, LL, Liang, D, Li, HZ, Su, YX, Zhang, YM, Yang, YX. Composition requirements of follow-up formula for 6-12-month-old infants: recommendations of a Chinese expert group. Asia Pacific Journal of Clinical Nutrition. 2019. 28:347-355. doi:10.6133/apjcn.201906_28(2).0017 | Outcome | -
39 | Harris, S. Nutrition and exercise: A personalised approach. The Art and Science of Personalising Care with Older People with Diabetes. 2018. #volume#:81-98. doi:10.1007/978-3-319-74360-8_5 | Study design | -
40 | Hermanky, M, Korninger, C, Fuchs, D, Strasser, B. Effects of a Protein Optimized Diet Combined with Moderate Resistance Training on the Postoperative Course in Older Patients with Hip Fracture. Aktuelle Ernahrungsmedizin. 2017. 42:180-187. doi:10.1055/s-0043-105466 | Pub. language | -
41 | Hilbig, A, Kersting, M. Effects of age and time on energy and macronutrient intake in German infants and young children: Results of the DONALD study. Journal of Pediatric Gastroenterology and Nutrition. 2006. 43:518-524. doi:10.1097/01.mpg.0000229548.69702.aa | Outcome | -
42 | Hoffer, LJ, Bistrian, BR. Appropriate protein provision in critical illness: A systematic and narrative review. American Journal of Clinical Nutrition. 2012. 96:591-600. doi:10.3945/ajcn.111.032078 | Health status | -
43 | Houston, DK, Nicklas, BJ, Ding, J, Harris, TB, Tylavsky, FA, Newman, AB, Jung, SL, Sahyoun, NR, Visser, M, Kritchevsky, SB. Dietary protein intake is associated with lean mass change in older, community-dwelling adults: The Health, Aging, and Body Composition (Health ABC) study. American Journal of Clinical Nutrition. 2008. 87:150-155. doi:10.1093/ajcn/87.1.150 | Outcome | -
44 | Iizaka, S, Kaitani, T, Nakagami, G, Sugama, J, Sanada, H. Clinical validity of the estimated energy requirement and the average protein requirement for nutritional status change and wound healing in older patients with pressure ulcers: A multicenter prospective cohort study. Geriatrics and Gerontology International. 2015. 15:1201-1209. doi:10.1111/ggi.12420 | Health status | -
45 | Isanejad, M, Sirola, J, Mursu, J, Kröger, H, Tuppurainen, M, Erkkilä, AT. Association of protein intake with bone mineral density and bone mineral content among elderly women: The OSTPRE fracture prevention study. Journal of Nutrition, Health and Aging. 2017. 21:622-630. doi:10.1007/s12603-016-0800-4 | Outcome | -
46 | Jordan, LY, Melanson, EL, Melby, CL, Hickey, MS, Miller, BF. Nitrogen balance in older individuals in energy balance depends on timing of protein intake. Journals of Gerontology - Series A Biological Sciences and Medical Sciences. 2010. 65 A:1068-1076. doi:10.1093/gerona/glq123 | Intervention/exposure | Comparator
47 | Juillet, B, Fouillet, H, Bos, C, Mariotti, F, Gausserès, N, Benamouzig, R, Tomé, D, Gaudichon, C. Increasing habitual protein intake results in reduced postprandial efficiency of peripheral, anabolic wheat protein nitrogen use in humans. American Journal of Clinical Nutrition. 2008. 87:666-678. doi:10.1093/ajcn/87.3.666 | Outcome | -
48 | Jun, S, Cowan, AE, Dwyer, JT, Campbell, WW, Thalacker-Mercer, AE, Gahche, JJ, Bailey, RL. Dietary Protein Intake Is Positively Associated with Appendicular Lean Mass and Handgrip Strength among Middle-Aged US Adults. Journal of Nutrition. 2021. 151:3755-3763. doi:10.1093/jn/nxab288 | Outcome | -
49 | Jung, HW, Kim, SW, Kim, IY, Lim, JY, Park, HS, Song, W, Yoo, HJ, Jang, HC, Kim, K, Park, Y, Park, YJ, Yang, SJ, Lee, HJ, Won, CW, Sarcopenia-Frailty Study Group of the Korean Geriatric, Society, the Korean Nutrition, Society. Protein intake recommendation for korean older adults to prevent sarcopenia: Expert consensus by the korean geriatric society and the korean nutrition society. Annals of Geriatric Medicine and Research. 2018. 22:167-175. doi:10.4235/agmr.18.0046 | Study design | -
50 | Khanal, P, He, L, Degens, H, Stebbings, GK, Onambele-Pearson, GL, Williams, AG, Thomis, M, Morse, CI. Dietary protein requirement threshold and micronutrients profile in healthy older women based on relative skeletal muscle mass. Nutrients. 2021. 13:#pages#. doi:10.3390/nu13093076 | Outcome | -
51 | Kiesswetter, E, Sieber, CC, Volkert, D. Protein intake in older people: Why, how much and how?. Zeitschrift fur Gerontologie und Geriatrie. 2020. 53:285-289. doi:10.1007/s00391-020-01723-4 | Study design | -
52 | Kiesswetter, E. Nutrition and sarcopenia. Osteologie. 2017. 26:28-31. doi:10.1055/s-0037-1622078 | Pub. language | -
53 | Koletzko, B, Broekaert, I, Demmelmair, H, Franke, J, Hannibal, I, Oberle, D, Schiess, S, Baumann, BT, Verwied-Jorky, S, Childhood Obesity Project EU. Protein intake in the first year of life: A risk factor for later obesity? The EU Childhood Obesity project. EARLY NUTRITION AND ITS LATER CONSEQUENCES: NEW OPPORTUNITIES: PERINATAL PROGRAMMING OF ADULT HEALTH - EC SUPPORTED RESEARCH. 2005. 569:69-79. doi:#electronic resource number# | Study design | Outcome
54 | Koopman, R, Wagenmakers, AJM, Manders, RJF, Zorenc, AHG, Senden, JMG, Gorselink, M, Keizer, HA, Van Loon, LJC. Combined ingestion of protein and free leucine with carbohydrate increases postexercise muscle protein synthesis in vivo in male subjects. American Journal of Physiology - Endocrinology and Metabolism. 2005. 288:E645-E653. doi:10.1152/ajpendo.00413.2004 | Outcome | -
55 | Koopman, R, Walrand, S, Beelen, M, Gijsen, AP, Kies, AK, Boirie, Y, Saris, WHM, Van Loon, LJC. Dietary protein digestion and absorption rates and the subsequent postprandial muscle protein synthetic response do not differ between young and elderly men. Journal of Nutrition. 2009. 139:1707-1713. doi:10.3945/jn.109.109173 | Intervention/exposure | Outcome
56 | Krok-Schoen, JL, Archdeacon Price, A, Luo, M, Kelly, OJ, Taylor, CA. Low Dietary Protein Intakes and Associated Dietary Patterns and Functional Limitations in an Aging Population: A NHANES Analysis. Journal of Nutrition, Health and Aging. 2019. 23:338-347. doi:10.1007/s12603-019-1174-1 | Outcome | -
57 | Kurpad, AV, Regan, MM, Raj, T, Maruthy, K, Gnanou, J, Young, VR. Intravenously infused C-13-leucine is retained in fasting healthy adult men. Journal of Nutrition. 2002. 132:1906-1908. doi:10.1093/jn/132.7.1906 | Intervention/exposure | Outcome
58 | Kurpad, AV, Regan, MM, Raj, T, Varalakshmi, S, Gnanou, J, Thankachan, P, Young, VR. Leucine requirement and splanchnic uptake of leucine in chronically undernourished adult Indian subjects. American Journal of Clinical Nutrition. 2003. 77:861-867. doi:10.1093/ajcn/77.4.861 | Health status | -
59 | Lancha Jr, AH, Zanella Jr, R, Tanabe, SGO, Andriamihaja, M, Blachier, F. Dietary protein supplementation in the elderly for limiting muscle mass loss. Amino Acids. 2017. 49:33-47. doi:10.1007/s00726-016-2355-4 | Study design | -
60 | Layman, DK. A protein-centric perspective for skeletal muscle metabolism and cardiometabolic health. Nutrition and Cardiometabolic Health. 2017. #volume#:333-347. doi:10.1201/9781315119410 | Study design | -
61 | Leser, S. The 2013 FAO report on dietary protein quality evaluation in human nutrition: Recommendations and implications. Nutrition Bulletin. 2013. 38:421-428. doi:10.1111/nbu.12063 | Study design | -
62 | Linn, T, Santosa, B, Grönemeyer, D, Aygen, S, Scholz, N, Busch, M, Bretzel, RG. Effect of long-term dietary protein intake on glucose metabolism in humans. Diabetologia. 2000. 43:1257-1265. doi:10.1007/s001250051521 | Outcome | -
63 | Liu, Z, Jahn, LA, Wei, L, Long, W, Barrett, EJ. Amino acids stimulate translation initiation and protein synthesis through an Akt-independent pathway in human skeletal muscle. Journal of Clinical Endocrinology and Metabolism. 2002. 87:5553-5558. doi:10.1210/jc.2002-020424 | Intervention/exposure | Outcome
64 | Lonnie, M, Hooker, E, Brunstrom, JM, Corfe, BM, Green, MA, Watson, AW, Williams, EA, Stevenson, EJ, Penson, S, Johnstone, AM. Protein for life: Review of optimal protein intake, sustainable dietary sources and the effect on appetite in ageing adults. Nutrients. 2018. 10:#pages#. doi:10.3390/nu10030360 | Study design | -
65 | Martinez, JA, Wertheim, BC, Thomson, CA, Bea, JW, Wallace, R, Allison, M, Snetselaar, L, Chen, Z, Nassir, R, Thompson, PA. Physical Activity Modifies the Association between Dietary Protein and Lean Mass of Postmenopausal Women. Journal of the Academy of Nutrition and Dietetics. 2017. 117:192-203.e1. doi:10.1016/j.jand.2016.10.009 | Outcome | -
66 | Mathewson, SL, Gordon, AL, Smith, K, Atherton, PJ, Greig, CA, Phillips, BE. Determining the influence of habitual dietary protein intake on physiological muscle parameters in youth and older age. Nutrients. 2021. 13:#pages#. doi:10.3390/nu13103560 | Outcome | -
67 | McCarthy, D, Berg, A. Weight loss strategies and the risk of skeletal muscle mass loss. Nutrients. 2021. 13:#pages#. doi:10.3390/nu13072473 | Study design | -
68 | Mendonça, N, Hengeveld, LM, Visser, M, Presse, N, Canhão, H, Simonsick, EM, Kritchevsky, SB, Newman, AB, Gaudreau, P, Jagger, C. Low protein intake, physical activity, and physical function in European and North American community-dwelling older adults: A pooled analysis of four longitudinal aging cohorts. American Journal of Clinical Nutrition. 2021. 114:29-41. doi:10.1093/ajcn/nqab051 | Outcome | -
69 | Michaelsen, KF. Protein requirements and intake. PEDIATRICS. 2000. 106:1293-1294. doi:#electronic resource number# | Study design | -
70 | Millward, DJ, Fereday, A, Gibson, NR, Cox, MC, Pacy, PJ. Efficiency of utilization of wheat and milk protein in healthy adults and apparent lysine requirements determined by a single-meal [1-C-13]leucine balance protocol. American Journal of Clinical Nutrition. 2002. 76:1326-1334. doi:10.1093/ajcn/76.6.1326 | Intervention/exposure | Outcome
71 | Millward, DJ, Fereday, A, Gibson, NR, Pacy, PJ. Human adult amino acid requirements: [1-13C]leucine balance evaluation of the efficiency of utilization and apparent requirements for wheat protein and lysine compared with those for milk protein in healthy adults. American Journal of Clinical Nutrition. 2000. 72:112-121. doi:10.1093/ajcn/72.1.112 | Intervention/exposure | Outcome
72 | Millward, DJ. An adaptive metabolic demand model for protein and amino acid requirements. British Journal of Nutrition. 2003. 90:249-260. doi:10.1079/BJN2003924 | Study design | -
73 | Mirzaei, H, Suarez, JA, Longo, VD. Protein and amino acid restriction, aging and disease: From yeast to humans. Trends in Endocrinology and Metabolism. 2014. 25:558-566. doi:10.1016/j.tem.2014.07.002 | Study design | -
74 | Mojtahedi, M, De Groot, LCPGM, Boekholt, HA, Van Raaij, JMA. Nitrogen balance of healthy Dutch women before and during pregnancy. American Journal of Clinical Nutrition. 2002. 75:1078-1083. doi:10.1093/ajcn/75.6.1078 | Intervention/exposure | Outcome
75 | Morais, JA, Chevalier, S, Gougeon, R. Protein turnover and requirements in the healthy and frail elderly. Journal of Nutrition, Health and Aging. 2006. 10:272-283. doi:#electronic resource number# | Study design | -
76 | Morens, C, Bos, C, Pueyo, ME, Benamouzig, R, Gausserès, N, Luengo, C, Tomé, D, Gaudichon, C. Increasing habitual protein intake accentuates differences in postprandial dietary nitrogen utilization between protein sources in humans. Journal of Nutrition. 2003. 133:2733-2740. doi:10.1093/jn/133.9.2733 | Outcome | -
77 | Morley, JE, Argiles, JM, Evans, WJ, Bhasin, S, Cella, D, Deutz, NEP, Doehner, W, Fearon, KCH, Ferrucci, L, Hellerstein, MK, Kalantar-Zadeh, K, Lochs, H, MacDonald, N, Mulligan, K, Muscaritoli, M, Ponikowski, P, Posthauer, ME, Fanelli, FR, Schambelan, M, Schols, AMWJ, Schuster, MW, Anker, SD. Nutritional recommendations for the management of sarcopenia. Journal of the American Medical Directors Association. 2010. 11:391-396. doi:10.1016/j.jamda.2010.04.014 | Study design | -
78 | Morley, JE, Bauer, JM. Nutrition and aging successfully. Current Opinion in Clinical Nutrition and Metabolic Care. 2017. 20:1-3. doi:10.1097/MCO.0000000000000330 | Study design | -
79 | Morris, S, Cater, JD, Green, MA, Johnstone, AM, Brunstrom, JM, Stevenson, EJ, Williams, EA, Corfe, BM. Inadequacy of protein intake in older UK adults. Geriatrics (Switzerland). 2020. 5:#pages#. doi:10.3390/geriatrics5010006 | Outcome | -
80 | Murphy, MM, Higgins, KA, Bi, X, Barraj, LM. Adequacy and sources of protein intake among pregnant women in the United States, NHANES 2003–2012. Nutrients. 2021. 13:1-13. doi:10.3390/nu13030795 | Outcome | -
81 | Mustafa, J, Ellison, RC, Singer, MR, Bradlee, ML, Kalesan, B, Holick, MF, Moore, LL. Dietary Protein and Preservation of Physical Functioning among Middle-Aged and Older Adults in the Framingham Offspring Study. American Journal of Epidemiology. 2018. 187:1411-1419. doi:10.1093/aje/kwy014 | Outcome | -
82 | Nilsson, A, Rojas, DM, Kadi, F. Impact of meeting different guidelines for protein intake on muscle mass and physical function in physically active older women. Nutrients. 2018. 10:#pages#. doi:10.3390/nu10091156 | Outcome | -
83 | Nowicki, GJ, Ślusarska, B, Bartoszek, A, Kocka, K, Deluga, A, Kachaniuk, H, Łuczyk, M. Moderation and mediation analysis of the relationship between total protein concentration and the risk of depressive disorders in older adults with function dependence in home care. Nutrients. 2018. 10:#pages#. doi:10.3390/nu10101374 | Outcome | -
84 | Nowson, C, O’Connell, S. Protein requirements and recommendations for older people: A review. Nutrients. 2015. 7:6874-6899. doi:10.3390/nu7085311 | Study design | -
85 | Nygren, J, Nair, KS. Differential regulation of protein dynamics in splanchnic and skeletal muscle beds by insulin and amino acids in healthy human subjects. Diabetes. 2003. 52:1377-1385. doi:10.2337/diabetes.52.6.1377 | Intervention/exposure | Outcome
86 | Overdevest, E, Dorhout, BG, Nicolaou, M, van Valkengoed, IGM, Haveman-Nies, A, Oztürk, H, de Groot, LCPGM, Tieland, M, Weijs, PJM. Dietary protein intake in older adults from ethnic minorities in the Netherlands, a mixed methods approach. Nutrients. 2021. 13:1-12. doi:10.3390/nu13010184 | Outcome | -
87 | Paddon-Jones, D, Leidy, H. Dietary protein and muscle in older persons. Current Opinion in Clinical Nutrition and Metabolic Care. 2014. 17:5-11. doi:10.1097/MCO.0000000000000011 | Study design | -
88 | Paddon-Jones, D, Rasmussen, BB. Dietary protein recommendations and the prevention of sarcopenia. Current Opinion in Clinical Nutrition and Metabolic Care. 2009. 12:86-90. doi:10.1097/MCO.0b013e32831cef8b | Study design | -
89 | Paddon-Jones, D, Sheffield-Moore, M, Katsanos, CS, Zhang, XJ, Wolfe, RR. Differential stimulation of muscle protein synthesis in elderly humans following isocaloric ingestion of amino acids or whey protein. Experimental Gerontology. 2006. 41:215-219. doi:10.1016/j.exger.2005.10.006 | Outcome | -
90 | Patro-Golab, B, Zalewski, BM, Kolodziej, M, Kouwenhoven, S, Poston, L, Godfrey, KM, Koletzko, B, van Goudoever, JB, Szajewska, H. Nutritional interventions or exposures in infants and children aged up to 3 years and their effects on subsequent risk of overweight, obesity and body fat: a systematic review of systematic reviews. Obesity Reviews. 2016. 17:1245-1257. doi:10.1111/obr.12476 | Outcome | -
91 | Paul, C, Leser, S, Oesser, S. Significant amounts of functional collagen peptides can be incorporated in the diet while maintaining indispensable amino acid balance. Nutrients. 2019. 11:#pages#. doi:10.3390/nu11051079 | Outcome | -
92 | Phillips, SM, Paddon-Jones, D, Layman, DK. Optimizing adult protein intake during catabolic health conditions. Advances in Nutrition. 2020. 11:S1058-S1069. doi:10.1093/ADVANCES/NMAA047 | Study design | -
93 | Phillips, SM, Tang, JE, Moore, DR. The role of milk- and soy-based protein in support of muscle protein synthesis and muscle protein accretion in young and elderly persons. Journal of the American College of Nutrition. 2009. 28:343-354. doi:10.1080/07315724.2009.10718096 | Study design | -
94 | Phillips, SM. Current Concepts and Unresolved Questions in Dietary Protein Requirements and Supplements in Adults. Frontiers in Nutrition. 2017. 4:#pages#. doi:10.3389/fnut.2017.00013 | Study design | -
95 | Pillai, RR, Kurpad, AV. Amino acid requirements in children and the elderly population. British Journal of Nutrition. 2012. 108:S44-S49. doi:10.1017/S0007114512002401 | Study design | -
96 | Prentice, P, Ong, KK, Schoemaker, MH, van Tol, EAF, Vervoort, J, Hughes, IA, Acerini, CL, Dunger, DB. Breast milk nutrient content and infancy growth. Acta Paediatrica. 2016. 105:641-647. doi:10.1111/apa.13362 | Intervention/exposure | Outcome
97 | Protein and amino acid requirements in human nutrition. World Health Organization technical report series. 2007. #volume#:1-265, back cover. doi:#electronic resource number# | Study design | -
98 | Raiha, NCR, Fazzolari-Nesci, A, Cajozzo, C, Puccio, G, Monestier, A, Moro, G, Minoli, I, Haschke-Becher, E, Bachmann, C, Van’t Hof, M, Fassler, ALC, Haschke, F. Whey predominant, whey modified infant formula with protein/energy ratio of 1.8 g/100 kcal: Adequate and safe for term infants from birth to four months. JOURNAL OF PEDIATRIC GASTROENTEROLOGY AND NUTRITION. 2002. 35:275-281. doi:10.1097/01.MPG.0000024570.18154.C7 | Outcome | -
99 | Reidy, PT, Walker, DK, Dickinson, JM, Gundermann, DM, Drummond, MJ, Timmerman, KL, Fry, CS, Borack, MS, Cope, MB, Mukherjea, R, Jennings, K, Volpi, E, Rasmussen, BB. Protein blend ingestion following resistance exercise promotes human muscle protein synthesis. Journal of Nutrition. 2013. 143:410-416. doi:10.3945/jn.112.168021 | Outcome | -
100 | Rennie, MJ. Anabolic resistance: The effects of aging, sexual dimorphism, and immobilization on human muscle protein turnover. Applied Physiology, Nutrition and Metabolism. 2009. 34:377-381. doi:10.1139/H09-012 | Study design | -
101 | Report of the scientific committee on food on the revision of essential requirements of infant formulae and follow-on formulae. Report of the Scientific Committee on Food on the Revision of Essential Requirements of Infant Formulae and Follow-on Formulae. 2003. #volume#:#pages#. doi:#electronic resource number# | Study design | -
102 | Rieu, I, Balage, M, Sornet, C, Giraudet, C, Pujos, E, Grizard, J, Mosoni, L, Dardevet, D. Leucine supplementation improves muscle protein synthesis in elderly men independently of hyperaminoacidaemia. Journal of Physiology. 2006. 575:305-315. doi:10.1113/jphysiol.2006.110742 | Outcome | -
103 | Roberts, SA, Thorpe, JM, Ball, RO, Pencharz, PB. Tyrosine requirement of healthy men receiving a fixed phenylalanine intake determined by using indicator amino acid oxidation. American Journal of Clinical Nutrition. 2001. 73:276-282. doi:#electronic resource number# | Intervention/exposure | -
104 | Rodriguez, NR, Miller, SL. Effective translation of current dietary guidance: Understanding and communicating the concepts of minimal and optimal levels of dietary protein. American Journal of Clinical Nutrition. 2015. 101:1353S-1358S. doi:10.3945/ajcn.114.084095 | Study design | -
105 | Rosenberger, C, Rechsteiner, M, Dietsche, R, Breidert, M. Energy and protein intake in 330 geriatric orthopaedic patients: Are the current nutrition guidelines applicable?. Clinical Nutrition ESPEN. 2019. 29:86-91. doi:10.1016/j.clnesp.2018.11.016 | Health status | -
106 | Rousset, S, Mirand, PP, Brandolini, M, Martin, JF, Boirie, Y. Daily protein intakes and eating patterns in young and elderly French. British Journal of Nutrition. 2003. 90:1107-1115. doi:10.1079/BJN20031004 | Outcome | -
107 | Shad, BJ, Thompson, JL, Breen, L. Does the muscle protein synthetic response to exercise and amino acid-based nutrition diminish with advancing age? a systematic review. American Journal of Physiology - Endocrinology and Metabolism. 2016. 311:E803-E817. doi:10.1152/ajpendo.00213.2016 | Outcome | -
108 | Soriano, G, Rossi, F, Sourdet, S. Protein intake and physical functioning in frail older subjects. Cahiers de Nutrition et de Dietetique. 2019. 54:61-68. doi:10.1016/j.cnd.2018.09.006 | Pub. language | -
109 | Suominen, MH, Jyvakorpi, SK, Pitkala, KH, Finne-Soveri, H, Hakala, P, Mannisto, S, Soini, H, Sarlio-Lahteenkorva, S. Nutritional guidelines for older people in Finland. Journal of Nutrition, Health and Aging. 2014. 18:861-867. doi:10.1007/s12603-014-0509-1 | Study design | Outcome
110 | Unni, US, Raj, T, Sambashivaiah, S, Kuriyan, R, Uthappa, S, Vaz, M, Regan, MM, Kurpad, AV. The effect of a controlled 8-week metabolic ward based lysine supplementation on muscle function, insulin sensitivity and leucine kinetics in young men. Clinical Nutrition. 2012. 31:903-910. doi:10.1016/j.clnu.2012.03.008 | Outcome | -
111 | van Zwienen-Pot, JI, Visser, M, Kruizenga, HM. Predictors for achieving adequate protein and energy intake in nursing home rehabilitation patients. Aging Clinical and Experimental Research. 2018. 30:799-809. doi:10.1007/s40520-017-0850-4 | Outcome | Health status
112 | Volpi, E, Campbell, WW, Dwyer, JT, Johnson, MA, Jensen, GL, Morley, JE, Wolfe, RR. Is the optimal level of protein intake for older adults greater than the recommended dietary allowance?. Journals of Gerontology - Series A Biological Sciences and Medical Sciences. 2013. 68:677-681. doi:10.1093/gerona/gls229 | Study design | -
113 | Volpi, E, Kobayashi, H, Sheffield-Moore, M, Mittendorfer, B, Wolfe, RR. Essential amino acids are primarily responsible for the amino acid stimulation of muscle protein anabolism in healthy elderly adults. American Journal of Clinical Nutrition. 2003. 78:250-258. doi:10.1093/ajcn/78.2.250 | Intervention/exposure | Outcome
114 | Walrand, S, Boirie, Y. Optimizing protein intake in aging. Current Opinion in Clinical Nutrition and Metabolic Care. 2005. 8:89-94. doi:10.1097/00075197-200501000-00014 | Study design | -
115 | Walrand, S, Short, KR, Bigelow, ML, Sweatt, AJ, Hutson, SM, Nair, KS. Functional impact of high protein intake on healthy elderly people. American Journal of Physiology - Endocrinology and Metabolism. 2008. 295:E921-E928. doi:10.1152/ajpendo.90536.2008 | Outcome | -
116 | Weijs, PJM, Wolfe, RR. Exploration of the protein requirement during weight loss in obese older adults. Clinical Nutrition. 2016. 35:394-398. doi:10.1016/j.clnu.2015.02.016 | Outcome | -
117 | Wirth, R, Volkert, D. Nutritional medicine in elderly patients: Advances and challenges. Zeitschrift fur Gerontologie und Geriatrie. 2017. 50:666-668. doi:10.1007/s00391-017-1278-3 | Pub. language | -
118 | Witard, OC, McGlory, C, Hamilton, DL, Phillips, SM. Growing older with health and vitality: a nexus of physical activity, exercise and nutrition. Biogerontology. 2016. 17:529-546. doi:10.1007/s10522-016-9637-9 | Study design | -
119 | Wolfe, RR, Miller, SL, Miller, KB. Optimal protein intake in the elderly. Clinical Nutrition. 2008. 27:675-684. doi:10.1016/j.clnu.2008.06.008 | Study design | -
120 | Yang, Y, Churchward-Venne, TA, Burd, NA, Breen, L, Tarnopolsky, MA, Phillips, SM. Myofibrillar protein synthesis following ingestion of soy protein isolate at rest and after resistance exercise in elderly men. Nutrition and Metabolism. 2012. 9:#pages#. doi:10.1186/1743-7075-9-57 | Outcome | -
121 | Yeung, SSY, Trappenburg, MC, Meskers, CGM, Maier, AB, Reijnierse, EM. Inadequate energy and protein intake in geriatric outpatients with mobility problems. Nutrition Research. 2020. 84:33-41. doi:10.1016/j.nutres.2020.09.007 | Outcome | -
122 | Yoshii, N, Sato, K, Ogasawara, R, Kurihara, T, Hamaoka, T, Fujita, S. Relationship between dietary protein or essential amino acid intake and training-induced muscle hypertrophy among older individuals. Journal of Nutritional Science and Vitaminology. 2017. 63:379-388. doi:10.3177/jnsv.63.379 | Outcome | -
123 | Zalewski, BM, Patro, B, Veldhorst, M, Kouwenhoven, S, Crespo Escobar, P, Calvo Lerma, J, Koletzko, B, van Goudoever, JB, Szajewska, H. Nutrition of infants and young children (one to three years) and its effect on later health: A systematic review of current recommendations (EarlyNutrition project). Critical Reviews in Food Science and Nutrition. 2017. 57:489-500. doi:10.1080/10408398.2014.888701 | Outcome | -