# Appendix 3-a Literature search strategy for the protein requirements evidence scan

Backward Citation Mining, Level 1

Date(s) Searched: January 27, 2022

Article | Database Used | Results | Results after Deduplication
Deutz | Scopus | 91 | 91
Bauer | Scopus | 252 | 205
Hörnell | WoS | 52 | 51
FAO/WHO | WoS | 130 | 124
Pedersen | Scopus | 42 | 27
EFSA | Scopus | 252 | 232
Total | | 819 | 730

In Hörnell, there were 10 references which WoS could not export, due to the nature of their citations (reports not in English, not in the WoS database).

Forward Citation Mining, Level 1

Date(s) Searched: January 28, 2022

Article | Database Used | Results | Results after Deduplication
Deutz | Scopus | 702 | 701
Bauer | Scopus | 1,128 | 782
Hörnell | WoS | 65 | 64
FAO/WHO | WoS | 12 | 12
Pedersen | Scopus | 49 | 15
EFSA | Scopus | 174 | 136
Total | | 2,129 | 1,710