# Appendix 2-n Duplication assessment for protein intake and sarcopenia evidence

Articles included in reviews | Relevant outcome(s) assessed | Source review(s)
Aguiar AF, Eur J Appl Physiol 2013 | Muscle mass; Muscle strength | Naseeb, 2017
Ahnfeldt-Mollerup P, Eur J Phys Rehabil 2015 | Muscle strength | Lin, 2021
Aleman-Mateo H, Clin Interv Aging 2012 | Lean body mass; Appendicular lean mass; Handgrip strength | Kirwan, 2021
Aleman-Mateo H, Clin Interv Aging 2014 | Lean body mass; Appendicular lean mass; Handgrip strength | Kirwan, 2021
Antonio J, Nutrition 2000 | Lean muscle mass gain | Lin, 2021
Arnarson A, Eur J Clin Nutr 2013 | Lean body mass | Kirwan, 2021
Beasley JM, J Nutr Health Aging 2016 | Whole skeletal muscle mass | Yaegashi, 2021
Bjorkman MP, Eur Geriatr Med 2012 | Skeletal muscle mass | Kirwan, 2021
Campbell WW, Am J Clin Nutr 1994 | Lean body mass | Kirwan, 2021
Carlsson M, J Nutr Health Aging 2011 | Lean body mass | Kirwan, 2021
Chale A, J Gerontol A Biol Sci Med Sci 2013 | Lean body mass | Kirwan, 2021
Chan R, J Nutr Health Aging 2014 | Appendicular skeletal muscle mass; Lower-limb Muscle functioning/strength | Yaegashi, 2021; Coelho-Júnior, 2018
Cheng YH, Clin Nutr 2019 | Lean muscle mass gain | Lin, 2021
Cramer JT, J Strength Cond Res 2012 | Lean muscle mass gain | Lin, 2021
Daly RM, Am J Clin Nutr 2014 | Muscle mass; Muscle strength | Naseeb, 2017
Dirks ML, J Am Med Dir Assoc 2017 | Lean body mass; Appendicular lean mass; Handgrip strength; Knee ext. strength | Kirwan, 2021
Dirks ML, J Nutr 2014 | Muscle mass; Muscle strength | Naseeb, 2017
Elstgeest LEM, Am J Clin Nutr 2020 | Appendicular skeletal muscle mass | Yaegashi, 2021
Englund DA, J Gerontol A Biol Sci Med Sci 2017 | Lean muscle mass gain; Muscle strengh | Lin, 2021
Ferguson-Stegall L, J Nutr Metab 2011 | Lean muscle mass gain | Lin, 2021
Flakoll PJ, J Appl Physiol 2004 | Lean muscle mass gain | Lin, 2021
Genaro Pde S, Nutr Clin Pract 2015 | Appendicular skeletal muscle mass | Yaegashi, 2021
Gingrich A, Nutrients 2017 | Whole skeletal muscle mass | Yaegashi, 2021
Gregorio L, J Nutr Health Aging 2014 | Appendicular skeletal muscle mass; Upper-limb Muscle Strength; Lower-limb Muscle Strength | Yaegashi, 2021; Coelho-Júnior, 2018
Gryson C, J Am Med Dir Assoc 2014 | Lean body mass; Appendicular lean mass | Kirwan, 2021
Gualano B, Exp Gerontol 2014 | Muscle mass; Muscle strength | Naseeb, 2017
Hashemi R, Nutrition 2015 | Sarcopenia | Naseeb, 2017
Houston DK, Am J Clin Nutr 2008 | Appendicular skeletal muscle mass | Yaegashi, 2021
Huang RY, Nutrients 2016 | Whole skeletal muscle mass | Yaegashi, 2021
Iglay HB, J Nutr Health Aging 2009 | Lean body mass | Kirwan, 2021
Isanejad M, Br J Nutr 2016 | Upper-limb Muscle Strength; Lower-limb Muscle Strength | Coelho-Júnior, 2018
Isanejad M, J Nutr Sci 2015 | Appendicular skeletal muscle mass | Yaegashi, 2021
Jonvik KL, Med Sci Sports Exerc 2019 | Lean muscle mass gain; Muscle strength | Lin, 2021
Jyvakorpi SK, Eur Geriatr Med 2020 | Appendicular skeletal muscle mass | Yaegashi, 2021
Kephart WC, Amino Acids 2016 | Lean muscle mass gain | Lin, 2021
Kim H, J Am Med Dir Association 2016 | Lean muscle mass gain; Muscle strength | Lin, 2021
Kim HK, J Am Geriatri Soc 2012 | Muscle mass; Muscle strength | Naseeb, 2017
Kim SH, Arch Gerontol Geriatr 2013 | Appendicular skeletal muscle mass; Sarcopenia | Yaegashi, 2021; Naseeb, 2017
Knuiman P, Am J Clin Nutr 2019 | Lean muscle mass gain | Lin, 2021
Larocque SC, J. Nutr. Gerontol. Geriatr 2015 | Upper-limb muscle strength | Coelho-Júnior, 2018
Leenders M, Med Sci Sports Exerc 2013 | Lean body mass | Kirwan, 2021
Li C, J Acad Nutr Diet 2021 | Lean body mass; Appendicular lean mass; Handgrip strength | Kirwan, 2021
Liao YH, NeuroRehabiliation 2019 | Lean muscle mass gain; Muscle strength | Lin, 2021
Markofski MM, J Gerontol A Biol Sci Med Sci 2019 | Lean muscle mass gain; Muscle strength | Lin, 2021
Meng X, J Bone Miner Res 2009 | Appendicular skeletal muscle mass | Yaegashi, 2021
Mitchell CJ, Am J Clin Nutr 2017 | Lean body mass; Appendicular lean mass; Handgrip strength | Kirwan, 2021
Nabuco HCG, Clin Nutr ESPEN 2019 | Lean body mass; Appendicular lean mass; Knee ext. strength | Kirwan, 2021
Nabuco HCG, J Aging Phys Act 2019 | Appendicular lean mass | Kirwan, 2021
Nabuco HCG, Nutrients 2018 | Knee ext. strength | Kirwan, 2021
Nahas PC, Nutrients 2019 | Lean body mass; Knee ext. strength | Kirwan, 2021
Nilsson A, Nutrients 2018 | Whole skeletal muscle mass | Yaegashi, 2021
Oh C, Nutr Res 2018 | Appendicular skeletal muscle mass | Yaegashi, 2021
Ormsbee MJ, Int J Sport Nutr Exerc Metab 2018 | Lean muscle mass gain; Muscle strength | Lin, 2021
Otsuka R, Public Health Nutr 2020 | Appendicular skeletal muscle mass | Yaegashi, 2021
Ottestad I, J Nutr Health Aging 2017 | Lean body mass | Kirwan, 2021
Rahi B, Eur. J. Nutr 2016 | Lower-limb Muscle Strength | Coelho-Júnior, 2018
Rossato LT, Nutrients 2017 | Lean body mass | Kirwan, 2021
Scott D, J Am Geriatr Soc 2010 | Muscle mass; Muscle strength | Naseeb, 2017
Shahar S, Clin Interv Aging 2013 | Lean body mass; Handgrip strength | Kirwan, 2021
Sugihara Junior P, Int J Sport Nutr Exerc Metab 2018 | Knee ext. strength | Kirwan, 2021
ten Haaf D, Nutrients 2018 | Upper-limb muscle strength; Lower-limb Muscle Strength | Coelho-Júnior, 2018
Ten Haaf DSM, J Cachexia Sarcopenia Muscle 2019 | Lean body mass; Handgrip strength | Kirwan, 2021
Thomson RL, Clin Nutr 2016 | Lean body mass; Handgrip strength | Kirwan, 2021
Tieland M, J Am Med Dir Assoc 2012 (a) | Lean body mass; Appendicular lean mass; Handgrip strength; Knee ext. strength; Muscle mass; Muscle strength | Kirwan, 2021; Naseeb, 2017
Tieland M, J Am Med Dir Assoc 2012 (b) | Lean body mass; Appendicular lean mass; Handgrip strength; Knee ext. strength; Muscle mass; Muscle strength | Kirwan, 2021; Naseeb, 2017
Valenzuela RE, Clin Interv Aging 2013 | Appendicular skeletal muscle mass | Yaegashi, 2021
Verdijk LB, Am J Clin Nutr 2009 | Lean body mass; Knee ext. strength | Kirwan, 2021
Verlaan S, Clin Nutr 2015 | Upper-limb muscle strength | Coelho-Júnior, 2018
Walker TB, Int J Sport Nutr Exerc Metab 2010 | Lean muscle mass gain | Lin, 2021
Yaegashi A, Nutrients 2021 | Appendicular skeletal muscle mass | Yaegashi, 2021
Zdzieblik D, Br J Nutr 2015 | Lean body mass | Kirwan, 2021
Zhu K, J Nutr 2015 | Lean body mass | Kirwan, 2021