# Appendix 2-m Duplication assessment for protein intake and renal health evidence^a^ a GFR; Glomerular filtration rate

Articles included in reviews | Relevant outcome(s) assessed | Source review(s)
Antonio J, J Int Soc Sports Nutr, 2016 | GFR | Devries 2018
Antonio J, J Nutr Metab, 2016 | GFR | Devries 2018
Bergstrom J, Acta Med Scand, 1985 | GFR | Devries 2018
Berryman CE, Am J Clin Nutr, 2016 | GFR | van Elswyk 2018
Brinkworth GD, Int J Obes Relat Metab Disord, 2004 | GFR | Devries 2018
Brinkworth GD, J Am Diet Assoc, 2010 | GFR | Devries 2018
Chu J, Am J Clin Nutr, 1975 | GFR | Devries 2018
Doorenbos CJ, Clin Sci (Lond), 1990 | GFR | van Elswyk 2018
Frank H, Am J Clin Nutr, 2009 | GFR | Devries 2018; van Elswyk 2018
Friedman A, Clin J Am Soc Nephrol, 2012 | GFR | Devries 2018
Gross J, Diabetes Care, 2002 | GFR | Devries 2018; van Elswyk 2018
Hegsted M, J Nutr, 1981 | GFR | Devries 2018
Herber-Gast GM, Am J Clin Nutr, 2016 | GFR | van Elswyk 2018
Jenkins D, Am J Clin Nutr, 2001 | GFR | Devries 2018; van Elswyk 2018
Johnston C, J Nutr, 2004 | GFR | Devries 2018
Juraschek SP, Am J Kidney Dis, 2013 | GFR | Devries 2018; van Elswyk 2018
Kerstetter JE, Am J Clin Nutr, 1997 | GFR | van Elswyk 2018
Kerstetter JE, Am J Clin Nutr, 1998 | GFR | Devries 2018; van Elswyk 2018
Kerstetter JE, Am J Clin Nutr, 2000 | GFR | van Elswyk 2018
Kerstetter JE, J Nutr, 2006 | GFR | van Elswyk 2018
Kim Y, J Nutr, 1979 | GFR | Devries 2018
Kitazato H, Nephron, 2002 | GFR | van Elswyk 2018
Larsen R, Diabetologia, 2011 | GFR | Devries 2018
Leidy H, Obesity, 2007 | GFR | Devries 2018
Longland T, Am J Clin Nutr, 2016 | GFR | Devries 2018
Luger M, Exp Clin Endocrinol Diabetes, 2013 | GFR | Devries 2018
Luscombe-Marsh ND, Am J Clin Nutr, 2005 | GFR | Devries 2018
Noakes M, Am J Clin Nutr, 2005 | GFR | Devries 2018
Ogna A, Eur J Nutr, 2016 | GFR | van Elswyk 2018
Poortmans JR, Int J Sport Nutr Exerc Metab, 2000 | GFR | van Elswyk 2018
Rebholz CM, Am J Nephrol, 2015 | Kidney disease incidence | van Elswyk 2018
Roughead Z, J Nutr, 2003 | GFR | Devries 2018; van Elswyk 2018
Skov A, Int J Obes Relat Metab Disord, 1999 | GFR | Devries 2018
Tay J, Medicine, 2015 | GFR | Devries 2018
Teo BW, Ann Acad Med Singapore, 2015 | GFR | van Elswyk 2018
Teunissen-Beekman K, Phys Rep, 2016 | GFR | Devries 2018
Velazquez Lopez L, Nutr Hosp, 2008 | GFR | van Elswyk 2018
Wagner E, J Am Diet Assoc, 2007 | GFR | Devries 2018
Walrand S, Am J Physiol Endocrinol Metab, 2008 | GFR | Devries 2018; van Elswyk 2018
Wycherley T, Nutr Diabetes, 2012 | GFR | Devries 2018
Zykova SN, Nutr J, 2015 | GFR | van Elswyk 2018