# Appendix 2-l Duplication assessment for protein intake and diabetes risk evidence

Articles included in reviews | Relevant outcome(s) assessed | Source review(s)
Alhazmi A, Public Health Nutr 2014 | Type 2 Diabetes | Shang, 2016; Ye, 2019; Zhao, 2019
Bao W, Diabetes Care 2013 | Type 2 Diabetes | Tian, 2017
Chen Z, Clin Nutr 2019 | Type 2 Diabetes | Fan, 2019
Ericson U, Br J Nutr 2013 | Type 2 Diabetes | Fan, 2019; Shang, 2016; Tian, 2017
Malik VS, Am J Epidemiol 2016 | Type 2 Diabetes | Fan, 2019; Shang, 2017; Tian, 2017; Ye, 2019; Zhao, 2019
Nanri A, PLoS One, 2015 | Type 2 Diabetes | Shang, 2018; Tian, 2017; Ye, 2019; Zhao, 2019
Shang X, Am J Clin Nutr 2016 | Type 2 Diabetes | Fan, 2019; Shang, 2019; Tian, 2017; Ye, 2019; Zhao, 2019
Sluijs I, Diabetes Care 2010 | Type 2 Diabetes | Fan, 2019; Shang, 2020; Tian, 2017
Song Y, Diabetes Care 2004 | Type 2 Diabetes | Shang, 2020; Ye, 2019; Zhao, 2019
Tinker LF, Am J Clin Nut. 2011 | Type 2 Diabetes | Shang, 2020; Tian, 2017; Ye, 2019; Zhao, 2019
Van Nielen M, Diabetes Care 2014 | Type 2 Diabetes | Shang, 2020; Tian, 2017; Ye, 2019; Zhao, 2019
Virtanen HEK, Br J Nutr 2017 | Type 2 Diabetes | Fan, 2019; Tian, 2017; Ye, 2019; Zhao, 2019