# Appendix 2-k Duplication assessment for protein intake and cardiovascular disease risk evidence

Articles included in reviews | Relevant outcome(s) assessed | Source review(s)
Aaltonen J, J Pediatr. 2008 | Offspring BP | van Elten, 2019
Adair LS, Circulation. 2001 | Offspring BP | van Elten, 2019
Alonso A, Archives of Medical Research 2006 | Hypertension/Blood pressure | Mousavi, 2020
Altorf-van der Kuil W, Journal of Hypertension 2010 | Hypertension/Blood pressure | Mousavi, 2020
Altorf-van der Kuil W, British Journal of Nutrition 2012 | Hypertension/Blood pressure | Mousavi, 2020
Bates CJ, Br J Nutr 2010 | CVD Mortality | Naghshi, 2020
Bernstein AM, Stroke 2012 | Stroke risk | Zhang, 2016
Blumfield M, Nutrients 2015 | Offspring BP | van Elten, 2019
Brinkworth GDM, Diabetologia 2004b | Blood pressure | Schwingshackl, 2019
Brinkworth GDM, International Journal of Obesity and Related Metabolic Disorders 2004a | Blood pressure | Schwingshackl, 2019
Budhathoki S, JAMA Intern Med 2019 | CVD Mortality | Naghshi, 2020; Qi, 2020; Chen, 2020
Buendia JR, American Journal of Hypertension 2015 | Hypertension/Blood pressure | Mousavi, 2020
Campans-Kuijpers MJ, Cardiovasc Diabetol 2015 | CVD Mortality | Naghshi, 2020
Campbell DD, British Journal of Nutrition 2012 | Blood pressure | Schwingshackl, 2019
Chan R, J Nutr Health Aging 2019 | CVD Mortality | Naghshi, 2020; Qi, 2020
Chen Z, Eur J Epidemiol 2020 | CVD Mortality | Qi, 2020; Chen, 2020
Clifton PM, Nutr Metab Cardiovasc Dis 2014 | Blood pressure | Dinu, 2020
Courand PY, Hypertension 2016 | CVD Mortality | Naghshi, 2020
Dalle Grave R, Obesity (Silver Spring) 2013 | Blood pressure | Schwingshackl, 2019
Dansinger ML, JAMA 2005 | Blood pressure | Schwingshackl, 2019
Dehghan M, Lancet 2017 | CVD Mortality | Naghshi, 2020; Qi, 2020
Dehghan M, The Lancet 2017 | Coronary heart diesease | Mousavi, 2020
Delbridge EA, American Journal of Clinical Nutrition 2009 | Blood pressure | Schwingshackl, 2019
Dong YJ, Br J Nutr 2013 | Blood pressure | Dinu, 2020; Sukhato, 2020
Doorenbos CJ, Clin Sci (Lond) 1990 | Blood pressure | van Elswyk, 2018
Esrey KL, J Clin Epidemiol 1996 | CVD Mortality | Naghshi, 2020
Frank H, Am J Clin Nutr 2009 | Blood pressure | van Elswyk, 2018
Gross JL, Diabetes Care 2002 | Blood pressure | van Elswyk, 2018
Halton TL, The New England Journal of Medicine 2006 | Coronary heart diesease | Mousavi, 2020
Haring B, PLoS One 2014 | Coronary heart diesease | Mousavi, 2020
Haring B, Stroke 2015 | Stroke risk | Zhang, 2016
Hernandez Alonso P, Clin Nutr 2016 | CVD Mortality | Naghshi, 2020; Qi, 2020
Huh SY, Int J Epidemiol 2005 | Offspring BP | van Elten, 2019
Iso H, Am. J. Epidemiology 2003 | Stroke risk | Zhang, 2016
Iso H, Circulation 2001 | Stroke risk | Zhang, 2016
Jacobs DR Jr, Am J Kidney Dis 2009 | Blood pressure | van Elswyk, 2018
Jenkins DJ, Am J Clin Nutr 2001 | Blood pressure | van Elswyk, 2018
Juraschek SP, Am J Kidney Dis 2013 | Blood pressure | van Elswyk, 2018
Kelemen LE, Am J Epidemiol 2005 | Coronary heart diesease; CVD Mortality | Mousavi, 2020; Naghshi, 2020 Chen, 2020
Khaw KT, N. Engl. J. Med. 1987 | Stroke risk | Zhang, 2016
Kim HH, Journal of Diabetes Investigation 2014 | Blood pressure | Schwingshackl, 2019
Kitazato H, Nephron 2002 | Blood pressure | van Elswyk, 2018
Krebs JD, Diabetologia 2012 | Blood pressure | Schwingshackl, 2019
Kurihara A, Journal of Atherosclerosis and Thrombosis 2019 | Coronary heart diesease | Mousavi, 2020
Lagiou P, BMJ 2012 | Stroke risk | Zhang, 2016
Larsson SC, Atherosclerosis 2012 | Stroke risk | Zhang, 2016
Leary SD, Arch Dis Child. 2005 | Offspring BP | van Elten, 2019
Leary SD, J Epidemiol Community Health. 2013 | Offspring BP | van Elten, 2019
Lelong H, Hypertension 2017 | Hypertension/Blood pressure | Mousavi, 2020
Levine ME, Cell Metabol 2014 | CVD Mortality | Naghshi, 2020; Qi, 2020; Chen, 2020
Luger M, Experimental and Clinical Endocrinology & Diabetes 2013 | Blood pressure | Schwingshackl, 2019
Nagata C, J. Nutr. 2015 | CVD Mortality; Stroke risk | Naghshi, 2020; Zhang, 2016
Normia J, J Hum Nutr Diet. 2013 | Offspring BP | van Elten, 2019
Nuttall FQ, Metabolism 2006 | Blood pressure | van Elswyk, 2018
Preis SR, AJCN 2010 | CVD Mortality; Stroke risk; Coronary heart diesease | Naghshi, 2020; Zhang, 2016; Mousavi, 2020
Prentice RL, Epidemiology 2011 | Stroke risk; Coronary heart diesease | Zhang, 2016; Mousavi, 2020
Rebholz CM, Am J Epidemiol 2012 | Blood pressure | Sukhato, 2020
Santesso, N Eur J Clin Nutr 2012 | Blood pressure | Dinu, 2020; Sukhato, 2020
Sauvaget C, Stroke 2004 | CVD Mortality; Stroke risk | Naghshi, 2020; Zhang, 2016
Schwingshackl L, Nutr J 2013 | Blood pressure | Dinu, 2020; Sukhato, 2020
Song M, JAMA Intern Med 2016 | CVD Mortality | Qi, 2020; Chen, 2020
Sun Y, Curr Dev Nutr 2019 | CVD Mortality | Naghshi, 2020
Talaei M, J Nutr 2014 | Stroke risk | Zhang, 2016
Tang M, Obesity (Silver Spring) 2013 | Blood pressure | Schwingshackl, 2019
Tharrey M, Int J Epidemiol 2018 | CVD Mortality | Qi, 2020
Tielemans S, J Hum Hypertens 2013 | Blood pressure | Sukhato, 2020
van den Hil LCL, Br J Nutr. 2013 | Offspring BP | van Elten, 2019
Velazquez LL, Nutr Hosp 2008 | Blood pressure | van Elswyk, 2018
Wallstrom P, PLoS One 2012 | Coronary heart disease | Mousavi, 2020
Watson N, Nutrients 2016 | Blood pressure | Schwingshackl, 2019
Wycherley TP, Am J Clin Nutr 2012 | Blood pressure | Dinu, 2020
Wycherley TP, Diabetes Care 2010 | Blood pressure | Schwingshackl, 2019
Zhao WT, Medicine 2018 | Blood pressure | Dinu, 2020; Sukhato, 2020