# Appendix 2-j Duplication assessment for protein intake and bone health evidence

Articles included in reviews | Relevant outcome(s) assessed | Source review(s)
Abelow BJ, Calcif Tissue Int, 1992 | Fracture (hip) | Darling 2019
Alekel DL, Am J Clin Nutr, 2000 | BMD/BMC | Darling 2019
Alexy U, Am J Clin Nutr, 2005 | BMC | Darling 2019
Alissa EM, J Am Coll Nutr, 2014 | BMD | Darling 2019
Alissa EM, J Bone Miner Metab, 2011 | BMD, Osteopenia | Darling 2019
Aoe S, Biosci Biotechnol Biochem, 2001 | BMD | Darling 2019
Aoe S, Osteoporos Int, 2005 | BMD | Darling 2019; Wallace 2017
Avenell A, Eur J Clin Nutr, 1994 | BMD | Wright 2019
Backx EMP, Int J Obes, 2016 | BMD/BMC | Wright 2019
Ballard TLP, Bone, 2006 | BMD/BMC | Wallace 2017
Beasley JM, Am J Clin Nutr, 2010 | BMD | Darling 2019
Beasley JM, Am J Clin Nutr, 2014 | BMD, Fracture (any, hip, spine, forearm) | Darling 2019; Groenendijk 2019; Shams-White 2017; Tsagari 2020; Wallace 2017
Bounds W, J Am Diet Assoc, 2005 | BMD/BMC | Darling 2019
Bowen J, J Nutr, 2004 | BMD | Wright 2019
Brehm BJ, J Clin Endocrinol Metab, 2005 | BMC | Wright 2019
Budek AZ, Osteoporos Int, 2007 | BMC | Darling 2019
Cauley JA, J Bone Miner Res, 2016 | Fracture (hip) | Groenendijk 2019; Shams-White 2017
Chan R, Food Nutr Bull, 2009 | BMD | Darling 2019
Chan R, J Nutr Health Aging, 2011 | BMD | Darling 2019
Chevalley T, J Bone Miner Res, 2014 | BMD/BMC | Cureneen 2018; Darling 2019; Groenendijk 2019
Chevalley T, J Clin Endocrinol Metab, 2011 | Fracture (any) | Darling 2019
Chevalley, J Bone Miner Res, 2008 | BMC | Darling 2019
Chiu JF, Calcif Tissue Int, 1997 | BMD, Osteopenia | Darling 2019
Clifton PM, Am J Clin Nutr, 2008 | BMD/BMC | Wright 2019
Coin A, Eur J Clin Nutr, 2008 | BMD | Darling 2019
Cooper C, Calcif Tissue Int, 1996 | BMD | Darling 2019
Courteix D, PloS One, 2015 | BMD/BMC | Wright 2019
Dargent-Molina P, J Bone Miner Res, 2008 | Fracture (any) | Cureneen 2018; Darling 2019; Shams-White 2017
Dawson-Hughes, Am J Clin Nutr, 2002 | BMD | Cureneen 2018; Darling 2019; Groenendijk 2019; Shams-White 2017; Tsagari 2020
Devine A, Am J Clin Nutr, 2005 | BMD | Cureneen 2018; Darling 2019; Groenendijk 2019; Wallace 2017
Ekbote VH, J Bone Miner Metab, 2011 | BMC | Darling 2019
Evans EM, Menopause, 2007 | BMD | Darling 2019
Fairweather-Tait SJ, Am J Clin Nutr, 2011 | BMD | Darling 2019
Farrin N, Saudi Med J, 2008 | Osteoporosis/Osteopenia | Darling 2019
Feskanich D, Am J Epidemiol, 1996 | Fracture (forearm, hip) | Darling 2019; Shams-White 2017
Flodin L, Clin Interv Aging, 2014 | BMD | Shams-White 2017; Tsagari 2020
Frassetto LA, J Gerontol A Biol Sci Med Sci, 2000 | Fracture (hip) | Darling 2019
Freudenheim JL, Am J Clin Nutr, 1986 | BMC | Darling 2019
Fung TT, Osteopporos Int, 2017 | Fracture (hip) | Groenendijk 2019; Wallace 2017
Geinoz G, Osteoporos Int, 1993 | BMD | Cureneen 2018; Darling 2019
Genaro PD, Nutr Clin Pract, 2015 | BMD/BMC | Darling 2019
Gregg EW, Osteoporos Int, 1999 | BMD | Darling 2019
Gunn CA, J Nutr Health Aging, 2014 | BMD, Osteoporosis | Darling 2019
Hannan MT, J Bone Miner Res, 2000 | BMD | Cureneen 2018; Darling 2019; Groenendijk 2019; Shams-White 2017; Tsagari 2020; Wallace 2017
Henderson NK, J Bone Miner Res, 1995 | BMD | Darling 2019
Hernandezavila M, Epidemiology, 1993 | BMD | Darling 2019
Hinton PS, Eur J Clin Nutr, 2010 | BMD/BMC | Wright 2019
Hinton PS, Eur J Clin Nutr, 2012 | BMD/BMC | Wright 2019
Hirota T, Am J Clin Nutr, 1992 | BMD | Darling 2019
Ho SC, Osteoporos Int, 2003 | BMD/BMC | Darling 2019
Ho SC, Osteoporos Int, 2008 | BMD/BMC | Darling 2019; Shams-White 2017; Tsagari 2020
Ho-Pham LT, Eur J Clin Nutr, 2012 | BMD/BMC | Darling 2019; Wallace 2017
Ho-Pham LT, Osteoporos Int, 2009 | BMD | Darling 2019
Hoppe C, Osteoporos Int, 2000 | BMC | Darling 2019
Horiuchi T, Osteoporos Int, 2000 | BMD | Darling 2019
Hu T, Brit J Nutr, 2014 | BMD | Darling 2019
Ilich JZ, Eur J Clin Nutr, 2003 | BMD/BMC | Cureneen 2018; Darling 2019
Isanejad M, J Nutr Health Aging, 2017 | BMC | Groenendijk 2019
Iuliano-Burns S, Osteoporos Int, 2005 | BMC | Darling 2019
Jaime PC, Sao Paulo Med J, 2006 | BMD | Darling 2019
Jesudason D, Am J Clin Nutr, 2013 | BMD | Shams-White 2017; Tsagari 2020; Wright 2019
Jones G, Am J Clin Nutr, 2001 | BMD | Darling 2019
Jones KW, Eur J Clin Nutr, 2013 | BMD/BMC | Wright 2019
Josse AR, J Clin Endocr Metab, 2012 | BMD/BMC | Wright 2019
Kenny AM, Am J Clin Nutr, 2009 | BMD | Darling 2019
Kerstetter JE, Calcif Tissue Int, 2000 | BMD | Cureneen 2018;
Kerstetter JE, J Clin Endocrinol Metab, 2015 | BMD | Cureneen 2018; Darling 2019; Shams-White 2017; Tsagari 2020; Wallace 2017
Key TJ, Public Health Nutr, 2007 | Fracture (any) | Darling 2019
Kim J, Asia Pac J Clin Nutr, 2008 | Osteoporosis | Cureneen 2018; Darling 2019
Knurick JR, Nutrients, 2015 | BMD | Darling 2019
Koh WP, Am J Epidemiol, 2009 | Fracture (hip) | Shams-White 2017
Kukuljan S, Osteoporos Int, 2009 | BMD | Shams-White 2017; Tsagari 2020
Kumar A, J Bone Miner Metab, 2010 | BMD | Darling 2019
Labouesse MA, Bone, 2014 | BMD/BMC | Wright 2019
Lacey JM, J Bone Miner Res, 1991 | BMC | Darling 2019
Langsetmo L, J Bone Miner Res, 2017 | BMD | Groenendijk 2019; Wallace 2017
Langsetmo L, J Nutr Health Aging, 2015 | BMD, Fracture (any) | Darling 2019; Shams-White 2017; Wallace 2017
Lau EMC, Eur J Clin Nutr, 1998 | BMD | Darling 2019
Li Z, Nutr J, 2010 | BMD | Shams-White 2017; Tsagari 2020; Wright 2019
Libuda L, Am J Clin Nutr, 2008 | BMC | Darling 2019
Libuda L, Br J Nutr, 2011 | BMC | Darling 2019
Liu X, Br J Nutr, 2013 | BMD | Wright 2019
Loenneke JP, Ann Nutr Metab, 2010 | BMD/BMC | Darling 2019
Macdonald HM, Am J Clin Nutr, 2005 | BMD | Darling 2019
Martinez-Ramirez MJ, Clin Nutr, 2012 | Fracture (any) | Cureneen 2018; Darling 2019
Meng X, J Bone Miner Res, 2009 | BMC | Darling 2019; Groenendijk 2019; Wallace 2017
Metz JA, Am J Clin Nutr, 1993 | BMD/BMC | Darling 2019
Meyer HE, Am J Epidemiol, 1997 | Fracture (hip) | Darling 2019; Shams-White 2017
Michaelsson K, Calcif Tissue Int, 1995 | BMD | Darling 2019
Misra D, Osteoporos Int, 2011 | Fracture (hip) | Cureneen 2018; Darling 2019; Groenendijk 2019; Shams-White 2017; Wallace 2017
Munger RG, Am J Clin Nutr, 1999 | Fracture (hip) | Cureneen 2018; Darling 2019; Shams-White 2017; Wallace 2017
Mussolino ME, J Bone Miner Res, 1998 | Fracture (hip) | Darling 2019; Shams-White 2017; Wallace 2017
Nakata Y, J Bone Miner Metab, 2008 | BMD/BMC | Wright 2019
Neville CE, Calcif Tissue Int, 2002 | BMD | Darling 2019
New SA, Am J Clin Nutr, 1997 | BMD | Darling 2019
Nieves JW, Osteoporos, 1992 | Fracture (hip) | Darling 2019
Orozco Lopez P, An Med Interna, 1998 | BMD | Darling 2019
Orwoll ES, Am J Clin Nutr, 1987 | BMC | Darling 2019
Park YJ, J Korean Acad Nurs, 2014 | BMD | Darling 2019
Pedone C, Bone, 2010 | BMD | Wallace 2017
Perez Durillo FT, Aten Primaria, 2011 | Fracture (hip) | Darling 2019
Pop LC, Am J Clin Nutr, 2015 | BMD/BMC | Wright 2019
Pop LC, Osteoporos Int, 2017 | BMD/BMC | Wright 2019
Preisinger E, Wien Klin Wochenschr, 1995 | Osteoporosis | Darling 2019
Pritchard JE, Int J Obes, 1996 | BMD/BMC | Wright 2019
Promislow JH, Am J Epidemiol, 2002 | BMD | Darling 2019; Shams-White 2017; Tsagari 2020
Quintas ME, Eur J Clin Nutr, 2003 | BMD | Darling 2019
Ramsdale SJ, Clin Sci, 1994 | BMD/BMC | Wright 2019
Rapuri PB, Am J Clin Nutr, 2003 | BMD | Cureneen 2018; Darling 2019; Groenendijk 2019; Wallace 2017
Recker RR, JAMA, 1992 | BMD | Shams-White 2017; Tsagari 2020
Ricci TA, J Bone Miner Res, 1998 | BMD/BMC | Wright 2019
Riedt CS, J Bone Miner Res, 2005 | BMD/BMC | Wright 2019
Rosado JL, J Am Diet Assoc, 2011 | BMC | Wright 2019
Rubinacci A, Minerva Med, 1992 | BMC | Darling 2019
Sahni S, J Bone Miner Res, 2010 | Fracture (hip) | Darling 2019; Shams-White 2017
Sahni S, Public Health Nutr, 2014 | BMD | Darling 2019; Shams-White 2017; Tsagari 2020; Wallace 2017
Samieri C, Osteoporos Int, 2013 | Fracture (hip, spine, wrist) | Darling 2019
Schurch MA, Ann Intern Med, 1998 | BMD | Darling 2019; Shams-White 2017; Tsagari 2020
Schwingel A, Revista Brasileira de Cineantropometria & Desempenho Humano, 2006 | BMC | Wright 2019
Sellmeyer DE, Am J Clin Nutr, 2001 | Fracture (hip) | Cureneen 2018; Darling 2019
Shapses SA, J Bone Miner Res, 2001 | BMD/BMC | Wright 2019
Skov AR, Obes Res, 2002 | BMD/BMC | Wright 2019
Sukumar D, J Bone Miner Res, 2011 | BMD | Shams-White 2017; Tsagari 2020; Wright 2019
Svendsen OL, Am J Med, 1993 | BMD | Wright 2019
Tang M, Nutr Res, 2013 | BMD/BMC | Wright 2019
Teegarden D, Am J Clin Nutr, 1998 | BMD/BMC | Darling 2019
Tengstrand B, Clin Nutr, 2007 | BMD | Shams-White 2017; Tsagari 2020
Thomas DT, J Am Coll Nutr, 2010 | BMD | Wright 2019
Thorpe M, J Nutr, 2008 | BMD | Cureneen 2018; Darling 2019; Shams-White 2017; Tsagari 2020; Wright 2019
Tirosh A, J Clin Endocrinol Metab, 2015 | BMD | Shams-White 2017; Tsagari 2020; Wright 2019
Tkatch L, J Am Coll Nutr, 1992 | BMD | Darling 2019
Tucker KL, Eur J Nutr, 2001 | BMD | Wallace 2017
Tylavsky FA, Am J Clin Nutr, 1988 | BMD/BMC | Darling 2019
Uenishi K, Osteoporos Int, 2007 | BMD | Darling 2019
Van Loan MD, Am J Clin Nutr, 1998 | BMD/BMC | Wright 2019
Vatanparast H, J Nutr, 2007 | BMD/BMC | Darling 2019
Villareal DT, Arch Intern Med, 2006 | BMD | Wright 2019
Vupadhyayula PM, Menopause, 2009 | BMD | Darling 2019
Wang MC, Oseoporos Int, 1997 | BMD/BMC | Cureneen 2018; Darling 2019
Weiss EP, Med Sci Sports Exerc, 2017 | BMD | Wright 2019
Wengreen HJ, J Bone Miner Res, 2004 | Fracture (hip) | Cureneen 2018; Darling 2019
Whiting SJ, J Am Coll Nutr, 2002 | BMD | Darling 2019
Yamamura J, Biosci Biotechnol Biochem, 2002 | BMD | Darling 2019
Yazdanpanah N, Bone, 2007 | BMD | Darling 2019
Zhang Q, Brit J Nutr, 2010 | BMC | Darling 2019
Zhang X, Arch Intern Med, 2005 | Fracture (any) | Darling 2019; Shams-White 2017
Zhong Y, Nutrition, 2009 | Fracture (any) | Cureneen 2018; Darling 2019
Zhu K, J Bone Miner Res, 2011 | BMD | Cureneen 2018; Darling 2019; Groenendijk 2019; Shams-White 2017; Tsagari 2020; Wallace 2017
Zou ZY, Eur J Nutr, 2009 | BMD | Darling 2019; Wallace 2017