# Appendix 2-i Duplication assessment for protein intake and all-cause mortality evidence

Articles included in reviews | Relevant outcome(s) assessed | Source review(s)
Argos M, Int J Cancer 2013 | All-cause mortality | Naghshi, 2020
Bates CJ, Br J Nutr 2010 | All-cause mortality | Naghshi, 2020; Qi, 2020; Chen, 2020
Borugian MJ, Cancer Epidemiol Biomarkers Prev 2004 | All-cause mortality | Naghshi, 2020
Budhathoki S, JAMA Intern Med 2019 | All-cause mortality | Naghshi, 2020; Qi, 2020; Chen, 2020
Campmans-Kuijpers MJ, Cardiovasc Diabetol 2015 | All-cause mortality | Naghshi, 2020
Chan R, J Nutr Health Aging 2019 | All-cause mortality | Naghshi, 2020; Qi, 2020
Chen Z, Eur J Epidemiol 2020 | All-cause mortality | Qi, 2020; Chen, 2020
Courand PY, Hypertension 2016 | All-cause mortality | Naghshi, 2020
Dehghan M, Lancet 2017 | All-cause mortality | Naghshi, 2020; Qi, 2020
Dwyer JT, Am J Public Health 1994 | All-cause mortality | Naghshi, 2020
Esrey KL, J Clin Epidemiol 1996 | All-cause mortality | Naghshi, 2020
Halbesma N, J Am Soc Nephrol 2009 | All-cause mortality | Naghshi, 2020
Hernandez Alonso P, Clin Nutr 2016 | All-cause mortality | Naghshi, 2020; Qi, 2020
Holmes MD, Cancer 1999 | All-cause mortality | Naghshi, 2020
Holmes MD, J Clin Oncol 2017 | All-cause mortality | Naghshi, 2020
Kelemen LE, Am J Epidemiol 2005 | All-cause mortality | Naghshi, 2020; Qi, 2020; Chen, 2020
Kurihara A, J Atheroscler Thromb 2019 | All-cause mortality | Chen, 2020
Levine ME, Cell Metab 2014 | All-cause mortality | Naghshi, 2020; Qi, 2020; Chen, 2020
Mendonca N, Eur J Nutr 2019 | All-cause mortality | Naghshi, 2020
Nagata C, J Nutr 2015 | All-cause mortality | Naghshi, 2020
Palli D, Cancer 2000 | All-cause mortality | Naghshi, 2020
Papanikolaou Y, Curr Dev Nutr 2019 | All-cause mortality | Naghshi, 2020
Payette H, J Gerontol A Biol Sci Med Sci 1999 | All-cause mortality | Naghshi, 2020
Preis SR, Am J Clin Nutr 2010 | All-cause mortality | Naghshi, 2020
Rohan TE, Nutr Cancer 1993 | All-cause mortality | Naghshi, 2020
Sauvaget C, Stroke 2004 | All-cause mortality | Naghshi, 2020
Smit E, Nutr Cancer 2007 | All-cause mortality | Naghshi, 2020
Song M, JAMA Intern Med 2016 | All-cause mortality | Naghshi, 2020; Qi, 2020; Chen, 2020
Song M, JNCI Cancer Spectr 2018 | All-cause mortality | Naghshi, 2020
Virtanen HEK, Am J Clin Nutr 2019 | All-cause mortality | Naghshi, 2020; Qi, 2020; Chen, 2020
Zaslavsky O, Am J Clin Nutr 2017 | All-cause mortality | Naghshi, 2020