# Appendix 2-h AMSTAR 2 assessment of review quality and funding source by outcome category^a^ a Q1*: Did the research questions and inclusion criteria for the review include the components of PICO?; Q2: Did the report of the review contain an explicit statement that the review methods were established prior to the conduct of the review and did the report justify any significant deviations from the protocol?; Q3: Did the review authors explain their selection of the study designs for inclusion in the review?; Q4*: Did the review authors use a comprehensive literature search strategy?; Q5: Did the review authors perform study selection in duplicate?; Q6: Did the review authors perform data extraction in duplicate?; Q7*: Did the review authors provide a list of excluded studies and justify the exclusions?; Q8*: Did the review authors describe the included studies in adequate detail?; Q9*: Did the review authors use a satisfactory technique for assessing the risk of bias [RoB] in individual studies that were included in the review?; Q10: Did the review authors report on the sources of funding for the studies included in the review?; Q11: If meta-analysis was performed did the review authors use appropriate methods for statistical combination of results?; Q12: If meta-analysis was performed, did the review authors assess the potential impact of RoB in individual studies on the results of the meta-analysis or other evidence synthesis?; Q13*: Did the review authors account for RoB in individual studies when interpreting/discussing the results of the review?; Q14: Did the review authors provide a satisfactory explanation for, and discussion of, any heterogeneity observed in the results of the review?; Q15*: If they performed quantitative synthesis did the review authors carry out an adequate investigation of publication bias [small study bias] and discuss its likely impact on the results of the review?; Q16*: Did the review authors report any potential sources of conflict of interest, including any funding they received for conducting the review? * denotes questions that were considered critical domains ^,b^ b Abbreviations: N: No; NM: No meta-analysis; PY: Probably yes; Q: Question; Y: Yes

Article | AMSTAR 2 | | | | | | | | | | | | | | | | Overall rating | Funding
Article | Q1 | Q2 | Q3 | Q4 | Q5 | Q6 | Q7 | Q8 | Q9 | Q10 | Q11 | Q12 | Q13 | Q14 | Q15 | Q16 | Overall rating | Funding
All-cause mortality
Chen, 2020^23^ | Y | PY | Y | PY | Y | N | PY | Y | PY | N | Y | Y | Y | Y | Y | Y | Moderate | None
Naghshi, 2020^24^ | Y | N | N | PY | N | Y | Y | Y | Y | N | Y | N | N | Y | Y | Y | Low | Tehran University of Medical Sciences
Qi, 2020^25^ | Y | PY | Y | PY | Y | N | Y | PY | PY | N | Y | Y | Y | N | Y | Y | Moderate | None
Bone health
Curneen, 2018^26^ | N | N | N | PY | N | N | N | Y | N | N | NM | NM | N | Y | NM | Y | Critically low | None
Darling, 2019^27^ | Y | N | Y | N | Y | N | PY | Y | Y | N | Y | Y | Y | Y | Y | Y | Low | Not reported
Groenendijk, 2019^28^ | Y | N | Y | Y | Y | Y | PY | Y | Y | N | Y | Y | Y | Y | Y | Y | Moderate | Jaap Schouten Foundation
Shams-White, 2017^29^ | Y | Y | Y | Y | Y | Y | PY | Y | Y | Y | Y | N | Y | Y | N | Y | Low | National Osteoporosis Foundation through support of Egg Nutrition Center and Dairy Management Inc
Tsagari, 2020^30^ | Y | N | Y | N | N | N | N | N | N | N | NM | NM | N | N | NM | Y | Critically low | Not reported
Wallace, 2017^31^ | Y | N | Y | Y | Y | Y | N | Y | N | N | Y | N | N | Y | N | Y | Critically low | Beef Checkoff through National Cattleman’s Beef Association
Wright, 2019^32^ | Y | Y | Y | Y | Y | Y | PY | Y | Y | N | Y | Y | Y | Y | N | Y | Low | NIH; Purdue University
Cardiovascular disease risk
Chen, 2020^23^ | Y | PY | Y | PY | Y | N | PY | Y | PY | N | Y | Y | Y | Y | Y | Y | Moderate | None
Dinu, 2020^33^ | Y | Y | Y | Y | Y | Y | PY | Y | Y | N | Y | Y | Y | Y | Y | Y | High | None
Mousavi, 2020^38^ | Y | PY | Y | PY | N | Y | Y | Y | PY | N | Y | Y | Y | Y | Y | Y | Moderate | Not reported
Naghshi, 2020^24^ | Y | N | N | PY | N | Y | Y | Y | Y | N | Y | N | N | Y | Y | Y | Low | Tehran University of Medical Sciences
Qi, 2020^25^ | Y | PY | Y | PY | Y | N | Y | PY | PY | N | Y | Y | Y | N | Y | Y | Moderate | None
Schwingshackl, 2019^34^ | Y | Y | Y | Y | N | Y | Y | Y | Y | N | Y | Y | Y | Y | Y | Y | Moderate | None
Sukhato, 2020^39^ | Y | Y | Y | PY | Y | Y | PY | Y | Y | N | NM | NM | Y | Y | NM | Y | High | Prince Mahidol Award Foundation; Thai Health Promotion Foundation; International Decision Support Initiative; Thailand Research Fund
Van Elswyk, 2018^35^ | Y | N | Y | N | N | N | Y | Y | Y | N | NM | NM | Y | Y | NM | Y | Low | Beef Checkoff
van Elten, 2019^37^ | Y | Y | Y | Y | Y | Y | PY | Y | Y | N | NM | NM | Y | Y | NM | Y | High | Dutch Heart Foundation; European Commission
Zhang, 2016^36^ | N | N | N | PY | N | N | N | PY | PY | N | Y | Y | Y | Y | Y | Y | Critically low | Not reported
Diabetes risk
Dinu, 2020^33^ | Y | Y | Y | Y | Y | Y | PY | Y | Y | N | Y | Y | Y | Y | Y | Y | High | None
Fan, 2019^42^ | Y | N | Y | Y | N | Y | PY | Y | Y | N | Y | Y | Y | Y | Y | Y | Moderate | National Key Research and Development Program of China; National Natural Science Foundation of China
Shang, 2016^43^ | Y | N | Y | PY | N | N | Y | Y | PY | N | Y | Y | Y | Y | Y | Y | Moderate | VicHealth; Cancer Council Victoria; Australian National Health and Medical Research Council
Tian, 2017^44^ | Y | N | Y | PY | N | N | PY | N | N | N | Y | N | N | Y | Y | Y | Critically low | National Natural Science Foundation of China; Harbin Medical University
Ye, 2019^45^ | Y | N | Y | Y | Y | Y | PY | Y | Y | N | Y | Y | Y | Y | Y | Y | Moderate | Not reported
Zhao, 2019^46^ | Y | N | Y | Y | Y | Y | Y | Y | Y | N | Y | N | Y | Y | Y | Y | Moderate | State Key Laboratory of Oncogenes and Related Genes
Renal health
Devries, 2018^63^ | Y | N | Y | PY | N | N | PY | Y | Y | N | Y | Y | Y | Y | Y | Y | Moderate | US National Dairy Council; Dairy Farmers of Canada; US National Beef Cattlemen’s Association
Van Elswyk, 2018^35^ | Y | N | Y | N | N | N | Y | Y | Y | N | NM | NM | Y | Y | NM | Y | Low | Beef Checkoff
Sarcopenia
Coelho-Junior, 2018^64^ | Y | N | Y | PY | Y | Y | PY | PY | N | N | Y | N | N | Y | N | Y | Critically low | Coordenação de Aperfeiçoamento de Pessoal de Nível Superior; Fundação de Amparo à Pesquisa do Estado de São Paulo; CNPq
Kirwan, 2021^67^ | Y | PY | Y | PY | Y | Y | PY | Y | Y | N | Y | N | N | Y | Y | Y | Low | Institute for Health Research at Liverpool John Moores University
Lin, 2021^53^ | Y | Y | Y | PY | Y | N | PY | Y | Y | N | Y | Y | N | Y | Y | Y | Low | Ministry of Science and Technology, Taiwan
Naseeb, 2017^66^ | N | N | N | N | N | N | N | PY | N | N | NM | NM | N | N | NM | Y | Critically low | Not reported
Yaegashi, 2021^65^ | Y | N | N | PY | Y | Y | N | Y | N | Y | NM | NM | N | Y | NM | Y | Critically low | Not reported