# Appendix 2-g Excluded articles for protein intake and appetite/satiety evidence scan (supplemental to chronic disease risk scan)

The following table lists the articles excluded after full-text screening for this evidence scan. At least one reason for exclusion is provided for each article, though this may not reflect all possible reasons. Information about articles excluded after title and abstract screening is available upon request.

# | Citation | Exclusion reason #1 | Exclusion reason #2
1 | Chapman, I, Oberoi, A, Giezenaar, C, Soenen, S. Rational Use of Protein Supplements in the Elderly-Relevance of Gastrointestinal Mechanisms. Nutrients. 2021. 13:#pages#. doi:10.3390/nu13041227 | Study Design | -
2 | Dela Cruz, J, Kahan, D. Pre-Sleep Casein Supplementation, Metabolism, and Appetite: A Systematic Review. Nutrients. 2021. 13:#pages#. doi:10.3390/nu13061872 | Intervention/Exposure | -
3 | Freire, RH, Alvarez-Leite, JI. Appetite control: hormones or diet strategies?. Curr Opin Clin Nutr Metab Care. 2020. 23:328-335. doi:10.1097/MCO.0000000000000675 | Study Design | -
4 | Hansen, TT, Astrup, A, Sjodin, A. Are Dietary Proteins the Key to Successful Body Weight Management? A Systematic Review and Meta-Analysis of Studies Assessing Body Weight Outcomes after Interventions with Increased Dietary Protein. Nutrients. 2021. 13:#pages#. doi:10.3390/nu13093193 | Outcome | -
5 | Li, M, Zhao, S, Wu, S, Yang, X, Feng, H. Effectiveness of Oral Nutritional Supplements on Older People with Anorexia: A Systematic Review and Meta-Analysis of Randomized Controlled Trials. Nutrients. 2021. 13:#pages#. doi:10.3390/nu13030835 | Intervention/Exposure | -
6 | Lonnie, M, Hooker, E, Brunstrom, JM, Corfe, BM, Green, MA, Watson, AW, Williams, EA, Stevenson, EJ, Penson, S, Johnstone, AM. Protein for Life: Review of Optimal Protein Intake, Sustainable Dietary Sources and the Effect on Appetite in Ageing Adults. Nutrients. 2018. 10:#pages#. doi:10.3390/nu10030360 | Study Design | -
7 | Lonnie, M, Laurie, I, Myers, M, Horgan, G, Russell, WR, Johnstone, AM. Exploring Health-Promoting Attributes of Plant Proteins as a Functional Ingredient for the Food Sector: A Systematic Review of Human Interventional Studies. Nutrients. 2020. 12:#pages#. doi:10.3390/nu12082291 | Intervention/Exposure | -
8 | Magkos, F. The role of dietary protein in obesity. Rev Endocr Metab Disord. 2020. 21:329-340. doi:10.1007/s11154-020-09576-3 | Study Design | -
9 | Mollahosseini, M, Shab-Bidar, S, Rahimi, MH, Djafarian, K. Effect of whey protein supplementation on long and short term appetite: A meta-analysis of randomized controlled trials. Clin Nutr ESPEN. 2017. 20:34-40. doi:10.1016/j.clnesp.2017.04.002 | Intervention/Exposure | -
10 | Moon, J, Koh, G. Clinical Evidence and Mechanisms of High-Protein Diet-Induced Weight Loss. J Obes Metab Syndr. 2020. 29:166-173. doi:10.7570/jomes20028 | Study Design | -
11 | Morales, Ms FE, Tinsley, GM, Gordon, PM. Acute and Long-Term Impact of High-Protein Diets on Endocrine and Metabolic Function, Body Composition, and Exercise-Induced Adaptations. J Am Coll Nutr. 2017. 36:295-305. doi:10.1080/07315724.2016.1274691 | Study Design | Outcome
12 | Ojha, U. Protein-induced satiation and the calcium-sensing receptor. Diabetes Metab Syndr Obes. 2018. 11:45-51. doi:10.2147/DMSO.S156597 | Study Design | -
13 | Qiu, M, Zhang, Y, Long, Z, He, Y. Effect of Protein-Rich Breakfast on Subsequent Energy Intake and Subjective Appetite in Children and Adolescents: Systematic Review and Meta-Analysis of Randomized Controlled Trials. Nutrients. 2021. 13:#pages#. doi:10.3390/nu13082840 | Intervention/Exposure | -
14 | Zhang, Y, Chen, X, Allison, DB, Xun, P. Efficacy and safety of a specific commercial high-protein meal-replacement product line in weight management: meta-analysis of randomized controlled trials. Crit Rev Food Sci Nutr. 2020. #volume#:1-12. doi:10.1080/10408398.2020.1829539 | Outcome | -