# Appendix 2-f Excluded articles for protein intake and sleep duration evidence scan (supplemental to chronic disease risk scan)

The following table lists the articles excluded after full-text screening for this evidence scan. At least one reason for exclusion is provided for each article, though this may not reflect all possible reasons. Information about articles excluded after title and abstract screening is available upon request.

# | Citation | Exclusion reason #1 | Exclusion reason #2
1 | Doherty, R, Madigan, S, Warrington, G, Ellis, J. Sleep and Nutrition Interactions: Implications for Athletes. Nutrients. 2019. 11:#pages#. doi:10.3390/nu11040822 | Study design | -
2 | Fenton, S, Burrows, TL, Skinner, JA, Duncan, MJ. The influence of sleep health on dietary intake: a systematic review and meta-analysis of intervention studies. J Hum Nutr Diet. 2021. 34:273-285. doi:10.1111/jhn.12813 | Intervention/exposure | Outcome
3 | Gratwicke, M, Miles, KH, Pyne, DB, Pumpa, KL, Clark, B. Nutritional Interventions to Improve Sleep in Team-Sport Athletes: A Narrative Review. Nutrients. 2021. 13:#pages#. doi:10.3390/nu13051586 | Study design | Intervention/exposure
4 | Kay-Stacey, M, Attarian, H. Advances in the management of chronic insomnia. Bmj. 2016. 354:i2123. doi:10.1136/bmj.i2123 | Intervention/exposure | -
5 | Laudisio, D, Barrea, L, Pugliese, G, Aprano, S, Castellucci, B, Savastano, S, Colao, A, Muscogiuri, G. A practical nutritional guide for the management of sleep disturbances in menopause. Int J Food Sci Nutr. 2021. 72:432-446. doi:10.1080/09637486.2020.1851658 | Study design | -
6 | Reis, CEG, Loureiro, LMR, Roschel, H, da Costa, THM. Effects of pre-sleep protein consumption on muscle-related outcomes - A systematic review. J Sci Med Sport. 2021. 24:177-182. doi:10.1016/j.jsams.2020.07.016 | Outcome | -
7 | Zhao, M, Tuo, H, Wang, S, Zhao, L. The Effects of Dietary Nutrition on Sleep and Sleep Disorders. Mediators Inflamm. 2020. 2020:3142874. doi:10.1155/2020/3142874 | Study design | -