# Appendix 2-e Excluded articles for protein intake and chronic disease risk evidence scan

The following table lists the articles excluded after full-text screening for this evidence scan. At least one reason for exclusion is provided for each article, though this may not reflect all possible reasons. Information about articles excluded after title and abstract screening is available upon request.

# | Citation | Exclusion reason #1 | Exclusion reason #2
1 | Adeva-Andany, MM, González-Lucán, M, Fernández-Fernández, C, Carneiro-Freire, N, Seco-Filgueira, M, Pedre-Piñeiro, AM. Effect of diet composition on insulin sensitivity in humans. Clin Nutr ESPEN. 2019. 33:29-38. doi:10.1016/j.clnesp.2019.05.014 | Study Design | -
2 | Adeva-Andany, MM, Rañal-Muíño, E, Vila-Altesor, M, Fernández-Fernández, C, Funcasta-Calderón, R, Castro-Quintela, E. Dietary habits contribute to define the risk of type 2 diabetes in humans. Clin Nutr ESPEN. 2019. 34:8-17. doi:10.1016/j.clnesp.2019.08.002 | Study Design | -
3 | Ahnen, RT, Jonnalagadda, SS, Slavin, JL. Role of plant protein in nutrition, wellness, and health. Nutr Rev. 2019. 77:735-747. doi:10.1093/nutrit/nuz028 | Study Design | -
4 | Al-Nimr, RI. Optimal Protein Intake during Weight Loss Interventions in Older Adults with Obesity. J Nutr Gerontol Geriatr. 2019. 38:50-68. doi:10.1080/21551197.2018.1544533 | Study Design | -
5 | Amirani, E, Milajerdi, A, Reiner, Ž, Mirzaei, H, Mansournia, MA, Asemi, Z. Effects of whey protein on glycemic control and serum lipoproteins in patients with metabolic syndrome and related conditions: a systematic review and meta-analysis of randomized controlled clinical trials. Lipids Health Dis. 2020. 19:209. doi:10.1186/s12944-020-01384-7 | Intervention/Exposure | -
6 | Ancu, O, Mickute, M, Guess, ND, Hurren, NM, Burd, NA, Mackenzie, RW. Does high dietary protein intake contribute to the increased risk of developing prediabetes and type 2 diabetes?. Appl Physiol Nutr Metab. 2021. 46:1-9. doi:10.1139/apnm-2020-0396 | Study Design | -
7 | Anton, SD, Hida, A, Mankowski, R, Layne, A, Solberg, LM, Mainous, AG, Buford, T. Nutrition and Exercise in Sarcopenia. Curr Protein Pept Sci. 2018. 19:649-667. doi:10.2174/1389203717666161227144349 | Study Design | -
8 | Aragon, AA, Schoenfeld, BJ, Wildman, R, Kleiner, S, VanDusseldorp, T, Taylor, L, Earnest, CP, Arciero, PJ, Wilborn, C, Kalman, DS, Stout, JR, Willoughby, DS, Campbell, B, Arent, SM, Bannock, L, Smith-Ryan, AE, Antonio, J. International society of sports nutrition position stand: diets and body composition. J Int Soc Sports Nutr. 2017. 14:16. doi:10.1186/s12970-017-0174-y | Study Design | -
9 | Artaza-Artabe, I, Sáez-López, P, Sánchez-Hernández, N, Fernández-Gutierrez, N, Malafarina, V. The relationship between nutrition and frailty: Effects of protein intake, nutritional supplementation, vitamin D and exercise on muscle metabolism in the elderly. A systematic review. Maturitas. 2016. 93:89-99. doi:10.1016/j.maturitas.2016.04.009 | Intervention/Exposure | Outcome
10 | Badely, M, Sepandi, M, Samadi, M, Parastouei, K, Taghdir, M. The effect of whey protein on the components of metabolic syndrome in overweight and obese individuals; a systematic review and meta-analysis. Diabetes Metab Syndr. 2019. 13:3121-3131. doi:10.1016/j.dsx.2019.11.001 | Intervention/Exposure | -
11 | Bai, GH, Tsai, MC, Tsai, HW, Chang, CC, Hou, WH. Effects of branched-chain amino acid-rich supplementation on EWGSOP2 criteria for sarcopenia in older adults: a systematic review and meta-analysis. Eur J Nutr. 2021. #volume#:#pages#. doi:10.1007/s00394-021-02710-0 | Intervention/Exposure | -
12 | Batsis, JA, Villareal, DT. Sarcopenic obesity in older adults: aetiology, epidemiology and treatment strategies. Nat Rev Endocrinol. 2018. 14:513-537. doi:10.1038/s41574-018-0062-9 | Study Design | -
13 | Beaudart, C, Dawson, A, Shaw, SC, Harvey, NC, Kanis, JA, Binkley, N, Reginster, JY, Chapurlat, R, Chan, DC, Bruyère, O, Rizzoli, R, Cooper, C, Dennison, EM. Nutrition and physical activity in the prevention and treatment of sarcopenia: systematic review. Osteoporos Int. 2017. 28:1817-1833. doi:10.1007/s00198-017-3980-9 | Intervention/Exposure | -
14 | Beaudart, C, Rabenda, V, Simmons, M, Geerinck, A, Araujo De Carvalho, I, Reginster, JY, Amuthavalli Thiyagarajan, J, Bruyère, O. Effects of Protein, Essential Amino Acids, B-Hydroxy B-Methylbutyrate, Creatine, Dehydroepiandrosterone and Fatty Acid Supplementation on Muscle Mass, Muscle Strength and Physical Performance in Older People Aged 60 Years and Over. A Systematic Review on the Literature. J Nutr Health Aging. 2018. 22:117-130. doi:10.1007/s12603-017-0934-z | Intervention/Exposure | -
15 | Bilancio, G, Cavallo, P, Ciacci, C, Cirillo, M. Dietary Protein, Kidney Function and Mortality: Review of the Evidence from Epidemiological Studies. Nutrients. 2019. 11:#pages#. doi:10.3390/nu11010196 | Study Design | -
16 | Boirie, Y, Guillet, C. Fast digestive proteins and sarcopenia of aging. Curr Opin Clin Nutr Metab Care. 2018. 21:37-41. doi:10.1097/mco.0000000000000427 | Study Design | -
17 | Bray, GA, Siri-Tarino, PW. The Role of Macronutrient Content in the Diet for Weight Management. Endocrinol Metab Clin North Am. 2016. 45:581-604. doi:10.1016/j.ecl.2016.04.009 | Study Design | -
18 | Camargo, LDR, Doneda, D, Oliveira, VR. Whey protein ingestion in elderly diet and the association with physical, performance and clinical outcomes. Exp Gerontol. 2020. 137:110936. doi:10.1016/j.exger.2020.110936 | Intervention/Exposure | -
19 | Cao, JJ. High Dietary Protein Intake and Protein-Related Acid Load on Bone Health. Curr Osteoporos Rep. 2017. 15:571-576. doi:10.1007/s11914-017-0408-6 | Study Design | -
20 | Castro-Barquero, S, Ruiz-León, AM, Sierra-Pérez, M, Estruch, R, Casas, R. Dietary Strategies for Metabolic Syndrome: A Comprehensive Review. Nutrients. 2020. 12:#pages#. doi:10.3390/nu12102983 | Study Design | -
21 | Chapman, S, Chung, HC, Rawcliffe, AJ, Izard, R, Smith, L, Roberts, JD. Does Protein Supplementation Support Adaptations to Arduous Concurrent Exercise Training? A Systematic Review and Meta-Analysis with Military Based Applications. Nutrients. 2021. 13:#pages#. doi:10.3390/nu13051416 | Intervention/Exposure | -
22 | Cheng, H, Kong, J, Underwood, C, Petocz, P, Hirani, V, Dawson, B, O’Leary, F. Systematic review and meta-analysis of the effect of protein and amino acid supplements in older adults with acute or chronic conditions. Br J Nutr. 2018. 119:527-542. doi:10.1017/s0007114517003816 | Intervention/Exposure | Health status
23 | Daly, RM. Exercise and nutritional approaches to prevent frail bones, falls and fractures: an update. Climacteric. 2017. 20:119-124. doi:10.1080/13697137.2017.1286890 | Study Design | -
24 | de Sousa, MV, da Silva Soares, DB, Caraça, ER, Cardoso, R. Dietary protein and exercise for preservation of lean mass and perspectives on type 2 diabetes prevention. Exp Biol Med (Maywood). 2019. 244:992-1004. doi:10.1177/1535370219861910 | Study Design | -
25 | Deane, CS, Bass, JJ, Crossland, H, Phillips, BE, Atherton, PJ. Animal, Plant, Collagen and Blended Dietary Proteins: Effects on Musculoskeletal Outcomes. Nutrients. 2020. 12:#pages#. doi:10.3390/nu12092670 | Study Design | -
26 | Dewansingh, P, Melse-Boonstra, A, Krijnen, WP, van der Schans, CP, Jager-Wittenaar, H, van den Heuvel, Eghm. Supplemental protein from dairy products increases body weight and vitamin D improves physical performance in older adults: a systematic review and meta-analysis. Nutr Res. 2018. 49:1-22. doi:10.1016/j.nutres.2017.08.004 | Intervention/Exposure | -
27 | Dirks, ML, Wall, BT, van Loon, LJC. Interventional strategies to combat muscle disuse atrophy in humans: focus on neuromuscular electrical stimulation and dietary protein. J Appl Physiol (1985). 2018. 125:850-861. doi:10.1152/japplphysiol.00985.2016 | Study Design | -
28 | Dos Reis Padilha, G, Sanches Machado d’Almeida, K, Ronchi Spillere, S, Corrêa Souza, G. Dietary Patterns in Secondary Prevention of Heart Failure: A Systematic Review. Nutrients. 2018. 10:#pages#. doi:10.3390/nu10070828 | Health status | -
29 | Drummen, M, Tischmann, L, Gatta-Cherifi, B, Adam, T, Westerterp-Plantenga, M. Dietary Protein and Energy Balance in Relation to Obesity and Co-morbidities. Front Endocrinol (Lausanne). 2018. 9:443. doi:10.3389/fendo.2018.00443 | Study Design | -
30 | Elmadfa, I, Meyer, AL. Animal Proteins as Important Contributors to a Healthy Human Diet. Annu Rev Anim Biosci. 2017. 5:111-131. doi:10.1146/annurev-animal-022516-022943 | Study Design | -
31 | Eriksen, KG, Lind, MV, Larnkjær, A, Mølgaard, C, Michaelsen, KF. Early Nutrition and Its Effect on Growth, Body Composition and Later Obesity. World Rev Nutr Diet. 2018. 117:111-128. doi:10.1159/000484502 | Study Design | -
32 | Eyre, S, Faxén-Irving, G, Attman, PO, Evans, M, Windahl, K, Wegener, S, Andersén, C, Nykvist-Raanaes, K, Einemo, S, Carrero, JJ. A practical approach to low protein diets in Sweden- 45 years of clinical use. BMC Nephrol. 2016. 17:89. doi:10.1186/s12882-016-0295-6 | Study Design | -
33 | Ezquerro, S, Rodríguez, A, Portincasa, P, Frühbeck, G. Effects of Diets on Adipose Tissue. Curr Med Chem. 2019. 26:3593-3612. doi:10.2174/0929867324666170518102340 | Study Design | Intervention/Exposure
34 | Feart, C. Nutrition and frailty: Current knowledge. Prog Neuropsychopharmacol Biol Psychiatry. 2019. 95:109703. doi:10.1016/j.pnpbp.2019.109703 | Study Design | -
35 | Fekete Á, A, Givens, DI, Lovegrove, JA. Can milk proteins be a useful tool in the management of cardiometabolic health? An updated review of human intervention trials. Proc Nutr Soc. 2016. 75:328-41. doi:10.1017/s0029665116000264 | Study Design | Intervention/Exposure
36 | Ferraro, PM, Bargagli, M, Trinchieri, A, Gambaro, G. Risk of Kidney Stones: Influence of Dietary Factors, Dietary Patterns, and Vegetarian-Vegan Diets. Nutrients. 2020. 12:#pages#. doi:10.3390/nu12030779 | Study Design | Intervention/Exposure
37 | Franzke, B, Neubauer, O, Cameron-Smith, D, Wagner, KH. Dietary Protein, Muscle and Physical Function in the Very Old. Nutrients. 2018. 10:#pages#. doi:10.3390/nu10070935 | Study Design | -
38 | Gielen, E, Beckwée, D, Delaere, A, De Breucker, S, Vandewoude, M, Bautmans, I. Nutritional interventions to improve muscle mass, muscle strength, and physical performance in older people: an umbrella review of systematic reviews and meta-analyses. Nutr Rev. 2021. 79:121-147. doi:10.1093/nutrit/nuaa011 | Intervention/Exposure | -
39 | Gimeno-Mallench, L, Sanchez-Morate, E, Parejo-Pedrajas, S, Mas-Bargues, C, Inglés, M, Sanz-Ros, J, Román-Domínguez, A, Olaso, G, Stromsnes, K, Gambini, J. The Relationship between Diet and Frailty in Aging. Endocr Metab Immune Disord Drug Targets. 2020. 20:1373-1382. doi:10.2174/1871530320666200513083212 | Study Design | -
40 | Grant, WB. Using Multicountry Ecological and Observational Studies to Determine Dietary Risk Factors for Alzheimer’s Disease. J Am Coll Nutr. 2016. 35:476-89. doi:10.1080/07315724.2016.1161566 | Study Design | Intervention/Exposure
41 | Grote, V, Theurich, M, Luque, V, Gruszfeld, D, Verduci, E, Xhonneux, A, Koletzko, B. Complementary Feeding, Infant Growth, and Obesity Risk: Timing, Composition, and Mode of Feeding. Nestle Nutr Inst Workshop Ser. 2018. 89:93-103. doi:10.1159/000486495 | Study Design | -
42 | Guasch-Ferré, M, Satija, A, Blondin, SA, Janiszewski, M, Emlen, E, O’Connor, LE, Campbell, WW, Hu, FB, Willett, WC, Stampfer, MJ. Meta-Analysis of Randomized Controlled Trials of Red Meat Consumption in Comparison With Various Comparison Diets on Cardiovascular Risk Factors. Circulation. 2019. 139:1828-1845. doi:10.1161/circulationaha.118.035225 | Intervention/Exposure | -
43 | Hanach, NI, McCullough, F, Avery, A. The Impact of Dairy Protein Intake on Muscle Mass, Muscle Strength, and Physical Performance in Middle-Aged to Older Adults with or without Existing Sarcopenia: A Systematic Review and Meta-Analysis. Adv Nutr. 2019. 10:59-69. doi:10.1093/advances/nmy065 | Intervention/Exposure | -
44 | Haschke, F, Grathwohl, D, Detzel, P, Steenhout, P, Wagemans, N, Erdmann, P. Postnatal High Protein Intake Can Contribute to Accelerated Weight Gain of Infants and Increased Obesity Risk. Nestle Nutr Inst Workshop Ser. 2016. 85:101-9. doi:10.1159/000439492 | Study Design | -
45 | Hellmuth, C, Uhl, O, Kirchberg, FF, Grote, V, Weber, M, Rzehak, P, Carlier, C, Ferre, N, Verduci, E, Gruszfeld, D, Socha, P, Koletzko, B. Effects of Early Nutrition on the Infant Metabolome. Nestle Nutr Inst Workshop Ser. 2016. 85:89-100. doi:10.1159/000439491 | Study Design | -
46 | Hertzler, SR, Lieblein-Boff, JC, Weiler, M, Allgeier, C. Plant Proteins: Assessing Their Nutritional Quality and Effects on Health and Physical Function. Nutrients. 2020. 12:#pages#. doi:10.3390/nu12123704 | Study Design | -
47 | Hidayat, K, Chen, GC, Wang, Y, Zhang, Z, Dai, X, Szeto, IMY, Qin, LQ. Effects of Milk Proteins Supplementation in Older Adults Undergoing Resistance Training: A Meta-Analysis of Randomized Control Trials. J Nutr Health Aging. 2018. 22:237-245. doi:10.1007/s12603-017-0899-y | Intervention/Exposure | -
48 | Hidayat, K, Du, HZ, Yang, J, Chen, GC, Zhang, Z, Li, ZN, Qin, LQ. Effects of milk proteins on blood pressure: a meta-analysis of randomized control trials. Hypertens Res. 2017. 40:264-270. doi:10.1038/hr.2016.135 | Intervention/Exposure | -
49 | Hou, L, Lei, Y, Li, X, Huo, C, Jia, X, Yang, J, Xu, R, Wang, X. Effect of Protein Supplementation Combined with Resistance Training on Muscle Mass, Strength and Function in the Elderly: A Systematic Review and Meta-Analysis. J Nutr Health Aging. 2019. 23:451-458. doi:10.1007/s12603-019-1181-2 | Intervention/Exposure | -
50 | Huang, LP, Condello, G, Kuo, CH. Effects of Milk Protein in Resistance Training-Induced Lean Mass Gains for Older Adults Aged ≥ 60 y: A Systematic Review and Meta-Analysis. Nutrients. 2021. 13:#pages#. doi:10.3390/nu13082815 | Intervention/Exposure | -
51 | Inaba, M, Okuno, S, Ohno, Y. Importance of Considering Malnutrition and Sarcopenia in Order to Improve the QOL of Elderly Hemodialysis Patients in Japan in the Era of 100-Year Life. Nutrients. 2021. 13:#pages#. doi:10.3390/nu13072377 | Study Design | Health status
52 | Ispoglou, T, Witard, OC, Duckworth, LC, Lees, MJ. The efficacy of essential amino acid supplementation for augmenting dietary protein intake in older adults: implications for skeletal muscle mass, strength and function. Proc Nutr Soc. 2021. 80:230-242. doi:10.1017/s0029665120008010 | Study Design | -
53 | Joshi, S, Hashmi, S, Shah, S, Kalantar-Zadeh, K. Plant-based diets for prevention and management of chronic kidney disease. Curr Opin Nephrol Hypertens. 2020. 29:16-21. doi:10.1097/mnh.0000000000000574 | Study Design | -
54 | Kirk, B, Prokopidis, K, Duque, G. Nutrients to mitigate osteosarcopenia: the role of protein, vitamin D and calcium. Curr Opin Clin Nutr Metab Care. 2021. 24:25-32. doi:10.1097/mco.0000000000000711 | Study Design | -
55 | Kitada, M, Ogura, Y, Monno, I, Koya, D. The impact of dietary protein intake on longevity and metabolic health. EBioMedicine. 2019. 43:632-640. doi:10.1016/j.ebiom.2019.04.005 | Study Design | -
56 | Ko, GJ, Obi, Y, Tortorici, AR, Kalantar-Zadeh, K. Dietary protein intake and chronic kidney disease. Curr Opin Clin Nutr Metab Care. 2017. 20:77-85. doi:10.1097/mco.0000000000000342 | Study Design | -
57 | Ko, GJ, Rhee, CM, Kalantar-Zadeh, K, Joshi, S. The Effects of High-Protein Diets on Kidney Health and Longevity. J Am Soc Nephrol. 2020. 31:1667-1679. doi:10.1681/asn.2020010028 | Study Design | Intervention/exposure
58 | Koliaki, C, Spinos, T, Spinou, Μ, Brinia Μ, E, Mitsopoulou, D, Katsilambros, N. Defining the Optimal Dietary Approach for Safe, Effective and Sustainable Weight Loss in Overweight and Obese Adults. Healthcare (Basel). 2018. 6:#pages#. doi:10.3390/healthcare6030073 | Study Design | -
59 | Labata-Lezaun, N, Llurda-Almuzara, L, López-de-Celis, C, Rodríguez-Sanz, J, González-Rueda, V, Hidalgo-García, C, Muniz-Pardos, B, Pérez-Bellmunt, A. Effectiveness of Protein Supplementation Combined with Resistance Training on Muscle Strength and Physical Performance in Elderly: A Systematic Review and Meta-Analysis. Nutrients. 2020. 12:#pages#. doi:10.3390/nu12092607 | Intervention/Exposure | -
60 | Lancha, AH, Jr, Zanella, R, Jr, Tanabe, SG, Andriamihaja, M, Blachier, F. Dietary protein supplementation in the elderly for limiting muscle mass loss. Amino Acids. 2017. 49:33-47. doi:10.1007/s00726-016-2355-4 | Study Design | -
61 | Le Couteur, DG, Solon-Biet, S, Cogger, VC, Mitchell, SJ, Senior, A, de Cabo, R, Raubenheimer, D, Simpson, SJ. The impact of low-protein high-carbohydrate diets on aging and lifespan. Cell Mol Life Sci. 2016. 73:1237-52. doi:10.1007/s00018-015-2120-y | Study Design | -
62 | Li, M, Liu, F. Effect of whey protein supplementation during resistance training sessions on body mass and muscular strength: a meta-analysis. Food Funct. 2019. 10:2766-2773. doi:10.1039/c9fo00182d | Intervention/Exposure | -
63 | Liao, CD, Chen, HC, Huang, SW, Liou, TH. The Role of Muscle Mass Gain Following Protein Supplementation Plus Exercise Therapy in Older Adults with Sarcopenia and Frailty Risks: A Systematic Review and Meta-Regression Analysis of Randomized Trials. Nutrients. 2019. 11:#pages#. doi:10.3390/nu11081713 | Intervention/Exposure | -
64 | Liao, CD, Lee, PH, Hsiao, DJ, Huang, SW, Tsauo, JY, Chen, HC, Liou, TH. Effects of Protein Supplementation Combined with Exercise Intervention on Frailty Indices, Body Composition, and Physical Function in Frail Older Adults. Nutrients. 2018. 10:#pages#. doi:10.3390/nu10121916 | Intervention/Exposure | Comparator
65 | Liao, CD, Tsauo, JY, Wu, YT, Cheng, CP, Chen, HC, Huang, YC, Chen, HC, Liou, TH. Effects of protein supplementation combined with resistance exercise on body composition and physical function in older adults: a systematic review and meta-analysis. Am J Clin Nutr. 2017. 106:1078-1091. doi:10.3945/ajcn.116.143594 | Intervention/Exposure | -
66 | Liao, CD, Wu, YT, Tsauo, JY, Chen, PR, Tu, YK, Chen, HC, Liou, TH. Effects of Protein Supplementation Combined with Exercise Training on Muscle Mass and Function in Older Adults with Lower-Extremity Osteoarthritis: A Systematic Review and Meta-Analysis of Randomized Trials. Nutrients. 2020. 12:#pages#. doi:10.3390/nu12082422 | Intervention/Exposure | -
67 | Lim, MT, Pan, BJ, Toh, DWK, Sutanto, CN, Kim, JE. Animal Protein versus Plant Protein in Supporting Lean Mass and Muscle Strength: A Systematic Review and Meta-Analysis of Randomized Controlled Trials. Nutrients. 2021. 13:#pages#. doi:10.3390/nu13020661 | Intervention/exposure | -
68 | Lind, MV, Larnkjær, A, Mølgaard, C, Michaelsen, KF. Dietary protein intake and quality in early life: impact on growth and obesity. Curr Opin Clin Nutr Metab Care. 2017. 20:71-76. doi:10.1097/mco.0000000000000338 | Study Design | -
69 | Lombardo, M, Bellia, C, Moletto, C, Aulisa, G, Padua, E, Della-Morte, D, Caprio, M, Bellia, A. Effects of Quality and Quantity of Protein Intake for Type 2 Diabetes Mellitus Prevention and Metabolic Control. Curr Nutr Rep. 2020. 9:329-337. doi:10.1007/s13668-020-00324-2 | Study Design | Outcome
70 | Lonnie, M, Laurie, I, Myers, M, Horgan, G, Russell, WR, Johnstone, AM. Exploring Health-Promoting Attributes of Plant Proteins as a Functional Ingredient for the Food Sector: A Systematic Review of Human Interventional Studies. Nutrients. 2020. 12:#pages#. doi:10.3390/nu12082291 | Intervention/Exposure | Outcome
71 | Magkos, F. Protein-Rich Diets for Weight Loss Maintenance. Curr Obes Rep. 2020. 9:213-218. doi:10.1007/s13679-020-00391-0 | Study Design | -
72 | Magkos, F. The role of dietary protein in obesity. Rev Endocr Metab Disord. 2020. 21:329-340. doi:10.1007/s11154-020-09576-3 | Study Design | -
73 | Mareschal, J, Genton, L, Collet, TH, Graf, C. Nutritional Intervention to Prevent the Functional Decline in Community-Dwelling Older Adults: A Systematic Review. Nutrients. 2020. 12:#pages#. doi:10.3390/nu12092820 | Intervention/Exposure | -
74 | Marshall, RN, Smeuninx, B, Morgan, PT, Breen, L. Nutritional Strategies to Offset Disuse-Induced Skeletal Muscle Atrophy and Anabolic Resistance in Older Adults: From Whole-Foods to Isolated Ingredients. Nutrients. 2020. 12:#pages#. doi:10.3390/nu12051533 | Study Design | -
75 | Martin-Cantero, A, Reijnierse, EM, Gill, BMT, Maier, AB. Factors influencing the efficacy of nutritional interventions on muscle mass in older adults: a systematic review and meta-analysis. Nutr Rev. 2021. 79:315-330. doi:10.1093/nutrit/nuaa064 | Intervention/Exposure | -
76 | Martínez-Amat, A, Aibar-Almazán, A, Fábrega-Cuadros, R, Cruz-Díaz, D, Jiménez-García, JD, Pérez-López, FR, Achalandabaso, A, Barranco-Zafra, R, Hita-Contreras, F. Exercise alone or combined with dietary supplements for sarcopenic obesity in community-dwelling older people: A systematic review of randomized controlled trials. Maturitas. 2018. 110:92-103. doi:10.1016/j.maturitas.2018.02.005 | Intervention/Exposure | -
77 | Master, PBZ, Macedo, RCO. Effects of dietary supplementation in sport and exercise: a review of evidence on milk proteins and amino acids. Crit Rev Food Sci Nutr. 2021. 61:1225-1239. doi:10.1080/10408398.2020.1756216 | Study Design | -
78 | Matonti, L, Blasetti, A, Chiarelli, F. Nutrition and growth in children. Minerva Pediatr. 2020. 72:462-471. doi:10.23736/s0026-4946.20.05981-2 | Study Design | -
79 | McCarthy, D, Berg, A. Weight Loss Strategies and the Risk of Skeletal Muscle Mass Loss. Nutrients. 2021. 13:#pages#. doi:10.3390/nu13072473 | Study Design | -
80 | Mendonça, N, Hengeveld, LM, Visser, M, Presse, N, Canhão, H, Simonsick, EM, Kritchevsky, SB, Newman, AB, Gaudreau, P, Jagger, C. Low protein intake, physical activity, and physical function in European and North American community-dwelling older adults: a pooled analysis of four longitudinal aging cohorts. Am J Clin Nutr. 2021. 114:29-41. doi:10.1093/ajcn/nqab051 | Study Design | Outcome
81 | Molino, S, Dossena, M, Buonocore, D, Verri, M. Sarcopenic Obesity: An Appraisal of the Current Status of Knowledge and Management in Elderly People. J Nutr Health Aging. 2016. 20:780-8. doi:10.1007/s12603-015-0631-8 | Study Design | -
82 | Morales, Ms FE, Tinsley, GM, Gordon, PM. Acute and Long-Term Impact of High-Protein Diets on Endocrine and Metabolic Function, Body Composition, and Exercise-Induced Adaptations. J Am Coll Nutr. 2017. 36:295-305. doi:10.1080/07315724.2016.1274691 | Study Design | -
83 | Morgan, PT, Harris, DO, Marshall, RN, Quinlan, JI, Edwards, SJ, Allen, SL, Breen, L. Protein Source and Quality for Skeletal Muscle Anabolism in Young and Older Adults: A Systematic Review and Meta-Analysis. J Nutr. 2021. 151:1901-1920. doi:10.1093/jn/nxab055 | Intervention/exposure | Comparator
84 | Morton, RW, Murphy, KT, McKellar, SR, Schoenfeld, BJ, Henselmans, M, Helms, E, Aragon, AA, Devries, MC, Banfield, L, Krieger, JW, Phillips, SM. A systematic review, meta-analysis and meta-regression of the effect of protein supplementation on resistance training-induced gains in muscle mass and strength in healthy adults. Br J Sports Med. 2018. 52:376-384. doi:10.1136/bjsports-2017-097608 | Intervention/Exposure | -
85 | Mu, Y, Kou, T, Wei, B, Lu, X, Liu, J, Tian, H, Zhang, W, Liu, B, Li, H, Cui, W, Wang, Q. Soy Products Ameliorate Obesity-Related Anthropometric Indicators in Overweight or Obese Asian and Non-Menopausal Women: A Meta-Analysis of Randomized Controlled Trials. Nutrients. 2019. 11:#pages#. doi:10.3390/nu11112790 | Intervention/Exposure | -
86 | Nachvak, SM, Moradi, S, Anjom-Shoae, J, Rahmani, J, Nasiri, M, Maleki, V, Sadeghi, O. Soy, Soy Isoflavones, and Protein Intake in Relation to Mortality from All Causes, Cancers, and Cardiovascular Diseases: A Systematic Review and Dose-Response Meta-Analysis of Prospective Cohort Studies. J Acad Nutr Diet. 2019. 119:1483-1500.e17. doi:10.1016/j.jand.2019.04.011 | Intervention/Exposure | -
87 | Naclerio, F, Larumbe-Zabala, E. Effects of Whey Protein Alone or as Part of a Multi-ingredient Formulation on Strength, Fat-Free Mass, or Lean Body Mass in Resistance-Trained Individuals: A Meta-analysis. Sports Med. 2016. 46:125-137. doi:10.1007/s40279-015-0403-y | Intervention/Exposure | -
88 | Narasaki, Y, Rhee, CM, Kramer, H, Kalantar-Zadeh, K. Protein intake and renal function in older patients. Curr Opin Clin Nutr Metab Care. 2021. 24:10-17. doi:10.1097/mco.0000000000000712 | Study Design | -
89 | O’Bryan, KR, Doering, TM, Morton, RW, Coffey, VG, Phillips, SM, Cox, GR. Do multi-ingredient protein supplements augment resistance training-induced gains in skeletal muscle mass and strength? A systematic review and meta-analysis of 35 trials. Br J Sports Med. 2020. 54:573-581. doi:10.1136/bjsports-2018-099889 | Intervention/Exposure | -
90 | O’Connell, ML, Coppinger, T, McCarthy, AL. The role of nutrition and physical activity in frailty: A review. Clin Nutr ESPEN. 2020. 35:1-11. doi:10.1016/j.clnesp.2019.11.003 | Study Design | -
91 | O’Keefe, JH, Bergman, N, Carrera-Bastos, P, Fontes-Villalba, M, DiNicolantonio, JJ, Cordain, L. Nutritional strategies for skeletal and cardiovascular health: hard bones, soft arteries, rather than vice versa. Open Heart. 2016. 3:e000325. doi:10.1136/openhrt-2015-000325 | Study Design | -
92 | Oktaviana, J, Zanker, J, Vogrin, S, Duque, G. The effect of protein supplements on functional frailty in older persons: A systematic review and meta-analysis. Arch Gerontol Geriatr. 2020. 86:103938. doi:10.1016/j.archger.2019.103938 | Intervention/Exposure | Outcome
93 | Parackal, S. Dietary Transition in the South Asian Diaspora: Implications for Diabetes Prevention Strategies. Curr Diabetes Rev. 2017. 13:482-487. doi:10.2174/1573399812666160901094741 | Study Design | -
94 | Pedro, RN, Aslam, AU, Bello, JO, Bhatti, KH, Philipraj, J, Sissoko, I, Vasconcellos, GS, Trinchieri, A, Buchholz, N. Nutrients, vitamins, probiotics and herbal products: an update of their role in urolithogenesis. Urolithiasis. 2020. 48:285-301. doi:10.1007/s00240-020-01182-x | Intervention/Exposure | -
95 | Petroni, ML, Caletti, MT, Dalle Grave, R, Bazzocchi, A, Aparisi Gómez, MP, Marchesini, G. Prevention and Treatment of Sarcopenic Obesity in Women. Nutrients. 2019. 11:#pages#. doi:10.3390/nu11061302 | Study Design | -
96 | Pimpin, L, Kranz, S, Liu, E, Shulkin, M, Karageorgou, D, Miller, V, Fawzi, W, Duggan, C, Webb, P, Mozaffarian, D. Effects of animal protein supplementation of mothers, preterm infants, and term infants on growth outcomes in childhood: a systematic review and meta-analysis of randomized trials. Am J Clin Nutr. 2019. 110:410-429. doi:10.1093/ajcn/nqy348 | Intervention/Exposure | -
97 | Pinto, CL, Botelho, PB, Pimentel, GD, Campos-Ferraz, PL, Mota, JF. Creatine supplementation and glycemic control: a systematic review. Amino Acids. 2016. 48:2103-29. doi:10.1007/s00726-016-2277-1 | Intervention/Exposure | -
98 | Piri Damaghi, M, Mirzababaei, A, Moradi, S, Daneshzad, E, Tavakoli, A, Clark, CCT, Mirzaei, K. Comparison of the effect of soya protein and whey protein on body composition: a meta-analysis of randomised clinical trials. Br J Nutr. 2021. #volume#:1-11. doi:10.1017/s0007114521001550 | Intervention/Exposure | Comparator
99 | Poscia, A, Milovanovic, S, La Milia, DI, Duplaga, M, Grysztar, M, Landi, F, Moscato, U, Magnavita, N, Collamati, A, Ricciardi, W. Effectiveness of nutritional interventions addressed to elderly persons: umbrella systematic review with meta-analysis. Eur J Public Health. 2018. 28:275-283. doi:10.1093/eurpub/ckx199 | Intervention/Exposure | -
100 | Reidy, PT, Rasmussen, BB. Role of Ingested Amino Acids and Protein in the Promotion of Resistance Exercise-Induced Muscle Protein Anabolism. J Nutr. 2016. 146:155-83. doi:10.3945/jn.114.203208 | Study Design | -
101 | Richter, M, Baerlocher, K, Bauer, JM, Elmadfa, I, Heseker, H, Leschik-Bonnet, E, Stangl, G, Volkert, D, Stehle, P. Revised Reference Values for the Intake of Protein. Ann Nutr Metab. 2019. 74:242-250. doi:10.1159/000499374 | Study Design | Outcome
102 | Rizzoli, R, Biver, E, Bonjour, JP, Coxam, V, Goltzman, D, Kanis, JA, Lappe, J, Rejnmark, L, Sahni, S, Weaver, C, Weiler, H, Reginster, JY. Benefits and safety of dietary protein for bone health-an expert consensus paper endorsed by the European Society for Clinical and Economical Aspects of Osteopororosis, Osteoarthritis, and Musculoskeletal Diseases and by the International Osteoporosis Foundation. Osteoporos Int. 2018. 29:1933-1948. doi:10.1007/s00198-018-4534-5 | Study Design | -
103 | Roberts, JL, Stein, AD. The Impact of Nutritional Interventions beyond the First 2 Years of Life on Linear Growth: A Systematic Review and Meta-Analysis. Adv Nutr. 2017. 8:323-336. doi:10.3945/an.116.013938 | Intervention/Exposure | -
104 | Rus, GE, Porter, J, Brunton, A, Crocker, M, Kotsimbos, Z, Percic, J, Polzella, L, Willet, N, Huggins, CE. Nutrition interventions implemented in hospital to lower risk of sarcopenia in older adults: A systematic review of randomised controlled trials. Nutr Diet. 2020. 77:90-102. doi:10.1111/1747-0080.12608 | Intervention/Exposure | Health status
105 | Russell, WR, Baka, A, Björck, I, Delzenne, N, Gao, D, Griffiths, HR, Hadjilucas, E, Juvonen, K, Lahtinen, S, Lansink, M, Loon, LV, Mykkänen, H, Östman, E, Riccardi, G, Vinoy, S, Weickert, MO. Impact of Diet Composition on Blood Glucose Regulation. Crit Rev Food Sci Nutr. 2016. 56:541-90. doi:10.1080/10408398.2013.792772 | Study Design | Intervention/Exposure
106 | Santos, J, Leitão-Correia, F, Sousa, MJ, Leão, C. Dietary Restriction and Nutrient Balance in Aging. Oxid Med Cell Longev. 2016. 2016:4010357. doi:10.1155/2016/4010357 | Study Design | -
107 | Severo, JS, da Silva Barros, VJ, Alves da Silva, AC, Luz Parente, JM, Lima, MM, Moreira Lima, AÂ, Dos Santos, AA, Matos Neto, EM, Tolentino, M. Effects of glutamine supplementation on inflammatory bowel disease: A systematic review of clinical trials. Clin Nutr ESPEN. 2021. 42:53-60. doi:10.1016/j.clnesp.2020.12.023 | Intervention/Exposure | Outcome
108 | Shad, BJ, Thompson, JL, Breen, L. Does the muscle protein synthetic response to exercise and amino acid-based nutrition diminish with advancing age? A systematic review. Am J Physiol Endocrinol Metab. 2016. 311:E803-e817. doi:10.1152/ajpendo.00213.2016 | Intervention/Exposure | -
109 | Shams-White, MM, Chung, M, Fu, Z, Insogna, KL, Karlsen, MC, LeBoff, MS, Shapses, SA, Sackey, J, Shi, J, Wallace, TC, Weaver, CM. Animal versus plant protein and adult bone health: A systematic review and meta-analysis from the National Osteoporosis Foundation. PLoS One. 2018. 13:e0192459. doi:10.1371/journal.pone.0192459 | Intervention/exposure | -
110 | Siddique, N, O’Donoghue, M, Casey, MC, Walsh, JB. Malnutrition in the elderly and its effects on bone health - A review. Clin Nutr ESPEN. 2017. 21:31-39. doi:10.1016/j.clnesp.2017.06.001 | Study Design | -
111 | Simonson, M, Boirie, Y, Guillet, C. Protein, amino acids and obesity treatment. Rev Endocr Metab Disord. 2020. 21:341-353. doi:10.1007/s11154-020-09574-5 | Study Design | -
112 | Singhal, A. Obesity in Toddlers and Young Children: Causes and Consequences. Nestle Nutr Inst Workshop Ser. 2020. 95:41-51. doi:10.1159/000511510 | Study Design | -
113 | Solfrizzi, V, Agosti, P, Lozupone, M, Custodero, C, Schilardi, A, Valiani, V, Sardone, R, Dibello, V, Di Lena, L, Lamanna, A, Stallone, R, Bellomo, A, Greco, A, Daniele, A, Seripa, D, Sabbà, C, Logroscino, G, Panza, F. Nutritional Intervention as a Preventive Approach for Cognitive-Related Outcomes in Cognitively Healthy Older Adults: A Systematic Review. J Alzheimers Dis. 2018. 64:S229-s254. doi:10.3233/jad-179940 | Intervention/Exposure | -
114 | Soultoukis, GA, Partridge, L. Dietary Protein, Metabolism, and Aging. Annu Rev Biochem. 2016. 85:5-34. doi:10.1146/annurev-biochem-060815-014422 | Study Design | -
115 | Spence, JD. Nutrition in Stroke Prevention. Semin Neurol. 2017. 37:259-266. doi:10.1055/s-0037-1603470 | Study Design | -
116 | Strasser, B, Wolters, M, Weyh, C, Krüger, K, Ticinesi, A. The Effects of Lifestyle and Diet on Gut Microbiota Composition, Inflammation and Muscle Performance in Our Aging Society. Nutrients. 2021. 13:#pages#. doi:10.3390/nu13062045 | Study Design | -
117 | Tang, M. Protein Intake during the First Two Years of Life and Its Association with Growth and Risk of Overweight. Int J Environ Res Public Health. 2018. 15:#pages#. doi:10.3390/ijerph15081742 | Study Design | -
118 | Ten Haaf, DSM, Nuijten, MAH, Maessen, MFH, Horstman, AMH, Eijsvogels, TMH, Hopman, MTE. Effects of protein supplementation on lean body mass, muscle strength, and physical performance in nonfrail community-dwelling older adults: a systematic review and meta-analysis. Am J Clin Nutr. 2018. 108:1043-1059. doi:10.1093/ajcn/nqy192 | Intervention/Exposure | -
119 | Thomas, DK, Quinn, MA, Saunders, DH, Greig, CA. Protein Supplementation Does Not Significantly Augment the Effects of Resistance Exercise Training in Older Adults: A Systematic Review. J Am Med Dir Assoc. 2016. 17:959.e1-9. doi:10.1016/j.jamda.2016.07.002 | Intervention/Exposure | Outcome
120 | Tieland, M, Franssen, R, Dullemeijer, C, van Dronkelaar, C, Kyung Kim, H, Ispoglou, T, Zhu, K, Prince, RL, van Loon, LJC, de Groot, Lcpgm. The Impact of Dietary Protein or Amino Acid Supplementation on Muscle Mass and Strength in Elderly People: Individual Participant Data and Meta-Analysis of RCT’s. J Nutr Health Aging. 2017. 21:994-1001. doi:10.1007/s12603-017-0896-1 | Intervention/Exposure | -
121 | Travers, J, Romero-Ortuno, R, Bailey, J, Cooney, MT. Delaying and reversing frailty: a systematic review of primary care interventions. Br J Gen Pract. 2019. 69:e61-e69. doi:10.3399/bjgp18X700241 | Intervention/Exposure | Outcome
122 | Tsuboi, M, Momosaki, R, Vakili, M, Abo, M. Nutritional supplementation for activities of daily living and functional ability of older people in residential facilities: A systematic review. Geriatr Gerontol Int. 2018. 18:197-210. doi:10.1111/ggi.13160 | Intervention/Exposure | Outcome
123 | Tu, DY, Kao, FM, Tsai, ST, Tung, TH. Sarcopenia among the Elderly Population: A Systematic Review and Meta-Analysis of Randomized Controlled Trials. Healthcare (Basel). 2021. 9:#pages#. doi:10.3390/healthcare9060650 | Intervention/Exposure | -
124 | Turton, J, Brinkworth, GD, Field, R, Parker, H, Rooney, K. An evidence-based approach to developing low-carbohydrate diets for type 2 diabetes management: A systematic review of interventions and methods. Diabetes Obes Metab. 2019. 21:2513-2525. doi:10.1111/dom.13837 | Health status | -
125 | van Wijngaarden, JP, Wojzischke, J, van den Berg, C, Cetinyurek-Yavuz, A, Diekmann, R, Luiking, YC, Bauer, JM. Effects of Nutritional Interventions on Nutritional and Functional Outcomes in Geriatric Rehabilitation Patients: A Systematic Review and Meta-Analysis. J Am Med Dir Assoc. 2020. 21:1207-1215.e9. doi:10.1016/j.jamda.2020.04.012 | Intervention/Exposure | -
126 | Vasconcelos, Qdjs, Bachur, TPR, Aragão, GF. Whey protein supplementation and its potentially adverse effects on health: a systematic review. Appl Physiol Nutr Metab. 2021. 46:27-33. doi:10.1139/apnm-2020-0370 | Intervention/Exposure | -
127 | Veena, SR, Gale, CR, Krishnaveni, GV, Kehoe, SH, Srinivasan, K, Fall, CH. Association between maternal nutritional status in pregnancy and offspring cognitive function during childhood and adolescence; a systematic review. BMC Pregnancy Childbirth. 2016. 16:220. doi:10.1186/s12884-016-1011-z | Intervention/Exposure | -
128 | Walrand, S. Dietary supplement intake among the elderly: hazards and benefits. Curr Opin Clin Nutr Metab Care. 2018. 21:465-470. doi:10.1097/mco.0000000000000512 | Study Design | -
129 | Westerterp-Plantenga, MS. Challenging energy balance - during sensitivity to food reward and modulatory factors implying a risk for overweight - during body weight management including dietary restraint and medium-high protein diets. Physiol Behav. 2020. 221:112879. doi:10.1016/j.physbeh.2020.112879 | Study Design | -
130 | Wirth, J, Hillesheim, E, Brennan, L. The Role of Protein Intake and its Timing on Body Composition and Muscle Function in Healthy Adults: A Systematic Review and Meta-Analysis of Randomized Controlled Trials. J Nutr. 2020. 150:1443-1460. doi:10.1093/jn/nxaa049 | Intervention/Exposure | -
131 | Wirunsawanya, K, Upala, S, Jaruvongvanich, V, Sanguankeo, A. Whey Protein Supplementation Improves Body Composition and Cardiovascular Risk Factors in Overweight and Obese Patients: A Systematic Review and Meta-Analysis. J Am Coll Nutr. 2018. 37:60-70. doi:10.1080/07315724.2017.1344591 | Intervention/Exposure | -
132 | Witard, OC, McGlory, C, Hamilton, DL, Phillips, SM. Growing older with health and vitality: a nexus of physical activity, exercise and nutrition. Biogerontology. 2016. 17:529-46. doi:10.1007/s10522-016-9637-9 | Study Design | -
133 | Witard, OC, Wardle, SL, Macnaughton, LS, Hodgson, AB, Tipton, KD. Protein Considerations for Optimising Skeletal Muscle Mass in Healthy Young and Older Adults. Nutrients. 2016. 8:181. doi:10.3390/nu8040181 | Study Design | Outcome
134 | Wu, G. Dietary protein intake and human health. Food Funct. 2016. 7:1251-65. doi:10.1039/c5fo01530h | Study Design | -
135 | Ye, J, Yu, Q, Mai, W, Liang, P, Liu, X, Wang, Y. Correction to: Dietary protein intake and subsequent risk of type 2 diabetes: a dose-response meta-analysis of prospective cohort studies. Acta Diabetol. 2019. 56:871. doi:10.1007/s00592-019-01365-y | Study Design | Pub. status
136 | Yue, H, Zhou, P, Xu, Z, Liu, L, Zong, A, Qiu, B, Liu, W, Jia, M, Du, F, Xu, T. Effect of low-protein diet on kidney function and nutrition in nephropathy: A systematic review and meta-analysis of randomized controlled trials. Clin Nutr. 2020. 39:2675-2685. doi:10.1016/j.clnu.2019.11.039 | Health status | -
137 | Zanini, B, Simonetto, A, Zubani, M, Castellano, M, Gilioli, G. The Effects of Cow-Milk Protein Supplementation in Elderly Population: Systematic Review and Narrative Synthesis. Nutrients. 2020. 12:#pages#. doi:10.3390/nu12092548 | Intervention/Exposure | -
138 | Zhang, J, Yu, Y, Wang, J. Protein Nutritional Support: The Classical and Potential New Mechanisms in the Prevention and Therapy of Sarcopenia. J Agric Food Chem. 2020. 68:4098-4108. doi:10.1021/acs.jafc.0c00688 | Study Design | -