# Appendix 2-d Bibliography of excluded reviews identified that evaluated plant and/or animal protein intake (not total protein intake)

# | Brief Citation | Full citation
1 | Chalvon-Demersay, 2017 | Chalvon-Demersay, T, Azzout-Marniche, D, Arfsten, J, Egli, L, Gaudichon, C, Karagounis, LG, Tomé, D. A Systematic Review of the Effects of Plant Compared with Animal Protein Sources on Features of Metabolic Syndrome. J Nutr. 2017. 147:281-292. doi:10.3945/jn.116.239574
2 | Shams-White, 2018 | Shams-White, MM, Chung, M, Fu, Z, Insogna, KL, Karlsen, MC, LeBoff, MS, Shapses, SA, Sackey, J, Shi, J, Wallace, TC, Weaver, CM. Animal versus plant protein and adult bone health: A systematic review and meta-analysis from the National Osteoporosis Foundation. PLoS One. 2018. 13:e0192459. doi:10.1371/journal.pone.0192459
3 | Nachvak, 2019 | Nachvak, SM, Moradi, S, Anjom-Shoae, J, Rahmani, J, Nasiri, M, Maleki, V, Sadeghi, O. Soy, Soy Isoflavones, and Protein Intake in Relation to Mortality from All Causes, Cancers, and Cardiovascular Diseases: A Systematic Review and Dose-Response Meta-Analysis of Prospective Cohort Studies. J Acad Nutr Diet. 2019. 119:1483-1500.e17. doi:10.1016/j.jand.2019.04.011
4 | Lonnie, 2020 | Lonnie, M, Laurie, I, Myers, M, Horgan, G, Russell, WR, Johnstone, AM. Exploring Health-Promoting Attributes of Plant Proteins as a Functional Ingredient for the Food Sector: A Systematic Review of Human Interventional Studies. Nutrients. 2020. 12. doi:10.3390/nu12082291
5 | Zhao, 2020 | Zhao, H, Song, A, Zheng, C, Wang, M, Song, G. Effects of plant protein and animal protein on lipid profile, body weight and body mass index on patients with hypercholesterolemia: a systematic review and meta-analysis. Acta Diabetol. 2020. 57:1169-1180. doi:10.1007/s00592-020-01534-4
6 | Pimpin, 2019 | Pimpin, L, Kranz, S, Liu, E, Shulkin, M, Karageorgou, D, Miller, V, Fawzi, W, Duggan, C, Webb, P, Mozaffarian, D. Effects of animal protein supplementation of mothers, preterm infants, and term infants on growth outcomes in childhood: a systematic review and meta-analysis of randomized trials. Am J Clin Nutr. 2019. 110:410-429. doi:10.1093/ajcn/nqy348
7 | Guasch-Ferre, 2019 | Guasch-Ferré, M, Satija, A, Blondin, SA, Janiszewski, M, Emlen, E, O’Connor, LE, Campbell, WW, Hu, FB, Willett, WC, Stampfer, MJ. Meta-Analysis of Randomized Controlled Trials of Red Meat Consumption in Comparison With Various Comparison Diets on Cardiovascular Risk Factors. Circulation. 2019. 139:1828-1845. doi:10.1161/circulationaha.118.035225