# Appendix 2-c Literature search strategy for protein intake and appetite/satiety evidence scan (supplemental to chronic disease risk scan)

Database: PubMed

Provider: U.S. National Library of Medicine

Date(s) Searched: January 5, 2022

Search # | Concept | String | Results
#1 | Protein | “dietary proteins”[MeSH] OR “Amino Acids”[MeSH] OR “Diet, High Protein”[MeSH] OR “protein intake”[TIAB] OR “high protein”[TIAB] OR “protein consumption”[TIAB] OR “protein supplement*”[TIAB] OR “increased protein”[tiab] | 939,469
#2 | Satiety | “Satiation”[Mesh] OR Satiet*[tiab] OR Satiat*[tiab] OR Appetite[tiab] OR Fullness[tiab] OR “Hunger”[MeSH] OR Hunger[tiab] OR “Desire to eat”[tiab] | 57,416
#3 | #1 AND #2 | | 3,023
#4 | Limiters | #3 AND (review[ptyp] OR scoping review[ti] OR qualitative review[ti] OR evidence review[ti] OR quantitative review[ti] OR meta-review[ti] OR critical review[ti] OR mixed studies review[ti] OR mapping review[ti] OR integrative review[ti] OR (literature[ti] AND review[ti]) OR systematic review[ptyp] OR systematic review[ti] OR meta-analysis[ptyp] OR meta-analysis[ti] OR meta-analyses[ti]); NOT (“Animals”[Mesh] NOT (“Animals”[Mesh] AND “Humans”[Mesh])); Language: English; Publication Date: past 5 years | 87