# Appendix 2-b Literature search strategy for protein intake and length of sleep evidence scan (supplemental to chronic disease risk scan)

Database: PubMed

Provider: U.S. National Library of Medicine

Date(s) Searched: December 15, 2021

Search # | Concept | Search String | # of Results
#1 | Protein | “dietary proteins”[MeSH] OR “Amino Acids”[MeSH] OR “Diet, High Protein”[MeSH] OR “protein intake”[TIAB] OR “high protein”[TIAB] OR “protein consumption”[TIAB] OR “protein supplement*”[TIAB] OR “increased protein”[tiab] | 936,791
#2 | Sleep | “sleep”[MeSH] OR “total sleep time”[tiab] OR “tst”[tiab] OR ((sleep*[tiab] OR nap[tiab] OR naps[tiab] OR napping[tiab]) AND (time[tiab] OR duration[tiab] OR quality[tiab] OR length[tiab] OR hour*[tiab])) | 181,296
#3 | Review | review[ptyp] OR scoping review[ti] OR qualitative review[ti] OR evidence review[ti] OR quantitative review[ti] OR meta-review[ti] OR critical review[ti] OR mixed studies review[ti] OR mapping review[ti] OR integrative review[ti] OR (literature[ti] AND review[ti]) OR systematic review[ptyp] OR systematic review[ti] OR meta-analysis[ptyp] OR meta-analysis[ti] OR meta-analyses[ti] | 3,134,720
#4 | #1 AND #2 AND #3 | | 355
#5 | Limiters | NOT (“Animals”[Mesh] NOT (“Animals”[Mesh] AND “Humans”[Mesh])); Language: English; Publication Date: 2016-present | 74