# Appendix 2-a Literature search strategy for protein intake and chronic disease risk evidence scan

Database: PubMed

Provider: U.S. National Library of Medicine

Date(s) Searched: December 17, 2021

Search # | Concept | String | Results
#1 | Protein | “dietary proteins”[MeSH] OR “Amino Acids”[MeSH] OR “Diet, High Protein”[MeSH] OR “protein intake”[TIAB] OR “high protein”[TIAB] OR “protein consumption”[TIAB] OR “protein supplement*”[TIAB] OR “increased protein”[tiab] | 938,484
#2 | GSBC | “Adipose Tissue”[Mesh] OR “Body Composition”[Mesh] OR “Body Weights and Measures”[MeSH:NoExp] OR “Body Fat Distribution”[Mesh] OR “Body Mass Index”[Mesh] OR “Body Size”[Mesh] OR “Skinfold Thickness”[Mesh] OR “Waist-Hip Ratio”[Mesh] OR “Overnutrition”[Mesh] OR “Growth”[Mesh:NoExp] OR anthropometr*[tiab] OR body fat[tiab] OR fat mass[tiab] OR fat free mass[tiab] OR lean mass[tiab] OR obese[tiab] OR obesity[tiab] OR underweight[tiab] OR overweight[tiab] OR weight status[tiab] OR head circumference[tiab] OR arm circumference[tiab] OR calf circumference[tiab] OR neck circumference[tiab] OR thigh circumference[tiab] OR waist circumference[tiab] OR waist to hip ratio[tiab] OR waist hip ratio[tiab] OR body mass index[tiab] OR BMI[tiab] OR adipos*[tiab] OR body weight[tiab] OR body height[tiab] OR body size[tiab] OR body composition[tiab] OR overnutrition[tiab] OR wasting[tiab] OR healthy weight[tiab] OR skin fold[tiab] OR skin folds[tiab] OR skinfold[tiab] OR skinfolds[tiab]; OR “Weight Reduction Programs”[Mesh] OR “Body-Weight Trajectory”[Mesh] OR “Weight Gain”[MeSH] OR “Weight Loss”[MeSH:NoExp] OR “Diet, Reducing”[Mesh] OR weight gain[tiab] OR diet reduc*[tiab] OR weight cycling[tiab] OR weight decreas*[tiab] OR weight watch*[tiab] OR weight control*[tiab] OR weight retention[tiab] OR weight management[tiab] OR (weight[tiab] AND (maint*[tiab] OR reduc*[tiab] OR loss*[tiab] OR chang*[tiab])); OR “Growth Charts”[Mesh] OR growth chart*[tiab]OR stunting[tiab] OR stunted[tiab] OR weight for height[tiab] OR stature for age[tiab] OR weight for age[tiab] OR height for age[tiab] OR length for age[tiab] OR weight for length[tiab] OR failure to thrive[tiab] | 1,394,632
#3 | CVD | “Cardiovascular Diseases”[Mesh:NoExp] OR “cardiovascular disease*”[tiab] OR “coronary artery disease”[tiab] OR “heart disease*”[tiab] OR “Heart Failure”[Mesh] OR “heart failure”[tiab] OR “myocardial infarction*”[tiab] OR “Myocardial Ischemia”[Mesh] OR “myocardial ischemia*”[tiab] OR “Stroke”[Mesh] OR “stroke*”[tiab] OR “angina”[tiab] OR “heart attack*”[tiab] OR “Venous Thrombosis”[Mesh] OR “venous thrombosis”[tiab] OR “hypertension”[tiab] OR Blood Pressure[Mesh:NoExp] OR “high blood pressure”[tiab] OR “Lipids/blood”[Mesh] OR “Cholesterol, HDL”[Mesh] OR “HDL cholesterol”[tiab] OR “Cholesterol, LDL”[Mesh] OR “LDL cholesterol”[tiab] OR “total cholesterol”[tiab] OR “blood cholesterol”[tiab] OR “Triglycerides”[Mesh] OR “triglycerides”[tiab] OR “Hypertension”[Mesh:NoExp] OR hypertensi*[tiab] OR “Hypertension, Pregnancy-Induced”[Mesh] OR “Pre-Eclamp*”[tiab] OR preeclamp*[tiab] OR Eclamp*[tiab] | 2,173,208
#4 | T2D | “Diabetes Mellitus”[Mesh:NoExp] OR “Diabetes Mellitus, Type 2”[Mesh] OR “type 2 diabet*”[tiab] OR “T2D”[tiab] OR “adult onset diabetes”[tiab] OR “Prediabetic State”[Mesh] OR “prediabet*”[tiab] OR “pre diabet*”[tiab] OR “Insulin Resistance”[Mesh] OR “insulin resistance”[tiab] OR “insulin resistant”[tiab] OR “glucose intolerance”[tiab] OR “glucose intolerant”[tiab] OR “glucose tolerance”[tiab] OR “glucose tolerant”[tiab] OR “Glycated Hemoglobin A”[Mesh] OR “hemoglobin A1c”[tiab] OR hba1c[tiab] OR “hba 1c”[tiab] OR “haemoglobin A1c”[tiab] OR “Hyperglycemia”[Mesh] OR “hyperglycemia”[tiab] OR hyperglycaemia[tiab] OR “Hypoglycemia”[Mesh] OR “hypoglycemia”[tiab] OR hypoglycaemia[tiab] OR ((impaired[tiab] OR glucose[tiab]) AND fasting[tiab]) OR “blood glucose”[MeSH] OR “blood glucose”[tiab] OR “plasma glucose”[tiab] OR “serum glucose”[tiab] OR “glycemi*”[tiab] OR glycaemi*[tiab] OR “blood sugar”[tiab] OR dysglycemi*[tiab] OR dysglycaemi*[tiab] OR hyperinsulinism[MeSH] OR hyperinsulin*[tiab] OR “Diabetes, Gestational”[Mesh] OR (gestation*[tiab] AND diabet*[tiab]) OR (“Maternal Nutritional Physiological Phenomena”[Mesh] AND diabet*[tiab]) | 660,434
#5 | Bone Health | “Bone Density”[Mesh] OR “bone density”[tiab] OR bone mineral density[tiab] OR “Bone Development”[Mesh] OR “bone development”[tiab] OR “Fractures, Bone”[Mesh] OR “Bone Diseases”[Mesh] OR bone disease*[tiab] OR bone turnover[tiab] OR bone loss[tiab] OR osteoporosis[tiab] OR “Osteoporosis”[Mesh] OR osteopen*[tiab] OR osteitis[tiab] OR osteolysis[tiab] OR “Rickets”[Mesh] OR Rickets[tiab] OR bone mineral*[tiab] OR “bone mass”[tiab] OR bone health*[tiab] OR “Bone Demineralization, Pathologic”[Mesh] OR bone demineral*[tiab] OR “Bone Remodeling”[Mesh] OR bone strength[tiab] OR bone formation[tiab] OR bone accretion[tiab] OR bone mineral accretion[tiab] OR ((bone[tiab] OR bones[tiab] OR “Bone and Bones”[Mesh]) AND (fracture*[tiab] OR remodel*[tiab] OR ossification[tiab] OR resorption[tiab] OR BMC[tiab] OR BMD[tiab] OR “Biomarkers”[Mesh] OR biomarker*[tiab])) | 918,688
#6 | Sarcopenia | “Muscular Atrophy”[MesH] OR “sarcopen*”[tiab] OR “presarcopen*”[tiab] OR “muscular atroph*”[tiab] OR “Muscle Fatigue”[Mesh] OR “muscle fatigue”[tiab] OR “Muscle Strength”[Mesh] OR “muscle strength*”[tiab] OR “muscle wast*”[tiab] OR “muscle weak*”[tiab] OR “muscle loss*”[tiab] OR “muscle function*”[tiab] OR “muscle mass”[tiab] OR “hand strength*”[tiab] OR “grip strength*”[tiab] OR “handgrip*”[tiab] OR “pinch strength*”[tiab] OR “Physical Functional Performance”[Mesh] OR “physical performance*”[tiab] | 150,647
#7 | Chronic Kidney Disease | “Kidney Diseases”[MeSH:NoExp] OR “Renal Insufficiency”[MeSH] OR “Nephrolithiasis”[MeSH] OR ((renal[tiab] OR kidney[tiab]) AND (insufficiency[tiab] OR disease[tiab] OR failure[tiab] OR chronic[tiab] OR endstage[tiab] OR end stage[tiab])) OR CKF[tiab] OR CKD[tiab] OR CRF[tiab] OR CRD[tiab] OR ESKD[tiab] OR ESRD[tiab] OR ESKF[tiab] OR ESRF[tiab] OR nephrolith[tiab] OR kidney stone*[tiab] OR kidney calcul*[tiab] OR renal stone*[tiab] OR renal calcul*[tiab] OR glomerular filtration rate[tiab] OR GFR[tiab] | 564,081
#8 | Dementia and Cognitive Decline | “Cognition Disorders”[Mesh] OR “Cognition”[Mesh] OR cognition[tiab] OR metacognition[tiab] OR neurocognitive[tiab] OR “Dementia”[Mesh] OR dementia[tiab] OR Alzheimer*[tiab] OR senility[tiab] OR senile[tiab] OR presenile[tiab] OR (cognit*[tiab] AND (function*[tiab] OR dysfunction*[tiab] OR declin*[tiab] OR deteriorat* OR degenerat*[tiab] OR disorder*[tiab] OR dysfunction*[tiab] OR reduct*[tiab] OR impair*[tiab] OR deficit*[tiab] OR deficien* OR progress*[tiab] OR perform*[tiab] OR abilit*[tiab])) | 727,154
#9 | Neurocognitive Health and Development | “Mental Disorders”[Mesh:NoExp] OR “Anxiety Disorders”[Mesh] OR “Mood disorders”[Mesh] OR “Motor Disorders”[Mesh] OR “Neurocognitive disorders”[Mesh:NoExp] OR “Cognition Disorders”[Mesh] OR “Neurodevelopmental disorders”[Mesh] OR “mental disorder*”[tiab] OR “Cognition”[Mesh] OR “cogniti*”[tiab] OR “metacogniti*”[tiab] OR “neurocogniti*”[tiab] OR “neurodevelop*”[tiab] OR “neurologic*”[tiab] OR “Depression”[Mesh] OR “depression”[tiab] OR “anxiety”[tiab] OR “Psychomotor Performance”[Mesh] OR “Psychomotor Disorders”[Mesh] OR psychomotor[tiab] OR “motor skill*”[tiab] OR “Executive Function”[Mesh] OR “executive function*”[tiab] OR “attention deficit disorder*”[tiab] OR “ADHD”[tiab] OR “attention deficit hyperactivity disorder”[tiab] OR “developmental disorder*”[tiab] OR “Autism”[tiab] OR “autistic”[tiab] OR “Asperger*”[tiab] OR “Communication Disorders”[Mesh] OR communication disorder*[tiab] OR “language processing”[tiab] OR “language delay*”[tiab] OR “Child Development”[Mesh] OR “child develop*”[tiab] OR “developmental delay*”[tiab] OR “developmental disabilit*”[tiab] OR “Problem Solving”[Mesh] OR “developmental domain*”[tiab] OR “Mental Processes”[Mesh:NoExp] OR “mental process*”[tiab] OR “Social development”[tiab] OR “emotional development”[tiab] OR “Visual Acuity”[MeSH:NoExp] OR “Aptitude”[Mesh] OR “Aptitude tests”[Mesh] OR “Achievement”[Mesh] OR “Intelligence”[MeSH] OR “Neuropsychological Tests”[MeSH] OR “visual acuity”[tiab] OR aptitude[tiab] OR intelligence[tiab] OR neuropsychologic*[tiab] OR (child health[tiab] AND wellbeing[tiab]) OR “educational status”[tiab] OR ((academic[tiab] OR education*[tiab] OR school[tiab]) AND (performance[tiab] OR achievement[tiab] OR attainment[tiab] OR failure[tiab] OR success[tiab])) | 2,298,792
#10 | ACM | (“Mortality”[Mesh] OR “mortality”[Subheading] OR mortality[tiab] OR death[ti]) | 1,492,965
#11 | Chronic Disease | “Chronic Disease”[Mesh] OR “chronic disease*”[tiab] | 637,337
#12 | Review | review[ptyp] OR scoping review[ti] OR qualitative review[ti] OR evidence review[ti] OR quantitative review[ti] OR meta-review[ti] OR critical review[ti] OR mixed studies review[ti] OR mapping review[ti] OR integrative review[ti] OR (literature[ti] AND review[ti]) OR systematic review[ptyp] OR systematic review[ti] OR meta-analysis[ptyp] OR meta-analysis[ti] OR meta-analyses[ti] | 3,136,213
#13 | #1 AND (#2 OR #3 OR #4 OR #5 OR #6 OR #7 OR #8 OR #9 OR #10 OR #11) AND #12 | | 19,679
#14 | Limiters | #13 NOT (“Animals”[Mesh] NOT (“Animals”[Mesh] AND “Humans”[Mesh])); Language: English; Publication Date: 2016-present | 3,859