# Appendix 1-b Excluded articles for high protein intake and acute adverse health effects evidence scan

The following table lists the articles excluded after full-text screening for this evidence scan. At least one reason for exclusion is provided for each article, though this may not reflect all possible reasons. Information about articles excluded after title and abstract screening is available upon request.

# | Citation | Exclusion reason #1 | Exclusion reason #2 | Exclusion reason #3
1 | Ancu, O.,Mickute, M.,Guess, N. D.,Hurren, N. M.,Burd, N. A.,Mackenzie, R. W.. Does high dietary protein intake contribute to the increased risk of developing prediabetes and type 2 diabetes?. Appl Physiol Nutr Metab. 2021. 46:1-9. doi:10.1139/apnm-2020-0396 . | Outcome | - | -
2 | Andreeva, E.,Tkeshelashvili, B.. Women dealing with hot flushes: the role of beta-alanine. Eur Rev Med Pharmacol Sci. 2020. 24:5148-5154. doi:10.26355/eurrev_202005_21209 . | Outcome | Health status | -
3 | Antonio, J.,Candow, D. G.,Forbes, S. C.,Gualano, B.,Jagim, A. R.,Kreider, R. B.,Rawson, E. S.,Smith-Ryan, A. E.,VanDusseldorp, T. A.,Willoughby, D. S.,Ziegenfuss, T. N.. Common questions and misconceptions about creatine supplementation: what does the scientific evidence really show?. J Int Soc Sports Nutr. 2021. 18:13. doi:10.1186/s12970-021-00412-w . | IV/E | - | -
4 | Arrieta-Cruz, I.,Gutierrez-Juarez, R.. The Role of Circulating Amino Acids in the Hypothalamic Regulation of Liver Glucose Metabolism. Adv Nutr. 2016. 7:790S-7S. doi:10.3945/an.115.011171 . | IV/E | Outcome | -
5 | Backus, K. M.. Applications of Reactive Cysteine Profiling. Curr Top Microbiol Immunol. 2019. 420:375-417. doi:10.1007/82_2018_120 . | IV/E | Outcome | -
6 | Badawy, A. A.,Namboodiri, A. M.,Moffett, J. R.. The end of the road for the tryptophan depletion concept in pregnancy and infection. Clin Sci (Lond). 2016. 130:1327-33. doi:10.1042/CS20160153 . | Outcome | | -
7 | Balestrino, M.. Role of Creatine in the Heart: Health and Disease. Nutrients. 2021. 13:#pages#. doi:10.3390/nu13041215 | IV/E | | -
8 | Barkovich, E.,Gropman, A. L.. Late Onset Ornithine Transcarbamylase Deficiency Triggered by an Acute Increase in Protein Intake: A Review of 10 Cases Reported in the Literature. Case Rep Genet. 2020. 2020:7024735. doi:10.1155/2020/7024735 . | Outcome | Health status | -
9 | Bird, J. A.,Barni, S.,Brown-Whitehorn, T. F.,du Toit, G.,Infante, S.,Nowak-Wegrzyn, A.. Food protein-induced enterocolitis syndrome oral food challenge: Time for a change?. Ann Allergy Asthma Immunol. 2021. 126:506-515. doi:10.1016/j.anai.2021.02.022 . | IV/E | - | -
10 | Blachier, F.,Blais, A.,Elango, R.,Saito, K.,Shimomura, Y.,Kadowaki, M.,Matsumoto, H.. Tolerable amounts of amino acids for human supplementation: summary and lessons from published peer-reviewed studies. Amino Acids. 2021. 53:1313-1328. doi:10.1007/s00726-021-03054-z . | Outcome | Non-human | -
11 | Cava, E.,Yeat, N. C.,Mittendorfer, B.. Preserving Healthy Muscle during Weight Loss. Adv Nutr. 2017. 8:511-519. doi:10.3945/an.116.014506 . | Outcome | - | -
12 | Curran, C. P.,Marczinski, C. A.. Taurine, caffeine, and energy drinks: Reviewing the risks to the adolescent brain. Birth Defects Res. 2017. 109:1640-1648. doi:10.1002/bdr2.1177 . | IV/E | - | -
13 | D’Arcy, E.,Rayner, J.,Hodge, A.,Ross, L. J.,Schoenaker, Dajm. The Role of Diet in the Prevention of Diabetes among Women with Prior Gestational Diabetes: A Systematic Review of Intervention and Observational Studies. J Acad Nutr Diet. 2020. 120:69-85 e7. doi:10.1016/j.jand.2019.07.021 . | Outcome | - | -
14 | Davani-Davari, D.,Karimzadeh, I.,Ezzatzadegan-Jahromi, S.,Sagheb, M. M.. Potential Adverse Effects of Creatine Supplement on the Kidney in Athletes and Bodybuilders. Iran J Kidney Dis. 2018. 12:253-260. doi:#electronic resource number# . | IV/E | - | -
15 | De Bandt, J. P.. Leucine and Mammalian Target of Rapamycin-Dependent Activation of Muscle Protein Synthesis in Aging. J Nutr. 2016. 146:2616S-2624S. doi:10.3945/jn.116.234518 . | IV/E | Outcome | -
16 | De Waele, E.,Jakubowski, J. R.,Stocker, R.,Wischmeyer, P. E.. Review of evolution and current status of protein requirements and provision in acute illness and critical care. Clin Nutr. 2021. 40:2958-2973. doi:10.1016/j.clnu.2020.12.032 . | Health status | - | -
17 | Dimina, L.,Mariotti, F.. The Postprandial Appearance of Features of Cardiometabolic Risk: Acute Induction and Prevention by Nutrients and Other Dietary Substances. Nutrients. 2019. 11:#pages#. doi:10.3390/nu11091963 . | IV/E | - | -
18 | Ding, X.,Bin, P.,Wu, W.,Chang, Y.,Zhu, G.. Tryptophan Metabolism, Regulatory T Cells, and Inflammatory Bowel Disease: A Mini Review. Mediators Inflamm. 2020. 2020:9706140. doi:10.1155/2020/9706140 . | Outcome | Health status | -
19 | Djuric, D.,Jakovljevic, V.,Zivkovic, V.,Srejovic, I.. Homocysteine and homocysteine-related compounds: an overview of the roles in the pathology of the cardiovascular and nervous systems. Can J Physiol Pharmacol. 2018. 96:991-1003. doi:10.1139/cjpp-2018-0112 . | Outcome | - | -
20 | Dolan, E.,Swinton, P. A.,Painelli, V. S.,Stephens Hemingway, B.,Mazzolani, B.,Infante Smaira, F.,Saunders, B.,Artioli, G. G.,Gualano, B.. A Systematic Risk Assessment and Meta-Analysis on the Use of Oral beta-Alanine Supplementation. Adv Nutr. 2019. 10:452-463. doi:10.1093/advances/nmy115 . | IV/E | - | -
21 | Dubo, S.,Gallegos, D.,Cabrera, L.,Sobrevia, L.,Zuniga, L.,Gonzalez, M.. Cardiovascular Action of Insulin in Health and Disease: Endothelial L-Arginine Transport and Cardiac Voltage-Dependent Potassium Channels. Front Physiol. 2016. 7:74. doi:10.3389/fphys.2016.00074 . | IV/E | Outcome | -
22 | Esse, R.,Barroso, M.,Tavares de Almeida, I.,Castro, R.. The Contribution of Homocysteine Metabolism Disruption to Endothelial Dysfunction: State-of-the-Art. Int J Mol Sci. 2019. 20:#pages#. doi:10.3390/ijms20040867 . | Outcome | - | -
23 | Franceschi, N.,Paraskevopoulos, K.,Waigmann, E.,Ramon, M.. Predictive Protein Toxicity and Its Use in Risk Assessment. Trends Biotechnol. 2017. 35:483-486. doi:10.1016/j.tibtech.2017.03.010 . | IV/E | Outcome | -
24 | Galvan, E.,Arentson-Lantz, E.,Lamon, S.,Paddon-Jones, D.. Protecting Skeletal Muscle with Protein and Amino Acid during Periods of Disuse. Nutrients. 2016. 8:#pages#. doi:10.3390/nu8070404 . | Outcome | - | -
25 | Haleem, D. J.. Improving therapeutics in anorexia nervosa with tryptophan. Life Sci. 2017. 178:87-93. doi:10.1016/j.lfs.2017.04.015 . | Health status | - | -
26 | Hansen, T. T.,Astrup, A.,Sjodin, A.. Are Dietary Proteins the Key to Successful Body Weight Management? A Systematic Review and Meta-Analysis of Studies Assessing Body Weight Outcomes after Interventions with Increased Dietary Protein. Nutrients. 2021. 13:#pages#. doi:10.3390/nu13093193 . | Outcome | - | -
27 | Harvey, Cjdc,Schofield, G. M.,Williden, M.. The use of nutritional supplements to induce ketosis and reduce symptoms associated with keto-induction: a narrative review. PeerJ. 2018. 6:e4488. doi:10.7717/peerj.4488 . | IV/E | Outcome | -
28 | Herring, C. M.,Bazer, F. W.,Johnson, G. A.,Wu, G.. Impacts of maternal dietary protein intake on fetal survival, growth, and development. Exp Biol Med (Maywood). 2018. 243:525-533. doi:10.1177/1535370218758275 . | Outcome | - | -
29 | Hoffmann, N. V.,Ahmed, A.,Fortunato, J. E.. Food protein-induced enterocolitis syndrome: Dynamic relationship among gastrointestinal symptoms, immune response, and the autonomic nervous system. Ann Allergy Asthma Immunol. 2021. 126:498-505. doi:10.1016/j.anai.2021.02.004 . | IV/E | - | -
30 | Holecek, M.. Branched-chain amino acids in health and disease: metabolism, alterations in blood plasma, and as supplements. Nutr Metab (Lond). 2018. 15:33. doi:10.1186/s12986-018-0271-1 . | Design | Health status | -
31 | Kang, J.,Ratamess, N. A.,Faigenbaum, A. D.,Bush, J. A.. Ergogenic Properties of Ketogenic Diets in Normal-Weight Individuals: A Systematic Review. J Am Coll Nutr. 2020. 39:665-675. doi:10.1080/07315724.2020.1725686 . | IV/E | - - | -
32 | Kim, J.,Kim, H.,Roh, H.,Kwon, Y.. Causes of hyperhomocysteinemia and its pathological significance. Arch Pharm Res. 2018. 41:372-383. doi:10.1007/s12272-018-1016-4 | Outcome | | -
33 | Kozich, V.,Stabler, S.. Lessons Learned from Inherited Metabolic Disorders of Sulfur-Containing Amino Acids Metabolism. J Nutr. 2020. 150:2506S-2517S. doi:10.1093/jn/nxaa134 . | Health status | - | -
34 | Lancha, A. H., Jr.,Zanella, R., Jr.,Tanabe, S. G.,Andriamihaja, M.,Blachier, F.. Dietary protein supplementation in the elderly for limiting muscle mass loss. Amino Acids. 2017. 49:33-47. doi:10.1007/s00726-016-2355-4 . | Outcome | - | -
35 | Lehotsky, J.,Tothova, B.,Kovalska, M.,Dobrota, D.,Benova, A.,Kalenska, D.,Kaplan, P.. Role of Homocysteine in the Ischemic Stroke and Development of Ischemic Tolerance. Front Neurosci. 2016. 10:538. doi:10.3389/fnins.2016.00538 . | Outcome | - | -
36 | Lekawanvijit, S.,Kompa, A. R.,Krum, H.. Protein-bound uremic toxins: a long overlooked culprit in cardiorenal syndrome. Am J Physiol Renal Physiol. 2016. 311:F52-62. doi:10.1152/ajprenal.00348.2015 . | IV/E | Health status | -
37 | Ma, N.,Tian, Y.,Wu, Y.,Ma, X.. Contributions of the Interaction Between Dietary Protein and Gut Microbiota to Intestinal Health. Curr Protein Pept Sci. 2017. 18:795-808. doi:10.2174/1389203718666170216153505 . | Outcome | Non-human | -
38 | Mastrorilli, C.,Santoro, A.,Procaccianti, M.,Pagliaro, G.,Caffarelli, C.. New insights into food protein-induced enterocolitis in children. Minerva Pediatr. 2020. 72:416-423. doi:10.23736/S0026-4946.20.05976-9 . | IV/E | | -
39 | Matthews, J. J.,Dolan, E.,Swinton, P. A.,Santos, L.,Artioli, G. G.,Turner, M. D.,Elliott-Sale, K. J.,Sale, C.. Effect of Carnosine or beta-Alanine Supplementation on Markers of Glycemic Control and Insulin Resistance in Humans and Animals: A Systematic Review and Meta-analysis. Adv Nutr. 2021. #volume#:#pages#. doi:10.1093/advances/nmab087 . | Outcome | - | -
40 | Mazzucato, M.,Fioretto, P.,Avogaro, A.. High-protein diet: A barrier to the nephroprotective effects of sodium-glucose co-transporter-2 inhibitors?. Diabetes Obes Metab. 2020. 22:1511-1515. doi:10.1111/dom.14071 . | Outcome | - | -
41 | Meftah, A.,Hasegawa, H.,Kantrowitz, J. T.. D-Serine: A Cross Species Review of Safety. Front Psychiatry. 2021. 12:726365. doi:10.3389/fpsyt.2021.726365 . | IV/E | - | -
42 | Mirzaei, H.,Raynes, R.,Longo, V. D.. The conserved role of protein restriction in aging and disease. Curr Opin Clin Nutr Metab Care. 2016. 19:74-9. doi:10.1097/MCO.0000000000000239 . | IV/E | - | -
43 | Moon, J.,Koh, G.. Clinical Evidence and Mechanisms of High-Protein Diet-Induced Weight Loss. J Obes Metab Syndr. 2020. 29:166-173. doi:10.7570/jomes20028 . | Outcome | - | -
44 | Moore, D. R.. Maximizing Post-exercise Anabolism: The Case for Relative Protein Intakes. Front Nutr. 2019. 6:147. doi:10.3389/fnut.2019.00147 . | Outcome | - | -
45 | Moulle, V. S.,Parnet, P.. Effects of Nutrient Intake during Pregnancy and Lactation on the Endocrine Pancreas of the Offspring. Nutrients. 2019. 11:#pages#. doi:10.3390/nu11112708 . | Outcome | - | -
46 | Mousa, A.,Naqash, A.,Lim, S.. Macronutrient and Micronutrient Intake during Pregnancy: An Overview of Recent Evidence. Nutrients. 2019. 11:#pages#. doi:10.3390/nu11020443 . | Outcome | - | -
47 | Moussa, M.,Papatsoris, A. G.,Abou Chakra, M.,Moussa, Y.. Update on cystine stones: current and future concepts in treatment. Intractable Rare Dis Res. 2020. 9:71-78. doi:10.5582/irdr.2020.03006 . | IV/E | Health status | -
48 | Nurul Adilah, Z.,Mohd Redzwan, S.. Effect of dietary macronutrients on aflatoxicosis: a mini-review. J Sci Food Agric. 2017. 97:2277-2281. doi:10.1002/jsfa.8234 . | IV/E | Non-human | -
49 | Osborn, D. A.,Schindler, T.,Jones, L. J.,Sinn, J. K.,Bolisetty, S.. Higher versus lower amino acid intake in parenteral nutrition for newborn infants. Cochrane Database Syst Rev. 2018. 3:CD005949. doi:10.1002/14651858.CD005949.pub2 . | Health status | - | -
50 | Pereira-da-Silva, L.,Rego, C.,Pietrobelli, A.. The Diet of Preschool Children in the Mediterranean Countries of the European Union: A Systematic Review. Int J Environ Res Public Health. 2016. 13:#pages#. doi:10.3390/ijerph13060572 . | IV/E | Outcome | -
51 | Phillips, S. M.,Paddon-Jones, D.,Layman, D. K.. Optimizing Adult Protein Intake During Catabolic Health Conditions. Adv Nutr. 2020. 11:S1058-S1069. doi:10.1093/advances/nmaa047 . | Outcome | - | -
52 | Popova, A. A.,Koksharova, O. A.. Neurotoxic Non-proteinogenic Amino Acid beta-N-Methylamino-L-alanine and Its Role in Biological Systems. Biochemistry (Mosc). 2016. 81:794-805. doi:10.1134/S0006297916080022 . | IV/E | Outcome | -
53 | Roberts, A.,Lynch, B.,Rietjens, Imcm. Risk Assessment Paradigm for Glutamate. Ann Nutr Metab. 2018. 73 Suppl 5:53-64. doi:10.1159/000494783 . | IV/E | - | -
54 | Saito, M.,Marumo, K.. The Effects of Homocysteine on the Skeleton. Curr Osteoporos Rep. 2018. 16:554-560. doi:10.1007/s11914-018-0469-1 . | IV/E | Outcome | -
55 | Shams-White, M. M.,Chung, M.,Du, M.,Fu, Z.,Insogna, K. L.,Karlsen, M. C.,LeBoff, M. S.,Shapses, S. A.,Sackey, J.,Wallace, T. C.,Weaver, C. M.. Dietary protein and bone health: a systematic review and meta-analysis from the National Osteoporosis Foundation. Am J Clin Nutr. 2017. 105:1528-1543. doi:10.3945/ajcn.116.145110 . | Outcome | - | -
56 | Shiao, S. P. K.,Lie, A.,Yu, C. H.. Meta-analysis of homocysteine-related factors on the risk of colorectal cancer. Oncotarget. 2018. 9:25681-25697. doi:10.18632/oncotarget.25355 . | IV/E | Outcome | -
57 | Sivashanmugam, M.,J, J.,V, U.,K, N. S.. Ornithine and its role in metabolic diseases: An appraisal. Biomed Pharmacother. 2017. 86:185-194. doi:10.1016/j.biopha.2016.12.024 . | IV/E | - | -
58 | Skovierova, H.,Vidomanova, E.,Mahmood, S.,Sopkova, J.,Drgova, A.,Cervenova, T.,Halasova, E.,Lehotsky, J.. The Molecular and Cellular Effect of Homocysteine Metabolism Imbalance on Human Health. Int J Mol Sci. 2016. 17:#pages#. doi:10.3390/ijms17101733 . | Design | Outcome | -
59 | Slater, G. J.,Sygo, J.,Jorgensen, M.. SPRINTING… Dietary Approaches to Optimize Training Adaptation and Performance. Int J Sport Nutr Exerc Metab. 2019. 29:85-94. doi:10.1123/ijsnem.2018-0273 . | Outcome | - | -
60 | Strasser, B.,Fuchs, D.. Diet Versus Exercise in Weight Loss and Maintenance: Focus on Tryptophan. Int J Tryptophan Res. 2016. 9:9-16. doi:10.4137/IJTR.S33385 . | IV/E | Outcome | -
61 | Thompson, M. E.,Noel, M. B.. Issues in Nutrition: Dietary Supplements. FP Essent. 2017. 452:18-25. doi:#electronic resource number# . | IV/E | Outcome | -
62 | Tielemans, M. J.,Garcia, A. H.,Peralta Santos, A.,Bramer, W. M.,Luksa, N.,Luvizotto, M. J.,Moreira, E.,Topi, G.,de Jonge, E. A.,Visser, T. L.,Voortman, T.,Felix, J. F.,Steegers, E. A.,Kiefte-de Jong, J. C.,Franco, O. H.. Macronutrient composition and gestational weight gain: a systematic review. Am J Clin Nutr. 2016. 103:83-99. doi:10.3945/ajcn.115.110742 . | Outcome | - | -
63 | Tome, D.. Admissible daily intake for glutamate. Curr Opin Clin Nutr Metab Care. 2020. 23:133-137. doi:10.1097/MCO.0000000000000624 . | IV/E | - | -
64 | Torre-Villalvazo, I.,Aleman-Escondrillas, G.,Valle-Rios, R.,Noriega, L. G.. Protein intake and amino acid supplementation regulate exercise recovery and performance through the modulation of mTOR, AMPK, FGF21, and immunity. Nutr Res. 2019. 72:1-17. doi:10.1016/j.nutres.2019.06.006 . | Outcome | - | -
65 | Turkozu, D.,Sanlier, N.. L-theanine, unique amino acid of tea, and its metabolism, health effects, and safety. Crit Rev Food Sci Nutr. 2017. 57:1681-1687. doi:10.1080/10408398.2015.1016141 . | IV/E | Outcome | -
66 | Volterman, K. A.,Atkinson, S. A.. Protein Needs of Physically Active Children. Pediatr Exerc Sci. 2016. 28:187-93. doi:10.1123/pes.2015-0257 . | IV/E | Outcome | -
67 | Wade, F.,Belhaj, K.,Poizat, C.. Protein tyrosine phosphatases in cardiac physiology and pathophysiology. Heart Fail Rev. 2018. 23:261-272. doi:10.1007/s10741-018-9676-1 . | IV/E | Outcome | -
68 | Wang, J.,Ji, H.. Influence of Probiotics on Dietary Protein Digestion and Utilization in the Gastrointestinal Tract. Curr Protein Pept Sci. 2019. 20:125-131. doi:10.2174/1389203719666180517100339 . | Outcome | - | -
69 | Zhang, S.,Zeng, X.,Ren, M.,Mao, X.,Qiao, S.. Novel metabolic and physiological functions of branched chain amino acids: a review. J Anim Sci Biotechnol. 2017. 8:10. doi:10.1186/s40104-016-0139-z . | IV/E | Outcome | -
70 | Zhuo, D. X.,Ragosta, M., 3rd,Patterson, B.. Tyrosine kinase inhibitor toxicity manifesting as comorbid Moyamoya syndrome and obstructive coronary artery disease: A case report and review of the literature. Catheter Cardiovasc Interv. 2019. 94:117-119. doi:10.1002/ccd.28189 . | Design | IV/E | Health status