# Appendix 1-a Literature search strategy for high protein intake and acute adverse health effects evidence scan

Database: PubMed

Provider: U.S. National Library of Medicine

Date(s) Searched: October 26, 2021

Search # | Concept | String | Results
#1 | Dietary Proteins and Amino Acids | “dietary proteins”[MeSH] OR “Amino Acids”[MeSH] OR “Diet, High Protein”[MeSH] OR “protein intake”[TIAB] OR “high protein”[TIAB] OR “protein consumption”[TIAB] OR “protein supplement*”[TIAB] OR “increased protein”[tiab] OR “amino acid*”[tiab] OR Histidine[tiab] OR isoleucine[tiab] OR leucine[tiab] OR lysine[tiab] OR methionine[tiab] OR cysteine[tiab] OR phenylalanine[tiab] OR tyrosine[tiab] OR threonine[tiab] OR tryptophan[tiab] OR valine[tiab] | 1,593,139
#2 | Upper Limits | “No-Observed-Adverse-Effect Level”[Mesh] OR “Upper limit*”[tiab] OR “upper reference level*”[tiab] OR toxicity[tiab] OR “upper safe limit*”[tiab] OR “tolerance”[tiab] OR “tolerable upper intake level”[tiab] OR “excessive intake”[tiab] OR “adverse effect*”[tiab] OR “excessive”[tiab] | 971,557
#3 | Review | review[ptyp] OR scoping review[ti] OR narrative review[ti] OR qualitative review[ti] OR evidence review[ti] OR quantitative review[ti] OR meta-review[ti] OR critical review[ti] OR mixed studies review[ti] OR mapping review[ti] OR integrative review[ti] OR (literature[ti] AND review[ti]) OR systematic review[ptyp] OR systematic review[ti] OR meta-analysis[ptyp] OR meta-analysis[ti] OR meta-analyses[ti] | 3,104,796
#4 | #1 AND #2 AND #3 | | 8,193
#5 | Limiters | NOT (“Animals”[Mesh] NOT (“Animals”[Mesh] AND “Humans”[Mesh])); Language: English; Publication Date: 2016-present | 2,377