# Appendix 0 Abbreviations

Abbreviation: Full name
AA: Amino acid(s)
ACM: All-cause mortality
AI: Adequate Intake
AMDR: Acceptable Macronutrient Distribution Range
AMSTAR: A MeaSurement Tool to Assess systematic Reviews
ARS: Agricultural Research Service
BMC: Bone mineral content
BMD: Bone mineral density
BMI: Body Mass Index
CNPP: Center for Nutrition Policy and Promotion
CVD: Cardiovascular disease
d: Day(s)
DRI: Dietary Reference Intakes
EAR: Estimated Average Requirement
eGFR: Estimated glomerular filtration rate
FDA: Food and Drug Administration
FDA: Food and Drug Administration
FNS: Food and Nutrition Service
g: Gram(s)
GFR: Glomerular filtration rate
GI: Gastrointestinal
GRAS: Generally recognized as safe
HbA1c: Hemoglobin A1c
HDI: Human Development Index
HHS: Health and Human Services
IAAO: Indicator amino acid oxidation
IOM: Institute of Medicine
kg: Kilogram(s)
MA: Meta-analysis
mg: Milligram(s)
N: Nitrogen
NESR: Nutrition Evidence Systematic Review
NGAD: Nutrition Guidance and Analysis Division
NIH: National Institutes of Health
NRCT: Non-randomized controlled trial
ODPHP: Office of Disease Prevention and Health Promotion
PCS: Prospective cohort study
PICO: Population, Intervention/exposure, comparator, outcome
RCT: Randomized controlled trial
RDA: Recommended Dietary Allowance
SR: Systematic Review
UL: Tolerable Upper Limit
USDA: United States Department of Agriculture
WG: DRI Protein Working Group
Working Group: Joint Canada-US Dietary Reference Intakes Working Group
y: Year(s)