# List of abbreviations

Abbreviation: Full name
% E: Percent energy
ADA: American Diabetes Association
AHEI-2010: Alternative Health Eating Index-2010
AMDR: Acceptable macronutrient distribution range
BMI: Body mass index
CVD: Cardiovascular disease
EVOO: Extra virgin olive oil
EPIC: European Prospective Investigation into Cancer and Nutrition
f/u: Follow-up
FFQ: Food frequency questionnaire
HbA1c: Hemoglobin A1c, glycosylated hemoglobin
HHS: United States Department of Health and Human Services
mo: Month(s)
N/A: Not applicable
NESR: Nutrition Evidence Systematic Review
NHS: Nurses’ Health Study
PREDIMED: Prevención con Dieta Mediterránea
PUFA: Polyunsaturated fatty acids
RCT: Randomized controlled trial
SES: Socoeconomic status
SSB: Sugar sweetened beverages
T2D: Type 2 diabetes
USDA: United States Department of Agriculture
wk: Week(s)
y: Year(s)