# METHODOLOGY

The NESR team used its rigorous, protocol-driven methodology to support the 2020 Dietary Guidelines Advisory Committee in updating an existing systematic review, using an existing systematic review, and conducting a new systematic review for the question: What is the relationship between dietary patterns consumed and risk of type 2 diabetes?.

NESR’s systematic review methodology involves:

- Developing a protocol,
- Searching for and selecting studies,
- Extracting data from and assessing the risk of bias of each included study,
- Synthesizing the evidence,
- Developing conclusion statements,
- Grading the evidence underlying the conclusion statements, and
- Recommending future research.

A detailed description of the methodology answering this systematic review question is available on the NESR website: https://nesr.usda.gov/2020-dietary-guidelines-advisory-committee-systematic-reviews, and can be found in 2020 Dietary Guidelines Advisory Committee Report, Part C: Methodology.^xvi^ This systematic review was peer reviewed by Federal scientists, and information about the peer review process can also be found in the Committee’s Report, Part C. Methodology. Additional information, including a description of and rationale for any modifications made to the protocol over the course of the Committee’s work, are described in the 2020 Dietary Guidelines Advisory Committee Report, Part D: Chapter 8. Dietary Patterns.

This document includes a systematic evidence scan and update to an existing systematic review based on conclusions drawn by the 2015 Dietary Guidelines Advisory Committee with support from USDA’s Nutrition Evidence Systematic Review (NESR) team. Information about the 2015 Dietary Guidelines Advisory Committee’s review of the evidence on dietary patterns and risk of type 2 diabetes can be found in their report, which is available at the following website: https://www.dietaryguidelines.gov/about-dietary-guidelines/previous-editions/2015-dietary-guidelines

Below are details of the final protocol as it was applied in the full systematic review described herein, including the:

- Analytic framework
- Literature searches and screening plan
- Literature searches and screening results

## ANALYTIC FRAMEWORK

The analytic framework (Figure 1) illustrates the overall scope of the systematic review question, including the population, the interventions and/or exposures, comparators, and outcomes of interest. It also includes definitions of key terms and identifies key confounders and other factors to be considered in the systematic review. The inclusion and exclusion criteria that follow provide additional information about how parts of the analytic framework were defined and operationalized for the review.

Figure 1 Analytic framework

An analytic framework visually represents the overall scope of the systematic review question, and depicts the contributing elements that were examined and evaluated, including the target population, intervention/exposure, comparator, outcomes, and key confounders. This is the analytic framework for the systematic review question on dietary patterns consumed and risk of type 2 diabetes. For this systematic review, the target population considered was children through older adults, who are healthy and/or at risk of chronic disease. The interventions or exposures considered were consumption of and/or adherence to a dietary pattern and their comparators were consumption of and/or adherence to a different dietary pattern or different levels of consumption of and/or adherence to a dietary pattern. The outcomes considered include hemoglobin A1C and risk of type 2 diabetes. The key confounders are sex, age, race/ethnicity, physical activity, anthropometry, and smoking. The other factors to be considered are total energy intake, alcohol intake (in adults), sodium intake, medications, socioeconomic status, family history of diabetes, and supplement usage.

## LITERATURE SEARCH AND SCREENING PLAN

### Inclusion and Exclusion Criteria

This table provides the inclusion and exclusion criteria for the systematic review. The inclusion and exclusion criteria are a set of characteristics used to determine which articles identified in the literature search were included in or excluded from the systematic review.

Table 5 Inclusion and exclusion criteria

Category | Inclusion Criteria | Exclusion Criteria
Study design | - Randomized controlled trials; - Non-randomized controlled trials, including quasi-experimental and controlled before and after studies; - Prospective cohort studies; - Retrospective cohort studies; - Nested case-control studies | - Uncontrolled trials; - Case-control studies; - Cross-sectional studies; - Uncontrolled before-and-after studies; - Narrative reviews; - Systematic reviews; - Meta-analyses
Intervention/exposure | - Studies that examine consumption of and/or adherence to a; 1 Dietary pattern [i.e., the quantities, proportions, variety, or combination of different foods, drinks, and nutrients (when available) in diets, and the frequency with which they are habitually consumed] including, at a minimum, a description of the foods and beverages in the pattern; ○ Dietary patterns may be measured or derived using a variety of approaches, such as adherence to a priori patterns (indices/scores), data driven patterns (factor or cluster analysis), reduced rank regression, or other methods, including clinical trials; and/or | - Studies that; 1a Do not provide a description of the dietary pattern, which at minimum, must include the foods and beverages in the pattern (i.e., studies that examine a labeled dietary pattern, but do not describe the foods and beverages consumed)
| - 2 Diet based on macronutrient distribution outside of the acceptable macronutrient distribution range (AMDR^xvii^) and; ○ Include the macronutrient distribution of carbohydrate, fat, and protein of the diet, and; ○ Include at least one macronutrient outside of the AMDR | - 2a Examine consumption of and/or adherence to a diet based on macronutrient proportion in which all macronutrients are within the AMDR; 2b Do not describe the entire macronutrient distribution of the diet (i.e., studies that only examine a single macronutrient in relation to outcomes)
Comparator | - Dietary patterns described by foods and beverages consumed:; ○ Consumption of and/or adherence to a different dietary pattern; ○ Different levels of consumption of and/or adherence to a dietary pattern; - Diets described by macronutrient distribution:; ○ Different macronutrient distributions of carbohydrate, fat, and protein | N/A
Outcomes ^xviii^ | - Intermediate outcomes (All included study designs in children, ages 2-18 years; Interventions only in adults):; ○ Hemoglobin A1C (HbA1C); - Endpoint outcomes (All included study designs in all included age groups):; ○ Type 2 diabetes | - Gestational diabetes during pregnancy and/or lactation; - Type 1 Diabetes; - Glucose; - Insulin; - Prediabetes
Date of publication | January 2014 – October 2019 (this date range is in addition to the original systematic review, which included articles published from January 1980-July 2013) | Articles published prior to January 1980 or after October 2019
| Additional search to cover macronutrient proportion diets; ○ January 2000– December 2013 | Additional search to cover macronutrient proportion diets; ○ Articles published prior to 2000
Publication status | Articles that have been peer-reviewed | Articles that have not been peer-reviewed and are not published in peer-reviewed journals (e.g., unpublished data, manuscripts, reports, abstracts, pre-prints and conference proceedings)
Language of publication | Articles published in English | Articles published in languages other than English
Country ^xix^ | Studies conducted in countries ranked as high or higher human development | Studies conducted in countries ranked as medium or lower human development
Study participants | - Human participants; - Males; - Females; - Women during pregnancy and lactation | - Non-human participants (i.e., animals)
Age of study participants | - Age at intervention or exposure:; ○ Children and adolescents (ages 2-18 years); ○ Adults (ages 19-64 years); ○ Older adults (ages 65 years and older) | - Age at intervention or exposure: N/A; ○ Infants and toddlers (birth to 24 months)
| - Age at outcome:; ○ Children and adolescents (ages 2-18 years); ○ Adults (ages 19-64 years); ○ Older adults (ages 65 years and older) | - Age at outcome; ○ Infants and toddlers (birth to 24 months)
Health status of study participants | - Studies that enroll participants who are healthy and/or at risk for chronic disease, including those with obesity; - Studies that enroll some participants diagnosed with a disease; - Studies that enroll some participants with type 2 diabetes | - Studies that exclusively enroll participants diagnosed with a disease, or hospitalized with an illness or injury; - Studies that exclusively enroll participants with type 2 diabetes (i.e., studies that aim to treat participants who have already been diagnosed with the endpoint outcomes of interest); - Addendum:; ○ Interventions designed to induce weight loss or treat overweight and obesity through energy-restriction/hypocaloric diets for the purposes of treating additional or other medical conditions.
Study duration | - Minimum length of intervention of 12 weeks | - Interventions less than 12 weeks
Size of study groups | - 30 participants per-arm, or; - A power calculation included for interventions; - n≥1,000 for observational studies | - Fewer than 30 participants per arm, or; - No power calculation reported for interventions; - Fewer than 1,000 participants for observational studies

### Electronic databases

Listed below are the databases searched to identify all potentially relevant articles that have been published to address the systematic review question. Two search strategies were developed and implemented each in three databases (PubMed, Cochrane Central Register of Controlled Trials (CENTRAL), and Embase).

#### Search 1: Literature search to update the existing systematic review

##### PubMed

- Provider: U.S. National Library of Medicine
- Date(s) Searched: October 21, 2019
- Date range searched: January 1, 2014-October 21, 2019
- Search Terms:
  - #1 - “dietary pattern*” OR “diet pattern*” OR “eating pattern*” OR “food pattern*” OR “diet quality*” OR “eating habit*” OR “dietary habit*” OR “diet habit*” OR “food habit*” OR “beverage habit*” OR “Feeding Behavior”[Mesh:NoExp] OR “dietary profile*” OR “food profile*” OR “diet profile*” OR “eating profile*” OR “dietary guideline* OR “dietary recommendation*” OR “dietary intake*” OR “eating style*” OR “Diet, Mediterranean”[Mesh] OR Mediterranean Diet*[tiab] OR “Dietary Approaches To Stop Hypertension”[Mesh] OR “Dietary Approaches To Stop Hypertension Diet*” OR “DASH diet*” OR “Diet, Gluten-Free”[Mesh] OR “Gluten Free diet*” OR “prudent diet*” OR “Diet, Paleolithic”[Mesh] OR Paleolithic Diet* OR “Diet, Vegetarian”[Mesh] OR vegetarian diet*[tiab] OR vegan diet* OR “Diet, Healthy”[Mesh] OR “plant based diet*” OR “Diet, Western”[Mesh] OR “western diet*” OR “Diet, Carbohydrate-Restricted”[Mesh] OR “low-carbohydrate diet*” OR “high carbohydrate diet*” OR “Ketogenic Diet*” OR “Nordic Diet*” OR “Diet, Fat-Restricted”[Mesh] OR “Diet, High-Fat”[Mesh] OR “Diet, High-Protein”[Mesh] OR high protein diet*[tiab] OR protein intake* OR high-fat diet* OR low fat diet* OR “Diet, Protein-Restricted”[Mesh] OR low protein diet* OR “Diet, Sodium-Restricted”[Mesh] OR low-sodium diet* OR low salt diet* OR ((“Dietary Proteins”[Mesh] OR dietary protein*[tiab] OR “Dietary Carbohydrates”[Mesh] OR dietary carbohydrate*[tiab] OR “Dietary Fats”[Mesh] OR dietary fat*[tiab] OR hypocaloric OR hypo-caloric) AND (diet[tiab] OR diets[tiab] OR consumption[tiab] OR intake[tiab] OR supplement*[tiab])) OR ((“Guideline Adherence”[Mesh] OR guideline adherence*) AND (diet[tiab] OR dietary[tiab] OR food[tiab] OR beverage*[tiab] OR nutrition*[tiab])) OR diet score* OR diet quality score* OR diet quality index* OR kidmed OR diet index* OR dietary index* OR food score* OR MedDietScore OR healthy eating index[tiab] OR ((pattern[tiab] OR patterns[tiab] OR consumption[tiab] OR habit*[tiab]) AND (“Diet”[Mesh:NoExp] OR diet[tiab] OR diets[tiab] OR dietary[tiab] OR “Food”[Mesh] OR food[tiab] OR foods[tiab] OR “Beverages”[Mesh] OR beverage[tiab] OR beverages[tiab]))
  - #2 - “Cardiovascular Diseases”[Mesh:NoExp] OR cardiovascular disease*[tiab] OR coronary artery disease[tiab] OR heart disease*[tiab] OR “Heart Failure”[Mesh] OR heart failure[tiab] OR “Myocardial Infarction”[Mesh] OR myocardial infarction*[tiab] OR “Myocardial Ischemia”[Mesh] OR Myocardial Ischemia*[tiab] OR “Stroke”[Mesh] OR stroke[tiab] OR angina[tiab] OR heart attack[tiab] OR “Venous Thrombosis”[Mesh] OR venous thrombosis[tiab] OR hypertension[tiab] OR high blood pressure[tiab] OR “Lipids/blood”[Mesh] OR “Cholesterol, HDL”[Mesh] OR HDL cholesterol[tiab] OR “Cholesterol, LDL”[Mesh] OR LDL cholesterol[tiab] OR total cholesterol[tiab] OR “Triglycerides”[Mesh] OR triglycerides[tiab]
  - #3 - “Diabetes Mellitus, Type 2”[Mesh] OR Type 2 diabetes[tiab] OR T2D[tiab] OR adult onset diabetes[tiab] OR “Prediabetic State”[Mesh] OR prediabet*[tiab] OR pre diabet* OR “Insulin Resistance”[Mesh] OR insulin resistance[tiab] OR “Glucose Intolerance”[Mesh] OR glucose intolerance[tiab] OR glucose tolerance[tiab] OR “Glycated Hemoglobin A”[Mesh] OR hemoglobin A1c[ti] OR “Hyperglycemia”[Mesh] OR “Hypoglycemia”[Mesh] OR ((impaired fasting[tiab] OR “Diabetes Mellitus”[Mesh:NoExp]) AND (glucose[tiab] OR glycemi*[tiab] OR high blood sugar[tiab] OR low blood sugar[tiab]))
  - #4 - “Body Weights and Measures”[Mesh] OR “Body Weight”[Mesh] OR obesity[tiab] OR obese[tiab] OR overweight[tiab] OR body mass index[tiab] OR BMI[tiab] OR underweight[tiab] OR wasting[tiab] OR healthy weight[tiab] OR “Body Composition”[Mesh] OR body composition[tiab] OR body fat[tiab] OR fat mass[tiab] OR fat free mass[tiab] OR body height[tiab] OR stunting[tiab] OR stunted[tiab] OR “Growth Charts”[Mesh] OR growth chart*[tiab] OR “Growth”[Mesh:NoExp] OR waist circumference[tiab] OR head circumference[tiab] OR arm circumference[tiab] OR thigh circumference[tiab] OR neck circumference[tiab] OR “Anthropometry”[Mesh:NoExp] OR “Overnutrition”[Mesh] OR anthropometr*[tiab] OR adiposity[tiab] OR calf circumference[tiab] OR skin fold*[tiab] OR healthy weight[tiab] OR weight for height[tiab] OR stature for age[tiab] OR weight for age[tiab] OR height for age[tiab] OR length for age[tiab] OR weight for length[tiab]
  - #5 - (#2 OR #3 OR #4)
  - #6 - ((#1 AND #5) NOT (“Animals”[Mesh] NOT (“Animals”[Mesh] AND “Humans”[Mesh])) NOT (editorial[ptyp] OR comment[ptyp] OR news[ptyp] OR letter[ptyp] OR review[ptyp] OR systematic review[ptyp] OR systematic review[ti] OR meta-analysis[ptyp] OR meta-analysis[ti] OR meta-analyses[ti] OR retracted publication[ptyp] OR retraction of publication[ptyp] OR retraction of publication[tiab] OR retraction notice[ti])
    Filters: Publication date from 2014/01/01 to 2019/10/21; English

##### Cochrane Central Register of Controlled Trials (CENTRAL)

- Provider: John Wiley & Sons
- Date(s) Searched: October 21, 2019
- Date range searched: January 1, 2014-October 21, 2019
- Search Terms:
  - #1 - (“dietary pattern*” OR “diet pattern*” OR “eating pattern*” OR “food pattern*” OR “diet quality*” OR “eating habit*” OR “dietary habit*” OR “diet habit*” OR “food habit*” OR “beverage habit*” OR [mh ^“Feeding Behavior”] OR “dietary profile*” OR “food profile*” OR “diet profile*” OR “eating profile*” OR “dietary guideline*” OR “dietary recommendation*” OR “dietary intake*” OR “eating style*” OR [mh “Diet, Mediterranean”] OR “Mediterranean Diet*” OR [mh “Dietary Approaches To Stop Hypertension”] OR “Dietary Approaches To Stop Hypertension Diet*” OR “DASH diet*” OR [mh “Diet, Gluten-Free”] OR “Gluten Free diet*” OR “prudent diet*” OR [mh “Diet, Paleolithic”] OR “Paleolithic Diet*” OR [mh “Diet, Vegetarian”] OR “vegetarian diet*” OR “vegan diet*” OR [mh “Diet, Healthy”] OR “plant based diet*” OR [mh “Diet, Western”] OR “western diet*” OR [mh “Diet, CarbohydrateRestricted”] OR “low-carbohydrate diet*” OR “high carbohydrate diet*” OR “Ketogenic Diet*” OR “Nordic Diet*” OR [mh “Diet, Fat-Restricted”] OR [mh “Diet, High-Fat”] OR [mh “Diet, High-Protein”] OR “high protein diet*” OR “protein intake*” OR “high-fat diet*” OR “low fat diet*” OR [mh “Diet, Protein-Restricted”] OR “low protein diet*” OR [mh “Diet, Sodium-Restricted”] OR “low-sodium diet*” OR “low salt diet*”):ti,ab,kw
  - #2 - (([mh “Dietary Proteins”] OR “dietary protein*” OR [mh “Dietary Carbohydrates”] OR “dietary carbohydrate*” OR [mh “Dietary Fats”] OR “dietary fat*” OR hypocaloric OR hypo-caloric) NEAR/6 (diet OR diets OR consumption OR intake OR supplement*))
  - #3 - ([mh “Guideline Adherence”] OR guideline adherence*) NEAR/6 (diet OR dietary OR food OR beverage* OR nutrition*))
  - #4 - (“diet score*” OR “diet quality score*” OR “diet quality index*” OR kidmed OR “diet index*” OR “dietary index*” OR “food score*” OR MedDietScore OR “healthy eating index*”):ti,ab,kw
  - #5 - (((pattern OR patterns OR consumption OR habit*) NEAR/6 ([mh ^Diet] OR diet OR diets OR dietary OR [mh Food] OR food OR foods OR [mh Beverages] OR beverage OR beverages))):ti,ab,kw
  - #6 - #1 OR #2 OR #3 OR #4 OR #5
  - #7 - [mh ^“Cardiovascular Diseases”] OR [mh “Heart Failure”] OR [mh “Myocardial Infarction”] OR [mh “Myocardial Ischemia”] OR [mh Stroke] OR [mh “Venous Thrombosis”] OR [mh Lipids/BL] OR [mh “Cholesterol, HDL”] OR [mh “Cholesterol, LDL”] OR [mh Triglycerides]”
  - #8 - (“cardiovascular disease*” OR “coronary artery disease*” OR “heart disease*” OR “heart failure*” OR “myocardial infarction*” OR “myocardial ischemia*” OR stroke OR angina OR “heart attack*” OR “venous thrombosis” OR hypertension OR “high blood pressure” OR “HDL cholesterol” OR “LDL cholesterol” OR “total cholesterol” OR triglycerides):ti,ab,kw
  - #9 - #7 OR #8
  - #10 - [mh “Diabetes Mellitus, Type 2”] OR [mh “Prediabetic State”] OR [mh “Insulin Resistance”] OR [mh “Glucose Intolerance”] OR [mh “Glycated Hemoglobin A”] OR [mh Hyperglycemia] OR [mh Hypoglycemia]
  - #11 - (“Type 2 diabetes” OR T2D OR “adult onset diabetes” OR prediabet* OR pre diabet* OR “insulin resistance” OR “glucose intolerance” OR “glucose tolerance” OR “hemoglobin A1c”):ti,ab,kw
  - #12 - (((“impaired fasting” OR [mh ^“Diabetes Mellitus”]) NEAR/6 (glucose OR glycemi* OR “high blood sugar” OR “low blood sugar”))):ti,ab,kw
  - #13 - #10 OR #11 OR #12
  - #14 - [mh “Body Weights and Measures”] OR [mh “Body Weight”] OR [mh “Body Composition”] OR [mh “Growth Charts”] OR [mh ^“Growth”] OR [mh ^“Anthropometry”] OR [mh “Overnutrition”]
  - #15 - (obesity OR obese OR overweight OR “body mass index” OR BMI OR underweight OR wasting OR “healthy weight” OR “body composition” OR “body fat” OR “fat mass” OR “fat free mass” OR “body height” OR stunting OR stunted OR “growth chart” OR “waist circumference” OR “head circumference” OR “arm circumference” OR “thigh circumference” OR “neck circumference” OR “calf circumference” OR anthropometr* OR adiposity OR “skin fold” OR “healthy weight” OR “weight for height” OR “stature for age” OR “weight for age” OR “height for age” OR “length for age” OR “weight for length”):ti,ab,kw
  - #16 - #14 OR #15
  - #17 - #9 OR #13 OR #16
  - #18 - #6 AND #17” with Publication Year from 2014 to 2019, in Trials (Word variations have been searched)

##### Embase

- Provider: Elsevier
- Date(s) Searched: October 21, 2019
- Date range searched: January 1, 2014-October 21, 2019
- Search Terms:
  - #1 - ‘feeding behavior’/de OR ‘mediterranean diet’/exp OR ‘dash diet’/exp OR ‘gluten free diet’/exp OR ‘paleolithic diet’/de OR ‘vegetarian diet’/exp OR ‘healthy diet’/de OR ‘western diet’/de OR ‘low carbohydrate diet’/exp OR ‘low fat diet’/de OR ‘lipid diet’/exp OR ‘protein diet’/exp OR ‘protein restriction’/de OR ‘sodium restriction’/de
  - #2 - ‘dietary pattern*’:ab,ti OR ‘diet pattern*’:ab,ti OR ‘eating pattern*’:ab,ti OR ‘food pattern*’:ab,ti OR ‘diet quality*’:ab,ti OR ‘eating habit*’:ab,ti OR ‘dietary habit*’:ab,ti OR ‘diet habit*’:ab,ti OR ‘food habit*’:ab,ti OR ‘beverage habit*’:ab,ti OR ‘dietary profile*’:ab,ti OR ‘food profile*’:ab,ti OR ‘diet profile*’:ab,ti OR ‘eating profile*’:ab,ti OR ‘dietary guideline*’:ab,ti OR ‘dietary recommendation*’:ab,ti OR ‘dietary intake*’:ab,ti OR ‘eating style*’:ab,ti OR ‘mediterranean diet*’:ab,ti OR ‘dietary approaches to stop hypertension diet*’:ab,ti OR ‘dash diet*’:ab,ti OR ‘gluten free diet*’:ab,ti OR ‘prudent diet*’:ab,ti OR ‘paleolithic diet*’:ab,ti OR ‘vegetarian diet*’:ab,ti OR ‘vegan diet*’:ab,ti OR ‘plant based diet*’:ab,ti OR ‘western diet*’:ab,ti OR ‘low-carbohydrate diet*’:ab,ti OR ‘high carbohydrate diet*’:ab,ti OR ‘ketogenic diet*’:ab,ti OR ‘nordic diet*’:ab,ti OR ‘high protein diet*’:ab,ti OR ‘protein intake*’:ab,ti OR ‘high-fat diet*’:ab,ti OR ‘low fat diet*’:ab,ti OR ‘low protein diet*’:ab,ti OR ‘low-sodium diet*’:ab,ti OR ‘low salt diet*’:ab,ti
  - #3 - ((‘dietary protein*’ OR ‘dietary carbohydrate*’ OR ‘dietary fat*’ OR hypocaloric OR hypo-caloric) NEAR/6 (diet OR diets OR consumption OR intake OR supplement)):ab,ti
  - #4 - (‘guideline adherence’ NEAR/6 (diet OR dietary OR food OR beverage OR nutrition*)):ab,ti
  - #5 - ‘diet score’:ab,ti OR ‘diet quality score’:ab,ti OR kidmed:ab,ti OR ‘diet index’:ab,ti OR ‘dietary index’:ab,ti OR ‘diet quality index’:ab,ti OR ‘food score’:ab,ti OR meddietscore:ab,ti OR ‘healthy eating index’:ab,ti
  - #6 - ((pattern OR patterns OR consumption OR habit*) NEAR/6 (diet OR diets OR dietary OR food OR foods OR beverage OR beverages)):ab,ti
  - #7 - #1 OR #2 OR #3 OR #4 OR #5 OR #6
  - #8 - ‘cardiovascular disease’/de OR ‘heart failure’/exp OR ‘heart infarction’/exp OR ‘heart muscle ischemia’/exp OR ‘cerebrovascular accident’/exp OR ‘vein thrombosis’/exp OR ‘high density lipoprotein cholesterol’/de OR ‘low density lipoprotein cholesterol’/de OR ‘triacylglycerol’/exp
  - #9 - ‘cardiovascular disease*’:ab,ti OR ‘coronary artery disease’:ab,ti OR ‘heart disease’:ab,ti OR ‘heart failure’:ab,ti OR ‘myocardial infarction*’:ab,ti OR ‘myocardial ischemia*’:ab,ti OR stroke:ab,ti OR angina:ab,ti OR ‘heart attack’:ab,ti OR ‘venous thrombosis’:ab,ti OR ‘hypertension’:ab,ti OR ‘high blood pressure’:ab,ti OR ‘hdl cholesterol’:ab,ti OR ‘ldl cholesterol’:ab,ti OR ‘total cholesterol’:ab,ti OR triglycerides:ab,ti
  - #10 - #8 OR #9
  - #11 - ‘non insulin dependent diabetes mellitus’/exp OR ‘impaired glucose tolerance’/exp OR ‘insulin resistance’/de OR ‘glucose intolerance’/de OR ‘glycosylated hemoglobin’/exp OR ‘hyperglycemia’/de OR ‘hypoglycemia’/exp
  - #12 - ‘type 2 diabetes’:ab,ti OR t2d:ab,ti OR ‘adult onset diabetes’:ab,ti OR prediabet*:ab,ti OR ‘pre diabet*’:ab,ti OR ‘insulin resistance’:ab,ti OR ‘glucose intolerance’:ab,ti OR ‘glucose tolerance’:ab,ti OR ‘hemoglobin a1c’:ab,ti
  - #13 - ((‘impaired fasting’ OR ‘diabetes mellitus]’) NEAR/6 (glucose OR glycemi* OR ‘high blood sugar’ OR ‘low blood sugar’)):ab,ti
  - #14 - #11 OR #12 OR #13
  - #15 - ‘weight, mass and size’/exp OR ‘body weight’/exp OR ‘body composition’/exp OR ‘growth chart’/de OR ‘growth’/de OR ‘anthropometry’/de OR ‘overnutrition’/exp
  - #16 - obesity:ab,ti OR obese:ab,ti OR overweight:ab,ti OR ‘body mass index’:ab,ti OR bmi:ab,ti OR underweight:ab,ti OR wasting:ab,ti OR ‘body composition’:ab,ti OR ‘body fat’:ab,ti OR ‘fat mass’:ab,ti OR ‘fat free mass’:ab,ti OR ‘body height’:ab,ti OR stunting:ab,ti OR stunted:ab,ti OR ‘growth chart*’:ab,ti OR ‘waist circumference’:ab,ti OR ‘head circumference’:ab,ti OR ‘arm circumference’:ab,ti OR ‘thigh circumference’:ab,ti OR ‘neck circumference’:ab,ti OR ‘calf circumference’:ab,ti OR anthropometr*:ab,ti OR adiposity:ab,ti OR ‘skin fold*’:ab,ti OR ‘healthy weight’:ab,ti OR ‘weight for height’:ab,ti OR ‘stature for age’:ab,ti OR ‘weight for age’:ab,ti OR ‘height for age’:ab,ti OR ‘length for age’:ab,ti OR ‘weight for length’:ab,ti
  - #17 - #15 OR #16
  - #18 - #10 OR #14 OR #17
  - #19 - #7 AND #18
  - #20 - #7 AND #18 AND ([article]/lim OR [article in press]/lim) AND [humans]/lim AND [english]/lim AND [2014-2019]/py NOT ([conference abstract]/lim OR [conference review]/lim OR [conference paper]/lim OR [editorial]/lim OR [erratum]/lim OR [letter]/lim OR [note]/lim OR [review]/lim OR [systematic review]/lim OR [meta analysis]/lim)

#### Search 2: Additional literature search to cover diets based on macronutrient distribution

##### PubMed

- Provider: U.S. National Library of Medicine
- Date(s) Searched: November 8, 2019
- Date range searched: January 1, 2000-December 31, 2013
- Search Terms:
  - #1 - Macronutrient* OR Macro-nutrient* OR “Dietary Carbohydrates”[Mesh] OR dietary carbohydrate* OR carbohydrate diet* OR “Diet, Carbohydrate-Restricted”[Mesh] OR carbohydrate-restrict* OR low carbohydrate* OR high carbohydrate* OR carbohydrate intake* OR “Dietary Proteins”[Mesh] OR protein diet* OR “Diet, Protein-Restricted”[Mesh] OR protein restrict* OR protein intake[tiab] OR low protein* OR “Diet, High-Protein”[Mesh] OR high protein* OR Ketogenic Diet* OR “Dietary Fats”[Mesh] OR dietary fat* OR fat intake* OR “Diet, High-Fat”[Mesh] OR high fat* OR “Diet, Fat-Restricted”[Mesh] OR fat-restricted* OR low fat*
  - #2 - “Cardiovascular Diseases”[Mesh:NoExp] OR cardiovascular disease*[tiab] OR coronary artery disease[tiab] OR heart disease*[tiab] OR “Heart Failure”[Mesh] OR heart failure[tiab] OR “Myocardial Infarction”[Mesh] OR myocardial infarction*[tiab] OR “Myocardial Ischemia”[Mesh] OR Myocardial Ischemia*[tiab] OR “Stroke”[Mesh] OR stroke[tiab] OR angina[tiab] OR heart attack[tiab] OR “Venous Thrombosis”[Mesh] OR venous thrombosis[tiab] OR hypertension[tiab] OR high blood pressure[tiab] OR “Lipids/blood”[Mesh] OR “Cholesterol, HDL”[Mesh] OR HDL cholesterol[tiab] OR “Cholesterol, LDL”[Mesh] OR LDL cholesterol[tiab]
  - #3 - “Diabetes Mellitus, Type 2”[Mesh] OR Type 2 diabetes[tiab] OR T2D[tiab] OR adult onset diabetes[tiab] OR “Prediabetic State”[Mesh] OR prediabet*[tiab] OR pre diabet* OR “Insulin Resistance”[Mesh] OR insulin resistance[tiab] OR “Glucose Intolerance”[Mesh] OR glucose intolerance[tiab] OR glucose tolerance[tiab] OR “Glycated Hemoglobin A”[Mesh] OR hemoglobin A1c[ti] OR “Hyperglycemia”[Mesh] OR “Hypoglycemia”[Mesh] OR ((impaired fasting[tiab] OR “Diabetes Mellitus”[Mesh:NoExp]) AND (glucose[tiab] OR glycemi*[tiab] OR high blood sugar[tiab] OR low blood sugar[tiab]))
  - #4 - “Body Weights and Measures”[Mesh] OR “Body Weight”[Mesh] OR obesity[tiab] OR obese[tiab] OR overweight[tiab] OR body mass index[tiab] OR BMI[tiab] OR underweight[tiab] OR wasting[tiab] OR healthy weight[tiab] OR “Body Composition”[Mesh] OR body composition[tiab] OR body fat[tiab] OR fat mass[tiab] OR fat free mass[tiab] OR body height[tiab] OR stunting[tiab] OR stunted[tiab] OR “Growth Charts”[Mesh] OR growth chart*[tiab] OR “Growth”[Mesh:NoExp] OR waist circumference[tiab] OR head circumference[tiab] OR arm circumference[tiab] OR thigh circumference[tiab] OR neck circumference[tiab] OR “Anthropometry”[Mesh:NoExp] OR “Overnutrition”[Mesh] OR anthropometr*[tiab] OR adiposity[tiab] OR calf circumference[tiab] OR skin fold*[tiab] OR healthy weight[tiab] OR weight for height[tiab] OR stature for age[tiab] OR weight for age[tiab] OR height for age[tiab] OR length for age[tiab] OR weight for length[tiab]
  - #5 - (#2 OR #3 OR #4)
  - #6 - (#1 AND #5) NOT (“Animals”[Mesh] NOT (“Animals”[Mesh] AND “Humans”[Mesh])) NOT (editorial[ptyp] OR comment[ptyp] OR news[ptyp] OR letter[ptyp] OR review[ptyp] OR systematic review[ptyp] OR systematic review[ti] OR meta-analysis[ptyp] OR meta-analysis[ti] OR meta-analyses[ti] OR retracted publication[ptyp] OR retraction of publication[ptyp] OR retraction of publication[tiab] OR retraction notice[ti])
    Filters: Publication date from 2000/01/01 to 2013/12/31; English

##### Cochrane Central Register of Controlled Trials (CENTRAL)

- Provider: John Wiley & Sons
- Date(s) Searched: November 8, 2019
- Date range searched: January 1, 2000-December 31, 2013
- Search Terms:
  - #1 - [mh “Dietary Carbohydrates”] OR [mh “Diet, Carbohydrate-Restricted”] OR [mh “Dietary Proteins”] OR [mh “Diet, Protein-Restricted”] OR [mh “Diet, High-Protein”] OR [mh “Dietary Fats”] OR [mh “Diet, High-Fat”] OR [mh “Diet, Fat-Restricted”]
  - #2 - (macronutrient* OR macro-nutrient* OR “dietary carbohydrate*” OR “carbohydrate diet*” OR “carbohydrate-restrict*” OR “low carbohydrate*” OR “high carbohydrate*” OR “carbohydrate intake*” OR “protein diet*” OR “protein restrict*” OR “protein intake” OR “low protein*” OR “high protein*” OR “Ketogenic Diet*” OR “dietary fat*” OR “fatty diet*” OR “high fat*” OR “fat-restricted*” OR “low fat*”):ti,ab,kw
  - #3 - #1 OR #2
  - #4 - [mh ^“Cardiovascular Diseases”] OR [mh “Heart Failure”] OR [mh “Myocardial Infarction”] OR [mh “Myocardial Ischemia”] OR [mh Stroke] OR [mh “Venous Thrombosis”] OR [mh Lipids/BL] OR [mh “Cholesterol, HDL”] OR [mh “Cholesterol, LDL”] OR [mh Triglycerides]
  - #5 - (“cardiovascular disease*” OR “coronary artery disease*” OR “heart disease*” OR “heart failure*” OR “myocardial infarction*” OR “myocardial ischemia*” OR stroke OR angina OR “heart attack*” OR “venous thrombosis” OR hypertension OR “high blood pressure” OR “HDL cholesterol” OR “LDL cholesterol” OR “total cholesterol” OR triglycerides):ti,ab,kw
  - #6 - #4 OR #5
  - #7 - [mh “Diabetes Mellitus, Type 2”] OR [mh “Prediabetic State”] OR [mh “Insulin Resistance”] OR [mh “Glucose Intolerance”] OR [mh “Glycated Hemoglobin A”] OR [mh Hyperglycemia] OR [mh Hypoglycemia]
  - #8 - (“Type 2 diabetes” OR T2D OR “adult onset diabetes” OR prediabet* OR pre diabet* OR “insulin resistance” OR “glucose intolerance” OR “glucose tolerance” OR “hemoglobin A1c”):ti,ab,kw”
  - #9 - ((“impaired fasting” OR [mh ^“Diabetes Mellitus”]) NEAR/6 (glucose OR glycemi* OR “high blood sugar” OR “low blood sugar”)):ti,ab,kw
  - #10 - #7 OR #8 OR #9
  - #11 - [mh “Body Weights and Measures”] OR [mh “Body Weight”] OR [mh “Body Composition”] OR [mh “Growth Charts”] OR [mh ^“Growth”] OR [mh ^“Anthropometry”] OR [mh “Overnutrition”]
  - #12 - (obesity OR obese OR overweight OR “body mass index” OR BMI OR underweight OR wasting OR “healthy weight” OR “body composition” OR “body fat” OR “fat mass” OR “fat free mass” OR “body height” OR stunting OR stunted OR “growth chart” OR “waist circumference” OR “head circumference” OR “arm circumference” OR “thigh circumference” OR “neck circumference” OR “calf circumference” OR anthropometr* OR adiposity OR “skin fold” OR “healthy weight” OR “weight for height” OR “stature for age” OR “weight for age” OR “height for age” OR “length for age” OR “weight for length”):ti,ab,kw
  - #13 - #11 OR #12
  - #14 - #6 OR #10 OR #13
  - #15 - #3 AND #14” with Publication Year from 2000 to 2013, in Trials (Word variations have been searched)

##### Embase

- Provider: Elsevier
- Date(s) Searched: November 8, 2019
- Date range searched: January 1, 2000-December 31, 2013
- Search Terms:
  - #1 - ‘macronutrient’/exp OR ‘carbohydrate diet’/exp OR ‘low carbohydrate diet’/exp OR ‘protein intake’/exp OR ‘protein restriction’/exp OR ‘protein diet’/exp OR ‘fat intake’/exp OR ‘lipid diet’/exp OR ‘low fat diet’/exp
  - #2 - macronutrient*:ab,ti OR ‘macro nutrient*’:ab,ti OR ‘dietary carbohydrate*’:ab,ti OR ‘carbohydrate diet*’:ab,ti OR ‘carbohydrate-restrict*’:ab,ti OR ‘low carbohydrate*’:ab,ti OR ‘high carbohydrate*’:ab,ti OR ‘carbohydrate intake*’:ab,ti OR ‘protein diet*’:ab,ti OR ‘protein restrict*’:ab,ti OR ‘protein intake’:ab,ti OR ‘low protein*’:ab,ti OR ‘high protein*’:ab,ti OR ‘ketogenic diet*’:ab,ti OR ‘dietary fat*’:ab,ti OR ‘fat intake*’:ab,ti OR ‘high fat*’:ab,ti OR ‘fat-restricted*’:ab,ti OR ‘low fat*’:ab,ti
  - #3 - #1 OR #2
  - #4 - ‘cardiovascular disease’/de OR ‘heart failure’/exp OR ‘heart infarction’/exp OR ‘heart muscle ischemia’/exp OR ‘cerebrovascular accident’/exp OR ‘vein thrombosis’/exp OR ‘high density lipoprotein cholesterol’/de OR ‘low density lipoprotein cholesterol’/de OR ‘triacylglycerol’/exp
  - #5 - ‘cardiovascular disease*’:ab,ti OR ‘coronary artery disease’:ab,ti OR ‘heart disease’:ab,ti OR ‘heart failure’:ab,ti OR ‘myocardial infarction*’:ab,ti OR ‘myocardial ischemia*’:ab,ti OR stroke:ab,ti OR angina:ab,ti OR ‘heart attack’:ab,ti OR ‘venous thrombosis’:ab,ti OR ‘hypertension’:ab,ti OR ‘high blood pressure’:ab,ti OR ‘hdl cholesterol’:ab,ti OR ‘ldl cholesterol’:ab,ti OR ‘total cholesterol’:ab,ti OR triglycerides:ab,ti
  - #6 - #4 OR #5
  - #7 - ‘non insulin dependent diabetes mellitus’/exp OR ‘impaired glucose tolerance’/exp OR ‘insulin resistance’/de OR ‘glucose intolerance’/de OR ‘glycosylated hemoglobin’/exp OR ‘hyperglycemia’/de OR ‘hypoglycemia’/exp
  - #8 - ‘type 2 diabetes’:ab,ti OR t2d:ab,ti OR ‘adult onset diabetes’:ab,ti OR prediabet*:ab,ti OR ‘pre diabet*’:ab,ti OR ‘insulin resistance’:ab,ti OR ‘glucose intolerance’:ab,ti OR ‘glucose tolerance’:ab,ti OR ‘hemoglobin a1c’:ab,ti
  - #9 - ((‘impaired fasting’ OR ‘diabetes mellitus]’) NEAR/6 (glucose OR glycemi* OR ‘high blood sugar’ OR ‘low blood sugar’)):ab,ti
  - #10 - #7 OR #8 OR #9
  - #11 - ‘weight, mass and size’/exp OR ‘body weight’/exp OR ‘body composition’/exp OR ‘growth chart’/de OR ‘growth’/de OR ‘anthropometry’/de OR ‘overnutrition’/exp
  - #12 - obesity:ab,ti OR obese:ab,ti OR overweight:ab,ti OR ‘body mass index’:ab,ti OR bmi:ab,ti OR underweight:ab,ti OR wasting:ab,ti OR ‘body composition’:ab,ti OR ‘body fat’:ab,ti OR ‘fat mass’:ab,ti OR ‘fat free mass’:ab,ti OR ‘body height’:ab,ti OR stunting:ab,ti OR stunted:ab,ti OR ‘growth chart*’:ab,ti OR ‘waist circumference’:ab,ti OR ‘head circumference’:ab,ti OR ‘arm circumference’:ab,ti OR ‘thigh circumference’:ab,ti OR ‘neck circumference’:ab,ti OR ‘calf circumference’:ab,ti OR anthropometr*:ab,ti OR adiposity:ab,ti OR ‘skin fold*’:ab,ti OR ‘healthy weight’:ab,ti OR ‘weight for height’:ab,ti OR ‘stature for age’:ab,ti OR ‘weight for age’:ab,ti OR ‘height for age’:ab,ti OR ‘length for age’:ab,ti OR ‘weight for length’:ab,ti
  - #13 - #11 OR #12
  - #14 - #6 OR #10 OR #13
  - #15 - #3 AND #14
  - #16 - #3 AND #14 AND ([article]/lim OR [article in press]/lim) AND [humans]/lim AND [english]/lim AND [2000-2013]/py NOT ([conference abstract]/lim OR [conference review]/lim OR [conference paper]/lim OR [editorial]/lim OR [erratum]/lim OR [letter]/lim OR [note]/lim OR [review]/lim OR [systematic review]/lim OR [meta analysis]/lim)

## LITERATURE SEARCH AND SCREENING RESULTS

The flow chart (Figure 2) below illustrates the literature searches and screening results for articles to answer this systematic review question, which were searched together with similar systematic review questions for screening efficiency The results of two electronic database searches, after removal of duplicates, were combined for efficiency and screened by two NESR analysts independently using a step-wise process by reviewing titles, abstracts, and full-texts to determine which articles met the inclusion criteria (Table 5) for each systematic review question depicted in the flow chart. Refer to Table 6 for the rationale for exclusion for each excluded full-text article. A manual search was done to find articles that were not identified when searching the electronic databases; all manually identified articles are also screened to determine whether they meet criteria for inclusion.

Figure 2 Flow chart of literature search and screening results^xx^

This flow chart illustrates the literature search and screening results for articles examining the relationship between dietary patterns and all-cause mortality. The literature search yielded 102,073 raw results of articles. During title screening, 50641 articles were screened out. During abstract screening, 10711 articles were screened out. During full-text screening, 2651 articles were screened out. During the hand search, 4 additional articles were identified to include. A total of 301 articles were included across 3 systematic review questions at the end of the search and screening process. Some articles included data for only one of the questions and some articles included data for more than one question.

### Excluded articles

The table below lists the articles excluded after full-text screening from two literature searches for this systematic review question, as well as two additional systematic review questions. At least one reason for exclusion is provided for each article, which may not reflect all possible reasons. Information about articles excluded after title and abstract screening is available upon request.

Table 6 Articles excluded after full text screening with rationale for exclusion

No. | Citation | Rationale
1 | Al Wattar B H, Dodds, J, Placzek, A, Beresford, L, Spyreli, E, Moore, A, Gonzalez Carreras, FJ, Austin, F, Murugesu, N, Roseboom, TJ, Bes-Rastrollo, M, Hitman, GA, Hooper, R, Khan, KS, Thangaratinam, S. Mediterranean-style diet in pregnant women with metabolic risk factors (ESTEEM): A pragmatic multicentre randomised trial. PLoS Med. 2019. 16:e1002857. doi:10.1371/journal.pmed.1002857 31335871 31335871 | Outcome; Participants
2 | . A low-carbohydrate diet reduces obesity and may improve dyslipidaemia compared with a low-fat diet. Evidence-Based Healthcare and Public Health. 2004. 8:370–372. doi:10.1016/j.ehbc.2004.09.006 | Study Design; Publication Status
3 | . Assessment of control of cardiovascular risk factors in obese posmenopausal women after monitoring a structured dietary education and exercise program. (SISIFO Program). Hipertension y riesgo vascular. 33 (3) (pp 103–110), 2016. Date of publication: 01 jul 2016.. 2016. :. doi:10.1016/j.hipert.2016.02.002 27005895 | Language
4 | . Brazil nut consumption improves postprandial satiety, blood glucose and insulin responses in healthy adults. Circulation. 2018. 138:. doi:unavailable | Publication Status
5 | . Compliance, palatability and feasibility of paleolithic and Australian guide to healthy eating diets in healthy women: a 4-week dietary intervention. Nutrients. 8 (8) (no pagination), 2016. Article number: 481. Date of publication: 06 aug 2016.. 2016. :. doi:10.3390/nu8080481 | Publication Status; Study duration
6 | . Diets that work. The Journal of clinical endocrinology and metabolism. 2014. 99:31A–32A. doi:unavailable | Publication Status
7 | . Effective dietary interventions for managing overweight and obesity in children. Nurs N Z. 2007. 13:30–1. doi:unavailable | Study Design; Publication Status
8 | . Healthier protein sources may cut risks of coronary heart disease. Substituting fish, poultry and low-fat dairy for red meat makes a difference. Heart Advis. 2010. 13:7. doi:unavailable | Intervention/Exposure; Publication Status
9 | . High fat diet more than a waistline worry. American journal of Alzheimer’s disease and other dementias. 2004. 19:330–331. doi:unavailable | Study Design; Publication Status
10 | . Mediterranean diets and metabolic syndrome status in the PREDIMED randomized trial. CMAJ : Canadian Medical Association journal = journal de l’Association medicale canadienne. 2018. 190:E808. doi:10.1503/cmaj.180791 | Publication Status
11 | . Mediterranean eating linked to lower diabetes risk. Harvard men’s health watch. 2014. 18:8. doi:unavailable | Study Design; Publication Status
12 | . Nutritional intervention based on mediterranean diet reduces blood pressure and immune cells response after immune stimulation. Annals of nutrition & metabolism. 2017. Conference: 10th Annual Conference of the International Symposium on Immunonutrition. Spain. 71:70–71. doi:unavailable | Publication Status
13 | . Physical activity rather than food knowledge/preferences underlie waist circumference improvements in early preventive programs. Digestive and liver disease. 2017. Conference: 24th National SIGENP Congress. Italy. 49:e284. doi:10.1016/j.dld.2017.09.115 | Publication Status
14 | . Short-term effects of different dietary approaches on body weight and body composition among obese female. Obesity facts. 2018. Conference: 25th European Congress on Obesity, ECO 2018. Austria. 11:135–136. doi:10.1159/000489691 | Publication Status
15 | . Summaries for Patients. Effect of Allowing Choice of Diet on Weight Loss. Ann Intern Med. 2015. 162:I–22. doi:10.7326/p15-9021 | Publication Status
16 | Aadland, EK, Lavigne, C, Graff, IE, Eng, O, Paquette, M, Holthe, A, Mellgren, G, Jacques, H, Liaset, B. Lean seafood intake reduces cardiovascular risk factors in healthy subjects. Annals of nutrition and metabolism. 2015. 67:335–336. doi:10.1159/000440895 | Intervention/Exposure; Study duration
17 | Aadland, EK, Lavigne, C, Graff, IE, Eng, O, Paquette, M, Holthe, A, Mellgren, G, Jacques, H, Liaset, B. Lean-seafood intake reduces cardiovascular lipid risk factors in healthy subjects: results from a randomized controlled trial with a crossover design. Am J Clin Nutr. 2015. 102:582–92. doi:10.3945/ajcn.115.112086 26224298 | Intervention/Exposure; Comparator
18 | Aballay, LR, Osella, AR, De La Quintana, AG, Diaz, MDP. Nutritional profile and obesity: results from a random-sample population-based study in Cordoba, Argentina. Eur J Nutr. 2016. 55:675–685. doi:10.1007/s00394-015-0887-0 25822107 | Study Design
19 | Abbasi, F, McLaughlin, T, Lamendola, C, Kim, HS, Tanaka, A, Wang, T, Nakajima, K, Reaven, GM. High carbohydrate diets, triglyceride-rich lipoproteins, and coronary heart disease risk. Am J Cardiol. 2000. 85:45–8. doi:10.1016/s0002-9149(99)00604-9 11078235 | Study duration
20 | Abdel-Megeid, FY, Abdelkarem, HM, El-Fetouh, AM. Unhealthy nutritional habits in university students are a risk factor for cardiovascular diseases. Saudi Medical Journal. 2011. 32:621–627. doi:unavailable21666946 | Study Design
21 | Aberg, G, Edman, G, Rossner, S. Perceived hunger, palatability, and adherence: A comparison of high- and low-fat diets. Obes Res Clin Pract. 2008. 2:71–142. doi:10.1016/j.orcp.2008.03.001 | Study duration; Health Status
22 | Abete, I, Parra, D, De Morentin, BM, Alfredo Martinez, J. Effects of two energy-restricted diets differing in the carbohydrate/protein ratio on weight loss and oxidative changes of obese men. Int J Food Sci Nutr. 2009. 60 Suppl 3:1–13. doi:10.1080/09637480802232625 | Study duration
23 | Abete, I, Parra, D, Martinez, JA. Legume-, fish-, or high-protein-based hypocaloric diets: effects on weight loss and mitochondrial oxidation in obese men. J Med Food. 2009. 12:100–8. doi:10.1089/jmf.2007.0700 19298202 | Study duration
24 | Abu-Saad, K, Novikov, I, Gimpelevitz, I, Benderly, M, Alpert, G, Goldbourt, U, Kalter-Leibovici, O. Micronutrient intake and adherence to DASH diet are associated with incident major adverse cardiovascular events and all-cause mortality in a bi-ethnic population. European heart journal. 2017. 38:1120-. doi:10.1093/eurheartj/ehx502.P5321 | Publication Status
25 | Acosta-Navarro, JC, Oki, AM, Antoniazzi, L, Bonfim, MAC, Hong, V, Gaspar, MCA, Sandrim, VC, Nogueira, A. Consumption of animal-based and processed food associated with cardiovascular risk factors and subclinical atherosclerosis biomarkers in men. Rev Assoc Med Bras (1992). 2019. 65:43–50. doi:10.1590/1806-9282.65.1.43 30758419 | Study Design
26 | Adachi, H, Hino, A. Trends in nutritional intake and serum cholesterol levels over 40 years in Tanushimaru, Japanese men. J Epidemiol. 2005. 15:85–9. doi:10.2188/jea.15.85 15930804 | Study Design
27 | Adamsson, V, Cederholm, T, Vessby, B, Risérus, U. Influence of a healthy Nordic diet on serum fatty acid composition and associations with blood lipoproteins - Results from the NORDIET study. Food and Nutrition Research. 2014. 58:. doi:10.3402/fnr.v58.24114 | Intervention/Exposure; Outcome
28 | Adamsson, V, Reumark, A, Fredriksson, IB, Hammarstrom, E, Vessby, B, Johansson, G, Riserus, U. Effects of a healthy Nordic diet on cardiovascular risk factors in hypercholesterolaemic subjects: a randomized controlled trial (NORDIET). J Intern Med. 2011. 269:150–9. doi:10.1111/j.1365-2796.2010.02290.x 20964740 | Intervention/Exposure; Publication Date Overlaps with Existing Review
29 | Adechian, S, Balage, M, Remond, D, Migne, C, Quignard-Boulange, A, Marset-Baglieri, A, Rousset, S, Boirie, Y, Gaudichon, C, Dardevet, D, Mosoni, L. Protein feeding pattern, casein feeding, or milk-soluble protein feeding did not change the evolution of body composition during a short-term weight loss program. Am J Physiol Endocrinol Metab. 2012. 303:E973–82. doi:10.1152/ajpendo.00285.2012 22895782 | Intervention/Exposure; Study duration
30 | Adelina, R. BMI correlated to dietary pattern of Indonesian college students lives in Taipei city, Taiwan. Pakistan Journal of Medical and Health Sciences. 2018. 12:1308–1311. doi:unavailable | Study Design; Intervention/Exposure
31 | Adochio, RL, Leitner, JW, Gray, K, Draznin, B, Cornier, MA. Early responses of insulin signaling to high-carbohydrate and high-fat overfeeding. Nutr Metab (Lond). 2009. 6:37. doi:10.1186/1743-7075-6-37 19781106 | Study duration
32 | Adriouch, S, Julia, C, Kesse-Guyot, E, Mejean, C, Ducrot, P, Peneau, S, Donnenfeld, M, Deschasaux, M, Menai, M, Hercberg, S, Touvier, M, Fezeu, LK. Prospective association between a dietary quality index based on a nutrient profiling system and cardiovascular disease risk. Eur J Prev Cardiol. 2016. 23:1669–76. doi:10.1177/2047487316640659 27000099 | Intervention/Exposure
33 | Adriouch, S, Lelong, H, Kesse-Guyot, E, Baudry, J, Lampuré, A, Galan, P, Hercberg, S, Touvier, M, Fezeu, LK. Compliance with nutritional and lifestyle recommendations in 13,000 patients with a cardiometabolic disease from the Nutrinet-Santé study. Nutrients. 2017. 9:. doi:10.3390/nu9060546 | Study Design
34 | Aeberli, I, Kaspar, M, Zimmermann, MB. Dietary intake and physical activity of normal weight and overweight 6 to 14 year old Swiss children. Swiss Med Wkly. 2007. 137:424–30. doi:17705105 | Study Design
35 | Aeberli, I, Spinas, GA, Lehmann, R, l’Allemand, D, Molinari, L, Zimmermann, MB. Diet determines features of the metabolic syndrome in 6- to 14-year-old children. Int J Vitam Nutr Res. 2009. 79:14–23. doi:10.1024/0300-9831.79.1.14 19838999 | Study Design
36 | Aguiar-Bloemer, AC, Japur, CC, Francisco, LV, Diez-Garcia, RW. Dietary quality differences between women with and without weight loss in nutritional treatment. Clinical Nutrition ESPEN. 2019. doi:10.1016/j.clnesp.2019.08.003 | Study Design
37 | Ahadi, Z, Qorbani, M, Kelishadi, R, Ardalan, G, Motlagh, ME, Asayesh, H, Zeynali, M, Chinian, M, Larijani, B, Shafiee, G, Heshmat, R. Association between breakfast intake with anthropometric measurements, blood pressure and food consumption behaviors among Iranian children and adolescents: the CASPIAN-IV study. Public Health. 2015. 129:740–7. doi:10.1016/j.puhe.2015.03.019 26043966 | Study Design; Intervention/Exposure
38 | Ahluwalia, N, Ferrieres, J, Dallongeville, J, Simon, C, Ducimetiere, P, Amouyel, P, Arveiler, D, Ruidavets, JB. Association of macronutrient intake patterns with being overweight in a population-based random sample of men in France. Diabetes Metab. 2009. 35:129–36. doi:10.1016/j.diabet.2008.09.006 19251447 | Study Design
39 | Ahmadi-Abhari, S, Luben, RN, Powell, N, Bhaniani, A, Chowdhury, R, Wareham, NJ, Forouhi, NG, Khaw, KT. Dietary intake of carbohydrates and risk of type 2 diabetes: the European Prospective Investigation into Cancer-Norfolk study. Br J Nutr. 2014. 111:342–52. doi:10.1017/s0007114513002298 23880355 | Intervention/Exposure
40 | Ahn, Y, Park, SJ, Kwack, HK, Kim, MK, Ko, KP, Kim, SS. Rice-eating pattern and the risk of metabolic syndrome especially waist circumference in Korean Genome and Epidemiology Study (KoGES). BMC Public Health. 2013. 13:61. doi:10.1186/1471-2458-13-61 23339671 | Study Design
41 | Ahuja, KD, Ashton, EL, Ball, MJ. Effects of two lipid-lowering, carotenoid-controlled diets on the oxidative modification of low-density lipoproteins in free-living humans. Clin Sci (Lond). 2003. 105:355–61. doi:10.1042/cs20030050 12780345 | Study duration
42 | Akbaraly, T, Wurtz, P, Singh-Manoux, A, Shipley, MJ, Haapakoski, R, Lehto, M, Desrumaux, C, Kahonen, M, Lehtimaki, T, Mikkila, V, Hingorani, A, Humphries, SE, Kangas, AJ, Soininen, P, Raitakari, O, Ala-Korpela, M, Kivimaki, M. Association of circulating metabolites with healthy diet and risk of cardiovascular disease: analysis of two cohort studies. Sci Rep. 2018. 8:8620. doi:10.1038/s41598-018-26441-1 29872056 | Intervention/Exposure
43 | Akbaraly, TN, Shipley, MJ, Ferrie, JE, Virtanen, M, Lowe, G, Hamer, M, Kivimaki, M. Long-term adherence to healthy dietary guidelines and chronic inflammation in the prospective Whitehall II study. Am J Med. 2015. 128:152–160.e4. doi:10.1016/j.amjmed.2014.10.002 25305231 | Outcome
44 | Akbari-Sedigh, A, Asghari, G, Yuzbashian, E, Dehghan, P, Imani, H, Mirmiran, P. Association of dietary pattern with carotid intima media thickness among children with overweight or obesity. Diabetol Metab Syndr. 2019. 11:77. doi:10.1186/s13098-019-0472-4 31528207 | Study Design
45 | Akdemir, M, Donmez, L, Polat, H. The effect of nutritional and physical activity interventions on nutritional status and obesity in primary school children: A cluster randomized controlled study. Kuwait Medical Journal. 2017. 49:105–113. doi:unavailable | Intervention/Exposure
46 | Akinyemi, RO, Allan, L, Owolabi, MO, Akinyemi, JO, Ogbole, G, Ajani, A, Firbank, M, Ogunniyi, A, Kalaria, RN. Profile and determinants of vascular cognitive impairment in African stroke survivors: the CogFAST Nigeria Study. J Neurol Sci. 2014. 346:241–9. doi:10.1016/j.jns.2014.08.042 25238666 | Intervention/Exposure
47 | Akita, S, Sacks, FM, Svetkey, LP, Conlin, PR, Kimura, G. Effects of the Dietary Approaches to Stop Hypertension (DASH) diet on the pressure-natriuresis relationship. Hypertension. 2003. 42:8–13. doi:10.1161/01.Hyp.0000074668.08704.6e 12756219 | Outcome
48 | Akter, S, Kurotani, K, Kashino, I, Goto, A, Mizoue, T, Noda, M, Sawada, N, Tsugane, S. High Dietary Acid Load Score Is Associated with Increased Risk of Type 2 Diabetes in Japanese Men: The Japan Public Health Center-based Prospective Study. J Nutr. 2016. 146:1076–83. doi:10.3945/jn.115.225177 27052540 | Intervention/Exposure
49 | Akter, S, Nanri, A, Mizoue, T, Noda, M, Sawada, N, Sasazuki, S, Tsugane, S. Dietary acid load and mortality among Japanese men and women: the Japan Public Health Center-based Prospective Study. Am J Clin Nutr. 2017. 106:146–154. doi:10.3945/ajcn.117.152876 28539378 | Intervention/Exposure
50 | Al Hourani, H, Atoum, M, Alboqai, O, Ismail, LC, Al Dhaheri, A, Hijjawi, N. Effectiveness of dietary intervention for obese women in Jordan. International Journal of Food Sciences and Nutrition. 2009. 60:76–82. doi:10.1080/09637480903022727 19548164 | Study Design
51 | Al Suwaidi, J. Dietary patterns and their association with acute coronary heart disease: Lessons from the REGARDS Study. Glob Cardiol Sci Pract. 2015. 2015:56. doi:10.5339/gcsp.2015.56 26779528 | Study Design
52 | Al-Delaimy, WK, Natarajan, L, Rock, CL, Sun, S, Flatt, SW, Pierce, JP. Insulin-like growth factor I, insulin-like growth factor I binding protein 1, insulin, glucose, and leptin serum levels are not influenced by a reduced-fat, high-fiber diet intervention. Cancer Epidemiol Biomarkers Prev. 2006. 15:1238–9. doi:10.1158/1055-9965.Epi-06-0160 16775190 | Study Design; Health Status
53 | Aldrich, ND, Reicks, MM, Sibley, SD, Redmon, JB, Thomas, W, Raatz, SK. Varying protein source and quantity do not significantly improve weight loss, fat loss, or satiety in reduced energy diets among midlife adults. Nutr Res. 2011. 31:104–12. doi:10.1016/j.nutres.2011.01.004 21419314 | Power/Size
54 | Alemany, JA, Nindl, BC, Kellogg, MD, Tharion, WJ, Young, AJ, Montain, SJ. Effects of dietary protein content on IGF-I, testosterone, and body composition during 8 days of severe energy deficit and arduous physical activity. J Appl Physiol (1985). 2008. 105:58–64. doi:10.1152/japplphysiol.00005.2008 18450989 | Study duration
55 | Alenazi, SA, Koura, HM, Zaki, SM, Mohamed, AH. Prevalence of Obesity Among Male Adolescents in Arar Saudi Arabia: Future Risk of Cardiovascular Disease. Indian J Community Med. 2015. 40:182–7. doi:10.4103/0970-0218.158864 26170543 | Study Design
56 | AlEssa, HB, Bhupathiraju, SN, Malik, VS, Wedick, NM, Campos, H, Rosner, B, Willett, WC, Hu, FB. Carbohydrate quality and quantity and risk of type 2 diabetes in US women. Am J Clin Nutr. 2015. 102:1543–53. doi:10.3945/ajcn.115.116558 26537938 | Intervention/Exposure
57 | Alexander, S, Ostfeld, RJ, Allen, K, Williams, KA. A plant-based diet and hypertension. J Geriatr Cardiol. 2017. 14:327–330. doi:10.11909/j.issn.1671-5411.2017.05.014 28630611 | Study Design
58 | Alexy, U, Sichert-Hellert, W, Kersting, M, Schultze-Pawlitschko, V. Pattern of long-term fat intake and BMI during childhood and adolescence--results of the DONALD Study. Int J Obes Relat Metab Disord. 2004. 28:1203–9. doi:10.1038/sj.ijo.0802708 15211368 | Power/Size
59 | Alhassan, S, Kim, S, Bersamin, A, King, AC, Gardner, CD. Dietary adherence and weight loss success among overweight women: results from the A TO Z weight loss study. Int J Obes (Lond). 2008. 32:985–91. doi:10.1038/ijo.2008.8 18268511 | Weight loss/Hypocaloric
60 | Alhazmi, A, Stojanovski, E, McEvoy, M, Garg, ML. Macronutrient intake and type 2 diabetes risk in middle-aged Australian women. Results from the Australian Longitudinal Study on Women’s Health. Public Health Nutr. 2014. 17:1587–94. doi:10.1017/s1368980013001870 23866795 | Intervention/Exposure
61 | Alimujiang, A, Colditz, GA, Gardner, JD, Park, Y, Berkey, CS, Sutcliffe, S. Childhood diet and growth in boys in relation to timing of puberty and adult height: the Longitudinal Studies of Child Health and Development. Cancer Causes Control. 2018. 29:915–926. doi:10.1007/s10552-018-1068-2 30109531 | Study Design; Intervention/Exposure; Outcome
62 | Alissa, EM, Bahjri, SM, Al-Ama, N, Ahmed, WH, Ferns, GA. High cardiovascular risk in young Saudi males: cardiovascular risk factors, diet and inflammatory markers. Clin Chim Acta. 2006. 365:288–96. doi:10.1016/j.cca.2005.09.007 16213478 | Study Design; Intervention/Exposure
63 | Aljuraiban, GS, Gibson, R, Oude Griep, LM, Okuda, N, Steffen, LM, Van Horn, L, Chan, Q. Perspective: The Application of A Priori Diet Quality Scores to Cardiovascular Disease Risk-A Critical Evaluation of Current Scoring Systems. Adv Nutr. 2019. :. doi:10.1093/advances/nmz059 | Study Design
64 | Allan, GM, Ivers, N, Sharma, AM. Diets for weight loss and prevention of negative health outcomes. Can Fam Physician. 2011. 57:894–5. doi:unavailable21841109 | Study Design; Publication Status
65 | Aller, EE, Larsen, TM, Claus, H, Lindroos, AK, Kafatos, A, Pfeiffer, A, Martinez, JA, Handjieva-Darlenska, T, Kunesova, M, Stender, S, Saris, WH, Astrup, A, van Baak, MA. Weight loss maintenance in overweight subjects on ad libitum diets with high or low protein content and glycemic index: the DIOGENES trial 12-month results. Int J Obes (Lond). 2014. 38:1511–7. doi:10.1038/ijo.2014.52 24675714 | Intervention/Exposure
66 | Aller, R, De Luis, DA, Izaola, O, La Calle, F, Del Olmo, L, Fernandez, L, Arranz, T, Gonzalez Hernandez, JM. Effect of soluble fiber intake in lipid and glucose leves in healthy subjects: A randomized clinical trial. Diabetes Research and Clinical Practice. 2004. 65:7–11. doi:10.1016/j.diabres.2003.11.005 15163472 | Intervention/Exposure; Comparator
67 | Allison, MA, Aragaki, AK, Ray, RM, Margolis, KL, Beresford, SA, Kuller, L, Jo O’Sullivan, M, Wassertheil-Smoller, S, Van Horn, L. A Randomized Trial of a Low-Fat Diet Intervention on Blood Pressure and Hypertension: Tertiary Analysis of the WHI Dietary Modification Trial. Am J Hypertens. 2016. 29:959–68. doi:10.1093/ajh/hpv196 26708006 | Intervention/Exposure
68 | Almohanna, A, Conforti, F, Eigel, W, Barbeau, W. Impact of Dietary Acculturation on the Food Habits, Weight, Blood Pressure, and Fasting Blood Glucose Levels of International College Students. J Am Coll Health. 2015. 63:307–14. doi:10.1080/07448481.2015.1025075 25774756 | Intervention/Exposure; Comparator
69 | Al-Nakeeb, Y, Lyons, M, Dodd, LJ, Al-Nuaim, A. An investigation into the lifestyle, health habits and risk factors of young adults. Int J Environ Res Public Health. 2015. 12:4380–94. doi:10.3390/ijerph120404380 25913183 | Intervention/Exposure
70 | Alnasir, FA, Fateha, BE. Low carbohydrate diet. Its effects on selected body parameters of obese patients. Saudi Med J. 2003. 24:949–52. doi:unavailable12973475 | Study Design
71 | Alonso, A, Beunza, JJ, Bes-Rastrollo, M, Pajares, RM, Martinez-Gonzalez, MA. Vegetable protein and fiber from cereal are inversely associated with the risk of hypertension in a Spanish cohort. Arch Med Res. 2006. 37:778–86. doi:10.1016/j.arcmed.2006.01.007 16824939 | Intervention/Exposure; Outcome
72 | Al-Sarraj, T, Saadi, H, Calle, MC, Volek, JS, Fernandez, ML. Carbohydrate restriction, as a first-line dietary intervention, effectively reduces biomarkers of metabolic syndrome in Emirati adults. J Nutr. 2009. 139:1667–76. doi:10.3945/jn.109.109603 19587123 | Study duration
73 | Al-Sarraj, T, Saadi, H, Volek, JS, Fernandez, ML. Carbohydrate restriction favorably alters lipoprotein metabolism in Emirati subjects classified with the metabolic syndrome. Nutr Metab Cardiovasc Dis. 2010. 20:720–6. doi:10.1016/j.numecd.2009.06.004 19748249 | Intervention/Exposure
74 | Al-Sarraj, T, Volek, JS, Saadi, H, Fernandez, ML. Carbohydrate restriction reduces dyslipidemias associated with atherogenic lipoprotein profiles in Emirati men and women with metabolic syndrome. FASEB journal. 2013. 27:. doi:unavailable | Publication Status
75 | Alshaikh, MK, Rawaf, S, Quezada-Yamamoto, H. Cardiovascular risk and fruit and vegetable consumption among women in KSA; A cross-sectional study. J Taibah Univ Med Sci. 2018. 13:444–451. doi:10.1016/j.jtumed.2018.06.001 31435360 | Study Design
76 | Alsharari, ZD, Leander, K, Sjogren, P, Carlsson, A, Cederholm, T, de Faire, U, Hellenius, ML, Marklund, M, Riserus, U. Association between carbohydrate intake and fatty acids in the de novo lipogenic pathway in serum phospholipids and adipose tissue in a population of Swedish men. Eur J Nutr. 2019. :. doi:10.1007/s00394-019-02058-6 | Study Design; Outcome
77 | Al-Sobayel, H, Al-Hazzaa, HM, Abahussain, NA, Qahwaji, DM, Musaiger, AO. Gender differences in leisure-time versus non-leisure-time physical activity among Saudi adolescents. Ann Agric Environ Med. 2015. 22:344–8. doi:10.5604/12321966.1152091 26094536 | Study Design; Intervention/Exposure
78 | Al-Solaiman, Y, Jesri, A, Mountford, WK, Lackland, DT, Zhao, Y, Egan, BM. DASH lowers blood pressure in obese hypertensives beyond potassium, magnesium and fibre. J Hum Hypertens. 2010. 24:237–46. doi:10.1038/jhh.2009.58 19626043 | Study duration
79 | Altorf-van der Kuil, W, Engberink, MF, De Neve, M, van Rooij, FJ, Hofman, A, van’t Veer, P, Witteman, JC, Franco, OH, Geleijnse, JM. Dietary amino acids and the risk of hypertension in a Dutch older population: the Rotterdam Study. Am J Clin Nutr. 2013. 97:403–10. doi:10.3945/ajcn.112.038737 23283504 | Intervention/Exposure
80 | Altorf-van der Kuil, W, Engberink, MF, van Rooij, FJ, Hofman, A, van’t Veer, P, Witteman, JC, Geleijnse, JM. Dietary protein and risk of hypertension in a Dutch older population: the Rotterdam study. J Hypertens. 2010. 28:2394–400. doi:10.1097/HJH.0b013e32833eff63 20827221 | Intervention/Exposure
81 | Alvarez-Alvarez, I, Toledo, E, Lecea, O, Salas-Salvado, J, Corella, D, Buil-Cosiales, P, Zomeno, MD, Vioque, J, Martinez, JA, Konieczna, J, Baron-Lopez, FJ, Lopez-Miranda, J, Estruch, R, Bueno-Cavanillas, A, Alonso-Gomez, AM, Tur, JA, Tinahones, FJ, Serra-Majem, L, Martin, V, Ortega-Calvo, M, Vazquez, C, Pinto, X, Vidal, J, Daimiel, L, Delgado-Rodriguez, M, Matia, P, Gonzalez, JI, Diaz-Lopez, A, Paz-Graniel, I, Munoz, MA, Fito, M, Pertusa-Martinez, S, Abete, I, Garcia-Rios, A, Ros, E, Ruiz-Canela, M, Martinez-Gonzalez, MA. Adherence to a priori dietary indexes and baseline prevalence of cardiovascular risk factors in the PREDIMED-Plus randomised trial. Eur J Nutr. 2019. :. doi:10.1007/s00394-019-01982-x | Study Design
82 | Ambrosini, GL, Emmett, PM, Northstone, K, Howe, LD, Tilling, K, Jebb, SA. Identification of a dietary pattern prospectively associated with increased adiposity during childhood and adolescence. Int J Obes (Lond). 2012. 36:1299–305. doi:10.1038/ijo.2012.127 22868831 | Publication Date Overlaps with Existing Review
83 | Ambrosini, GL, Emmett, PM, Northstone, K, Jebb, SA. Tracking a dietary pattern associated with increased adiposity in childhood and adolescence. Obesity (Silver Spring). 2014. 22:458–65. doi:10.1002/oby.20542 23804590 | Outcome
84 | Ambrosini, GL, Solis-Trapala, I, Ahern, AL, Fuller, NR, Holzapfel, C, Hauner, H, Caterson, ID, Jebb, SA. Greater improvements in diet quality among overweight participants following a group-based commercial weight loss programme than those receiving support to lose weight in primary care. Nutr J. 2018. 17:64. doi:10.1186/s12937-018-0370-x 29973211 | Intervention/Exposure
85 | Ambroszkiewicz, J, Chelchowska, M, Rowicka, G, Klemarczyk, W, Strucinska, M, Gajewska, J. Anti-Inflammatory and Pro-Inflammatory Adipokine Profiles in Children on Vegetarian and Omnivorous Diets. Nutrients. 2018. 10:. doi:10.3390/nu10091241 | Study Design
86 | Ambroszkiewicz, J, Chelchowska, M, Szamotulska, K, Rowicka, G, Klemarczyk, W, Strucinska, M, Gajewska, J. Bone status and adipokine levels in children on vegetarian and omnivorous diets. Clin Nutr. 2019. 38:730–737. doi:10.1016/j.clnu.2018.03.010 29609869 | Study Design
87 | Ambroszkiewicz, J, Klemarczyk, W, Gajewska, J, Chelchowska, M, Rowicka, G, Oltarzewski, M, Laskowska-Klita, T. Serum concentration of adipocytokines in prepubertal vegetarian and omnivorous children. Med Wieku Rozwoj. 2011. 15:326–34. doi:unavailable22006488 | Study Design
88 | Ambroszkiewicz, J, Laskowska-Klita, T, Klemarczyk, W. Low serum leptin concentration in vegetarian prepubertal children. Rocz Akad Med Bialymst. 2004. 49:103–5. doi:unavailable15631323 | Study Design
89 | Amini, P, Maghsoudi, Z, Feizi, A, Ghiasvand, R, Askari, G. Effects of High Protein and Balanced Diets on Lipid Profiles and Inflammation Biomarkers in Obese and Overweight Women at Aerobic Clubs: A Randomized Clinical Trial. Int J Prev Med. 2016. 7:110. doi:10.4103/2008-7802.190608 27833724 | Intervention/Exposure
90 | Amor, AJ, Masana, L, Soriguer, F, Goday, A, Calle-Pascual, A, Gaztambide, S, Rojo-Martinez, G, Valdes, S, Gomis, R, Ortega, E. Estimating Cardiovascular Risk in Spain by the European Guidelines on Cardiovascular Disease Prevention in Clinical Practice. Rev Esp Cardiol (Engl Ed). 2015. 68:417–25. doi:10.1016/j.rec.2014.05.023 25444376 | Study Design
91 | Ampatzoglou, A, Atwal, KK, Maidens, CM, Williams, CL, Ross, AB, Thielecke, F, Jonnalagadda, SS, Kennedy, OB, Yaqoob, P. Increased whole grain consumption does not affect blood biochemistry, body composition, or gut microbiology in healthy, low-habitual whole grain consumers. J Nutr. 2015. 145:215–21. doi:10.3945/jn.114.202176 25644340 | Intervention/Exposure
92 | An, R, Burd, NA. Change in daily energy intake associated with pairwise compositional change in carbohydrate, fat and protein intake among US adults, 1999-2010. Public Health Nutr. 2015. 18:1343–52. doi:10.1017/s1368980014001876 25203716 | Study Design
93 | Anders, S, Schroeter, C. Diabetes, diet-health behavior, and obesity. Front Endocrinol (Lausanne). 2015. 6:33. doi:10.3389/fendo.2015.00033 25852643 | Study Design
94 | Andersen, LB, Arnberg, K, Trolle, E, Michaelsen, KF, Bro, R, Pipper, CB, Molgaard, C. The effects of water and dairy drinks on dietary patterns in overweight adolescents. Int J Food Sci Nutr. 2016. 67:314–24. doi:10.3109/09637486.2016.1150435 26903408 | Outcome
95 | Andersen, LB, Molgaard, C, Ejlerskov, KT, Trolle, E, Michaelsen, KF, Bro, R, Pipper, CB. Development of Dietary Patterns Spanning Infancy and Toddlerhood: Relation to Body Size, Composition and Metabolic Risk Markers at Three Years. AIMS Public Health. 2015. 2:332–357. doi:10.3934/publichealth.2015.3.332 29546114 | Study Design; Intervention/Exposure; AGE: Intervention/Exposure
96 | Anderson, AL, Harris, TB, Houston, DK, Tylavsky, FA, Lee, JS, Sellmeyer, DE, Sahyoun, NR. Relationships of dietary patterns with body composition in older adults differ by gender and PPAR-gamma Pro12Ala genotype. Eur J Nutr. 2010. 49:385–94. doi:10.1007/s00394-010-0096-9 20174813 | Study Design
97 | Anderson, AL, Harris, TB, Tylavsky, FA, Perry, SE, Houston, DK, Hue, TF, Strotmeyer, ES, Sahyoun, NR. Dietary patterns and survival of older adults. J Am Diet Assoc. 2011. 111:84–91. doi:10.1016/j.jada.2010.10.012 21185969 | Outcome
98 | Anderson, AL, Harris, TB, Tylavsky, FA, Perry, SE, Houston, DK, Lee, JS, Kanaya, AM, Sahyoun, NR. Dietary patterns, insulin sensitivity and inflammation in older adults. Eur J Clin Nutr. 2012. 66:18–24. doi:10.1038/ejcn.2011.162 21915138 | Outcome
99 | Anderson, AS, Haynie, KR, McMillan, RP, Osterberg, KL, Boutagy, NE, Frisard, MI, Davy, BM, Davy, KP, Hulver, MW. Early skeletal muscle adaptations to short-term high-fat diet in humans before changes in insulin sensitivity. Obesity (Silver Spring). 2015. 23:720–4. doi:10.1002/oby.21031 25820254 | Power/Size
100 | Anderson-Vasquez, HE, Perez-Martinez, P, Ortega Fernandez, P, Wanden-Berghe, C. Impact of the consumption of a rich diet in butter and it replacement for a rich diet in extra virgin olive oil on anthropometric, metabolic and lipid profile in postmenopausal women. Nutr Hosp. 2015. 31:2561–70. doi:10.3305/nh.2015.31.6.8732 26040366 | Study duration
101 | Andersson, J, Mellberg, C, Otten, J, Ryberg, M, Rinnstrom, D, Larsson, C, Lindahl, B, Hauksson, J, Johansson, B, Olsson, T. Left ventricular remodelling changes without concomitant loss of myocardial fat after long-term dietary intervention. Int J Cardiol. 2016. 216:92–6. doi:10.1016/j.ijcard.2016.04.050 27149238 | Study Design; Intervention/Exposure; Outcome
102 | Andrikopoulos, S. The Paleo diet and diabetes. Med J Aust. 2016. 205:151–2. doi:10.5694/mja16.00347 27510338 | Publication Status
103 | Angelis, A, Ioakeimidis, N, Aznaouridis, K, Georgakopoulos, C, Gourgouli, I, Rokas, K, Terentes, D, Zisimos, K, Chrysohoou, C, Aggeli, K, , . Mediterranean diet adherence in essential hypertension middle aged men, outcome in endogenous testosterone left ventricular geometry and central haemodynamics. European heart journal. Conference: european society of cardiology, ESC congress 2017. Spain. 2017. 38:1054. doi:10.1093/eurheartj/ehx502.5027 | Publication Status
104 | Anglin, JC, Borchardt, N, Ramos, E, Mhoon, K. Diet quality of adults using intuitive eating for weight loss - pilot study. Nutr Health. 2013. 22:255–64. doi:10.1177/0260106015601943 26399269 | Intervention/Exposure; Study duration
105 | Anil, S, Charlton, KE, Tapsell, LC, Probst, Y, Ndanuko, R, Batterham, MJ. Identification of dietary patterns associated with blood pressure in a sample of overweight Australian adults. J Hum Hypertens. 2016. 30:672–678. doi:10.1038/jhh.2016.10 27011257 | Study Design
106 | Ankarfeldt, MZ, Angquist, L, Jakobsen, MU, Overvad, K, Tjonneland, A, Halkjaer, J, Astrup, A, Sorensen, TI. Interactions of dietary protein and adiposity measures in relation to subsequent changes in body weight and waist circumference. Obesity (Silver Spring). 2014. 22:2097–103. doi:10.1002/oby.20812 24942843 | Intervention/Exposure
107 | Ankarfeldt, MZ, Ängquist, L, Stocks, T, Jakobsen, MU, Overvad, K, Halkjær, J, Saris, WHM, Astrup, A, Sørensen, TIA. Body composition, dietary protein and body weight regulation. Reconciling conflicting results from intervention and observational studies?. PLoS ONE. 2014. 9:. doi:10.1371/journal.pone.0101134 | Study Design; Intervention/Exposure
108 | Ankarfeldt, MZ, Gottliebsen, K, Angquist, L, Astrup, A, Heitmann, BL, Sorensen, TI. Dietary protein and urinary nitrogen in relation to 6-year changes in fat mass and fat-free mass. Int J Obes (Lond). 2015. 39:162–8. doi:10.1038/ijo.2014.80 24840082 | Power/Size
109 | Annuzzi, G, Bozzetto, L, Costabile, G, Della Corte, G, Anniballi, G, Vitale, M, Cocozza, S, Giacco, R, Vetrani, C, Rivieccio, A, , . Effects of dietary polyphenols and/or n-3 fatty acids on postprandial lipaemia in people at high cardiovascular risk: the Etherpaths project. Diabetologia. 2012. 55:S362. doi:10.1007/s00125-012-2688-9 | Publication Status
110 | Anonymous, . Popular diets equally effective for losing weight. Journal of family practice. 2005. 54:306. doi:unavailable | Publication Status
111 | Antonio de Luis, D, Izaola, O, Primo, D, Aller, R. Modifications of serum levels of omentin-1 and other cardiovascular risk factors following weight loss secondary to a Mediterranean hypocaloric diet. Clin Nutr. 2018. 37:2280–2283. doi:10.1016/j.clnu.2017.11.009 29198435 | Study Design; Intervention/Exposure
112 | Antonio, J, Ellerbroek, A, Evans, C, Silver, T, Peacock, CA. High protein consumption in trained women: bad to the bone?. J Int Soc Sports Nutr. 2018. 15:6. doi:10.1186/s12970-018-0210-6 29434529 | Power/Size
113 | Antonio, J, Ellerbroek, A, Silver, T, Vargas, L, Peacock, C. The effects of a high protein diet on indices of health and body composition--a crossover trial in resistance-trained men. J Int Soc Sports Nutr. 2016. 13:3. doi:10.1186/s12970-016-0114-2 26778925 | Power/Size
114 | Antonio, J, Ellerbroek, A, Silver, T, Vargas, L, Tamayo, A, Buehn, R, Peacock, CA. A High Protein Diet Has No Harmful Effects: A One-Year Crossover Study in Resistance-Trained Males. J Nutr Metab. 2016. 2016:9104792. doi:10.1155/2016/9104792 27807480 | Power/Size
115 | Antonio, J, Peacock, CA, Ellerbroek, A, Fromhoff, B, Silver, T. The effects of consuming a high protein diet (4.4 g/kg/d) on body composition in resistance-trained individuals. J Int Soc Sports Nutr. 2014. 11:19. doi:10.1186/1550-2783-11-19 24834017 | Study duration
116 | Anwar, A, Aslam, S, Akram, A. A comparative study of dietary patterns in the patients with coronary artery disease and control. Pakistan Journal of Medical and Health Sciences. 2017. 11:1541–1542. doi:unavailable | Study Design
117 | Apolzan, JW, Hsia, DS, Martin, CK. Effects of a higher vs. lower protein diet on weight loss in teenagers: results from a randomized controlled trial. FASEB journal. 2016. 30:. doi:unavailable | Publication Status
118 | Apolzan, JW, Hsia, DS, Martin, CK. Effects of a higher vs. Lower protein energy restricted diet on parameters of the metabolic syndrome in adolescents: a randomized, controlled trial. Diabetes. 2016. 65:A336-. doi:10.2337/db16-861-1374 | Publication Status
119 | Appannah, G, Pot, GK, Huang, RC, Oddy, WH, Beilin, LJ, Mori, TA, Jebb, SA, Ambrosini, GL. Identification of a dietary pattern associated with greater cardiometabolic risk in adolescence. Nutr Metab Cardiovasc Dis. 2015. 25:643–50. doi:10.1016/j.numecd.2015.04.007 26026208 | Study Design
120 | Appannah, G, Pot, GK, Oddy, WH, Jebb, SA, Ambrosini, GL. Determinants of a dietary pattern linked with greater metabolic risk and its tracking during adolescence. J Hum Nutr Diet. 2018. 31:218–227. doi:10.1111/jhn.12519 28975676 | Outcome
121 | Appel, LJ, Sacks, FM, Carey, VJ, Obarzanek, E, Swain, JF, Miller, ER, 3rd, Conlin, PR, Erlinger, TP, Rosner, BA, Laranjo, NM, Charleston, J, McCarron, P, Bishop, LM. Effects of protein, monounsaturated fat, and carbohydrate intake on blood pressure and serum lipids: results of the OmniHeart randomized trial. Jama. 2005. 294:2455–64. doi:10.1001/jama.294.19.2455 16287956 | Intervention/Exposure; Publication Date Overlaps with Existing Review
122 | Arabshahi, S, Lahmann, PH, Hughes, MC, Williams, GW, van der Pols, JC. Dietary behaviours, weight loss attempts and change in waist circumference: 15-year longitudinal study in Australian adults. Asia Pac J Clin Nutr. 2017. 26:657–664. doi:10.6133/apjcn.062016.04 28582816 | Intervention/Exposure
123 | Arabzadegan, N, Daneshzad, E, Fatahi, S, Moosavian, SP, Surkan, PJ, Azadbakht, L. Effects of dietary whole grain, fruit, and vegetables on weight and inflammatory biomarkers in overweight and obese women. Eat Weight Disord. 2019. :. doi:10.1007/s40519-019-00757-x | Intervention/Exposure
124 | Archer, WR, Lamarche, B, Deriaz, O, Landry, N, Corneau, L, Despres, JP, Bergeron, J, Couture, P, Bergeron, N. Variations in body composition and plasma lipids in response to a high-carbohydrate diet. Obes Res. 2003. 11:978–86. doi:10.1038/oby.2003.135 12917503 | Study duration
125 | Archer, WR, Lamarche, B, St-Pierre, AC, Mauger, JF, Deriaz, O, Landry, N, Corneau, L, Despres, JP, Bergeron, J, Couture, P, Bergeron, N. High carbohydrate and high monounsaturated fatty acid diets similarly affect LDL electrophoretic characteristics in men who are losing weight. J Nutr. 2003. 133:3124–9. doi:10.1093/jn/133.10.3124 14519795 | Study duration
126 | Archero, F, Ricotti, R, Solito, A, Carrera, D, Civello, F, Di Bella, R, Bellone, S, Prodam, F. Adherence to the Mediterranean Diet among School Children and Adolescents Living in Northern Italy and Unhealthy Food Behaviors Associated to Overweight. Nutrients. 2018. 10:. doi:10.3390/nu10091322 | Study Design
127 | Arciero, PJ, Ormsbee, MJ, Gentile, CL, Nindl, BC, Brestoff, JR, Ruby, M. Increased protein intake and meal frequency reduces abdominal fat during energy balance and energy deficit. Obesity (Silver Spring). 2013. 21:1357–66. doi:10.1002/oby.20296 23703835 | Study duration
128 | Ard, JD, Lewis, KH, Rothberg, A, Auriemma, A, Coburn, SL, Cohen, SS, Loper, J, Matarese, L, Pories, WJ, Periman, S. Effectiveness of a Total Meal Replacement Program (OPTIFAST Program) on Weight Loss: Results from the OPTIWIN Study. Obesity. 2019. 27:22–29. doi:10.1002/oby.22303 30421863 | Intervention/Exposure
129 | Arefhosseini, SR, Edwards, CA, Malkova, D, Higgins, S. Effect of advice to increase carbohydrate and reduce fat intake on dietary profile and plasma lipid concentrations in healthy postmenopausal women. Ann Nutr Metab. 2009. 54:138–44. doi:10.1159/000210435 19339775 | Study Design
130 | Arguin, H, Tremblay, A, Blundell, JE, Despres, JP, Richard, D, Lamarche, B, Drapeau, V. Impact of a non-restrictive satiating diet on anthropometrics, satiety responsiveness and eating behaviour traits in obese men displaying a high or a low satiety phenotype. Br J Nutr. 2017. 118:750–760. doi:10.1017/s0007114517002549 29185929 | Study Design; Intervention/Exposure
131 | Armeno, M, Verini, A, Del Pino, M, Araujo, MB, Mestre, G, Reyes, G, Caraballo, RH. A Prospective Study on Changes in Nutritional Status and Growth Following Two Years of Ketogenic Diet (KD) Therapy in Children with Refractory Epilepsy. Nutrients. 2019. 11:. doi:10.3390/nu11071596 | Health Status
132 | Arnlov, J, Lind, L, Sundstrom, J, Andren, B, Vessby, B, Lithell, H. Insulin resistance, dietary fat intake and blood pressure predict left ventricular diastolic function 20 years later. Nutr Metab Cardiovasc Dis. 2005. 15:242–9. doi:10.1016/j.numecd.2004.10.002 16054547 | Intervention/Exposure; Outcome
133 | Arnold, K, Weinhold, KR, Andridge, R, Johnson, K, Orchard, TS. Improving Diet Quality Is Associated with Decreased Inflammation: Findings from a Pilot Intervention in Postmenopausal Women with Obesity. J Acad Nutr Diet. 2018. 118:2135–2143. doi:10.1016/j.jand.2018.05.014 30139630 | Study Design
134 | Arouca, A, Moreno, L, Marcos, A, Kafatos, A, Michels, N, De Henauw, S. Diet as a moderator in the association of adiposity and sedentary behavior with inflammatory biomarkers in european adolescents. Annals of nutrition & metabolism. 2018. 73:201-. doi:10.1159/000493135 | Publication Status
135 | Arredondo, A, Torres, C, Orozco, E, Pacheco, S, Huang, F, Zambrano, E, Bolanos-Jimenez, F. Socio-economic indicators, dietary patterns, and physical activity as determinants of maternal obesity in middle-income countries: Evidences from a cohort study in Mexico. Int J Health Plann Manage. 2019. 34:e713–e725. doi:10.1002/hpm.2684 30350426 | Study Design; Outcome
136 | Arsiwalla, DD, Arnold, AW, Teel, KP, Ulrich, PV, Gropper, SS. The interactive role of eating regulation and stress in the prediction of weight-related outcomes among college students. Stress Health. 2018. 34:59–71. doi:10.1002/smi.2760 28516733 | Study Design; Intervention/Exposure
137 | Arvidsson, E, Viguerie, N, Andersson, I, Verdich, C, Langin, D, Arner, P. Effects of different hypocaloric diets on protein secretion from adipose tissue of obese women. Diabetes. 2004. 53:1966–71. doi:10.2337/diabetes.53.8.1966 15277374 | Outcome
138 | Asano, M, Kushida, M, Yamamoto, K, Tomata, Y, Tsuji, I, Tsuduki, T. Abdominal Fat in Individuals with Overweight Reduced by Consumption of a 1975 Japanese Diet: A Randomized Controlled Trial. Obesity (Silver Spring). 2019. 27:899–907. doi:10.1002/oby.22448 30985996 | Intervention/Exposure
139 | Asghari, G, Yuzbashian, E, Mirmiran, P, Hooshmand, F, Najafi, R, Azizi, F. Dietary Approaches to Stop Hypertension (DASH) Dietary Pattern Is Associated with Reduced Incidence of Metabolic Syndrome in Children and Adolescents. J Pediatr. 2016. 174:178–184.e1. doi:10.1016/j.jpeds.2016.03.077 27156186 | Power/Size
140 | Asghari, G, Yuzbashian, E, Mirmiran, P, Mahmoodi, B, Azizi, F. Fast Food Intake Increases the Incidence of Metabolic Syndrome in Children and Adolescents: Tehran Lipid and Glucose Study. PLoS One. 2015. 10:e0139641. doi:10.1371/journal.pone.0139641 26447855 | Intervention/Exposure
141 | Ashourpour, M, Kaveh, MH, Ta Bata Baee, HR, Ta Ghdir, M, Salehi, M. Dietary pattern of children with malnutrition in a Persian population. Gazzetta Medica Italiana Archivio per le Scienze Mediche. 2018. 177:185–192. doi:10.23736/S0393-3660.17.03577-X | Study Design
142 | Ashton, EL, Pomeroy, S, Foster, JE, Kaye, RS, Nestel, PJ, Ball, M. Diet high in monounsaturated fat does not have a different effect on arterial elasticity than a low-fat, high-carbohydrate diet. J Am Diet Assoc. 2000. 100:537–42. doi:10.1016/s0002-8223(00)00167-x 10812378 | Study duration
143 | Ashworth, A, Mitchell, K, Blackwell, JR, Vanhatalo, A, Jones, AM. High-nitrate vegetable diet increases plasma nitrate and nitrite concentrations and reduces blood pressure in healthy women. Public Health Nutr. 2015. 18:2669–78. doi:10.1017/s1368980015000038 25683748 | Intervention/Exposure; Study duration
144 | Assmann, KE, Adjibade, M, Andreeva, VA, Hercberg, S, Galan, P, Kesse-Guyot, E. Association Between Adherence to the Mediterranean Diet at Midlife and Healthy Aging in a Cohort of French Adults. J Gerontol A Biol Sci Med Sci. 2018. 73:347–354. doi:10.1093/gerona/glx066 28460137 | Outcome
145 | Assmann, KE, Adjibade, M, Shivappa, N, Hebert, JR, Wirth, MD, Touvier, M, Akbaraly, T, Hercberg, S, Galan, P, Julia, C, Kesse-Guyot, E. The Inflammatory Potential of the Diet at Midlife Is Associated with Later Healthy Aging in French Adults. J Nutr. 2018. 148:437–444. doi:10.1093/jn/nxx061 29546305 | Intervention/Exposure; Outcome
146 | Assmann, KE, Joslowski, G, Buyken, AE, Cheng, G, Remer, T, Kroke, A, Gunther, AL. Prospective association of protein intake during puberty with body composition in young adulthood. Obesity (Silver Spring). 2013. 21:E782–9. doi:10.1002/oby.20516 23788493 | Power/Size
147 | Assmann, KE, Lassale, C, Andreeva, VA, Jeandel, C, Hercberg, S, Galan, P, Kesse-Guyot, E. A Healthy Dietary Pattern at Midlife, Combined with a Regulated Energy Intake, Is Related to Increased Odds for Healthy Aging. J Nutr. 2015. 145:2139–45. doi:10.3945/jn.115.210740 26246320 | Outcome
148 | Assmann, KE, Lassale, C, Galan, P, Hercberg, S, Kesse-Guyot, E. Dietary quality and 6-year anthropometric changes in a sample of French middle-aged overweight and obese adults. PLoS One. 2014. 9:e87083. doi:10.1371/journal.pone.0087083 24516542 | Intervention/Exposure
149 | Astrup, A, Damsgaard, CT, Papadaki, A, Jensen, SM, Dalskov, SM, Hlavaty, P, Saris, WHM, Martinez, JA, Handjieva-Darlenska, T, Rohr-Andersen, M, , . 1 The use of an ad libitum higher-protein, low-glycemic index diet in overweight children: the Diogenes Study. FASEB journal. 2013. 27:. doi:unavailable | Publication Status
150 | Astrup, A, Hjorth, MF, Ritz, C, Poulsen, SK, Larsen, TM, Zohar, Y. Pretreatment fasting plasma glucose and insulin as determinants of weight loss success: the new nordic diet study. Diabetes. 2017. 66:A205-. doi:unavailable | Publication Status
151 | Astrup, A, Rodrigues, D, Bendtsen, L, Larsen, T, Ritz, C, Handijeva-Darlenska, T, Van Baak, M, Martinez, J, Saris, W. The importance of amounts of protein, and the protein to carbohydrate ratio for weight control: analyses from the DiOGenes study. Obesity reviews. 2014. 15:181. doi:10.1111/obr.12152 | Publication Status
152 | Astrup, A, Rodrigues, DMT, Bendtsen, LQ, Larsen, TM, Ritz, C. Role of protein and fat content, and protein/carbohydrate ratio in weight maintenance? The DiOGenes Study. Annals of nutrition and metabolism. Conference: 12th european nutrition conference, FENS 2015. Berlin germany. Conference start: 20151020. Conference end: 20151023. Conference publication: (var.pagings). 2015. 67:156–157. doi:10.1159/000440895 | Publication Status
153 | Astrup, A. Protein, carbs and fats in personalized weight control-efficacy, effectiveness and safety. Obesity facts. 2014. 7:3. doi:10.1159/000363668 | Publication Status
154 | Astrup, A. The role of protein and carbohydrates for weight loss and maintenance: evidence from the Diogenes study. Australasian medical journal. 2011. 4:717. doi:unavailable | Publication Status
155 | Ata, SM, Vaishnav, U, Puglisi, M, Lofgren, IE, Wood, RJ, Volek, JS, Fernandez, ML. Macronutrient composition and increased physical activity modulate plasma adipokines and appetite hormones during a weight loss intervention. J Womens Health (Larchmt). 2010. 19:139–45. doi:10.1089/jwh.2009.1472 20088670 | Study Design
156 | Aude, YW, Agatston, AS, Lopez-Jimenez, F, Lieberman, EH, Marie, Almon, Hansen, M, Rojas, G, Lamas, GA, Hennekens, CH. The national cholesterol education program diet vs a diet lower in carbohydrates and higher in protein and monounsaturated fat: a randomized trial. Arch Intern Med. 2004. 164:2141–6. doi:10.1001/archinte.164.19.2141 15505128 | Intervention/Exposure
157 | Auslander, W, Haire-Joshu, D, Houston, C, Rhee, CW, Williams, JH. A controlled evaluation of staging dietary patterns to reduce the risk of diabetes in African-American women. Diabetes Care. 2002. 25:809–14. doi:10.2337/diacare.25.5.809 11978673 | Intervention/Exposure
158 | Austel, A, Ranke, C, Wagner, N, Gorge, J, Ellrott, T. Weight loss with a modified Mediterranean-type diet using fat modification: a randomized controlled trial. Eur J Clin Nutr. 2015. 69:878–84. doi:10.1038/ejcn.2015.11 25690866 | Intervention/Exposure
159 | Avanzini, F, Marzona, I, Baviera, M, Barlera, S, Milani, V, Caimi, V, Longoni, P, Tombesi, M, Silletta, MG, Tognoni, G, Roncaglioni, MC. Improving cardiovascular prevention in general practice: Results of a comprehensive personalized strategy in subjects at high risk. Eur J Prev Cardiol. 2016. 23:947–55. doi:10.1177/2047487315613664 26525065 | Comparator; Outcome
160 | Aynaci, G, Akdemir, O. The Relationship Between Lifestyle, Health Promotion Lifestyle Profile II And High Blood Pressure In University Students. Open Access Maced J Med Sci. 2018. 6:1756–1761. doi:10.3889/oamjms.2018.314 30338003 | Study Design; Intervention/Exposure
161 | Azadbakht, L, Izadi, V, Surkan, PJ, Esmaillzadeh, A. Effect of a High Protein Weight Loss Diet on Weight, High-Sensitivity C-Reactive Protein, and Cardiovascular Risk among Overweight and Obese Women: A Parallel Clinical Trial. Int J Endocrinol. 2013. 2013:971724. doi:10.1155/2013/971724 23986778 | Intervention/Exposure
162 | Azadbakht, L, Kimiagar, M, Mehrabi, Y, Zadeh, AE. Soy inclusion in the diet improves features of the metabolic syndrome: a randomized cross-over study in postmenopausal women. Iranian journal of diabetes and lipid disorders. 2007. 7:E11. doi:unavailable | Language
163 | Azadbakht, L, Kimiagar, M, Mehrabi, Y, Zadeh, AE. To determine the effects of soy consumption on markers of inflammation and endothelial function in postmenopausal women with the metabolic syndrome. Iranian journal of diabetes and lipid disorders. 2007. 6:81–92, E46. doi:unavailable | Language
164 | Azadbakht, L, Mirmiran, P, Esmaillzadeh, A, Azizi, F. Better dietary adherence and weight maintenance achieved by a long-term moderate-fat diet. Br J Nutr. 2007. 97:399–404. doi:10.1017/s0007114507328602 17298711 | Intervention/Exposure
165 | Azadbakht, L, Mirmiran, P, Esmaillzadeh, A, Azizi, T, Azizi, F. Beneficial effects of a Dietary Approaches to Stop Hypertension eating plan on features of the metabolic syndrome. Diabetes Care. 2005. 28:2823–31. doi:10.2337/diacare.28.12.2823 16306540 | Publication Date Overlaps with Existing Review
166 | Babio, N, Becerra-Tomas, N, Martinez-Gonzalez, MA, Corella, D, Estruch, R, Ros, E, Sayon-Orea, C, Fito, M, Serra-Majem, L, Aros, F, Lamuela-Raventos, RM, Lapetra, J, Gomez-Gracia, E, Fiol, M, Diaz-Lopez, A, Sorli, JV, Martinez, JA, Salas-Salvado, J. Consumption of Yogurt, Low-Fat Milk, and Other Low-Fat Dairy Products Is Associated with Lower Risk of Metabolic Syndrome Incidence in an Elderly Mediterranean Population. J Nutr. 2015. 145:2308–16. doi:10.3945/jn.115.214593 26290009 | Intervention/Exposure
167 | Backx, EM, Tieland, M, Borgonjen-van den Berg, KJ, Claessen, PR, van Loon, LJ, de Groot, LC. Protein intake and lean body mass preservation during energy intake restriction in overweight older adults. Int J Obes (Lond). 2016. 40:299–304. doi:10.1038/ijo.2015.182 26471344 | Weight loss/Hypocaloric
168 | Bacopoulou, F, Landis, G, Rentoumis, A, Tsitsika, A, Efthymiou, V. Mediterranean diet decreases adolescent waist circumference. Eur J Clin Invest. 2017. 47:447–455. doi:10.1111/eci.12760 28407234 | Study Design
169 | Bagherniya, M, Sharma, M, Mostafavi Darani, F, Maracy, MR, Safarian, M, Allipour Birgani, R, Bitarafan, V, Keshavarz, SA. School-Based Nutrition Education Intervention Using Social Cognitive Theory for Overweight and Obese Iranian Adolescent Girls: A Cluster Randomized Controlled Trial. Int Q Community Health Educ. 2017. 38:37–45. doi:10.1177/0272684x17749566 29298634 | Intervention/Exposure
170 | Bahadori, B, Yazdani-Biuki, B, Krippl, P, Brath, H, Uitz, E, Wascher, TC. Low-fat, high-carbohydrate (low-glycaemic index) diet induces weight loss and preserves lean body mass in obese healthy subjects: results of a 24-week study. Diabetes Obes Metab. 2005. 7:290–3. doi:10.1111/j.1463-1326.2004.00445.x 15811147 | Study Design; Intervention/Exposure
171 | Bahari, T, Uemura, H, Katsuura-Kamano, S, Yamaguchi, M, Nakamoto, M, Miki, K, Ishizu, M, Arisawa, K. Nutrient-Derived Dietary Patterns and Their Association With Metabolic Syndrome in a Japanese Population. J Epidemiol. 2018. 28:194–201. doi:10.2188/jea.JE20170010 29151477 | Study Design
172 | Bai, G, Zhang, J, Zhao, C, Wang, Y, Qi, Y, Zhang, B. Adherence to a healthy lifestyle and a DASH-style diet and risk of hypertension in Chinese individuals. Hypertens Res. 2017. 40:196–202. doi:10.1038/hr.2016.119 27604345 | Outcome; Country
173 | Bailes, JR, Strow, MT, Werthammer, J, McGinnis, RA, Elitsur, Y. Effect of low-carbohydrate, unlimited calorie diet on the treatment of childhood obesity: a prospective controlled study. Metab Syndr Relat Disord. 2003. 1:221–5. doi:10.1089/154041903322716697 18370665 | Intervention/Exposure
174 | Bailey, BW, Perkins, A, Tucker, LA, LeCheminant, JD, Tucker, JM, Moncur, B. Adherence to the 2010 Dietary Guidelines for Americans and the relationship to adiposity in young women. J Nutr Educ Behav. 2015. 47:86–93. doi:10.1016/j.jneb.2014.08.011 25438714 | Study Design
175 | Bailey, BW, Sullivan, DK, Kirk, EP, Donnelly, JE. Dietary predictors of visceral adiposity in overweight young adults. Br J Nutr. 2010. 103:1702–5. doi:10.1017/s0007114509993771 20100377 | Study Design; Study duration
176 | Bajaj, A, Rader, DJ. Can changes in the plasma lipidome help explain the cardiovascular benefits of the Mediterranean diet?. Am J Clin Nutr. 2017. 106:965–966. doi:10.3945/ajcn.117.165886 28903958 | Study Design
177 | Bajerska, J, Chmurzynska, A, Muzsik, A, Krzyzanowska, P, Madry, E, Malinowska, AM, Walkowiak, J. Weight loss and metabolic health effects from energy-restricted Mediterranean and Central-European diets in postmenopausal women: A randomized controlled trial. Sci Rep. 2018. 8:11170. doi:10.1038/s41598-018-29495-3 30042488 | Weight loss/Hypocaloric
178 | Bajerska, J, Chmurzynska, A, Muzsik, A, Menclewicz, K, Krzyzanowska, P, Walkowiak, J. Adherence to the mediterranean and the central european diets in relation to weight loss changes in postmenopausal women with diagnosed metabolic syndrome. Annals of nutrition & metabolism. 2017. 71:994-. doi:10.1159/000480486 | Publication Status
179 | Bajerska, J, Chmurzynska, A, Muzsik, A, Menclewicz, K, Krzyzanowska, P, Walkowiak, J. Effects of a 16-week dietary intervention with either a mediterranean diet or a central european diet on anthropometric parameters in obese postmenopausal with diagnosed metabolic syndrome. Annals of nutrition & metabolism. 2017. 71:994–995. doi:10.1159/000480486 | Publication Status
180 | Bakker, LE, van Schinkel, LD, Guigas, B, Streefland, TC, Jonker, JT, van Klinken, JB, van der Zon, GC, Lamb, HJ, Smit, JW, Pijl, H, Meinders, AE, Jazet, IM. A 5-day high-fat, high-calorie diet impairs insulin sensitivity in healthy, young South Asian men but not in Caucasian men. Diabetes. 2014. 63:248–58. doi:10.2337/db13-0696 24357702 | Study duration
181 | Bales, CW, Porter Starr, KN, Orenduff, MC, McDonald, SR, Molnar, K, Jarman, AK, Onyenwoke, A, Mulder, H, Payne, ME, Pieper, CF. Influence of Protein Intake, Race, and Age on Responses to a Weight-Reduction Intervention in Obese Women(). Curr Dev Nutr. 2017. 1:. doi:10.3945/cdn.117.000703 | Intervention/Exposure; Health Status
182 | Ballard, KD, Quann, EE, Kupchak, BR, Volk, BM, Kawiecki, DM, Fernandez, ML, Seip, RL, Maresh, CM, Kraemer, WJ, Volek, JS. Dietary carbohydrate restriction improves insulin sensitivity, blood pressure, microvascular function, and cellular adhesion markers in individuals taking statins. Nutr Res. 2013. 33:905–12. doi:10.1016/j.nutres.2013.07.022 24176230 | Study Design
183 | Ballesteros-Pomar, MD, Calleja-Fernandez, AR, Vidal-Casariego, A, Urioste-Fondo, AM, Cano-Rodriguez, I. Effectiveness of energy-restricted diets with different protein:carbohydrate ratios: the relationship to insulin sensitivity. Public Health Nutr. 2010. 13:2119–26. doi:10.1017/s1368980009991881 19889249 | Power/Size
184 | Balthazar, EA, de Oliveira, MR. Differences in dietary pattern between obese and eutrophic children. BMC Res Notes. 2011. 4:567. doi:10.1186/1756-0500-4-567 22206728 | Study Design
185 | Bamberger, C, Rossmeier, A, Lechner, K, Wu, L, Waldmann, E, Stark, RG, Altenhofer, J, Henze, K, Parhofer, KG. A Walnut-Enriched Diet Reduces Lipids in Healthy Caucasian Subjects, Independent of Recommended Macronutrient Replacement and Time Point of Consumption: a Prospective, Randomized, Controlled Trial. Nutrients. 2017. 9:. doi:10.3390/nu9101097 | Study duration
186 | Banini, AE, Allen, JC, Allen, HG, Boyd, LC, Lartey, A. Fatty acids, diet, and body indices of type II diabetic American whites and blacks and Ghanaians. Nutrition. 2003. 19:722–6. doi:10.1016/s0899-9007(03)00108-4 12921880 | Study Design
187 | Bansal, S, Cramp, L, Blalock, D, Zelleke, T, Carpenter, J, Kao, A. The ketogenic diet: Initiation at goal calories versus gradual caloric advancement. Pediatric Neurology. 2014. 50:26–30. doi:10.1016/j.pediatrneurol.2013.08.006 24200038 | Study Design; Outcome
188 | Banuls, C, Martinez-Triguero, ML, Lopez-Ruiz, A, Morillas, C, Lacomba, R, Victor, VM, Rocha, M, Hernandez-Mijares, A. Evaluation of cardiovascular risk and oxidative stress parameters in hypercholesterolemic subjects on a standard healthy diet including low-fat milk enriched with plant sterols. J Nutr Biochem. 2010. 21:881–6. doi:10.1016/j.jnutbio.2009.07.001 19889524 | Intervention/Exposure; Comparator
189 | Barchitta, M, Quattrocchi, A, Adornetto, V, Marchese, AE, Agodi, A. Tumor necrosis factor-alpha -308 G>A polymorphism, adherence to Mediterranean diet, and risk of overweight/obesity in young women. Biomed Res Int. 2014. 2014:742620. doi:10.1155/2014/742620 25028665 | Study Design
190 | Barnard, ND, Scialli, AR, Bertron, P, Hurlock, D, Edmonds, K, Talev, L. Effectiveness of a low-fat vegetarian diet in altering serum lipids in healthy premenopausal women. Am J Cardiol. 2000. 85:969–72. doi:10.1016/s0002-9149(99)00911-x 10760336 | Study duration
191 | Barnard, ND, Scialli, AR, Turner-McGrievy, G, Lanou, AJ, Glass, J. The effects of a low-fat, plant-based dietary intervention on body weight, metabolism, and insulin sensitivity. Am J Med. 2005. 118:991–7. doi:10.1016/j.amjmed.2005.03.039 16164885 | Power/Size
192 | Barnes, TL, French, SA, Mitchell, NR, Wolfson, J. Fast-food consumption, diet quality and body weight: cross-sectional and prospective associations in a community sample of working adults. Public Health Nutr. 2016. 19:885–92. doi:10.1017/s1368980015001871 26074150 | Comparator; Outcome
193 | Barnett, TD, Barnard, ND, Radak, TL. Development of symptomatic cardiovascular disease after self-reported adherence to the Atkins diet. J Am Diet Assoc. 2009. 109:1263–5. doi:10.1016/j.jada.2009.04.003 19559147 | Study Design
194 | Baron, KG, Reid, KJ, Horn, LV, Zee, PC. Contribution of evening macronutrient intake to total caloric intake and body mass index. Appetite. 2013. 60:246–251. doi:10.1016/j.appet.2012.09.026 23036285 | Study duration
195 | Barona, J, Jones, JJ, Kopec, RE, Comperatore, M, Andersen, C, Schwartz, SJ, Lerman, RH, Fernandez, ML. A Mediterranean-style low-glycemic-load diet increases plasma carotenoids and decreases LDL oxidation in women with metabolic syndrome. J Nutr Biochem. 2012. 23:609–15. doi:10.1016/j.jnutbio.2011.02.016 21775117 | Intervention/Exposure
196 | Barros, L, Lopes, C, Oliveira, A. Child and family characteristics are associated with a dietary variety index in 4-year-old children from the Generation XXI cohort. Nutr Res. 2019. 63:76–85. doi:10.1016/j.nutres.2018.12.001 30824400 | Study Design
197 | Basciani, S, Costantini, D, Contini, S, Persichetti, A, Watanabe, M, Mariani, S, Lubrano, C, Spera, G, Lenzi, A, Gnessi, L. Safety and efficacy of a multiphase dietetic protocol with meal replacements including a step with very low calorie diet. Endocrine. 2015. 48:863–70. doi:10.1007/s12020-014-0355-2 25063307 | Study Design; Study duration
198 | Basharat, S, Gilani, SA, Burq, AI, Bashir, S. Low glycaemic index diet is effective in managing weight among obese postpartum women. Journal of the Pakistan Medical Association. 2018. 68:548–552. doi:unavailable29808043 | Intervention/Exposure
199 | Baskaran, C, Carson, TL, Campoverde Reyes, KJ, Becker, KR, Slattery, MJ, Tulsiani, S, Eddy, KT, Anderson, EJ, Hubbard, JL, Misra, M, Klibanski, A. Macronutrient intake associated with weight gain in adolescent girls with anorexia nervosa. Int J Eat Disord. 2017. 50:1050–1057. doi:10.1002/eat.22732 28593722 | Intervention/Exposure
200 | Bathrellou, E, Kontogianni, MD, Chrysanthopoulou, E, Georgousopoulou, E, Chrysohoou, C, Pitsavos, C, Panagiotakos, D. Adherence to a DASH-style diet and cardiovascular disease risk: The 10-year follow-up of the ATTICA study. Nutr Health. 2019. 25:225–230. doi:10.1177/0260106019862995 31319758 | Power/Size
201 | Batis, C, Mendez, MA, Gordon-Larsen, P, Sotres-Alvarez, D, Adair, L, Popkin, B. Using both principal component analysis and reduced rank regression to study dietary patterns and diabetes in Chinese adults. Public Health Nutr. 2016. 19:195–203. doi:10.1017/s1368980014003103 26784586 | Country
202 | Batis, C, Mendez, MA, Sotres-Alvarez, D, Gordon-Larsen, P, Popkin, B. Dietary pattern trajectories during 15 years of follow-up and HbA1c, insulin resistance and diabetes prevalence among Chinese adults. J Epidemiol Community Health. 2014. 68:773–9. doi:10.1136/jech-2013-203560 24729424 | Country
203 | Baulderstone, L, Yaxley, A, Luszcz, M, Miller, M Diet Liberalisation in Older Australians Decreases Frailty without Increasing the Risk of Developing Chronic Disease J Frailty Aging, 2012 1(4): 174–82.doi 10.14283/jfa.2012.27 27093318 | Intervention/Exposure ?
204 | Baudry, J, Mejean, C, Peneau, S, Galan, P, Hercberg, S, Lairon, D, Kesse-Guyot, E. Health and dietary traits of organic food consumers: results from the NutriNet-Sante study. Br J Nutr. 2015. 114:2064–73. doi:10.1017/s0007114515003761 26429066 | Study Design
205 | Bauer, LB, Reynolds, LJ, Douglas, SM, Kearney, ML, Hoertel, HA, Shafer, RS, Thyfault, JP, Leidy, HJ. A pilot study examining the effects of consuming a high-protein vs normal-protein breakfast on free-living glycemic control in overweight/obese ‘breakfast skipping’ adolescents. Int J Obes (Lond). 2015. 39:1421–4. doi:10.1038/ijo.2015.101 26028058 | Intervention/Exposure
206 | Baxheinrich, A, Stratmann, B, Lee-Barkey, YH, Tschoepe, D, Wahrburg, U. Effects of a rapeseed oil-enriched hypoenergetic diet with a high content of alpha-linolenic acid on body weight and cardiovascular risk profile in patients with the metabolic syndrome. Br J Nutr. 2012. 108:682–91. doi:10.1017/s0007114512002875 22894911 | Intervention/Exposure
207 | Baxter, KA, Ware, RS, Batch, JA, Truby, H. Predicting success: factors associated with weight change in obese youth undertaking a weight management program. Obes Res Clin Pract. 2013. 7:e147–e154. doi:10.1016/j.orcp.2011.09.004 24331776 | Intervention/Exposure
208 | Bazzano, LA, He, J, Ogden, LG, Loria, CM, Whelton, PK. Dietary fiber intake and reduced risk of coronary heart disease in US men and women: the National Health and Nutrition Examination Survey I Epidemiologic Follow-up Study. Arch Intern Med. 2003. 163:1897–904. doi:10.1001/archinte.163.16.1897 12963562 | Intervention/Exposure
209 | Bazzano, LA, Reynolds, K, Hu, T, Yao, L, Bunol, C, Liu, Y, Chen, CS, He, J. Effect of a low-carbohydrate diet on weight and cardiovascular risk factors: a randomized controlled trial. Circulation. 2012. 125:. doi:unavailable | Publication Status
210 | Bazzocchi, A, Santoro, A, Mercatelli, D, Ponti, F, Diano, D, Zanirato Rambaldi, G, Scurti, M, Berendsen, A, Pietruszka, B, Jennings, A, , . New dietary strategies addressing the specific needs of elderly population for a healthy aging in Europe (NU-AGE): the effect of a tailored Mediterranean diet on body composition. Skeletal radiology. 2017. 46:856-. doi:10.1007/s00256-017-2619-4 | Publication Status
211 | Beasley, J, Viswanathan, S, Wylie-Rosett, J. Associations between change in DASH diet scores and CVD risk factors in the PREMIER Trial. FASEB journal. 2014. 28:. doi:unavailable | Publication Status
212 | Beasley, JM, Yi, SS, Ahn, J, Kwon, SC, Wylie-Rosett, J. Dietary Patterns in Chinese Americans are Associated with Cardiovascular Disease Risk Factors, the Chinese American Cardiovascular Health Assessment (CHA CHA). J Immigr Minor Health. 2019. 21:1061–1069. doi:10.1007/s10903-018-0800-z 30097786 | Study Design
213 | Beauchesne-Rondeau, E, Gascon, A, Bergeron, J, Jacques, H. Plasma lipids and lipoproteins in hypercholesterolemic men fed a lipid-lowering diet containing lean beef, lean fish, or poultry. Am J Clin Nutr. 2003. 77:587–93. doi:10.1093/ajcn/77.3.587 12600847 | Study duration
214 | Beavers, KM, Gordon, MM, Easter, L, Beavers, DP, Hairston, KG, Nicklas, BJ, Vitolins, MZ. Effect of protein source during weight loss on body composition, cardiometabolic risk and physical performance in abdominally obese, older adults: a pilot feeding study. Journal of nutrition, health & aging. 2014. 19:87–95. doi:10.1007/s12603-015-0438-7 | Intervention/Exposure
215 | Beavers, KM, Nesbit, BA, Kiel, JR, Sheedy, JL, Arterburn, LM, Collins, AE, Ford, SA, Henderson, RM, Coleman, CD, Beavers, DP. Effect of an Energy-Restricted, Nutritionally Complete, Higher Protein Meal Plan on Body Composition and Mobility in Older Adults With Obesity: A Randomized Controlled Trial. J Gerontol A Biol Sci Med Sci. 2019. 74:929–935. doi:10.1093/gerona/gly146 30629126 | Intervention/Exposure
216 | Beck, KL, Jones, B, Ullah, I, McNaughton, SA, Haslett, SJ, Stonehouse, W. Associations between dietary patterns, socio-demographic factors and anthropometric measurements in adult New Zealanders: an analysis of data from the 2008/09 New Zealand Adult Nutrition Survey. Eur J Nutr. 2018. 57:1421–1433. doi:10.1007/s00394-017-1421-3 28378296 | Study Design
217 | Becker, GF, Passos, EP, Moulin, CC. Short-term effects of a hypocaloric diet with low glycemic index and low glycemic load on body adiposity, metabolic variables, ghrelin, leptin, and pregnancy rate in overweight and obese infertile women: a randomized controlled trial. Am J Clin Nutr. 2015. 102:1365–72. doi:10.3945/ajcn.115.117200 26561614 | Intervention/Exposure
218 | Becquey, E, Savy, M, Danel, P, Dabire, HB, Tapsoba, S, Martin-Prevel, Y. Dietary patterns of adults living in Ouagadougou and their association with overweight. Nutr J. 2010. 9:13. doi:10.1186/1475-2891-9-13 20307296 | Study Design
219 | Bedard, A, Corneau, L, Dodin, S, Lemieux, S. Sex Differences in the Effects of Repeated Taste Exposure to the Mediterranean Diet: A 6-month Follow-up Study. Can J Diet Pract Res. 2016. 77:125–32. doi:10.3148/cjdpr-2015-052 26916988 | Study Design; Study duration
220 | Bedard, A, Corneau, L, Lamarche, B, Dodin, S, Lemieux, S. Sex Differences in the Impact of the Mediterranean Diet on LDL Particle Size Distribution and Oxidation. Nutrients. 2015. 7:3705–23. doi:10.3390/nu7053705 25988764 | Study duration
221 | Bedard, A, Corneau, L, Vohl, MC, Dodin, S, Lemieux, S. Effect of the Mediterranean diet on the lipid-lipoprotein profile: is it influenced by the family history of dyslipidemia?. J Nutrigenet Nutrigenomics. 2014. 7:177–87. doi:10.1159/000374116 25766081 | Study Design; Study duration
222 | Bedard, A, Dodin, S, Corneau, L, Lemieux, S. Impact of the traditional Mediterranean diet on the Framingham risk score and the metabolic syndrome according to sex. Metab Syndr Relat Disord. 2014. 12:95–101. doi:10.1089/met.2012.0076 24438432 | Study Design; Intervention/Exposure
223 | Bedard, A, Garcia-Aymerich, J, Sanchez, M, Le Moual, N, Clavel-Chapelon, F, Boutron-Ruault, MC, Maccario, J, Varraso, R. Confirmatory Factor Analysis Compared with Principal Component Analysis to Derive Dietary Patterns: A Longitudinal Study in Adult Women. J Nutr. 2015. 145:1559–68. doi:10.3945/jn.114.204479 25995279 | Outcome
224 | Bédard, A, Lamarche, B, Corneau, L, Dodin, S, Lemieux, S. Sex differences in the impact of the Mediterranean diet on systemic inflammation. Nutrition Journal. 2015. 14:. doi:10.1186/s12937-015-0035-y | Outcome
225 | Bekkouche, L, Bouchenak, M, Malaisse, WJ, Yahia, DA. The Mediterranean diet adoption improves metabolic, oxidative, and inflammatory abnormalities in Algerian metabolic syndrome patients. Horm Metab Res. 2014. 46:274–82. doi:10.1055/s-0033-1363657 24446153 | Comparator
226 | Belanger, M, Poirier, M, Jbilou, J, Scarborough, P. Modelling the impact of compliance with dietary recommendations on cancer and cardiovascular disease mortality in Canada. Public Health. 2014. 128:222–30. doi:10.1016/j.puhe.2013.11.003 24612957 | Study Design
227 | Belin, RJ, Greenland, P, Allison, M, Martin, L, Shikany, JM, Larson, J, Tinker, L, Howard, BV, Lloyd-Jones, D, Van Horn, L. Diet quality and the risk of cardiovascular disease: The Women’s Health Initiative (WHI). American Journal of Clinical Nutrition. 2011. 94:49–57. doi:10.3945/ajcn.110.011221 | Intervention/Exposure; Publication Date Overlaps with Existing Review
228 | Bello, JK, Stulberg, DB, Zhou, Y, Wang, C. Physical Activity and Consumption Patterns of Reproductive-Aged Women by BMI Category. Matern Child Health J. 2018. 22:713–724. doi:10.1007/s10995-018-2440-2 29344750 | Study Design; Intervention/Exposure
229 | Bel-Serrat, S, Mouratidou, T, Bornhorst, C, Peplies, J, De Henauw, S, Marild, S, Molnar, D, Siani, A, Tornaritis, M, Veidebaum, T, Krogh, V, Moreno, LA. Food consumption and cardiovascular risk factors in European children: the IDEFICS study. Pediatr Obes. 2013. 8:225–36. doi:10.1111/j.2047-6310.2012.00107.x 23225768 | Study Design
230 | Bel-Serrat, S, Ojeda-Rodriguez, A, Heinen, MM, Buoncristiano, M, Abdrakhmanova, S, Duleva, V, Sant’Angelo, VF, Fijalkowska, A, Hejgaard, T, Huidumac, C, Hyska, J, Kujundzic, E, Milanovic, SM, Ovezmyradova, G, Perez-Farinos, N, Petrauskiene, A, Rito, AI, Shengelia, L, Braunerova, RT, Rutter, H, Murrin, CM, Kelleher, CC, Breda, J. Clustering of Multiple Energy Balance-Related Behaviors in School Children and its Association with Overweight and Obesity-WHO European Childhood Obesity Surveillance Initiative (COSI 2015(-)2017). Nutrients. 2019. 11:. doi:10.3390/nu11030511 | Study Design
231 | Bemelmans, WJ, Broer, J, de Vries, JH, Hulshof, KF, May, JF, Meyboom-De Jong, B. Impact of Mediterranean diet education versus posted leaflet on dietary habits and serum cholesterol in a high risk population for cardiovascular disease. Public Health Nutr. 2000. 3:273–83. doi:10.1017/s1368980000000318 10979147 | Intervention/Exposure; Comparator
232 | Ben Ayed, H, Yaich, S, Ben Hmida, M, Trigui, M, Ben Jemaa, M, Jedidi, J, Karray, R, Mejdoub, Y, Feki, H, Kassis, M, Damak, J. Prevalence, determinants and outcomes of general and abdominal obesity in medical students. Obesity Medicine. 2019. 13:39–44. doi:10.1016/j.obmed.2018.12.007 | Study Design; Intervention/Exposure
233 | Berard, E, Bongard, V, Haas, B, Dallongeville, J, Moitry, M, Cottel, D, Ruidavets, JB, Ferrieres, J. Score of Adherence to 2016 European Cardiovascular Prevention Guidelines Predicts Cardiovascular and All-Cause Mortality in the General Population. Can J Cardiol. 2017. 33:1298–1304. doi:10.1016/j.cjca.2017.06.008 28866076 | Study Design; Intervention/Exposure
234 | Berg, CM, Lappas, G, Strandhagen, E, Wolk, A, Toren, K, Rosengren, A, Aires, N, Thelle, DS, Lissner, L. Food patterns and cardiovascular disease risk factors: the Swedish INTERGENE research program. Am J Clin Nutr. 2008. 88:289–97. doi:10.1093/ajcn/88.2.289 18689363 | Study Design; Publication Date Overlaps with Existing Review
235 | Bergeron, N, Chiu, S, Williams, PT, King S M, Krauss, RM. Effects of red meat, white meat, and nonmeat protein sources on atherogenic lipoprotein measures in the context of low compared with high saturated fat intake: a randomized controlled trial. Am J Clin Nutr. 2019. :. doi:10.1093/ajcn/nqz035 | Study duration
236 | Berglund, L, Lefevre, M, Ginsberg, HN, Kris-Etherton, PM, Elmer, PJ, Stewart, PW, Ershow, A, Pearson, TA, Dennis, BH, Roheim, PS, Ramakrishnan, R, Reed, R, Stewart, K, Phillips, KM. Comparison of monounsaturated fat with carbohydrates as a replacement for saturated fat in subjects with a high metabolic risk profile: studies in the fasting and postprandial states. Am J Clin Nutr. 2007. 86:1611–20. doi:10.1093/ajcn/86.5.1611 18065577 | Study duration
237 | Bergouignan, A, Gozansky, WS, Barry, DW, Leitner, W, MacLean, PS, Hill, JO, Draznin, B, Melanson, EL. Increasing dietary fat elicits similar changes in fat oxidation and markers of muscle oxidative capacity in lean and obese humans. PLoS One. 2012. 7:e30164. doi:10.1371/journal.pone.0030164 22253914 | Study duration
238 | Berkey, CS, Rockett, HR, Field, AE, Gillman, MW, Frazier, AL, Camargo, CA, Jr, Colditz, GA. Activity, dietary intake, and weight changes in a longitudinal study of preadolescent and adolescent boys and girls. Pediatrics. 2000. 105:E56. doi:10.1542/peds.105.4.e56 10742377 | Intervention/Exposure
239 | Berlin, KS, Kamody, RC, Thurston, IB, Banks, GG, Rybak, TM, Ferry, RJ, Jr. Physical Activity, Sedentary Behaviors, and Nutritional Risk Profiles and Relations to Body Mass Index, Obesity, and Overweight in Eighth Grade. Behav Med. 2017. 43:31–39. doi:10.1080/08964289.2015.1039956 25909358 | Study Design; Intervention/Exposure
240 | Bermudez, OI, Velez-Carrasco, W, Schaefer, EJ, Tucker, KL. Dietary and plasma lipid, lipoprotein, and apolipoprotein profiles among elderly Hispanics and non-Hispanics and their association with diabetes. Am J Clin Nutr. 2002. 76:1214–21. doi:10.1093/ajcn/76.6.1214 12450885 | Study Design
241 | Bernstein, AM, Sun, Q, Hu, FB, Stampfer, MJ, Manson, JE, Willett, WC. Major dietary protein sources and risk of coronary heart disease in women. Circulation. 2010. 122:876–83. doi:10.1161/circulationaha.109.915165 20713902 | Intervention/Exposure
242 | Berryman, CE, Fleming, JA, Kris-Etherton, PM. Inclusion of Almonds in a Cholesterol-Lowering Diet Improves Plasma HDL Subspecies and Cholesterol Efflux to Serum in Normal-Weight Individuals with Elevated LDL Cholesterol. J Nutr. 2017. 147:1517–1523. doi:10.3945/jn.116.245126 28615375 | Intervention/Exposure
243 | Bersamin, A, Luick, BR, King, IB, Stern, JS, Zidenberg-Cherr, S. Westernizing diets influence fat intake, red blood cell fatty acid composition, and health in remote Alaskan Native communities in the center for Alaska Native health study. J Am Diet Assoc. 2008. 108:266–73. doi:10.1016/j.jada.2007.10.046 18237575 | Study Design
244 | Bertoli, S, Neri, IG, Trentani, C, Ferraris, C, De Amicis, R, Battezzati, A, Veggiotti, P, De Giorgis, V, Tagliabue, A. Short-term effects of ketogenic diet on anthropometric parameters, body fat distribution, and inflammatory cytokine production in GLUT1 deficiency syndrome. Nutrition. 2015. 31:981–7. doi:10.1016/j.nut.2015.02.017 26059372 | Health Status
245 | Bertz, F, Winkvist, A, Brekke, HK. Sustainable weight loss among overweight and obese lactating women is achieved with an energy-reduced diet in line with dietary recommendations: results from the LEVA randomized controlled trial. J Acad Nutr Diet. 2015. 115:78–86. doi:10.1016/j.jand.2014.05.017 25088520 | Weight loss/Hypocaloric
246 | Berz, JP, Singer, MR, Guo, X, Daniels, SR, Moore, LL. Use of a DASH food group score to predict excess weight gain in adolescent girls in the National Growth and Health Study. Arch Pediatr Adolesc Med. 2011. 165:540–6. doi:10.1001/archpediatrics.2011.71 21646587 | Publication Date Overlaps with Existing Review
247 | Best, TH, Franz, DN, Gilbert, DL, Nelson, DP, Epstein, MR. Cardiac complications in pediatric patients on the ketogenic diet. Neurology. 2000. 54:2328–30. doi:10.1212/wnl.54.12.2328 10881264 | Study Design; Comparator
248 | Bethancourt, HJ, Kratz, M, O’Connor, K. A short-term religious “fast” from animal products has a minimal impact on cardiometabolic health biomarkers irrespective of concurrent shifts in distinct plant-based food groups. Am J Clin Nutr. 2019. 110:722–732. doi:10.1093/ajcn/nqz153 31380559 | Study duration
249 | Beulen, Y, Martinez-Gonzalez, MA, van de Rest, O, Salas-Salvado, J, Sorli, JV, Gomez-Gracia, E, Fiol, M, Estruch, R, Santos-Lozano, JM, Schroder, H, Alonso-Gomez, A, Serra-Majem, L, Pinto, X, Ros, E, Becerra-Tomas, N, Gonzalez, JI, Fito, M, Martinez, JA, Gea, A. Quality of Dietary Fat Intake and Body Weight and Obesity in a Mediterranean Population: Secondary Analyses within the PREDIMED Trial. Nutrients. 2018. 10:. doi:10.3390/nu10122011 | Intervention/Exposure
250 | Beydoun, HA, Huang, S, Beydoun, MA, Hossain, S, Zonderman, AB. Mediating-Moderating Effect of Allostatic Load on the Association between Dietary Approaches to Stop Hypertension Diet and All-Cause and Cause-Specific Mortality: 2001-2010 National Health and Nutrition Examination Surveys. Nutrients. 2019. 11:. doi:10.3390/nu11102311 | Intervention/Exposure
251 | Beyerlein, A, Uusitalo, UM, Virtanen, SM, Vehik, K, Yang, J, Winkler, C, Kersting, M, Koletzko, S, Schatz, D, Aronsson, CA, Elding Larsson, H, Krischer, JP, Ziegler, AG, Norris, JM, Hummel, S. Intake of Energy and Protein is Associated with Overweight Risk at Age 5.5 Years: Results from the Prospective TEDDY Study. Obesity (Silver Spring). 2017. 25:1435–1441. doi:10.1002/oby.21897 28650578 | Study Design; Intervention/Exposure
252 | Bhargava, A, Guthrie, JF. Unhealthy eating habits, physical exercise and macronutrient intakes are predictors of anthropometric indicators in the Women’s Health Trial: Feasibility Study in Minority Populations. Br J Nutr. 2002. 88:719–28. doi:10.1079/bjn2002739 12493094 | Intervention/Exposure; Comparator
253 | Bhattacharyya, M, Maity, S, Bandyopadhyay, S. Exploring the Missing Links Between Dietary Habits and Diseases. IEEE Trans Nanobioscience. 2017. 16:226–238. doi:10.1109/tnb.2017.2654121 28103559 | Study Design
254 | Bian, JT, Szczurek, M, Ranieri, C, Grizelj, I, Cavka, A, Robinson, A, Marsh, G, Li, K, Sanyaolu, RA, Shinde, S, , . Weight loss with low carbohydrate diets improves flow induced vasodilation in resistance arteries. Circulation. 2014. 130:. doi:unavailable | Publication Status
255 | Bianco, A, Thomas, E, Bellafiore, M, Martines, F, Messina, G, Battaglia, G, Karsten, B, Sahin, FN, Bielec, G, Paoli, A, Palma, A. Mediterranean diet and dietary protein supplementation as possible predicting variables of weight management: An update of the protein project. Acta Medica Mediterranea. 2015. 31:1265–1270. doi:unavailable | Study Design
256 | Biazzi Leal, D, Altenburg de Assis, MA, Hinnig, PF, Schmitt, J, Soares Lobo, A, Bellisle, F, Di Pietro, PF, Vieira, FK, de Moura Araujo, PH, de Andrade, DF. Changes in Dietary Patterns from Childhood to Adolescence and Associated Body Adiposity Status. Nutrients. 2017. 9:. doi:10.3390/nu9101098 | Power/Size
257 | Bihuniak, JD, Ramos, A, Huedo-Medina, T, Hutchins-Wiese, H, Kerstetter, JE, Kenny, AM. Adherence to a Mediterranean-Style Diet and Its Influence on Cardiovascular Risk Factors in Postmenopausal Women. J Acad Nutr Diet. 2016. 116:1767–1775. doi:10.1016/j.jand.2016.06.377 27568885 | Study Design; Intervention/Exposure
258 | Bilenko, N, Fraser, D, Vardi, H, Shai, I, Shahar, DR. Mediterranean diet and cardiovascular diseases in an Israeli population. Prev Med. 2005. 40:299–305. doi:10.1016/j.ypmed.2004.06.004 15533543 | Study Design
259 | Binns, A, Gray, M, Henson, AC, Fort, IL. Changes in Lean Mass and Serum Myostatin with Habitual Protein Intake and High-Velocity Resistance Training. J Nutr Health Aging. 2017. 21:1111–1117. doi:10.1007/s12603-017-0883-6 29188869 | Intervention/Exposure
260 | Bisschop, PH, Ackermans, MT, Endert, E, Ruiter, AF, Meijer, AJ, Kuipers, F, Sauerwein, HP, Romijn, JA. The effect of carbohydrate and fat variation in euenergetic diets on postabsorptive free fatty acid release. Br J Nutr. 2002. 87:555–9. doi:10.1079/bjnbjn2002578 12067425 | Study duration
261 | Bisschop, PH, Bandsma, RH, Stellaard, F, ter Harmsel, A, Meijer, AJ, Sauerwein, HP, Kuipers, F, Romijn, JA. Low-fat, high-carbohydrate and high-fat, low-carbohydrate diets decrease primary bile acid synthesis in humans. Am J Clin Nutr. 2004. 79:570–6. doi:10.1093/ajcn/79.4.570 15051599 | Study duration
262 | Bisschop, PH, de Metz, J, Ackermans, MT, Endert, E, Pijl, H, Kuipers, F, Meijer, AJ, Sauerwein, HP, Romijn, JA. Dietary fat content alters insulin-mediated glucose metabolism in healthy men. Am J Clin Nutr. 2001. 73:554–9. doi:10.1093/ajcn/73.3.554 11237931 | Study duration
263 | Bjerregaard, P, Pedersen, HS, Mulvad, G. The associations of a marine diet with plasma lipids, blood glucose, blood pressure and obesity among the inuit in Greenland. Eur J Clin Nutr. 2000. 54:732–7. doi:10.1038/sj.ejcn.1601088 11002386 | Intervention/Exposure
264 | Black, MH, Watanabe, RM, Trigo, E, Takayanagi, M, Lawrence, JM, Buchanan, TA, Xiang, AH. High-fat diet is associated with obesity-mediated insulin resistance and beta-cell dysfunction in Mexican Americans. J Nutr. 2013. 143:479–85. doi:10.3945/jn.112.170449 23343677 | Study Design
265 | Black, MH, Watanabe, RM, Trigo, E, Takayanagi, M, Lawrence, JM, Buchanan, TA, Xiang, AH. High-fat diet is associated with obesity-mediated insulin resistance and β-cell dysfunction in Mexican Americans. Journal of Nutrition. 2013. 143:479–485. doi:10.3945/jn.112.170449 | Power/Size; Study Design
266 | Black, RN, Spence, M, McMahon, RO, Cuskelly, GJ, Ennis, CN, McCance, DR, Young, IS, Bell, PM, Hunter, SJ. Effect of eucaloric high- and low-sucrose diets with identical macronutrient profile on insulin resistance and vascular risk: a randomized controlled trial. Diabetes. 2006. 55:3566–72. doi:10.2337/db06-0220 17130505 | Intervention/Exposure; Publication Date Overlaps with Existing Review
267 | Bladbjerg, EM, Larsen, TM, Due, A, Stender, S, Astrup, A, Jespersen, J. Effects on markers of inflammation and endothelial cell function of three ad libitum diets differing in type and amount of fat and carbohydrate: a 6-month randomised study in obese individuals. Br J Nutr. 2011. 106:123–9. doi:10.1017/s0007114510005829 21320366 | Power/Size
268 | Blesso, CN, Andersen, CJ, Barona, J, Volek, JS, Fernandez, ML. Whole egg consumption improves lipoprotein profiles and insulin sensitivity to a greater extent than yolk-free egg substitute in individuals with metabolic syndrome. Metabolism. 2013. 62:400–10. doi:10.1016/j.metabol.2012.08.014 23021013 | Intervention/Exposure; Comparator
269 | Blesso, CN, Andersen, CJ, Barona, J, Volk, B, Volek, JS, Fernandez, ML. Effects of carbohydrate restriction and dietary cholesterol provided by eggs on clinical risk factors in metabolic syndrome. J Clin Lipidol. 2013. 7:463–71. doi:10.1016/j.jacl.2013.03.008 24079288 | Power/Size
270 | Bligh, HF, Godsland, IF, Frost, G, Hunter, KJ, Murray, P, MacAulay, K, Hyliands, D, Talbot, DC, Casey, J, Mulder, TP, Berry, MJ. Plant-rich mixed meals based on Palaeolithic diet principles have a dramatic impact on incretin, peptide YY and satiety response, but show little effect on glucose and insulin homeostasis: an acute-effects randomised study. Br J Nutr. 2015. 113:574–84. doi:10.1017/s0007114514004012 25661189 | Study duration
271 | Block, JP. Mediterranean diet lowers cardiovascular risk even without weight loss. Journal of clinical outcomes management. 2013. 20:150–152. doi:unavailable | Publication Status
272 | Blomfield, RL, Collins, CE, Hutchesson, MJ, Young, MD, Jensen, ME, Callister, R, Morgan, PJ. Impact of self-help weight loss resources with or without online support on the dietary intake of overweight and obese men: the SHED-IT randomised controlled trial. Obes Res Clin Pract. 2014. 8:e476–87. doi:10.1016/j.orcp.2013.09.004 25263837 | Intervention/Exposure
273 | Blomquist, C, Chorell, E, Ryberg, M, Mellberg, C, Worrsjo, E, Makoveichuk, E, Larsson, C, Lindahl, B, Olivecrona, G, Olsson, T. Decreased lipogenesis-promoting factors in adipose tissue in postmenopausal women with overweight on a Paleolithic-type diet. Eur J Nutr. 2018. 57:2877–2886. doi:10.1007/s00394-017-1558-0 29075849 | Power/Size
274 | Bloomer, RJ, Gunnels, TA, Schriefer, JM. Comparison of a Restricted and Unrestricted Vegan Diet Plan with a Restricted Omnivorous Diet Plan on Health-Specific Measures. Healthcare (Basel). 2015. 3:544–55. doi:10.3390/healthcare3030544 27417779 | Study Design; Study duration
275 | Blumenthal, JA, Sherwood, A, Smith, PJ, Mabe, S, Watkins, L, Lin, PH, Craighead, LW, Babyak, M, Tyson, C, Young, K, Ashworth, M, Kraus, W, Liao, L, Hinderliter, A. Lifestyle modification for resistant hypertension: The TRIUMPH randomized clinical trial. Am Heart J. 2015. 170:986–994.e5. doi:10.1016/j.ahj.2015.08.006 26542509 | Study Design; Intervention/Exposure
276 | Boden-Albala, B, Elkind, MS, White, H, Szumski, A, Paik, MC, Sacco, RL. Dietary total fat intake and ischemic stroke risk: the Northern Manhattan Study. Neuroepidemiology. 2009. 32:296–301. doi:10.1159/000204914 19246935 | Intervention/Exposure
277 | Boers, I, Muskiet, FA, Berkelaar, E, Schut, E, Penders, R, Hoenderdos, K, Wichers, HJ, Jong, MC. Favourable effects of consuming a Palaeolithic-type diet on characteristics of the metabolic syndrome: a randomized controlled pilot-study. Lipids Health Dis. 2014. 13:160. doi:10.1186/1476-511x-13-160 25304296 | Study duration
278 | Bogart, LM, Elliott, MN, Uyeda, K, Hawes-Dawson, J, Klein, DJ, Schuster, MA. Preliminary healthy eating outcomes of SNaX, a pilot community-based intervention for adolescents. Journal of Adolescent Health. 2011. 48:196–202. doi:10.1016/j.jadohealth.2010.06.004 | Intervention/Exposure
279 | Bogl, LH, Pietilainen, KH, Rissanen, A, Kangas, AJ, Soininen, P, Rose, RJ, Ala-Korpela, M, Kaprio, J. Association between habitual dietary intake and lipoprotein subclass profile in healthy young adults. Nutr Metab Cardiovasc Dis. 2013. 23:1071–8. doi:10.1016/j.numecd.2012.11.007 23333726 | Study Design
280 | Bogomolova, S, Zarnowiecki, D, Wilson, A, Fielder, A, Procter, N, Itsiopoulos, C, O’Dea, K, Strachan, J, Ballestrin, M, Champion, A, Parletta, N. Dietary intervention for people with mental illness in South Australia. Health Promot Int. 2018. 33:71–83. doi:10.1093/heapro/daw055 27476869 | Study Design; Health Status
281 | Bonaccio, M, Di Castelnuovo, A, Costanzo, S, Persichillo, M, De Curtis, A, Donati, MB, de Gaetano, G, Iacoviello, L. Adherence to the traditional Mediterranean diet and mortality in subjects with diabetes. Prospective results from the MOLI-SANI study. Eur J Prev Cardiol. 2016. 23:400–7. doi:10.1177/2047487315569409 25648935 | Health Status
282 | Bondia-Pons, I, Martinez, JA, de la Iglesia, R, Lopez-Legarrea, P, Poutanen, K, Hanhineva, K, Zulet Mde, L. Effects of short- and long-term Mediterranean-based dietary treatment on plasma LC-QTOF/MS metabolic profiling of subjects with metabolic syndrome features: The Metabolic Syndrome Reduction in Navarra (RESMENA) randomized controlled trial. Mol Nutr Food Res. 2015. 59:711–28. doi:10.1002/mnfr.201400309 25641909 | Intervention/Exposure; Outcome
283 | Bondonno, NP, Lewis, JR, Blekkenhorst, LC, Shivappa, N, Woodman, RJ, Bondonno, CP, Ward, NC, Hebert, JR, Thompson, PL, Prince, RL, Hodgson, JM. Dietary inflammatory index in relation to sub-clinical atherosclerosis and atherosclerotic vascular disease mortality in older women. Br J Nutr. 2017. 117:1577–1586. doi:10.1017/s0007114517001520 28673375 | Intervention/Exposure
284 | Bonfanti, N, Fernández, JM, Gomez-Delgado, F, Pérez-Jiménez, F. Effect of two hypocaloric diets and their combination with physical exercise on basal metabolic rate and body composition. Nutricion hospitalaria. 2014. 29:635–643. doi:10.3305/nh.2014.29.3.7119 24559009 | Language
285 | Booth, A, Nowson, C, Worsley, A, Magerison, C, Jorna, M. Dietary approaches for weight loss with increased intakes of fruit, vegetables and dairy products. Nutrition & dietetics. 2008. 65:115–120. doi:unavailable | Intervention/Exposure; Publication Date Overlaps with Existing Review
286 | Bopp, MJ, Houston, DK, Lenchik, L, Easter, L, Kritchevsky, SB, Nicklas, BJ. Lean mass loss is associated with low protein intake during dietary-induced weight loss in postmenopausal women. J Am Diet Assoc. 2008. 108:1216–20. doi:10.1016/j.jada.2008.04.017 18589032 | Study Design; Intervention/Exposure
287 | Borges, CA, Marchioni, DML, Levy, RB, Slater, B. Dietary patterns associated with overweight among Brazilian adolescents. Appetite. 2018. 123:402–409. doi:10.1016/j.appet.2018.01.001 29355584 | Study Design
288 | Bortolotti, M, Kreis, R, Debard, C, Cariou, B, Faeh, D, Chetiveaux, M, Ith, M, Vermathen, P, Stefanoni, N, Le, KA, Schneiter, P, Krempf, M, Vidal, H, Boesch, C, Tappy, L. High protein intake reduces intrahepatocellular lipid deposition in humans. Am J Clin Nutr. 2009. 90:1002–10. doi:10.3945/ajcn.2008.27296 19710199 | Study duration
289 | Bosco, G, Lodi, A, Cenci, L, Grimaldi, K, Parmagnani, A, Paoli, A. Hunger-related hormones, body composition and metabolism in overweight subjects two months after a mediterranean ketogenetic diet weight loss program. Eating and weight disorders. 2014. 19:423. doi:10.1007/s40519-014-0134-3 | Publication Status
290 | Bosse, MC, Davis, SC, Puhl, SM, Pedersen, M, Low, V, Reiner, L, Dominguez, T, Seals, N. Effects of Zone diet macronutrient proportions on blood lipids, blood glucose, body composition, and treadmill exercise performance. Nutrition Research. 2004. 24:521–530. doi:10.1016/j.nutres.2004.04.001 | Study duration
291 | Boucher, AB, Adesanya, EA, Owei, I, Gilles, AK, Ebenibo, S, Wan, J, Edeoga, C, Dagogo-Jack, S. Dietary habits and leisure-time physical activity in relation to adiposity, dyslipidemia, and incident dysglycemia in the pathobiology of prediabetes in a biracial cohort study. Metabolism. 2015. 64:1060–7. doi:10.1016/j.metabol.2015.05.015 26116207 | Intervention/Exposure
292 | Bouillon, K, Singh-Manoux, A, Jokela, M, Shipley, MJ, Batty, GD, Brunner, EJ, Sabia, S, Tabák, AG, Akbaraly, T, Ferrie, JE, Kivimäki, M. Decline in low-density lipoprotein cholesterol concentration: Lipid-lowering drugs, diet, or physical activity? Evidence from the Whitehall II study. Heart. 2011. 97:923–930. doi:10.1136/hrt.2010.216309 21487128 | Outcome
293 | Bounds, RG, Grandjean, PW, O’Brien, BC, Inman, C, Crouse, SF. Diet and short term plasma lipoprotein-lipid changes after exercise in trained Men. Int J Sport Nutr Exerc Metab. 2000. 10:114–27. doi:10.1123/ijsnem.10.2.114 10861333 | Study duration
294 | Bowen, J, Noakes, M, Clifton, P. High dairy-protein versus high mixed-protein energy restricted diets - the effect on bone turnover and calcium excretion in overweight adults. Asia pacific journal of clinical nutrition. 2003. 12 Suppl:S52. doi:unavailable | Intervention/Exposure; Publication Status
295 | Bowen, J, Noakes, M, Clifton, PM. A high dairy protein, high-calcium diet minimizes bone turnover in overweight adults during weight loss. J Nutr. 2004. 134:568–73. doi:10.1093/jn/134.3.568 14988448 | Intervention/Exposure; Comparator
296 | Bowen, J, Noakes, M, Clifton, PM. Effect of calcium and dairy foods in high protein, energy-restricted diets on weight loss and metabolic parameters in overweight adults. Int J Obes (Lond). 2005. 29:957–65. doi:10.1038/sj.ijo.0802895 15711601 | Intervention/Exposure; Comparator
297 | Bowen, KJ, Kris-Etherton, PM, Jones, PJ, Reddivari, L. Effects of diets that vary in fatty acid composition on fecal short-chain fatty acid levels and their relationship with circulating lipids and lipoproteins. Circulation. 2019. 139:. doi:10.1161/circ.139.suppl_1.P293 | Publication Status
298 | Bowling, A, Davison, K, Haneuse, S, Beardslee, W, Miller, DP. ADHD Medication, Dietary Patterns, Physical Activity, and BMI in Children: A Longitudinal Analysis of the ECLS-K Study. Obesity (Silver Spring). 2017. 25:1802–1808. doi:10.1002/oby.21949 28834373 | Intervention/Exposure
299 | Bowman, SA, Spence, JT. A comparison of low-carbohydrate vs. high-carbohydrate diets: energy restriction, nutrient quality and correlation to body mass index. J Am Coll Nutr. 2002. 21:268–74. doi:10.1080/07315724.2002.10719220 12074255 | Study Design
300 | Boyle, KE, Canham, JP, Consitt, LA, Zheng, D, Koves, TR, Gavin, TP, Holbert, D, Neufer, PD, Ilkayeva, O, Muoio, DM, Houmard, JA. A high-fat diet elicits differential responses in genes coordinating oxidative metabolism in skeletal muscle of lean and obese individuals. J Clin Endocrinol Metab. 2011. 96:775–81. doi:10.1210/jc.2010-2253 21190973 | Study duration
301 | Bozzetto, L, Annuzzi, G, Pacini, G, Costabile, G, Vetrani, C, Vitale, M, Griffo, E, Giacco, A, De Natale, C, Cocozza, S, Della Pepa, G, Tura, A, Riccardi, G, Rivellese, AA. Polyphenol-rich diets improve glucose metabolism in people at high cardiometabolic risk: a controlled randomised intervention trial. Diabetologia. 2015. 58:1551–60. doi:10.1007/s00125-015-3592-x 25906754 | Intervention/Exposure
302 | Brader, L, Uusitupa, M, Dragsted, LO, Hermansen, K. Effects of an isocaloric healthy Nordic diet on ambulatory blood pressure in metabolic syndrome: a randomized SYSDIET sub-study. Eur J Clin Nutr. 2014. 68:57–63. doi:10.1038/ejcn.2013.192 24129358 | Study Design; Publication Status
303 | Brader, L, Uusitupa, M, Hermansen, K. Beneficial effects of a Healthy Nordic diet on ambulatory blood pressure in subjects with the metabolic syndrome: a SYSDIET sub study. Obesity reviews. 2011. 12:230. doi:10.1111/j.1467-789X.2011.00889.x | Study Design; Intervention/Exposure; Publication Status
304 | Bradley, U, Spence, M, Courtney, CH, McKinley, MC, Ennis, CN, McCance, DR, McEneny, J, Bell, PM, Young, IS, Hunter, SJ. Low-fat versus low-carbohydrate weight reduction diets: effects on weight loss, insulin resistance, and cardiovascular risk: a randomized control trial. Diabetes. 2009. 58:2741–8. doi:10.2337/db09-0098 19720791 | Study duration
305 | Braha, K, Cupak, A, Pokrivcak, J, Qineti, A, Rizov, M. Economic analysis of the link between diet quality and health: Evidence from Kosovo. Econ Hum Biol. 2017. 27:261–274. doi:10.1016/j.ehb.2017.08.003 28930700 | Study Design; Outcome
306 | Brand-Miller, JC, Colagiuri, S, Gan, ST. Insulin sensitivity predicts glycemia after a protein load. Metabolism. 2000. 49:1–5. doi:10.1016/s0026-0495(00)90488-8 | Study duration
307 | Branis, NM, Etesami, M, Walker, RW, Berk, ES, Albu, JB. Effect of a 1-week, eucaloric, moderately high-fat diet on peripheral insulin sensitivity in healthy premenopausal women. BMJ Open Diabetes Res Care. 2015. 3:e000100. doi:10.1136/bmjdrc-2015-000100 | Study duration
308 | Brassard, D, Tessier-Grenier, M, Allaire, J, Rajendiran, E, She, Y, Ramprasath, V, Gigleux, I, Talbot, D, Levy, E, Tremblay, A, Jones, PJ, Couture, P, Lamarche, B. Comparison of the impact of SFAs from cheese and butter on cardiometabolic risk factors: a randomized controlled trial. Am J Clin Nutr. 2017. 105:800–809. doi:10.3945/ajcn.116.150300 28251937 | Intervention/Exposure; Comparator
309 | Bravo-Herrera, MD, Lopez-Miranda, J, Marin, C, Gomez, P, Gomez, MJ, Moreno, JA, Perez-Martinez, P, Blanco, A, Jimenez-Gomez, Y, Perez-Jimenez, F. Tissue factor expression is decreased in monocytes obtained from blood during Mediterranean or high carbohydrate diets. Nutr Metab Cardiovasc Dis. 2004. 14:128–32. doi:unavailable15330271 | Study duration
310 | Bray, GA, Champagne, CM. Dietary Patterns May Modify Central Adiposity. Journal of the American Dietetic Association. 2009. 109:1354–1355. doi:10.1016/j.jada.2009.05.013 19631040 | Publication Status
311 | Bray, GA, Lovejoy, JC, Most-Windhauser, M, Smith, SR, Volaufova, J, Denkins, Y, de Jonge, L, Rood, J, Lefevre, M, Eldridge, AL, Peters, JC. A 9-mo randomized clinical trial comparing fat-substituted and fat-reduced diets in healthy obese men: the Ole Study. Am J Clin Nutr. 2002. 76:928–34. doi:10.1093/ajcn/76.5.928 12399262 | Intervention/Exposure; Comparator
312 | Bray, GA, Redman, LM, de Jonge, L, Rood, J, Smith, SR. Effect of Three Levels of Dietary Protein on Metabolic Phenotype of Healthy Individuals With 8 Weeks of Overfeeding. J Clin Endocrinol Metab. 2016. 101:2836–43. doi:10.1210/jc.2016-1313 27159194 | Power/Size
313 | Bray, GA, Redman, LM, de Jonge, L, Rood, J, Sutton, EF, Smith, SR. Plasma Amino Acids During 8 Weeks of Overfeeding: Relation to Diet Body Composition and Fat Cell Size in the PROOF Study. Obesity (Silver Spring). 2018. 26:324–331. doi:10.1002/oby.22087 29280309 | Intervention/Exposure; Outcome
314 | Bray, GA, Ryan, DH, Johnson, W, Champagne, CM, Johnson, CM, Rood, J, Williamson, DA, Sacks, FM. Markers of dietary protein intake are associated with successful weight loss in the POUNDS Lost trial. Clin Obes. 2017. 7:166–175. doi:10.1111/cob.12188 28340516 | Weight loss/Hypocaloric
315 | Bray, GA, Smith, SR, de Jonge, L, Xie, H, Rood, J, Martin, CK, Most, M, Brock, C, Mancuso, S, Redman, LM. Effect of dietary protein content on weight gain, energy expenditure, and body composition during overeating: a randomized controlled trial. Jama. 2012. 307:47–55. doi:10.1001/jama.2011.1918 22215165 | Study duration
316 | Bray, GA, Smith, SR, DeJonge, L, de Souza, R, Rood, J, Champagne, CM, Laranjo, N, Carey, V, Obarzanek, E, Loria, CM, Anton, SD, Ryan, DH, Greenway, FL, Williamson, D, Sacks, FM. Effect of diet composition on energy expenditure during weight loss: the POUNDS LOST Study. Int J Obes (Lond). 2012. 36:448–55. doi:10.1038/ijo.2011.173 21946707 | Intervention/Exposure; Weight loss/Hypocaloric; Study duration
317 | Bray, GA, Vollmer, WM, Sacks, FM, Obarzanek, E, Svetkey, LP, Appel, LJ. A further subgroup analysis of the effects of the DASH diet and three dietary sodium levels on blood pressure: results of the DASH-Sodium Trial. Am J Cardiol. 2004. 94:222–7. doi:10.1016/j.amjcard.2004.03.070 15246908 | Study Design; Intervention/Exposure
318 | Brehm, BJ, Seeley, RJ, Daniels, SR, D’Alessio, DA. A randomized trial comparing a very low carbohydrate diet and a calorierestricted low fat diet on body weight and cardiovascular risk factors in healthy women. J Clin Endocrinol Metab. 2003. 88:1617–23. doi:10.1210/jc.2002-021480 12679447 | Power/Size
319 | Brehm, BJ, Spang, SE, Lattin, BL, Seeley, RJ, Daniels, SR, D’Alessio, DA. The role of energy expenditure in the differential weight loss in obese women on low-fat and low-carbohydrate diets. J Clin Endocrinol Metab. 2005. 90:1475–82. doi:10.1210/jc.2004-1540 15598683 | Power/Size
320 | Breitenbach, Z, Raposa, B, Szabó, Z, Polyák, É, Szűcs, Z, Kubányi, J, Figler, M. Examination of Hungarian college students’ eating habits, physical activity and body composition. European Journal of Integrative Medicine. 2016. 8:13–17. doi:10.1016/j.eujim.2016.11.007 | Study Design
321 | Brennan, IM, Luscombe-Marsh, ND, Seimon, RV, Otto, B, Horowitz, M, Wishart, JM, Feinle-Bisset, C. Effects of fat, protein, and carbohydrate and protein load on appetite, plasma cholecystokinin, peptide YY, and ghrelin, and energy intake in lean and obese men. Am J Physiol Gastrointest Liver Physiol. 2012. 303:G129–40. doi:10.1152/ajpgi.00478.2011 22556143 | Study duration
322 | Bril, N, Shelef, I, Schwarzfuchs, D, Serfaty, D, Gepner, Y, Lerner, M, Cohen, N, Shemesh, E, Tangi-Rosental, O, Sarusi, B, , . Acute diet induced thermogenesis (DIT), specific foods, and visceral adiposity. Clinical nutrition. 2013. 32:S24–S25. doi:unavailable | Publication Status
323 | Brinkworth, GD, Buckley, JD, Noakes, M, Clifton, PM. Renal function following long-term weight loss in individuals with abdominal obesity on a very-low-carbohydrate diet vs high-carbohydrate diet. J Am Diet Assoc. 2010. 110:633–8. doi:10.1016/j.jada.2009.12.016 20338292 | Weight loss/Hypocaloric
324 | Brinkworth, GD, Noakes, M, Buckley, JD, Keogh, JB, Clifton, PM. Long-term effects of a very-low-carbohydrate weight loss diet compared with an isocaloric low-fat diet after 12 mo. Am J Clin Nutr. 2009. 90:23–32. doi:10.3945/ajcn.2008.27326 19439458 | Weight loss/Hypocaloric
325 | Brinkworth, GD, Noakes, M, Keogh, JB, Luscombe, ND, Wittert, GA, Clifton, PM. Long-term effects of a high-protein, low-carbohydrate diet on weight control and cardiovascular risk markers in obese hyperinsulinemic subjects. Int J Obes Relat Metab Disord. 2004. 28:661–70. doi:10.1038/sj.ijo.0802617 15007396 | Power/Size
326 | Brito Beck da Silva, K, Leovigildo Fiaccone, R, Couto, RD, Ribeiro-Silva Rde, C. EVALUATION OF THE EFFECTS OF A PROGRAMME PROMOTING ADEQUATE AND HEALTHY EATING ON ADOLESCENT HEALTH MARKERS: AN INTERVENTIONAL STUDY. Nutr Hosp. 2015. 32:1582–90. doi:10.3305/nh.2015.32.4.9512 26545521 | Intervention/Exposure
327 | Brito Beck da Silva, K, Ortelan, N, Giardini Murta, S, Sartori, I, Couto, RD, Leovigildo Fiaccone, R, Lima Barreto, M, Jones Bell, M, Barr Taylor, C, Ribeiro-Silva, RC. Evaluation of the Computer-Based Intervention Program Stayingfit Brazil to Promote Healthy Eating Habits: The Results from a School Cluster-Randomized Controlled Trial. Int J Environ Res Public Health. 2019. 16:. doi:10.3390/ijerph16101674 | Intervention/Exposure; Outcome
328 | Brixval, CS, Andersen, LB, Heitmann, BL. Fat intake and weight development from 9 to 16 years of age: the European youth heart study - a longitudinal study. Obes Facts. 2009. 2:166–70. doi:10.1159/000219134 20054221 | Intervention/Exposure
329 | Brons, C, Jensen, CB, Storgaard, H, Hiscock, NJ, White, A, Appel, JS, Jacobsen, S, Nilsson, E, Larsen, CM, Astrup, A, Quistorff, B, Vaag, A. Impact of short-term high-fat feeding on glucose and insulin metabolism in young healthy men. J Physiol. 2009. 587:2387–97. doi:10.1113/jphysiol.2009.169078 19332493 | Study duration
330 | Brooking, LA, Williams, SM, Mann, JI. Effects of macronutrient composition of the diet on body fat in indigenous people at high risk of type 2 diabetes. Diabetes Res Clin Pract. 2012. 96:40–6. doi:10.1016/j.diabres.2011.11.021 22178004 | Study duration
331 | Brouwer-Brolsma, EM, van Lee, L, Streppel, MT, Sluik, D, van de Wiel, AM, de Vries, JHM, Geelen, A, Feskens, EJM. Nutrition Questionnaires plus (NQplus) study, a prospective study on dietary determinants and cardiometabolic health in Dutch adults. BMJ Open. 2018. 8:e020228. doi:10.1136/bmjopen-2017-020228 | Study Design; Outcome
332 | Brown, DL, Conley, KM, Sanchez, BN, Resnicow, K, Cowdery, JE, Sais, E, Murphy, J, Skolarus, LE, Lisabeth, LD, Morgenstern, LB. A Multicomponent Behavioral Intervention to Reduce Stroke Risk Factor Behaviors: The Stroke Health and Risk Education Cluster-Randomized Controlled Trial. Stroke. 2015. 46:2861–7. doi:10.1161/strokeaha.115.010678 26374480 | Intervention/Exposure
333 | Browning, JD, Baker, JA, Rogers, T, Davis, J, Satapati, S, Burgess, SC. Short-term weight loss and hepatic triglyceride reduction: evidence of a metabolic advantage with dietary carbohydrate restriction. Am J Clin Nutr. 2011. 93:1048–52. doi:10.3945/ajcn.110.007674 21367948 | Study duration
334 | Browning, JD, Davis, J, Saboorian, MH, Burgess, SC. A low-carbohydrate diet rapidly and dramatically reduces intrahepatic triglyceride content. Hepatology. 2006. 44:487–8. doi:10.1002/hep.21264 16871586 | Publication Status
335 | Brunerova, L, Smejkalova, V, Potockova, J, Andel, M. A comparison of the influence of a high-fat diet enriched in monounsaturated fatty acids and conventional diet on weight loss and metabolic parameters in obese non-diabetic and Type 2 diabetic patients. Diabet Med. 2007. 24:533–40. doi:10.1111/j.1464-5491.2007.02104.x 17381504 | Intervention/Exposure
336 | Bruno, E, Manoukian, S, Venturelli, E, Oliverio, A, Rovera, F, Iula, G, Morelli, D, Peissel, B, Azzolini, J, Roveda, E, Pasanisi, P. Adherence to Mediterranean Diet and Metabolic Syndrome in BRCA Mutation Carriers. Integr Cancer Ther. 2018. 17:153–160. doi:10.1177/1534735417721015 28741383 | Outcome
337 | Brynes, AE, Adamson, J, Dornhorst, A, Frost, GS. The beneficial effect of a diet with low glycaemic index on 24 h glucose profiles in healthy young people as assessed by continuous glucose monitoring. Br J Nutr. 2005. 93:179–82. doi:10.1079/bjn20041318 15788110 | Study duration
338 | Bucher Della Torre, S, Wild, P, Dorribo, V, Amati, F, Danuser, B. Eating Habits of Professional Firefighters: Comparison With National Guidelines and Impact Healthy Eating Promotion Program. J Occup Environ Med. 2019. 61:e183–e190. doi:10.1097/jom.0000000000001565 31268938 | Study Design
339 | Buckland, NJ, Camidge, D, Croden, F, Lavin, JH, Stubbs, RJ, Hetherington, MM, Blundell, JE, Finlayson, G. A Low Energy-Dense Diet in the Context of a Weight-Management Program Affects Appetite Control in Overweight and Obese Women. J Nutr. 2018. 148:798–806. doi:10.1093/jn/nxy041 30053284 | Intervention/Exposure
340 | Buendia, JR, Bradlee, ML, Singer, MR, Moore, LL. Diets higher in protein predict lower high blood pressure risk in Framingham Offspring Study adults. Am J Hypertens. 2015. 28:372–9. doi:10.1093/ajh/hpu157 25194158 | Outcome
341 | Bui, Q. Dietary fat modification and the risk of future cardiovascular events and mortality. Am Fam Physician. 2013. 87:609–10. doi:unavailable23668523 | Study Design; Publication Status
342 | Buijsse, B, Boeing, H, Drogan, D, Schulze, MB, Feskens, EJ, Amiano, P, Barricarte, A, Clavel-Chapelon, F, de Lauzon-Guillain, B, Fagherazzi, G, Fonseca-Nunes, A, Franks, PW, Huerta, JM, Jakobsen, MU, Kaaks, R, Key, TJ, Khaw, KT, Masala, G, Moskal, A, Nilsson, PM, Overvad, K, Pala, V, Panico, S, Redondo, ML, Ricceri, F, Rolandsson, O, Sanchez, MJ, Sluijs, I, Spijkerman, AM, Tjonneland, A, Tumino, R, van der, Dl A, van der Schouw, YT, Langenberg, C, Sharp, SJ, Forouhi, NG, Riboli, E, Wareham, NJ. Consumption of fatty foods and incident type 2 diabetes in populations from eight European countries. Eur J Clin Nutr. 2015. 69:455–61. doi:10.1038/ejcn.2014.249 25424603 | Intervention/Exposure
343 | Buijsse, B, Jacobs, DR, Jr, Steffen, LM, Kromhout, D, Gross, MD. Plasma Ascorbic Acid, A Priori Diet Quality Score, and Incident Hypertension: A Prospective Cohort Study. PLoS One. 2015. 10:e0144920. doi:10.1371/journal.pone.0144920 26683190 | Outcome
344 | Buil-Cosiales, P, Toledo, E, Salas-Salvadó, J, Zazpe, I, Farràs, M, Basterra-Gortari, FJ, Diez-Espino, J, Estruch, R, Corella, D, Ros, E, Marti, A, Gómez-Gracia, E, Ortega-Calvo, M, Arós, F, Moñino, M, Serra-Majem, L, Pintó, X, Lamuela-Raventós, RM, Babio, N, Gonzalez, JI, Fitó, M, Martínez-González, MA. Association between dietary fibre intake and fruit, vegetable or whole-grain consumption and the risk of CVD: Results from the PREvención con DIeta MEDiterránea (PREDIMED) trial. British Journal of Nutrition. 2016. 116:534–546. doi:10.1017/S0007114516002099 | Intervention/Exposure
345 | Buil-Cosiales, P, Zazpe, I, Toledo, E, Corella, D, Salas-Salvado, J, Diez-Espino, J, Ros, E, Fernandez-Creuet Navajas, J, Santos-Lozano, JM, Aros, F, Fiol, M, Castaner, O, Serra-Majem, L, Pinto, X, Lamuela-Raventos, RM, Marti, A, Basterra-Gortari, FJ, Sorli, JV, Verdu-Rotellar, JM, Basora, J, Ruiz-Gutierrez, V, Estruch, R, Martinez-Gonzalez, MA. Fiber intake and all-cause mortality in the Prevencion con Dieta Mediterranea (PREDIMED) study. Am J Clin Nutr. 2014. 100:1498–507. doi:10.3945/ajcn.114.093757 25411285 | Intervention/Exposure
346 | Bullo, M, Casas, R, Portillo, MP, Basora, J, Estruch, R, Garcia-Arellano, A, Lasa, A, Juanola-Falgarona, M, Aros, F, Salas-Salvado, J. Dietary glycemic index/load and peripheral adipokines and inflammatory markers in elderly subjects at high cardiovascular risk. Nutr Metab Cardiovasc Dis. 2013. 23:443–50. doi:10.1016/j.numecd.2011.09.009 22209741 | Outcome
347 | Bunyard, LB, Dennis, KE, Nicklas, BJ. Dietary intake and changes in lipoprotein lipids in obese, postmenopausal women placed on an American Heart Association Step 1 diet. J Am Diet Assoc. 2002. 102:52–7. doi:10.1016/s0002-8223(02)90016-7 11794502 | Study Design
348 | Burger, KN, Beulens, JW, Boer, JM, Spijkerman, AM, van der, Dl A. Dietary glycemic load and glycemic index and risk of coronary heart disease and stroke in Dutch men and women: the EPIC-MORGEN study. PLoS One. 2011. 6:e25955. doi:10.1371/journal.pone.0025955 21998729 | Intervention/Exposure
349 | Burgess, B, Raynor, HA, Tepper, BJ. PROP Nontaster Women Lose More Weight Following a Low-Carbohydrate Versus a Low-Fat Diet in a Randomized Controlled Trial. Obesity (Silver Spring). 2017. 25:1682–1690. doi:10.1002/oby.21951 28841772 | Intervention/Exposure; Comparator
350 | Burke, LE, Hudson, AG, Warziski, MT, Styn, MA, Music, E, Elci, OU, Sereika, SM. Effects of a vegetarian diet and treatment preference on biochemical and dietary variables in overweight and obese adults: a randomized clinical trial. Am J Clin Nutr. 2007. 86:588–96. doi:10.1093/ajcn/86.3.588 17823421 | Intervention/Exposure; Publication Date Overlaps with Existing Review
351 | Burke, LE, Styn, MA, Steenkiste, AR, Music, E, Warziski, M, Choo, J. A randomized clinical trial testing treatment preference and two dietary options in behavioral weight management: preliminary results of the impact of diet at 6 months--PREFER study. Obesity (Silver Spring). 2006. 14:2007–17. doi:10.1038/oby.2006.235 17135618 | Intervention/Exposure
352 | Burke, LE, Warziski, M, Styn, MA, Music, E, Hudson, AG, Sereika, SM. A randomized clinical trial of a standard versus vegetarian diet for weight loss: the impact of treatment preference. Int J Obes (Lond). 2008. 32:166–76. doi:10.1038/sj.ijo.0803706 17700579 | Intervention/Exposure; Publication Date Overlaps with Existing Review
353 | Burke, V, Beilin, LJ, Cutt, HE, Mansour, J, Williams, A, Mori, TA. A lifestyle program for treated hypertensives improved health-related behaviors and cardiovascular risk factors, a randomized controlled trial. J Clin Epidemiol. 2007. 60:133–41. doi:10.1016/j.jclinepi.2006.05.012 17208119 | Intervention/Exposure
354 | Burkhart, SJ, Pelly, FE. Dietary intake of athletes seeking nutrition advice at a major international competition. Nutrients. 2016. 8:. doi:10.3390/nu8100638 | Study Design
355 | Buscemi, S, Verga, S, Tranchina, MR, Cottone, S, Cerasola, G. Effects of hypocaloric very-low-carbohydrate diet vs. Mediterranean diet on endothelial function in obese women*. Eur J Clin Invest. 2009. 39:339–47. doi:10.1111/j.1365-2362.2009.02091.x 19302563 | Study duration
356 | Buschard, K, Thomassen, K, Lynge, E, Vejborg, I, Tjonneland, A, von Euler-Chelpin, M, Andersen, ZJ. Diabetes, diabetes treatment, and mammographic density in Danish Diet, Cancer, and Health cohort. Cancer Causes Control. 2017. 28:13–21. doi:10.1007/s10552-016-0829-z 27832382 | Intervention/Exposure
357 | Buteau-Poulin, D, Poirier, P, Despres, JP, Almeras, N. Assessing nutritional quality as a ‘vital sign’ of cardiometabolic health. Br J Nutr. 2019. 122:195–205. doi:10.1017/s0007114519001016 31182170 | Study Design
358 | Buyken, AE, Flood, V, Empson, M, Rochtchina, E, Barclay, AW, Brand-Miller, J, Mitchell, P. Carbohydrate nutrition and inflammatory disease mortality in older adults. Am J Clin Nutr. 2010. 92:634–43. doi:10.3945/ajcn.2010.29390 20573797 | Intervention/Exposure
359 | Byrne, DW, Rolando, LA, Aliyu, MH, McGown, PW, Connor, LR, Awalt, BM, Holmes, MC, Wang, L, Yarbrough, MI. Modifiable Healthy Lifestyle Behaviors: 10-Year Health Outcomes From a Health Promotion Program. Am J Prev Med. 2016. 51:1027–1037. doi:10.1016/j.amepre.2016.09.012 27866595 | Intervention/Exposure
360 | Cade, JE, Burley, VJ, Greenwood, DC. The UK Women’s Cohort Study: comparison of vegetarians, fish-eaters and meat-eaters. Public Health Nutr. 2004. 7:871–8. doi:unavailable15482612 | Intervention/Exposure
361 | Cai, J, Nuli, R, Zhang, Y, Zhang, Y, Abudusemaiti, M, Kadeer, A, Tian, X, Xiao, H. Association of Dietary Patterns with Type 2 Diabetes Mellitus among Middle-Aged Adults in Uygur Population of Xinjiang Region. J Nutr Sci Vitaminol (Tokyo). 2019. 65:362–374. doi:10.3177/jnsv.65.362 31474687 | Study Design
362 | Cai, J, Zhang, Y, Nuli, R, Zhang, Y, Abudusemaiti, M, Kadeer, A, Tian, X, Xiao, H. Interaction between dietary patterns and TCF7L2 polymorphisms on type 2 diabetes mellitus among Uyghur adults in Xinjiang Province, China. Diabetes Metab Syndr Obes. 2019. 12:239–255. doi:10.2147/dmso.S191759 30858716 | Study Design; Intervention/Exposure
363 | Cakir, M, Akbulut, UE, Okten, A. Association between Adherence to the Mediterranean Diet and Presence of Nonalcoholic Fatty Liver Disease in Children. Child Obes. 2016. 12:279–85. doi:10.1089/chi.2015.0197 26871614 | Study Design
364 | Calleja Fernandez, A, Vidal Casariego, A, Cano Rodriguez, I, Ballesteros Pomar, MD. One-year effectiveness of two hypocaloric diets with different protein/carbohydrate ratios in weight loss and insulin resistance. Nutr Hosp. 2012. 27:2093–101. doi:10.3305/nh.2012.27.6.6133 23588462 | Power/Size
365 | Camargo, A, Meneses, ME, Pérez-Martínez, P, Delgado-Lista, J, Rangel-Zúñiga, OA, Marín, C, Almadén, Y, Yubero-Serrano, EM, González-Guardia, L, Fuentes, F, Tinahones, FJ, Roche, HM, Malagón, MM, Pérez-Jiménez, F, López-Miranda, J. Dietary fat modifies lipid metabolism in the adipose tissue of metabolic syndrome patients. Genes and Nutrition. 2014. 9:. doi:10.1007/s12263-014-0409-3 | Outcome
366 | Cameron, JD, Riou, ME, Tesson, F, Goldfield, GS, Rabasa-Lhoret, R, Brochu, M, Doucet, E. The TaqIA RFLP is associated with attenuated intervention-induced body weight loss and increased carbohydrate intake in post-menopausal obese women. Appetite. 2013. 60:111–116. doi:10.1016/j.appet.2012.09.010 23032305 | Intervention/Exposure
367 | Camhi, SM, Crouter, SE, Hayman, LL, Must, A, Lichtenstein, AH. Lifestyle Behaviors in Metabolically Healthy and Unhealthy Overweight and Obese Women: A Preliminary Study. PLoS One. 2015. 10:e0138548. doi:10.1371/journal.pone.0138548 26383251 | Study Design; Intervention/Exposure
368 | Camhi, SM, Stefanick, ML, Katzmarzyk, PT, Young, DR. Metabolic syndrome and changes in body fat from a low-fat diet and/or exercise randomized controlled trial. Obesity (Silver Spring). 2010. 18:548–54. doi:10.1038/oby.2009.304 19798074 | Intervention/Exposure; Publication Date Overlaps with Existing Review
369 | Camhi, SM, Whitney Evans, E, Hayman, LL, Lichtenstein, AH, Must, A. Healthy eating index and metabolically healthy obesity in U.S. adolescents and adults. Prev Med. 2015. 77:23–7. doi:10.1016/j.ypmed.2015.04.023 25937589 | Study Design
370 | Caminhotto Rde, O, Fonseca, FL, Castro, NC, Arantes, JP, Sertie, RA. Atkins diet program rapidly decreases atherogenic index of plasma in trained adapted overweight men. Arch Endocrinol Metab. 2015. 59:568–71. doi:10.1590/2359-3997000000106 26421667 | Study duration
371 | Campbell, CP, Raubenheimer, D, Badaloo, AV, Gluckman, PD, Martinez, C, Gosby, A, Simpson, SJ, Osmond, C, Boyne, MS, Forrester, TE. Developmental contributions to macronutrient selection: a randomized controlled trial in adult survivors of malnutrition. Evol Med Public Health. 2016. 2016:158–69. doi:10.1093/emph/eov030 26817484 | Study duration; Health Status
372 | Campbell, DD, Meckling, KA. Effect of the protein:carbohydrate ratio in hypoenergetic diets on metabolic syndrome risk factors in exercising overweight and obese women. Br J Nutr. 2012. 108:1658–71. doi:10.1017/s0007114511007215 22243943 | Power/Size
373 | Campbell, EK, Fidahusain, M, Campbell Ii, TM. Evaluation of an Eight-Week Whole-Food Plant-Based Lifestyle Modification Program. Nutrients. 2019. 11:. doi:10.3390/nu11092068 | Study Design; Intervention/Exposure
374 | Campbell, TC. A plant-based diet and animal protein: questioning dietary fat and considering animal protein as the main cause of heart disease. J Geriatr Cardiol. 2017. 14:331–337. doi:10.11909/j.issn.1671-5411.2017.05.011 28630612 | Study Design
375 | Campbell, WW, Kim, JE, Amankwaah, AF, Gordon, SL, Weinheimer-Haus, EM. Higher Total Protein Intake and Change in Total Protein Intake Affect Body Composition but Not Metabolic Syndrome Indexes in Middle-Aged Overweight and Obese Adults Who Perform Resistance and Aerobic Exercise for 36 Weeks. J Nutr. 2015. 145:2076–83. doi:10.3945/jn.115.213595 26246322 | Intervention/Exposure
376 | Campbell, WW, O’Connor, LE, Li, J, Sayer, RD, Wright, AJ. Adopting, abandoning, and re-adopting healthy eating patterns sends cardiovascular disease risk factors on a rollercoaster ride. FASEB journal. 2017. 31:. doi:unavailable | Publication Status
377 | Campbell, WW, Tang, M. Protein intake, weight loss, and bone mineral density in postmenopausal women. J Gerontol A Biol Sci Med Sci. 2010. 65:1115–22. doi:10.1093/gerona/glq083 20605872 | Intervention/Exposure
378 | Campos-Nonato, I, Hernandez, L, Barquera, S. Effect of a High-Protein Diet versus Standard-Protein Diet on Weight Loss and Biomarkers of Metabolic Syndrome: A Randomized Clinical Trial. Obes Facts. 2017. 10:238–251. doi:10.1159/000471485 28601864 | Intervention/Exposure
379 | Can, AS, Uysal, C, Palaoglu, KE. Short term effects of a low-carbohydrate diet in overweight and obese subjects with low HDL-C levels. BMC Endocr Disord. 2010. 10:18. doi:10.1186/1472-6823-10-18 21062488 | Study Design
380 | Canfi, A, Gepner, Y, Schwarzfuchs, D, Golan, R, Shahar, DR, Fraser, D, Witkow, S, Greenberg, I, Sarusi, B, Vardi, H, Friger, M, Stampfer, MJ, Shai, I. Effect of changes in the intake of weight of specific food groups on successful body weight loss during a multi-dietary strategy intervention trial. J Am Coll Nutr. 2011. 30:491–501. doi:10.1080/07315724.2011.10719995 22331684 | Intervention/Exposure; Publication Date Overlaps with Existing Review
381 | Cano-Ibanez, N, Bueno-Cavanillas, A, Martinez-Gonzalez, MA, Salas-Salvado, J, Corella, D, Freixer, GL, Romaguera, D, Vioque, J, Alonso-Gomez, AM, Warnberg, J, Martinez, JA, Serra-Majem, L, Estruch, R, Tinahones, FJ, Lapetra, J, Pinto, X, Tur, JA, Garcia-Rios, A, Garcia-Molina, L, Delgado-Rodriguez, M, Matia-Martin, P, Daimiel, L, Martin-Sanchez, V, Vidal, J, Vazquez, C, Ros, E, Bartolome-Resano, J, Palau-Galindo, A, Portoles, O, Torres, L, Miquel, Fiol, Sanchez, MTC, Sorto-Sanchez, C, Moreno-Morales, N, Abete, I, Alvarez-Perez, J, Sacanella, E, Bernal-Lopez, MR, Santos-Lozano, JM, Fanlo-Maresma, M, Bouzas, C, Razquin, C, Becerra-Tomas, N, Ortega-Azorin, C, Limona R L, Morey, M, Roman-Macia, J, Goicolea-Guemez, L, Vazquez-Ruiz, Z, Barrubes, L, Fito, M, Gea, A. Effect of changes in adherence to Mediterranean diet on nutrient density after 1-year of follow-up: results from the PREDIMED-Plus Study. Eur J Nutr. 2019. :. doi:10.1007/s00394-019-02087-1 | Outcome
382 | Carbajo, MA, Castro, MJ, Kleinfinger, S, Gomez-Arenas, S, Ortiz-Solorzano, J, Wellman, R, Garcia-Ianza, C, Luque, E. Effects of a balanced energy and high protein formula diet (Vegestart complet(R)) vs. low-calorie regular diet in morbid obese patients prior to bariatric surgery (laparoscopic single anastomosis gastric bypass): a prospective, double-blind randomized study. Nutr Hosp. 2010. 25:939–48. doi:unavailable21519764 | Intervention/Exposure; Study duration; Health Status
383 | Cardel, M, Lemas, DJ, Jackson, KH, Friedman, JE, Fernandez, JR. Higher Intake of PUFAs Is Associated with Lower Total and Visceral Adiposity and Higher Lean Mass in a Racially Diverse Sample of Children. J Nutr. 2015. 145:2146–52. doi:10.3945/jn.115.212365 26269238 | Study Design
384 | Cardillo, S, Seshadri, P, Iqbal, N. The effects of a low-carbohydrate versus low-fat diet on adipocytokines in severely obese adults: three-year follow-up of a randomized trial. Eur Rev Med Pharmacol Sci. 2006. 10:99–106. doi:unavailable16875041 | Study duration; Health Status
385 | Cardoso, DA, Moreira, AS, de Oliveira, GM, Raggio Luiz, R, Rosa, G. A COCONUT EXTRA VIRGIN OIL-RICH DIET INCREASES HDL CHOLESTEROL AND DECREASES WAIST CIRCUMFERENCE AND BODY MASS IN CORONARY ARTERY DISEASE PATIENTS. Nutr Hosp. 2015. 32:2144–52. doi:10.3305/nh.2015.32.5.9642 26545671 | Health Status
386 | Carpentier, A, Zinman, B, Leung, N, Giacca, A, Hanley, AJ, Harris, SB, Hegele, RA, Lewis, GF. Free fatty acid-mediated impairment of glucose-stimulated insulin secretion in nondiabetic Oji-Cree individuals from the Sandy Lake community of Ontario, Canada: a population at very high risk for developing type 2 diabetes. Diabetes. 2003. 52:1485–95. doi:10.2337/diabetes.52.6.1485 12765961 | Study duration
387 | Carstens, MT, Goedecke, JH, Dugas, L, Evans, J, Kroff, J, Levitt, NS, Lambert, EV. Fasting substrate oxidation in relation to habitua dietary fat intake and insulin resistance in non-diabetic women: A case for metabolic flexibility?. Nutrition and Metabolism. 2013. 10:. doi:10.1186/1743-7075-10-8 | Study Design
388 | Carty, CL, Kooperberg, C, Neuhouser, ML, Tinker, L, Howard, B, Wactawski-Wende, J, Beresford, SA, Snetselaar, L, Vitolins, M, Allison, M, Budrys, N, Prentice, R, Peters, U. Low-fat dietary pattern and change in body-composition traits in the Women’s Health Initiative Dietary Modification Trial. Am J Clin Nutr. 2011. 93:516–24. doi:10.3945/ajcn.110.006395 21177798 | Publication Date Overlaps with Existing Review
389 | Casas, R, Sacanella, E, Urpí-Sardà, M, Corella, D, Castañer, O, Lamuela-Raventos, RM, Salas-Salvadó, J, Martínez-González, MA, Ros, E, Estruch, R. Long-Term Immunomodulatory Effects of a Mediterranean Diet in Adults at High Risk of Cardiovascular Disease in the PREvención con DIeta MEDiterránea (PREDIMED) Randomized Controlled Trial. Journal of nutrition. 2016. 146:1684–1693. doi:10.3945/jn.115.229476 | Study Design; Outcome
390 | Casazza, K, Cardel, M, Dulin-Keita, A, Hanks, LJ, Gower, BA, Newton, AL, Wallace, S. Reduced carbohydrate diet to improve metabolic outcomes and decrease adiposity in obese peripubertal African American girls. J Pediatr Gastroenterol Nutr. 2012. 54:336–42. doi:10.1097/MPG.0b013e31823df207 22067112 | Study duration
391 | Casazza, K, Dulin-Keita, A, Gower, BA, Fernandez, JR. Relationships between reported macronutrient intake and insulin dynamics in a multi-ethnic cohort of early pubertal children. Int J Pediatr Obes. 2009. 4:249–56. doi:10.3109/17477160902763366 19922039 | Study Design
392 | Casazza, K. A reduced carbohydrate diet results in loss in lean mass in peripubertal African American girls. FASEB journal. 2010. 24:. doi:unavailable | Publication Status
393 | Cases, J, Romain, C, Dallas, C, Gerbi, A, Cloarec, M. Regular consumption of Fiit-ns, a polyphenol extract from fruit and vegetables frequently consumed within the Mediterranean diet, improves metabolic ageing of obese volunteers: a randomized, double-blind, parallel trial. Int J Food Sci Nutr. 2015. 66:120–5. doi:10.3109/09637486.2014.971229 25358490 | Intervention/Exposure
394 | Cassady, BA, Charboneau, NL, Brys, EE, Crouse, KA, Beitz, DC, Wilson, T. Effects of low carbohydrate diets high in red meats or poultry, fish and shellfish on plasma lipids and weight loss. Nutr Metab (Lond). 2007. 4:23. doi:10.1186/1743-7075-4-23 17974023 | Study duration
395 | Cassani, RS, Fassini, PG, Silvah, JH, Lima, CM, Marchini, JS. Impact of weight loss diet associated with flaxseed on inflammatory markers in men with cardiovascular risk factors: a clinical study. Nutrition journal. 2015. 14:5. doi:10.1186/1475-2891-14-5 25577201 | Intervention/Exposure
396 | Castaldo, G, Monaco, L, Castaldo, L, Galdo, G, Cereda, E. An observational study of sequential protein-sparing, very low-calorie ketogenic diet (Oloproteic diet) and hypocaloric Mediterranean-like diet for the treatment of obesity. Int J Food Sci Nutr. 2016. 67:696–706. doi:10.1080/09637486.2016.1186157 27193396 | Study Design; Publication Status
397 | Castro, Mbtd, Araujo, MC, Barbosa Cunha, D, Bezerra, IN, Adegboye, ARA, Kac, G, Sichieri, R. Effect of high protein intake and nutritional advice on body weight maintainance among overweight and obese postpartum women. Annals of nutrition & metabolism. 2017. 71:845–846. doi:10.1159/000480486 | Publication Status
398 | Cataife, G. Small area estimation of obesity prevalence and dietary patterns: a model applied to Rio de Janeiro city, Brazil. Health Place. 2014. 26:47–52. doi:10.1016/j.healthplace.2013.12.004 24368257 | Study Design
399 | Catenacci, VA, Odgen, L, Phelan, S, Thomas, JG, Hill, J, Wing, RR, Wyatt, H. Dietary habits and weight maintenance success in high versus low exercisers in the National Weight Control Registry. J Phys Act Health. 2014. 11:1540–8. doi:10.1123/jpah.2012-0250 24385447 | Intervention/Exposure
400 | Cayanan, EA, Hoyos, CM, Djavadkhani, Y, Wong, KKW, Yee, BY, Phillips, C, Marshall, NS, Grunstein, RR. Effectiveness of two maintenance diets following a very vow energy diet to reduce cardio-metabolic risk in obese sleep apnea patients: a randomised controlled trial. Obesity reviews. 2016. 17:38-. doi:10.1111/obr.12400 | Publication Status
401 | Cayanan, EA, Marshall, NS, Hoyos, CM, Djavadkhani, Y, Yee, B, Wong, KK, Grunstein, RR. Effectiveness of two maintenance diets following a very low energy diet to reduce cardiometabolic risk in obese sleep apnea patients: a randomised controlled trial. Journal of sleep research. 2014. 23:68-. doi:10.1111/jsr.12213 | Publication Status
402 | Celis-Morales, C, Livingstone, KM, Affleck, A, Navas-Carretero, S, San-Cristobal, R, Martinez, JA, Marsaux, CFM, Saris, WHM, O’Donovan, CB, Forster, H, Woolhead, C, Gibney, ER, Walsh, MC, Brennan, L, Gibney, M, Moschonis, G, Lambrinou, CP, Mavrogianni, C, Manios, Y, Macready, AL, Fallaize, R, Lovegrove, JA, Kolossa, S, Daniel, H, Traczyk, I, Drevon, CA, Mathers, JC. Correlates of overall and central obesity in adults from seven European countries: findings from the Food4Me Study. Eur J Clin Nutr. 2018. 72:207–219. doi:10.1038/s41430-017-0004-y 29242527 | Study Design
403 | Cespedes, EM, Hu, FB, Redline, S, Rosner, B, Gillman, MW, Rifas-Shiman, SL, Taveras, EM. Chronic insufficient sleep and diet quality: Contributors to childhood obesity. Obesity (Silver Spring). 2016. 24:184–90. doi:10.1002/oby.21196 26592489 | Study Design; Outcome
404 | Chai, L, Collins, C, May, C, Holder, C, Brown, LJ, Burrows, T. An online telehealth nutrition intervention to support parents in child weight management - A randomised feasibility controlled trial. Obesity facts. 2019. 12:111–112. doi:10.1159/000489691 | Publication Status
405 | Champagne, CM, Bray, G, Sacks, F, Miketinas, D. Fiber intake, dietary energy density, and diet-type predict 6-month weight-loss in free-living adults who adhered to prescribed macronutrient and energy composition of varying diets. FASEB journal. 2017. 31:. doi:unavailable | Publication Status
406 | Champagne, CM, Broyles, ST, Moran, LD, Cash, KC, Levy, EJ, Lin, PH, Batch, BC, Lien, LF, Funk, KL, Dalcin, A, Loria, C, Myers, VH. Dietary intakes associated with successful weight loss and maintenance during the Weight Loss Maintenance trial. J Am Diet Assoc. 2011. 111:1826–35. doi:10.1016/j.jada.2011.09.014 22117658 | Weight loss/Hypocaloric
407 | Chan, R, Leung, J, Woo, J, Kwok, T. Associations of dietary protein intake on subsequent decline in muscle mass and physical functions over four years in ambulant older Chinese people. J Nutr Health Aging. 2014. 18:171–7. doi:10.1007/s12603-013-0379-y 24522470 | Intervention/Exposure; Country
408 | Chang, JJ, Bena, J, Kannan, S, Kim, J, Burguera, B, Kashyap, SR. LIMITED CARBOHYDRATE REFEEDING INSTRUCTION FOR LONG-TERM WEIGHT MAINTENANCE FOLLOWING A KETOGENIC, VERY-LOW-CALORIE MEAL PLAN. Endocr Pract. 2017. 23:649–656. doi:10.4158/ep161383.Or 28225305 | Intervention/Exposure
409 | Chang, L, Vethakkan, S, Nesaretnam, K, Teng, K. Effects of exchanging dietary saturated fatty acids or carbohydrate for monounsaturated fatty acids on inflammatory responses in abdominally obese Malaysians: a randomized controlled trial. Obesity reviews. 2014. 15:94-. doi:10.1111/obr.12149 | Publication Status
410 | Chang, LF, Vethakkan, SR, Nesaretnam, K, Sanders, TA, Teng, KT. Adverse effects on insulin secretion of replacing saturated fat with refined carbohydrate but not with monounsaturated fat: A randomized controlled trial in centrally obese subjects. J Clin Lipidol. 2016. 10:1431–1441.e1. doi:10.1016/j.jacl.2016.09.006 27919361 | Intervention/Exposure
411 | Chaparro, MP, Crespi, CM, Anderson, CE, Wang, MC, Whaley, SE. The 2009 Special Supplemental Nutrition Program for Women, Infants, and Children (WIC) food package change and children’s growth trajectories and obesity in Los Angeles County. Am J Clin Nutr. 2019. 109:1414–1421. doi:10.1093/ajcn/nqy347 31011750 | Intervention/Exposure
412 | Chaput, JP, Tremblay, A, Rimm, EB, Bouchard, C, Ludwig, DS. A novel interaction between dietary composition and insulin secretion: effects on weight gain in the Quebec Family Study. Am J Clin Nutr. 2008. 87:303–9. doi:10.1093/ajcn/87.2.303 18258618 | Intervention/Exposure
413 | Charkiewicz, AE, Jamiolkowski, J, Pedzinski, B, Krzyzak, M, Maslach, D, Szpak, A, Omeljaniuk, WJ. Changes in Dietary Patterns and the Nutritional Status in Men in the Metallurgical Industry in Poland Over A 21-Year Period. Ann Nutr Metab. 2018. 72:161–171. doi:10.1159/000485389 29466796 | Study Design; Comparator
414 | Chauveau, P, Vendrely, B, El Haggan, W, Barthe, N, Rigalleau, V, Combe, C, Aparicio, M. Body composition of patients on a very low-protein diet: a two-year survey with DEXA. J Ren Nutr. 2003. 13:282–7. doi:unavailable14566765 | Health Status
415 | Chavez Palencia, C, Larrosa Haro, A, Romero Velarde, E, Lopez-Uriarte, PJ. Efficacy of a modified carbohydrate diet in obese women. Annals of nutrition & metabolism. 2017. 71:1034–1035. doi:10.1159/000480486 | Publication Status
416 | Chee, C, Mansell, P, Stephens, F, Cordon, S, Kavani, M, Bawden, S, Hoad, C, Gowland, P, Macdonald, I. Differential effects of carbohydrate vs fat overfeeding on liver fat content and lipid metabolism in healthy overweight males. Diabetologia. 2015. 58:S336. doi:10.1007/s00125-015-3687-4 | Publication Status
417 | Chen, Q, Turban, S, Miller, ER, Appel, LJ. The effects of dietary patterns on plasma renin activity: results from the Dietary Approaches to Stop Hypertension trial. J Hum Hypertens. 2012. 26:664–9. doi:10.1038/jhh.2011.87 22048714 | Publication Date Overlaps with Existing Review
418 | Chen, ST, Maruthur, NM, Appel, LJ. The effect of dietary patterns on estimated coronary heart disease risk: results from the Dietary Approaches to Stop Hypertension (DASH) trial. Circ Cardiovasc Qual Outcomes. 2010. 3:484–9. doi:10.1161/circoutcomes.109.930685 20807884 | Intervention/Exposure; Publication Date Overlaps with Existing Review
419 | Chen, X, Pang, Z, Li, K. Dietary fat, sedentary behaviors and the prevalence of the metabolic syndrome among Qingdao adults. Nutr Metab Cardiovasc Dis. 2009. 19:27–34. doi:10.1016/j.numecd.2008.01.010 18472251 | Study Design; Country
420 | Chen, Y, Xiang, J, Wang, Z, Xiao, Y, Zhang, D, Chen, X, Li, H, Liu, M, Zhang, Q. Associations of Bone Mineral Density with Lean Mass, Fat Mass, and Dietary Patterns in Postmenopausal Chinese Women: A 2-Year Prospective Study. PLoS One. 2015. 10:e0137097. doi:10.1371/journal.pone.0137097 26335921 | Country
421 | Cheraghi, Z, Mirmiran, P, Mansournia, MA, Moslehi, N, Khalili, D, Nedjat, S. The association between nutritional exposures and metabolic syndrome in the Tehran Lipid and Glucose Study (TLGS): a cohort study. Public Health. 2016. 140:163–171. doi:10.1016/j.puhe.2016.07.003 27498945 | Intervention/Exposure; Outcome
422 | Cheraghi, Z, Nedjat, S, Mirmiran, P, Moslehi, N, Mansournia, N, Etminan, M, Mansournia, MA, McCandless, LC. Effects of food items and related nutrients on metabolic syndrome using Bayesian multilevel modelling using the Tehran Lipid and Glucose Study (TLGS): A cohort study. BMJ Open. 2018. 8:. doi:10.1136/bmjopen-2017-020642 | Intervention/Exposure
423 | Chiu, S, Bergeron, N, Williams, PT, Bray, GA, Sutherland, B, Krauss, RM. Comparison of the DASH (Dietary Approaches to Stop Hypertension) diet and a higher-fat DASH diet on blood pressure and lipids and lipoproteins: a randomized controlled trial. Am J Clin Nutr. 2016. 103:341–7. doi:10.3945/ajcn.115.123281 26718414 | Study duration
424 | Chiu, S, Williams, PT, Dawson, T, Bergman, RN, Stefanovski, D, Watkins, SM, Krauss, RM. Diets high in protein or saturated fat do not affect insulin sensitivity or plasma concentrations of lipids and lipoproteins in overweight and obese adults. J Nutr. 2014. 144:1753–9. doi:10.3945/jn.114.197624 25332473 | Study duration
425 | Chiu, TH, Huang, HY, Chiu, YF, Pan, WH, Kao, HY, Chiu, JP, Lin, MN, Lin, CL. Taiwanese vegetarians and omnivores: dietary composition, prevalence of diabetes and IFG. PLoS One. 2014. 9:e88547. doi:10.1371/journal.pone.0088547 24523914 | Study Design; Country
426 | Chiu, THT, Pan, WH, Lin, MN, Lin, CL. Vegetarian diet, change in dietary patterns, and diabetes risk: a prospective study. Nutr Diabetes. 2018. 8:12. doi:10.1038/s41387-018-0022-4 29549240 | Intervention/Exposure
427 | Chiu, YF, Hsu, CC, Chiu, TH, Lee, CY, Liu, TT, Tsao, CK, Chuang, SC, Hsiung, CA. Cross-sectional and longitudinal comparisons of metabolic profiles between vegetarian and non-vegetarian subjects: a matched cohort study. Br J Nutr. 2015. 114:1313–20. doi:10.1017/s0007114515002937 26355190 | Country
428 | Chiuve, SE, Sandhu, RK, Moorthy, MV, Glynn, RJ, Albert, CM. Dietary Fat Intake Is Differentially Associated with Risk of Paroxysmal Compared with Sustained Atrial Fibrillation in Women. J Nutr. 2015. 145:2092–101. doi:10.3945/jn.115.212860 26180251 | Intervention/Exposure; Outcome
429 | Choi, H, Song, S, Kim, J, Chung, J, Yoon, J, Paik, HY, Song, Y. High carbohydrate intake was inversely associated with high-density lipoprotein cholesterol among Korean adults. Nutr Res. 2012. 32:100–6. doi:10.1016/j.nutres.2011.12.013 22348458 | Study Design
430 | Choi, SE, Brandeau, ML, Basu, S. Expansion of the National Salt Reduction Initiative: A Mathematical Model of Benefits and Risks of Population-Level Sodium Reduction. Med Decis Making. 2016. 36:72–85. doi:10.1177/0272989x15583846 25926284 | Study Design; Intervention/Exposure
431 | Chomentowski, P, Dube, JJ, Amati, F, Stefanovic-Racic, M, Zhu, S, Toledo, FG, Goodpaster, BH. Moderate exercise attenuates the loss of skeletal muscle mass that occurs with intentional caloric restriction-induced weight loss in older, overweight to obese adults. J Gerontol A Biol Sci Med Sci. 2009. 64:575–80. doi:10.1093/gerona/glp007 19276190 | Intervention/Exposure; Comparator
432 | Chong, MF, Fielding, BA, Frayn, KN. Mechanisms for the acute effect of fructose on postprandial lipemia. Am J Clin Nutr. 2007. 85:1511–20. doi:10.1093/ajcn/85.6.1511 17556686 | Study duration
433 | Christie, C. Proposed Dietary Guidelines 2015 and Implications for Cardiovascular Disease and Diabetes. J Cardiovasc Nurs. 2015. 30:375–8. doi:10.1097/jcn.0000000000000286 26262915 | Study Design
434 | Chuang, SY, Chiu, TH, Lee, CY, Liu, TT, Tsao, CK, Hsiung, CA, Chiu, YF. Vegetarian diet reduces the risk of hypertension independent of abdominal obesity and inflammation: a prospective study. J Hypertens. 2016. 34:2164–71. doi:10.1097/hjh.0000000000001068 27512965 | Intervention/Exposure; Outcome; Country
435 | Chun, BO, Yun, ME, Kim, IM, Lee, JK. Effects of short-term training camp including aerobic exercise and vegetarian diet on body composition, physical fitness and blood biochemical parameters in collegians. Gazzetta Medica Italiana Archivio per le Scienze Mediche. 2017. 176:289–298. doi:10.23736/S0393-3660.16.03277-0 | Study duration
436 | Chung, GKK, Yu, RHY, Ho, SSY, Woo, J, Ho, SC. Associations of consuming specific fruit and vegetable subgroups with LDL-C status in early postmenopausal Chinese women. Menopause. 2018. 25:436–443. doi:10.1097/gme.0000000000001008 29088018 | Intervention/Exposure; Outcome; Country
437 | Chung, HV, Iversen, CS, Lai, M, Saka, S, Mahabub-ul Anwar, M, Nigg, CR. Omega-3 fatty acids from fish, other nutrient intake, and lifestyle factors: exploring the relationship in children. Asia Pac J Public Health. 2014. 26:517–26. doi:10.1177/1010539513485970 23666831 | Study Design; Intervention/Exposure
438 | Churm, R, Prior, SL, Stephens, JW, Caplin, S, Barry, J, Luzio, SD, Bracken, RM. The hepatic and metabolic impact of a three week hypocaloric diet in overweight patients: a pilot study. Diabetic medicine. 2017. 34:105–106. doi:10.1111/dme.13302 | Publication Status
439 | Claessens, M, van Baak, MA, Monsheimer, S, Saris, WH. The effect of a low-fat, high-protein or high-carbohydrate ad libitum diet on weight loss maintenance and metabolic risk factors. Int J Obes (Lond). 2009. 33:296–304. doi:10.1038/ijo.2008.278 19153580 | Intervention/Exposure
440 | Clamp, LD, Hume, DJ, Lambert, EV, Kroff, J. Successful and unsuccessful weight-loss maintainers: strategies to counteract metabolic compensation following weight loss. J Nutr Sci. 2018. 7:e20. doi:10.1017/jns.2018.11 29988905 | Intervention/Exposure; Study duration
441 | Clark, RL, Famodu, OA, Holaskova, I, Infante, AM, Murray, PJ, Olfert, IM, McFadden, JW, Downes, MT, Chantler, PD, Duespohl, MW, Cuff, CF, Olfert, MD. Educational intervention improves fruit and vegetable intake in young adults with metabolic syndrome components. Nutr Res. 2019. 62:89–100. doi:10.1016/j.nutres.2018.11.010 30803510 | Study Design
442 | Clarys, P, Deriemaeker, P, Huybrechts, I, Hebbelinck, M, Mullie, P. Dietary pattern analysis: a comparison between matched vegetarian and omnivorous subjects. Nutr J. 2013. 12:82. doi:10.1186/1475-2891-12-82 23758767 | Study Design
443 | Clemente-Postigo, M, Queipo-OrtunoBoto-Ordonez, MI, Coin-Araguez, L, Roca-Rodriguez, MM, Delgado-Lista, J, Cardona, F, Andres-Lacueva, C, Tinahones, FJ. The effect of acute and chronic red wine consumption on lipopolysaccharide concentrations. Journal of diabetes. 2013. 5:73. doi:10.1111/1753-0407.12032 | Publication Status
444 | Clifton, PM, Keogh, JB, Foster, PR, Noakes, M. Effect of weight loss on inflammatory and endothelial markers and FMD using two low-fat diets. Int J Obes (Lond). 2005. 29:1445–51. doi:10.1038/sj.ijo.0803039 16172619 | Intervention/Exposure
445 | Clifton, PM, Keogh, JB, Noakes, M. Long-term effects of a high-protein weight-loss diet. Am J Clin Nutr. 2008. 87:23–9. doi:10.1093/ajcn/87.1.23 18175733 | Weight loss/Hypocaloric
446 | Clifton, PM, Noakes, M, Keogh, J, Foster, P. Effect of an energy reduced high protein red meat diet on weight loss and metabolic parameters in obese women. Asia pacific journal of clinical nutrition. 2003. 12 Suppl:S10. doi:unavailable | Intervention/Exposure; Publication Status
447 | Clifton, PM, Noakes, M, Keogh, JB. Very low-fat (12%) and high monounsaturated fat (35%) diets do not differentially affect abdominal fat loss in overweight, nondiabetic women. J Nutr. 2004. 134:1741–5. doi:10.1093/jn/134.7.1741 15226463 | Intervention/Exposure
448 | Clifton, PM, Turner, K, Keogh, JB. Effect of lean red meat and dairy on insulin sensitivity. Diabetes. 2015. 64:A23. doi:10.2337/db151385 | Publication Status
449 | Clinton, CM, O’Brien, S, Law, J, Renier, CM, Wendt, MR. Whole-foods, plant-based diet alleviates the symptoms of osteoarthritis. Arthritis. 2015. 2015:708152. doi:10.1155/2015/708152 25815212 | Outcome
450 | Cohen, J, Rimm, EB, Martínez-González, MA, Salas-Salvadó, J, Covas, MI, Corella, D, Lamuela-Raventós, RM, Estruch, R. The association between obesity status and long-term adherence to mediterranean diet in the predimed trial. Circulation. 2013. 127:. doi:unavailable | Publication Status
451 | Cohen, JF, Kraak, VI, Choumenkovitch, SF, Hyatt, RR, Economos, CD. The CHANGE study: a healthy-lifestyles intervention to improve rural children’s diet quality. J Acad Nutr Diet. 2014. 114:48–53. doi:10.1016/j.jand.2013.08.014 24126295 | Intervention/Exposure; Outcome
452 | Coleman, MD, Nickols-Richardson, SM. Urinary ketones reflect serum ketone concentration but do not relate to weight loss in overweight premenopausal women following a low-carbohydrate/high-protein diet. J Am Diet Assoc. 2005. 105:608–11. doi:10.1016/j.jada.2005.01.004 15800565 | Study Design; Outcome
453 | Coles, LT, Fletcher, EA, Galbraith, CE, Clifton, PM. Patient freedom to choose a weight loss diet in the treatment of overweight and obesity: a randomized dietary intervention in type 2 diabetes and pre-diabetes. Int J Behav Nutr Phys Act. 2014. 11:64. doi:10.1186/1479-5868-11-64 24886191 | Intervention/Exposure; Health Status
454 | Coletta, AM, Sanchez, B, O’Connor, A, Dalton, R, Springer, S, Koozehchian, MS, Murano, PS, Woodman, CR, Rasmussen, C, Kreider, RB. Alignment of diet prescription to genotype does not promote greater weight loss success in women with obesity participating in an exercise and weight loss program. Obes Sci Pract. 2018. 4:554–574. doi:10.1002/osp4.305 30574349 | Study Design; Intervention/Exposure
455 | Colette, C, Percheron, C, Pares-Herbute, N, Michel, F, Pham, TC, Brillant, L, Descomps, B, Monnier, L. Exchanging carbohydrates for monounsaturated fats in energy-restricted diets: effects on metabolic profile and other cardiovascular risk factors. Int J Obes Relat Metab Disord. 2003. 27:648–56. doi:10.1038/sj.ijo.0802299 12833107 | Study duration
456 | Colica, C, Merra, G, Gasbarrini, A, De Lorenzo, A, Cioccoloni, G, Gualtieri, P, Perrone, MA, Bernardini, S, Bernardo, V, Di Renzo, L, Marchetti, M. Efficacy and safety of very-low-calorie ketogenic diet: a double blind randomized crossover study. Eur Rev Med Pharmacol Sci. 2017. 21:2274–2289. doi:unavailable28537652 | Study duration
457 | Colombo, C, Muti, P, Pala, V, Cavalleri, A, Venturelli, E, Locardi, M, Berrino, F, Secreto, G. Plant-based diet, serum fatty acid profile, and free radicals in postmenopausal women: the diet and androgens (DIANA) randomized trial. Int J Biol Markers. 2005. 20:169–76. doi:unavailable16240844 | Intervention/Exposure
458 | Conlin, PR, Chow, D, Miller, ER, 3rd, Svetkey, LP, Lin, PH, Harsha, DW, Moore, TJ, Sacks, FM, Appel, LJ. The effect of dietary patterns on blood pressure control in hypertensive patients: results from the Dietary Approaches to Stop Hypertension (DASH) trial. Am J Hypertens. 2000. 13:949–55. doi:10.1016/s0895-7061(99)00284-8 10981543 | Intervention/Exposure
459 | Cook, CM, McCormick, CN, Knowles, M, Kaden, VN. A Commercially Available Portion-Controlled Diet Program Is More Effective for Weight Loss than a Self-Directed Diet: Results from a Randomized Clinical Trial. Front Nutr. 2017. 4:55. doi:10.3389/fnut.2017.00055 29164129 | Intervention/Exposure
460 | Cooper, JA, Watras, AC, Adams, AK, Schoeller, DA. Effects of dietary fatty acid composition on 24-h energy expenditure and chronic disease risk factors in men. Am J Clin Nutr. 2009. 89:1350–6. doi:10.3945/ajcn.2008.27419 19321562 | Study duration
461 | Cooper, JA, Watras, AC, Shriver, T, Adams, AK, Schoeller, DA. Influence of dietary fatty acid composition and exercise on changes in fat oxidation from a high-fat diet. J Appl Physiol (1985). 2010. 109:1011–8. doi:10.1152/japplphysiol.01025.2009 20651220 | Study duration
462 | Corella, D, Coltell, O, Ortega-Azorin, C, Portoles, O, Barragan, R, Saez-Tormo, G, Burguete, C, Castello, A, Ordovas, JM, Sorli, JV. FNDC5 polymorphisms and cardiovascular risk factors and disease. Modulation by Mediterranean diet and physical activity. Annals of nutrition and metabolism. 2015. 67:286–287. doi:10.1159/000440895 | Publication Status
463 | Corella, D, Ortega-Azorín, C, Sorlí, JV, Portolés, O, Asensio, EM, Saiz, C, Osma, R, Guillem-Saiz, P, González, JI, Coltell, O. Mediterranean diet, adiponectin levels, genetic polymorphisms and incidence of cardiovascular diseases in the predimedvalencia study. Cardiology (switzerland). 2014. 128:64-. doi:10.1159/000365062 | Publication Status
464 | Corella, D. Mediterranean diet and cardiovascular health: teachings of the PREDIMED study. Advances in nutrition (bethesda, md.). 2014. 5:330S–336S. doi:10.3945/an.113.005389 | Study Design
465 | Cormier, H, Thifault, E, Garneau, V, Tremblay, A, Drapeau, V, Perusse, L, Vohl, MC. Association between yogurt consumption, dietary patterns, and cardio-metabolic risk factors. Eur J Nutr. 2016. 55:577–587. doi:10.1007/s00394-015-0878-1 25772635 | Intervention/Exposure; Comparator
466 | Cornier, MA, Bergman, BC, Bessesen, DH. The effects of short-term overfeeding on insulin action in lean and reduced-obese individuals. Metabolism: Clinical and Experimental. 2006. 55:1207–1214. doi:10.1016/j.metabol.2006.05.003 16919540 | Study duration
467 | Cornier, MA, Donahoo, WT, Pereira, R, Gurevich, I, Westergren, R, Enerback, S, Eckel, PJ, Goalstone, ML, Hill, JO, Eckel, RH, Draznin, B. Insulin sensitivity determines the effectiveness of dietary macronutrient composition on weight loss in obese women. Obes Res. 2005. 13:703–9. doi:10.1038/oby.2005.79 15897479 | Intervention/Exposure
468 | Corsino, L, Rocha-Goldberg, MP, Batch, BC, Ortiz-Melo, DI, Bosworth, HB, Svetkey, LP. The Latino Health Project: Pilot testing a culturally adapted behavioral weight loss intervention in obese and overweight Latino adults. Ethnicity and Disease. 2012. 22:51–57. doi:unavailable22774309 | Study Design; Intervention/Exposure; Outcome
469 | Cosgrove, K, Johnston, CS. Examining the Impact of Adherence to a Vegan Diet on Acid-Base Balance in Healthy Adults. Plant Foods Hum Nutr. 2017. 72:308–313. doi:10.1007/s11130-017-0620-7 28677099 | Study duration
470 | Costa, MB, Ferreira, SR, Franco, LJ, Gimeno, SG, Iunes, M. Dietary patterns in a high-risk population for glucose intolerance. Japanese-Brazilian Diabetes Study Group. J Epidemiol. 2000. 10:111–7. doi:10.2188/jea.10.111 10778035 | Study Design
471 | Costa, S, Pinto, A, Santos, AC, Oliveira, A. The association of problematic eating behaviours with food quality and body mass index at 7 years of age. Eur J Clin Nutr. 2019. 73:549–557. doi:10.1038/s41430-018-0169-z 29748660 | Intervention/Exposure
472 | Couch, SC, Saelens, BE, Hinn, K, Dart, KB, Khoury, P, Mitsnefes, M, Daniels, SR, Urbina, EM. Effects of a clinic-initiated behavioral nutrition intervention emphasizing the dash diet on blood pressure control in adolescents with elevated blood pressure. Journal of the american society of hypertension. 2014. 8:e116. doi:10.1016/j.jash.2014.03.262 | Publication Status
473 | Couch, SC, Saelens, BE, Levin, L, Dart, K, Falciglia, G, Daniels, SR. The efficacy of a clinic-based behavioral nutrition intervention emphasizing a DASH-type diet for adolescents with elevated blood pressure. J Pediatr. 2008. 152:494–501. doi:10.1016/j.jpeds.2007.09.022 18346503 | Intervention/Exposure; Publication Date Overlaps with Existing Review
474 | Couch, SC, Saelens, BE. Factors Associated with Pediatric Hypertension in Mexico. Journal of the American Dietetic Association. 2009. 109:992–995. doi:10.1016/j.jada.2009.03.015 19465180 | Study Design; Publication Status
475 | Courie, R, Gaillard, M, Lainas, P, Hansel, B, Naveau, S, Dagher, I, Tranchart, H. Weight outcome after 2 years of a diet that excludes six processed foods: exploratory study of the “1,2,3 diet” in a moderately obese population. Diabetes Metab Syndr Obes. 2018. 11:345–355. doi:10.2147/dmso.S165598 30034246 | Study Design; Intervention/Exposure
476 | Coyle, EF, Jeukendrup, AE, Oseto, MC, Hodgkinson, BJ, Zderic, TW. Low-fat diet alters intramuscular substrates and reduces lipolysis and fat oxidation during exercise. Am J Physiol Endocrinol Metab. 2001. 280:E391–8. doi:10.1152/ajpendo.2001.280.3.E391 11171592 | Study duration
477 | Craig, LC, McNeill, G, Macdiarmid, JI, Masson, LF, Holmes, BA. Dietary patterns of school-age children in Scotland: association with socio-economic indicators, physical activity and obesity. Br J Nutr. 2010. 103:319–34. doi:10.1017/s0007114509991942 19835641 | Study Design
478 | Crane, MM, Jeffery, RW, Sherwood, NE. Exploring Gender Differences in a Randomized Trial of Weight Loss Maintenance. Am J Mens Health. 2017. 11:369–375. doi:10.1177/1557988316681221 27923968 | Intervention/Exposure
479 | Crichton, GE, Alkerwi, A. Dairy food intake is positively associated with cardiovascular health: findings from Observation of Cardiovascular Risk Factors in Luxembourg study. Nutr Res. 2014. 34:1036–44. doi:10.1016/j.nutres.2014.04.002 25476191 | Intervention/Exposure
480 | Crujeiras, A, Bellido, D, Sajoux, I, Moreno, B, Casanueva, F. Comparison of a very low-calorie-ketogenic diet with a standard low-calorie diet in the treatment of obesity: values at 24 months of treatment. Obesity facts. Conference: european obesity summit (EOS): 1st joint congress of EASO and IFSO-EC. Gothenburg sweden. Conference start: 20160601. Conference end: 20160604. Conference publication: (var.pagings). 2016. 9:253. doi:10.1159/000446744 | Publication Status
481 | Cuenca-Garcia, M, Ortega, FB, Ruiz, JR, Gonzalez-Gross, M, Labayen, I, Jago, R, Martinez-Gomez, D, Dallongeville, J, Bel-Serrat, S, Marcos, A, Manios, Y, Breidenassel, C, Widhalm, K, Gottrand, F, Ferrari, M, Kafatos, A, Molnar, D, Moreno, LA, De Henauw, S, Castillo, MJ, Sjostrom, M. Combined influence of healthy diet and active lifestyle on cardiovascular disease risk factors in adolescents. Scand J Med Sci Sports. 2014. 24:553–62. doi:10.1111/sms.12022 23237548 | Study Design
482 | Cueto-Galan, R, Baron, FJ, Valdivielso, P, Pinto, X, Corbella, E, Gomez-Gracia, E, Warnberg, J. Changes in fatty liver index after consuming a Mediterranean diet: 6-year follow-up of the PREDIMED-Malaga trial. Med Clin (Barc). 2017. 148:435–443. doi:10.1016/j.medcli.2016.11.032 28126231 | Outcome
483 | Culling, KS, Neil, HA, Gilbert, M, Frayn, KN. Effects of short-term low- and high-carbohydrate diets on postprandial metabolism in non-diabetic and diabetic subjects. Nutr Metab Cardiovasc Dis. 2009. 19:345–51. doi:10.1016/j.numecd.2007.09.003 18083355 | Study duration
484 | Cunha, DB, da Costa, THM, da Veiga, GV, Pereira, RA, Sichieri, R. Ultra-processed food consumption and adiposity trajectories in a Brazilian cohort of adolescents: ELANA study. Nutr Diabetes. 2018. 8:28. doi:10.1038/s41387-018-0043-z 29795367 | Intervention/Exposure
485 | Czekajlo, A, Rozanska, D, Zatonska, K, Szuba, A, Regulska-Ilow, B. Association between dietary patterns and cardiovascular risk factors in a selected population of Lower Silesia (PURE Study Poland). Ann Agric Environ Med. 2018. 25:635–641. doi:10.26444/aaem/76321 30586977 | Study Design
486 | da Costa, TH, Reis, CE, da Silva, FV, Casulari, LA. Improvement in metabolic parameters in obese subjects after 16 weeks on a Brazilian-staple calorie-restricted diet. Nutr Res Pract. 2014. 8:410–6. doi:10.4162/nrp.2014.8.4.410 25110561 | Weight loss/Hypocaloric
487 | da Silva, SM, Luiz, RR, Pereira, RA. Risk and protection factors for cardiovascular diseases among adults of Cuiaba, Mato Grosso, Brazil. Rev Bras Epidemiol. 2015. 18:425–38. doi:10.1590/1980-5497201500020011 26083513 | Study Design
488 | Dabbagh-Moghaddam, A, Kamali, M, Hojjati, A, Foroughi, M, Ghiasvand, R, Askari, G, Hosseinzadeh, J. The Relationship between Dietary Patterns with Blood Pressure in Iranian Army Staffs. Adv Biomed Res. 2018. 7:127. doi:10.4103/abr.abr_35_18 30310775 | Study Design
489 | Dahlman, I, Linder, K, Arvidsson Nordstrom, E, Andersson, I, Liden, J, Verdich, C. Changes in adipose tissue gene expression with energy-restricted diets in obese women Am J Clin Nutr. 2005 Sep;82(3): 709. American journal of clinical nutrition. 2005. 81:1275-1285. doi:unavailable | Study duration
490 | Dai, J, Krasnow, RE, Reed, T. Midlife moderation-quantified healthy diet and 40-year mortality risk from CHD: the prospective National Heart, Lung, and Blood Institute Twin Study. Br J Nutr. 2016. 116:326–34. doi:10.1017/s0007114516001914 27188259 | Power/Size
491 | Dallas Hall, W, Feng, Z, George, VA, Lewis, CE, Oberman, A, Huber, M, Fouad, M, Cutler, JA. Low-fat diet: Effect on athropometrics, blood pressure, glucose, and insulin in older women. Ethnicity and Disease. 2003. 13:337–343. doi:unavailable12894958 | Intervention/Exposure
492 | Dalle Grave, R, Calugi, S, Gavasso, I, El Ghoch, M, Marchesini, G. A randomized trial of energy-restricted high-protein versus high-carbohydrate, low-fat diet in morbid obesity. Obesity (Silver Spring). 2013. 21:1774–81. doi:10.1002/oby.20320 23408532 | Intervention/Exposure
493 | Dalzill, C, Nigam, A, Juneau, M, Guilbeault, V, Latour, E, Mauriege, P, Gayda, M. Intensive lifestyle intervention improves cardiometabolic and exercise parameters in metabolically healthy obese and metabolically unhealthy obese individuals. Can J Cardiol. 2014. 30:434–40. doi:10.1016/j.cjca.2013.11.033 24561010 | Study Design; Intervention/Exposure
494 | Damasceno, NR, Sala-Vila, A, Cofan, M, Perez-Heras, AM, Fito, M, Ruiz-Gutierrez, V, Martinez-Gonzalez, MA, Corella, D, Aros, F, Estruch, R, Ros, E. Mediterranean diet supplemented with nuts reduces waist circumference and shifts lipoprotein subfractions to a less atherogenic pattern in subjects at high cardiovascular risk. Atherosclerosis. 2013. 230:347–53. doi:10.1016/j.atherosclerosis.2013.08.014 24075767 | Outcome; Publication Date Overlaps with Existing Review
495 | Damsgaard, CT, Dalskov, SM, Laursen, RP, Ritz, C, Hjorth, MF, Lauritzen, L, Sorensen, LB, Petersen, RA, Andersen, MR, Stender, S, Andersen, R, Tetens, I, Molgaard, C, Astrup, A, Michaelsen, KF. Provision of healthy school meals does not affect the metabolic syndrome score in 8-11-year-old children, but reduces cardiometabolic risk markers despite increasing waist circumference. Br J Nutr. 2014. 112:1826–36. doi:10.1017/s0007114514003043 25323030 | Intervention/Exposure
496 | Damsgaard, CT, Papadaki, A, Jensen, SM, Ritz, C, Dalskov, SM, Hlavaty, P, Saris, WH, Martinez, JA, Handjieva-Darlenska, T, Andersen, MR, Stender, S, Larsen, TM, Astrup, A, Molgaard, C, Michaelsen, KF. Higher protein diets consumed ad libitum improve cardiovascular risk markers in children of overweight parents from eight European countries. J Nutr. 2013. 143:810–7. doi:10.3945/jn.112.173427 23596158 | Intervention/Exposure
497 | D’Anci, KE, Watts, KL, Kanarek, RB, Taylor, HA. Low-carbohydrate weight-loss diets. Effects on cognition and mood. Appetite. 2009. 52:96–103. doi:10.1016/j.appet.2008.08.009 18804129 | Outcome; Study duration
498 | Daniels, SR. DASH to stop metabolic syndrome. Journal of Pediatrics. 2016. 174:1–3. doi:10.1016/j.jpeds.2016.05.040 | Publication Status
499 | Daniuseviciute-Brazaite, L, Abromaitiene, L. Evaluation of students’ dietary behaviours depending on gender. Progress in Nutrition. 2018. 20:21–29. doi:10.23751/pn.v20i1.6247 | Study Design; Intervention/Exposure
500 | Dansinger, ML, Gleason, JA, Griffith, JL, Selker, HP, Schaefer, EJ. Comparison of the Atkins, Ornish, Weight Watchers, and Zone diets for weight loss and heart disease risk reduction: a randomized trial. Jama. 2005. 293:43–53. doi:10.1001/jama.293.1.43 15632335 | Weight loss/Hypocaloric
501 | Darakhshan, F, Pelloux, V, Rouault, C, Laromiguiere, M, Debrus, G, Massiera, F, Basdevant, A, Clément, K, Rizkalla, SW. Effect of a high-protein-low-glycaemic-index hypocaloric diet on adiposity markers, cardiovascular and metabolic risk factors: a randomised controlled trial. Diabetes. 2010. :. doi:unavailable | Publication Status
502 | Das, SK, Roberts, SB, Bhapkar, MV, Villareal, DT, Fontana, L, Martin, CK, Racette, SB, Fuss, PJ, Kraus, WE, Wong, WW, Saltzman, E, Pieper, CF, Fielding, RA, Schwartz, AV, Ravussin, E, Redman, LM. Body-composition changes in the Comprehensive Assessment of Long-term Effects of Reducing Intake of Energy (CALERIE)-2 study: a 2-y randomized controlled trial of calorie restriction in nonobese humans. Am J Clin Nutr. 2017. 105:913–927. doi:10.3945/ajcn.116.137232 28228420 | Intervention/Exposure
503 | Dashti, HM, Al-Zaid, NS, Mathew, TC, Al-Mousawi, M, Talib, H, Asfar, SK, Behbahani, AI. Long term effects of ketogenic diet in obese subjects with high cholesterol level. Mol Cell Biochem. 2006. 286:1–9. doi:10.1007/s11010-005-9001-x 16652223 | Study Design; Intervention/Exposure
504 | Dashti, HM, Bo-Abbas, YY, Asfar, SK, Mathew, TC, Hussein, T, Behbahani, A, Khoursheed, MA, Al-Sayer, HM, Al-Zaid, NS. Ketogenic diet modifies the risk factors of heart disease in obese patients. Nutrition. 2003. 19:901–2. doi:10.1016/s0899-9007(03)00161-8 14559328 | Intervention/Exposure
505 | Dashti, HM, Mathew, TC, Hussein, T, Asfar, SK, Behbahani, A, Khoursheed, MA, Al-Sayer, HM, Bo-Abbas, YY, Al-Zaid, NS. Long-term effects of a ketogenic diet in obese patients. Exp Clin Cardiol. 2004. 9:200–5. doi:unavailable19641727 | Study Design; Intervention/Exposure
506 | Datta Banik, S, Andrade Olalde, AC, Rodriguez, L, Dickinson, F. The effect of socioeconomic indicators and macronutrient intake rate on body composition in adolescents 12 to 16 years old in Merida, Yucatan. Anthropol Anz. 2014. 71:347–68. doi:10.1127/0003-5548/2014/0402 25775454 | Study Design
507 | Dauchet, L, Kesse-Guyot, E, Czernichow, S, Bertrais, S, Estaquio, C, Peneau, S, Vergnaud, AC, Chat-Yung, S, Castetbon, K, Deschamps, V, Brindel, P, Hercberg, S. Dietary patterns and blood pressure change over 5-y follow-up in the SU.VI.MAX cohort. Am J Clin Nutr. 2007. 85:1650–6. doi:10.1093/ajcn/85.6.1650 17556705 | Publication Date Overlaps with Existing Review
508 | D’Auria, E, Fabiano, V, Bertoli, S, Bedogni, G, Bosetti, A, Pendezza, E, Sartorio, MUA, Leone, A, Spadafranca, A, Borsani, B, Stucchi, F, Battezzati, A, Zuccotti, GV. Growth Pattern, Resting Energy Expenditure, and Nutrient Intake of Children with Food Allergies. Nutrients. 2019. 11:. doi:10.3390/nu11020212 | Study Design
509 | Davis, JN, Kelly, LA, Lane, CJ, Ventura, EE, Byrd-Williams, CE, Alexandar, KA, Azen, SP, Chou, CP, Spruijt-Metz, D, Weigensberg, MJ, Berhane, K, Goran, MI. Randomized control trial to improve adiposity and insulin resistance in overweight Latino adolescents. Obesity (Silver Spring). 2009. 17:1542–8. doi:10.1038/oby.2009.19 19247280 | Intervention/Exposure
510 | Davis, JN, Ventura, EE, Alexander, KE, Salguero, LE, Weigensberg, MJ, Crespo, NC, Spruijt-Metz, D, Goran, MI. Feasibility of a home-based versus classroom-based nutrition intervention to reduce obesity and type 2 diabetes in Latino youth. Int J Pediatr Obes. 2007. 2:22–30. doi:10.1080/17477160601133077 17763007 | Intervention/Exposure
511 | de Castro, MB, Kac, G, de Leon, AP, Sichieri, R. High-protein diet promotes a moderate postpartum weight loss in a prospective cohort of Brazilian women. Nutrition. 2009. 25:1120–8. doi:10.1016/j.nut.2009.02.006 19818279 | Intervention/Exposure; Country
512 | de Castro, MB, Sichieri, R, Barbosa Brito Fdos, S, Nascimento, S, Kac, G. Mixed dietary pattern is associated with a slower decline of body weight change during postpartum in a cohort of Brazilian women. Nutr Hosp. 2014. 29:519–25. doi:10.3305/nh.2014.29.3.7155 24558993 | Power/Size
513 | de Castro, MBT, Cunha, DB, Araujo, MC, Bezerra, IN, Adegboye, ARA, Kac, G, Sichieri, R. High protein diet promotes body weight loss among Brazilian postpartum women. Matern Child Nutr. 2019. 15:e12746. doi:10.1111/mcn.12746 30381901 | Intervention/Exposure
514 | de Deus, RM, Mingoti, SA, Jaime, PC, Lopes, AC. The impact of a nutritional intervention on the nutritional status and anthropometric profile of participants in the health Gym Programme in Brazil. Cien Saude Colet. 2015. 20:1937–46. doi:10.1590/1413-81232015206.11882014 26060972 | Intervention/Exposure
515 | de Ferranti, SD, Milliren, CE, Denhoff, ER, Quinn, N, Osganian, SK, Feldman, HA, Ebbeling, CB, Ludwig, DS. Providing food to treat adolescents at risk for cardiovascular disease. Obesity (Silver Spring). 2015. 23:2109–17. doi:10.1002/oby.21246 26337820 | Power/Size
516 | De Goede, J, Verschuren, WM, Boer, JM, Kromhout, D, Geleijnse, JM. N-6 and n-3 fatty acid cholesteryl esters in relation to incident stroke in a Dutch adult population: a nested case-control study. Nutr Metab Cardiovasc Dis. 2013. 23:737–43. doi:10.1016/j.numecd.2012.03.001 22633188 | Intervention/Exposure
517 | de Haas, SCM, de Jonge, EAL, Voortman, T, Graaff, JSD, Franco, OH, Ikram, MA, Rivadeneira, F, Kiefte-de Jong, JC, Schoufour, JD. Dietary patterns and changes in frailty status: the Rotterdam study. European Journal of Nutrition. 2018. 57:2365–2375. doi:10.1007/s00394-017-1509-9 28744573 | Outcome
518 | De La Iglesia, R, Lopez-Legarrea, P, Abete, I, Navas-Carrtero, S, Martinez, JA, Zulet, MA. The beneficial effects of the resmena dietary pattern on OxLDL in patients with metabolic syndrome. Annals of nutrition and metabolism. 2013. 63:171. doi:10.1159/000354245 | Publication Status
519 | de la Iglesia, R, Lopez-Legarrea, P, Celada, P, Sanchez-Muniz, FJ, Martinez, JA, Zulet, MA. Beneficial effects of the RESMENA dietary pattern on oxidative stress in patients suffering from metabolic syndrome with hyperglycemia are associated to dietary TAC and fruit consumption. Int J Mol Sci. 2013. 14:6903–19. doi:10.3390/ijms14046903 23535332 | Power/Size
520 | De Lorenzo, A, Petroni, ML, De Luca, PP, Andreoli, A, Morini, P, Iacopino, L, Innocente, I, Perriello, G. Use of quality control indices in moderately hypocaloric Mediterranean diet for treatment of obesity. Diabetes Nutr Metab. 2001. 14:181–8. doi:unavailable11716286 | Study Design
521 | de Luis, D, Izaola, O, Primo, D, Aller, R. Role of rs670 variant of APOA1 gene on metabolic response after a high fat vs. a low fat hypocaloric diets in obese human subjects. J Diabetes Complications. 2019. 33:249–254. doi:10.1016/j.jdiacomp.2018.10.015 30467071 | Intervention/Exposure; Comparator
522 | de Luis, DA, Aller, R, Izaola, O, Bachiller, R, Pacheco, D. Cardiovascular risk factors and adipocytokines levels after two hypocaloric diets with different fat distribution in obese subjects and rs6923761 gene variant of glucagon-like peptide 1 receptor. J Endocrinol Invest. 2014. 37:853–9. doi:10.1007/s40618-014-0116-3 24969551 | Intervention/Exposure; Comparator
523 | De Luis, DA, Aller, R, Izaola, O, De La Fuente, B, Conde, R, Eiros Bouza, JM. Relation of -55CT polymorphism of UCP3 gene with weight loss and metabolic changes after a high monounsaturated fat diet in obese non diabetic patients. Eur Rev Med Pharmacol Sci. 2013. 17:2810–5. doi:unavailable24174365 | Intervention/Exposure
524 | de Luis, DA, Aller, R, Izaola, O, de la Fuente, B, Conde, R, Sagrado, MG, Primo, D. Evaluation of weight loss and adipocytokines levels after two hypocaloric diets with different macronutrient distribution in obese subjects with rs9939609 gene variant. Diabetes Metab Res Rev. 2012. 28:663–8. doi:10.1002/dmrr.2323 22865603 | Intervention/Exposure
525 | De Luis, DA, Aller, R, Izaola, O, De La Fuente, B, Primo, D, Conde, R, Sagrado, MG. Evaluation of weight loss and adipocytokine levels after two hypocaloric diets with different macronutrient distribution in obese subjects with the rs6923761 gene variant of glucagon-like peptide 1 receptor. Annals of Nutrition and Metabolism. 2014. 63:277–282. doi:10.1159/000356710 | Intervention/Exposure
526 | de Luis, DA, Aller, R, Izaola, O, Diaz Soto, G, Lopez Gomez, JJ, Gomez Hoyos, E, Torres, B, Villar, A, Romero, E. Effects of a High-Protein/Low-Carbohydrate versus a Standard Hypocaloric Diet on Weight and Cardiovascular Risk Factors during 9 Months: Role of a Genetic Variation in the Cannabinoid Receptor Gene (CNR1) (G1359A Polymorphism). Ann Nutr Metab. 2015. 66:125–31. doi:10.1159/000375412 25766592 | Comparator
527 | de Luis, DA, Aller, R, Izaola, O, Gonzalez Sagrado, M, Bellioo, D, Conde, R. Effects of a low-fat versus a low-carbohydrate diet on adipocytokines in obese adults. Horm Res. 2007. 67:296–300. doi:10.1159/000099329 17284923 | Outcome; Health Status
528 | de Luis, DA, Aller, R, Izaola, O, Gonzalez Sagrado, M, Conde, R. Effect of two different hypocaloric diets in transaminases and insulin resistance in nonalcoholic fatty liver disease and obese patients. Nutr Hosp. 2010. 25:730–5. doi:unavailable21336428 | Power/Size
529 | De Luis, DA, Aller, R, Izaola, O, González Sagrado, M, Conde, R. The effects of a low-fat versus a low carbohydrate diet in obese adults. Medicina clinica. 2009. 132:203–207. doi:10.1016/j.medcli.2008.03.003 19237002 | Language
530 | De Luis, DA, Aller, R, Izaola, O, Pacheco, D. ROLE OF RS9939609 FTO GENE VARIANT IN WEIGHT LOSS, INSULIN RESISTANCE AND METABOLIC PARAMETERS AFTER A HIGH MONOUNSATURATED VS A HIGH POLYUNSATURATED FAT HYPOCALORIC DIETS. Nutr Hosp. 2015. 32:175–81. doi:10.3305/nh.2015.32.1.9169 26262713 | Intervention/Exposure; Comparator
531 | de Luis, DA, Aller, R, Izaola, O, Primo, D, Urdiales, S, Romero, E. Effects of a High-Protein/Low-Carbohydrate Diet versus a Standard Hypocaloric Diet on Weight and Cardiovascular Risk Factors: Role of a Genetic Variation in the rs9939609 FTO Gene Variant. J Nutrigenet Nutrigenomics. 2015. 8:128–36. doi:10.1159/000441142 26457804 | Weight loss/Hypocaloric
532 | de Luis, DA, Aller, R, Izaola, O, Romero, E. Effects of a high-protein/low-carbohydrate versus a standard hypocaloric diet on adipocytokine levels and cardiovascular risk factors during 9 months, role of rs6923761 gene variant of glucagon-like peptide 1 receptor. J Endocrinol Invest. 2015. 38:1183–9. doi:10.1007/s40618-015-0304-9 26015316 | Weight loss/Hypocaloric
533 | de Luis, DA, Izaola, O, Aller, R, de la Fuente, B, Bachiller, R, Romero, E. Effects of a high-protein/low carbohydrate versus a standard hypocaloric diet on adipocytokine levels and insulin resistance in obese patients along 9 months. J Diabetes Complications. 2015. 29:950–4. doi:10.1016/j.jdiacomp.2015.06.002 26166555 | Weight loss/Hypocaloric
534 | de Luis, DA, Izaola, O, de la Fuente, B, Primo, D, Romero, E. Role of Fatty Acid-Binding Protein 2 Ala54Thr Genotype on Weight Loss and Cardiovascular Risk Factors after a High-Protein/Low-Carbohydrate versus a Standard Hypocaloric Diet during 9 Months. Ann Nutr Metab. 2015. 67:81–6. doi:10.1159/000438947 26316042 | Weight loss/Hypocaloric
535 | de Luis, DA, Izaola, O, Primo, D, Aller, R. Different effects of high-protein/low-carbohydrate versus standard hypocaloric diet on insulin resistance and lipid profile: Role of rs16147 variant of neuropeptide Y. Diabetes Res Clin Pract. 2019. 156:107825. doi:10.1016/j.diabres.2019.107825 31449874 | Intervention/Exposure; Comparator
536 | de Luis, DA, Izaola, O, Primo, D, Aller, R. Polymorphism rs16147 of the Neuropeptide Y Gene Modifies the Response of Cardiovascular Risk Biomarkers and Adipokines to Two Hypocaloric Diets. J Nutrigenet Nutrigenomics. 2017. 10:63–72. doi:10.1159/000478528 28787737 | Intervention/Exposure; Comparator
537 | de Luis, DA, Izaola, O, Primo, D, de la Fuente, B, Mulero, I, Aller, R. The rs1862513 Variant in Resistin Gene-Modified Insulin Resistance and Insulin Levels after Weight Loss Secondary to Hypocaloric Diet. Ann Nutr Metab. 2016. 69:256–262. doi:10.1159/000453676 28064279 | Study Design; Intervention/Exposure
538 | de Luis, DA, Izaola, O, Primo, D, Ovalle, HF, Lopez, JJ, Gomez, E, Ortola, A, Aller, R. Biochemical, Anthropometric and Lifestyle Factors Related with Weight Maintenance after Weight Loss Secondary to a Hypocaloric Mediterranean Diet. Ann Nutr Metab. 2017. 71:217–223. doi:10.1159/000484446 29136612 | Study Design; Intervention/Exposure
539 | de Luis, DA, Perez Castrillon, JL, Aller, R, Izaola, O, Bachiller, C. Response of osteocalcin and insulin resistance after a hypocaloric diet in obese patients. Eur Rev Med Pharmacol Sci. 2015. 19:2174–9. doi:unavailable26166639 | Study Design
540 | de Luis, DA, Romero, E, Izaola, O, Primo, D, Aller, R. Cardiovascular Risk Factors and Insulin Resistance after Two Hypocaloric Diets with Different Fat Distribution in Obese Subjects: Effect of the rs10767664 Gene Variant in Brain-Derived Neurotrophic Factor. J Nutrigenet Nutrigenomics. 2017. 10:163–171. doi:10.1159/000485248 29339649 | Intervention/Exposure; Comparator
541 | de Luis, DA, Sagrado, MG, Conde, R, Aller, R, Izaola, O. The effects of two different hypocaloric diets on glucagon-like peptide 1 in obese adults, relation with insulin response after weight loss. J Diabetes Complications. 2009. 23:239–43. doi:10.1016/j.jdiacomp.2007.12.006 18413175 | Weight loss/Hypocaloric
542 | de Mello, VD, Schwab, U, Kolehmainen, M, Koenig, W, Siloaho, M, Poutanen, K, Mykkanen, H, Uusitupa, M. A diet high in fatty fish, bilberries and wholegrain products improves markers of endothelial function and inflammation in individuals with impaired glucose metabolism in a randomised controlled trial: the Sysdimet study. Diabetologia. 2011. 54:2755–67. doi:10.1007/s00125-011-2285-3 21870174 | Intervention/Exposure
543 | De Miguel-Etayo, P, Moreno, LA, Santabarbara, J, Martin-Matillas, M, Azcona-San Julian, MC, Marti Del Moral, A, Campoy, C, Marcos, A, Garagorri, JM. Diet quality index as a predictor of treatment efficacy in overweight and obese adolescents: The EVASYON study. Clin Nutr. 2019. 38:782–790. doi:10.1016/j.clnu.2018.02.032 29730135 | Study Design; Comparator
544 | de Paula Franco, E, Moraes de Oliveira, GM, Raggio Luiz, R, Rosa, G. EFFECT OF HYPOENERGETIC DIET COMBINED WITH CONSUMPTION OF COCONUT FLOUR IN OVERWEIGHT WOMEN. Nutr Hosp. 2015. 32:2012–8. doi:10.3305/nh.2015.32.5.9661 26545655 | Intervention/Exposure
545 | de Roos, NM, Bots, ML, Siebelink, E, Schouten, E, Katan, MB. Flow-mediated vasodilation is not impaired when HDL-cholesterol is lowered by substituting carbohydrates for monounsaturated fat. Br J Nutr. 2001. 86:181–8. doi:10.1079/bjn2001365 11502231 | Study duration
546 | de Rougemont, A, Normand, S, Nazare, JA, Skilton, MR, Sothier, M, Vinoy, S, Laville, M. Beneficial effects of a 5-week low-glycaemic index regimen on weight control and cardiovascular risk factors in overweight non-diabetic subjects. Br J Nutr. 2007. 98:1288–98. doi:10.1017/s0007114507778674 17617942 | Intervention/Exposure; Comparator
547 | de Souza, RGM, Gomes, AC, de Castro, IA, Mota, JF. A baru almond-enriched diet reduces abdominal adiposity and improves high-density lipoprotein concentrations: a randomized, placebo-controlled trial. Nutrition. 2018. 55–56:154–160. doi:10.1016/j.nut.2018.06.001 | Intervention/Exposure
548 | de Souza, RJ, Bray, GA, Carey, VJ, Hall, KD, LeBoff, MS, Loria, CM, Laranjo, NM, Sacks, FM, Smith, SR. Effects of 4 weight-loss diets differing in fat, protein, and carbohydrate on fat mass, lean mass, visceral adipose tissue, and hepatic fat: results from the POUNDS LOST trial. Am J Clin Nutr. 2012. 95:614–25. doi:10.3945/ajcn.111.026328 22258266 | Weight loss/Hypocaloric
549 | de Souza, RJ, Swain, JF, Appel, LJ, Sacks, FM. Alternatives for macronutrient intake and chronic disease: a comparison of the OmniHeart diets with popular diets and with dietary recommendations. Am J Clin Nutr. 2008. 88:1–11. doi:10.1093/ajcn/88.1.1 18614716 | Intervention/Exposure; Outcome
550 | Dearborn, JL, Qiao, Y, Guallar, E, Steffen, LM, Gottesman, RF, Zhang, Y, Wasserman, BA. Polyunsaturated fats, carbohydrates and carotid disease: The Atherosclerosis Risk in Communities (ARIC) Carotid MRI study. Atherosclerosis. 2016. 251:361–366. doi:10.1016/j.atherosclerosis.2016.05.024 27234460 | Outcome
551 | DeClercq, V, Cui, Y, Forbes, C, Grandy, SA, Keats, M, Parker, L, Sweeney, E, Yu, ZM, Dummer, TJB. Association between Diet Quality and Adiposity in the Atlantic PATH Cohort. Nutrients. 2017. 9:. doi:10.3390/nu9101155 | Study Design
552 | Decombaz, J, Fleith, M, Hoppeler, H, Kreis, R, Boesch, C. Effect of diet on the replenishment of intramyocellular lipids after exercise. Eur J Nutr. 2000. 39:244–7. doi:10.1007/s003940070002 11395983 | Study duration
553 | Decombaz, J, Schmitt, B, Ith, M, Decarli, B, Diem, P, Kreis, R, Hoppeler, H, Boesch, C. Postexercise fat intake repletes intramyocellular lipids but no faster in trained than in sedentary subjects. Am J Physiol Regul Integr Comp Physiol. 2001. 281:R760–9. doi:10.1152/ajpregu.2001.281.3.R760 11506990 | Intervention/Exposure; Study duration
554 | Defoort, C, Vincent-Baudry, S, Lairon, D. Effects of 3-month Mediterranean-type diet on postprandial TAG and apolipoprotein B48 in the Medi-RIVAGE cohort. Public Health Nutr. 2011. 14:2302–8. doi:10.1017/s1368980011002552 22166188 | Outcome
555 | Dehghan, M, Mente, A, Zhang, X, Swaminathan, S, Li, W, Mohan, V, Iqbal, R, Kumar, R, Wentzel-Viljoen, E, Rosengren, A, Amma, LI, Avezum, A, Chifamba, J, Diaz, R, Khatib, R, Lear, S, Lopez-Jaramillo, P, Liu, X, Gupta, R, Mohammadifard, N, Gao, N, Oguz, A, Ramli, AS, Seron, P, Sun, Y, Szuba, A, Tsolekile, L, Wielgosz, A, Yusuf, R, Hussein Yusufali, A, Teo, KK, Rangarajan, S, Dagenais, G, Bangdiwala, SI, Islam, S, Anand, SS, Yusuf, S. Associations of fats and carbohydrate intake with cardiovascular disease and mortality in 18 countries from five continents (PURE): a prospective cohort study. Lancet. 2017. 390:2050–2062. doi:10.1016/s0140-6736(17)32252-3 28864332 | Intervention/Exposure; Comparator
556 | Dekker, LH, van Dam, RM, Snijder, MB, Peters, RJ, Dekker, JM, de Vries, JH, de Boer, EJ, Schulze, MB, Stronks, K, Nicolaou, M. Comparable Dietary Patterns Describe Dietary Behavior across Ethnic Groups in the Netherlands, but Different Elements in the Diet Are Associated with Glycated Hemoglobin and Fasting Glucose Concentrations. J Nutr. 2015. 145:1884–91. doi:10.3945/jn.114.207472 26136591 | Outcome
557 | Delgado Floody, PA, Caamano Navarrete, F, Jerez Mayorga, D, Cofre-Lizama, A, Guzman-Guzman, IP. The association between children’s food habits, anthropometric parameters and health-related quality of life in Chilean school-age children. Nutr Hosp. 2019. 36:1061–1066. doi:10.20960/nh.02643 31516011 | Study Design; Outcome
558 | Della Pepa, G, Vetrani, C, Vitale, M, Bozzetto, L, Costabile, G, Cipriano, P, Mangione, A, Patti, L, Riccardi, G, Rivellese, AA, Annuzzi, G. Effects of a diet naturally rich in polyphenols on lipid composition of postprandial lipoproteins in high cardiometabolic risk individuals: an ancillary analysis of a randomized controlled trial. Eur J Clin Nutr. 2019. :. doi:10.1038/s41430-019-0459-0 | Intervention/Exposure
559 | Dello Russo, M, Ahrens, W, De Henauw, S, Eiben, G, Hebestreit, A, Kourides, Y, Lissner, L, Molnar, D, Moreno, LA, Pala, V, Veidebaum, T, Siani, A, Russo, P. The Impact of Adding Sugars to Milk and Fruit on Adiposity and Diet Quality in Children: A Cross-Sectional and Longitudinal Analysis of the Identification and Prevention of Dietary- and Lifestyle-Induced Health Effects in Children and Infants (IDEFICS) Study. Nutrients. 2018. 10:. doi:10.3390/nu10101350 | Outcome
560 | Demol, S, Yackobovitch-Gavan, M, Shalitin, S, Nagelberg, N, Gillon-Keren, M, Phillip, M. Low-carbohydrate (low & high-fat) versus high-carbohydrate low-fat diets in the treatment of obesity in adolescents. Acta Paediatr. 2009. 98:346–51. doi:10.1111/j.1651-2227.2008.01051.x 18826492 | Intervention/Exposure
561 | Denke, MA. Dietary prescriptions to control dyslipidemias. Circulation. 2002. 105:132–5. doi:10.1161/hc0202.103479 11790687 | Study Design
562 | Denke, MA. Metabolic effects of high-protein, low-carbohydrate diets. American Journal of Cardiology. 2001. 88:59–61. doi:10.1016/S0002-9149(01)01586-7 | Publication Status
563 | Denova-Gutierrez, E, Munoz-Aguirre, P, Shivappa, N, Hebert, JR, Tolentino-Mayo, L, Batis, C, Barquera, S. Dietary Inflammatory Index and Type 2 Diabetes Mellitus in Adults: The Diabetes Mellitus Survey of Mexico City. Nutrients. 2018. 10:. doi:10.3390/nu10040385 | Study Design; Intervention/Exposure
564 | Denova-Gutierrez, E, Tucker, KL, Flores, M, Barquera, S, Salmeron, J. Dietary Patterns Are Associated with Predicted Cardiovascular Disease Risk in an Urban Mexican Adult Population. J Nutr. 2016. 146:90–7. doi:10.3945/jn.115.217539 26581684 | Outcome
565 | Deriemaeker, P, Aerenhouts, D, De Ridder, D, Hebbelinck, M, Clarys, P. Health aspects, nutrition and physical characteristics in matched samples of institutionalized vegetarian and non-vegetarian elderly (> 65yrs). Nutr Metab (Lond). 2011. 8:37. doi:10.1186/1743-7075-8-37 21672249 | Study Design
566 | Derks, IPM, Bolhuis, K, Sijbrands, EJG, Gaillard, R, Hillegers, MHJ, Jansen, PW. Predictors and patterns of eating behaviors across childhood: Results from The Generation R study. Appetite. 2019. 141:104295. doi:10.1016/j.appet.2019.05.026 31128200 | Intervention/Exposure
567 | Detopoulou, P, Fragopoulou, E, Alepoudea, E, Nomikos, T, Kalogeropoulos, N, Antonopoulou, S. Associations between erythrocyte fatty acids and Mediterranean diet in Greek volunteers. Hellenic Journal of Atherosclerosis. 2018. 9:17–31. doi:unavailable | Publication Status
568 | Devlin, BL, Leveritt, MD, Kingsley, M, Belski, R. Dietary Intake, Body Composition, and Nutrition Knowledge of Australian Football and Soccer Players: Implications for Sports Nutrition Professionals in Practice. Int J Sport Nutr Exerc Metab. 2017. 27:130–138. doi:10.1123/ijsnem.2016-0191 27710165 | Study Design
569 | Di Daniele, N, Petramala, L, Di Renzo, L, Sarlo, F, Della Rocca, DG, Rizzo, M, Fondacaro, V, Iacopino, L, Pepine, CJ, De Lorenzo, A. Body composition changes and cardiometabolic benefits of a balanced Italian Mediterranean Diet in obese patients with metabolic syndrome. Acta Diabetologica. 2013. 50:409–416. doi:10.1007/s00592-012-0445-7 23188216 | Study Design; Intervention/Exposure
570 | Di Renzo, L, Cioccoloni, G, Falco, S, Abenavoli, L, Moia, A, Sinibaldi Salimei, P, De Lorenzo, A. Influence of FTO rs9939609 and Mediterranean diet on body composition and weight loss: a randomized clinical trial. J Transl Med. 2018. 16:308. doi:10.1186/s12967-018-1680-7 30419927 | Study duration
571 | Di Renzo, L, Marsella, LT, Sarlo, F, Soldati, L, Gratteri, S, Abenavoli, L, De Lorenzo, A. C677T gene polymorphism of MTHFR and metabolic syndrome: response to dietary intervention. J Transl Med. 2014. 12:329. doi:10.1186/s12967-014-0329-4 25432492 | Intervention/Exposure
572 | Diaf, M, Khaled, MB, Sellam, F. Correlation between dietary fat intake and atherogenic indices in normal, overweight and obese adults with or without type 2 diabetes. Romanian Journal of Diabetes, Nutrition and Metabolic Diseases. 2015. 22:347–360. doi:10.1515/rjdnmd-2015-0041 | Study Design; Intervention/Exposure
573 | Diaz, KM, Booth, JN, 3rd, Calhoun, DA, Irvin, MR, Howard, G, Safford, MM, Muntner, P, Shimbo, D. Healthy lifestyle factors and risk of cardiovascular events and mortality in treatment-resistant hypertension: the Reasons for Geographic and Racial Differences in Stroke study. Hypertension. 2014. 64:465–71. doi:10.1161/hypertensionaha.114.03565 24914189 | Health Status
574 | Diaz-Gutierrez, J, Ruiz-Canela, M, Gea, A, Fernandez-Montero, A, Martinez-Gonzalez, MA. Association Between a Healthy Lifestyle Score and the Risk of Cardiovascular Disease in the SUN Cohort. Rev Esp Cardiol (Engl Ed). 2018. 71:1001–1009. doi:10.1016/j.rec.2017.10.038 29287797 | Intervention/Exposure
575 | Diaz-Gutierrez, J, Ruiz-Estigarribia, L, Bes-Rastrollo, M, Ruiz-Canela, M, Martin-Moreno, JM, Martinez-Gonzalez, MA. The role of lifestyle behaviour on the risk of hypertension in the SUN cohort: The hypertension preventive score. Prev Med. 2019. 123:171–178. doi:10.1016/j.ypmed.2019.03.026 30902699 | Intervention/Exposure; Outcome
576 | DiBello, JR, Kraft, P, McGarvey, ST, Goldberg, R, Campos, H, Baylin, A. Comparison of 3 methods for identifying dietary patterns associated with risk of disease. Am J Epidemiol. 2008. 168:1433–43. doi:10.1093/aje/kwn274 18945692 | Study Design
577 | Diethelm, K, Gunther, AL, Schulze, MB, Standl, M, Heinrich, J, Buyken, AE. Prospective relevance of dietary patterns at the beginning and during the course of primary school to the development of body composition. Br J Nutr. 2014. 111:1488–98. doi:10.1017/s0007114513004017 24382029 | Power/Size
578 | Diez-Espino, J, Basterra-Gortari, FJ, Salas-Salvado, J, Buil-Cosiales, P, Corella, D, Schroder, H, Estruch, R, Ros, E, Gomez-Gracia, E, Aros, F, Fiol, M, Lapetra, J, Serra-Majem, L, Pinto, X, Babio, N, Quiles, L, Fito, M, Marti, A, Toledo, E. Egg consumption and cardiovascular disease according to diabetic status: The PREDIMED study. Clin Nutr. 2017. 36:1015–1021. doi:10.1016/j.clnu.2016.06.009 27448949 | Intervention/Exposure
579 | Diez-Espino, J, Buil-Cosiales, P, Babio, N, Toledo, E, Corella, D, Ros, E, Fito, M, Gomez-Gracia, E, Estruch, R, Fiol, M, Lapetra, J, Alonso-Gomez, A, Serra-Majem, L, Pinto, X, Sorli, JV, Munoz, MA, Basora, J, Martinez-Gonzalez, MA. Impact of Life’s Simple 7 on the incidence of major cardiovascular events in high-risk Spanish adults in the PREDIMED study cohort. Rev Esp Cardiol (Engl Ed). 2019. :. doi:10.1016/j.rec.2019.05.010 | Outcome
580 | Dimitriadis, D, Mamplekou, E, Dimitriadis, P, Komessidou, V, Dimitriadis, G, Papageorgiou, C. The Association between Obesity and Symptoms of Psychopathology and its Relationship with Sedentary Behavior and Mediterranean Diet. Isr J Psychiatry Relat Sci. 2016. 53:17–24. doi:unavailable | Study Design
581 | Ding, M, Ellervik, C, Huang, T, Jensen, MK, Curhan, GC, Pasquale, LR, Kang, JH, Wiggs, JL, Hunter, DJ, Willett, WC, Rimm, EB, Kraft, P, Chasman, DI, Qi, L, Hu, FB, Qi, Q. Diet quality and genetic association with body mass index: results from 3 observational studies. Am J Clin Nutr. 2018. 108:1291–1300. doi:10.1093/ajcn/nqy203 30351367 | Intervention/Exposure
582 | Ding, N, Wang, X, Tucker, KL, Weisskopf, MG, Sparrow, D, Hu, H, Park, SK. Dietary patterns, bone lead and incident coronary heart disease among middle-aged to elderly men. Environ Res. 2019. 168:222–229. doi:10.1016/j.envres.2018.09.035 30317107 | Power/Size
583 | Dinu, M, Colombini, B, Pagliai, G, Cesari, F, Gori, A, Giusti, B, Marcucci, R, Sofi, F. Effects of a dietary intervention with Mediterranean and vegetarian diets on hormones that influence energy balance: results from the CARDIntervention/ExposureG study. Int J Food Sci Nutr. 2019. :1–8. doi:10.1080/09637486.2019.1658723 | Intervention/Exposure
584 | Dinu, M, Pagliai, G, Colombini, B, Sereni, A, Gori, AM, Giusti, B, Marcucci, R, Casini, A, Sofi, F. Dietary intervention with vegetarian and mediterranean diets for cardiovascular prevention: effects on hormones involved in the energy balance. Nutrition, metabolism and cardiovascular diseases. 2019. 29:881-. doi:10.1016/j.numecd.2019.05.038 | Publication Status
585 | Dipla, K, Makri, M, Zafeiridis, A, Soulas, D, Tsalouhidou, S, Mougios, V, Kellis, S. An isoenergetic high-protein, moderate-fat diet does not compromise strength and fatigue during resistance exercise in women. Br J Nutr. 2008. 100:283–6. doi:10.1017/s0007114507898679 18618943 | Study duration
586 | Dipnall, JF, Pasco, JA, Meyer, D, Berk, M, Williams, LJ, Dodd, S, Jacka, FN. The association between dietary patterns, diabetes and depression. J Affect Disord. 2015. 174:215–24. doi:10.1016/j.jad.2014.11.030 25527991 | Study Design
587 | Divens, LL, Carter-Holmes, DV. Optimizing Blood Pressure in African-American Women with Dietary Approaches to Stop Hypertension (DASH). J Natl Black Nurses Assoc. 2019. 30:1–6. doi:unavailable | Study Design
588 | Djuric, Z, Ren, J, Blythe, J, VanLoon, G, Sen, A. A Mediterranean dietary intervention in healthy American women changes plasma carotenoids and fatty acids in distinct clusters. Nutr Res. 2009. 29:156–63. doi:10.1016/j.nutres.2009.03.001 19358929 | Publication Date Overlaps with Existing Review
589 | Dolman, RC, Wentzel-Viljoen, E, Jerling, JC, Feskens, EJ, Kruger, A, Pieters, M. The use of predefined diet quality scores in the context of CVD risk during urbanization in the South African Prospective Urban and Rural Epidemiological (PURE) study. Public Health Nutr. 2014. 17:1706–16. doi:10.1017/s1368980013002206 23952977 | Country
590 | Domenech, M, Roman, P, Lapetra, J, Garcia de la Corte, FJ, Sala-Vila, A, de la Torre, R, Corella, D, Salas-Salvado, J, Ruiz-Gutierrez, V, Lamuela-Raventos, RM, Toledo, E, Estruch, R, Coca, A, Ros, E. Mediterranean diet reduces 24-hour ambulatory blood pressure, blood glucose, and lipids: one-year randomized, clinical trial. Hypertension. 2014. 64:69–76. doi:10.1161/hypertensionaha.113.03353 24799608 | Intervention/Exposure
591 | Dominguez, LJ, Bes-Rastrollo, M, de la Fuente-Arrillaga, C, Toledo, E, Beunza, JJ, Barbagallo, M, Martinez-Gonzalez, MA. Similar prediction of total mortality, diabetes incidence and cardiovascular events using relative- and absolute-component Mediterranean diet score: the SUN cohort. Nutr Metab Cardiovasc Dis. 2013. 23:451–8. doi:10.1016/j.numecd.2011.10.009 22402062 | Outcome; Publication Date Overlaps with Existing Review
592 | Dominguez-Reyes, T, Astudillo-Lopez, CC, Salgado-Goytia, L, Munoz-Valle, JF, Salgado-Bernabe, AB, Guzman-Guzman, IP, Castro-Alarcon, N, Moreno-Godinez, ME, Parra-Rojas, I. Interaction of dietary fat intake with APOA2, APOA5 and LEPR polymorphisms and its relationship with obesity and dyslipidemia in young subjects. Lipids Health Dis. 2015. 14:106. doi:10.1186/s12944-015-0112-4 26365669 | Intervention/Exposure
593 | Dominique Ashen, M, Blumenthal, RS. Low HDL cholesterol levels. New England Journal of Medicine. 2005. 353:1252–1260. doi:10.1056/NEJMcp044370 | Study Design; Publication Status
594 | Donahoo, W, Wyatt, HR, Kriehn, J, Stuht, J, Dong, F, Hosokawa, P, Grunwald, GK, Johnson, SL, Peters, JC, Hill, JO. Dietary fat increases energy intake across the range of typical consumption in the United States. Obesity (Silver Spring). 2008. 16:64–9. doi:10.1038/oby.2007.31 18223614 | Study duration
595 | Dong, D, Bilger, M, van Dam, RM, Finkelstein, EA. Consumption Of Specific Foods And Beverages And Excess Weight Gain Among Children And Adolescents. Health Aff (Millwood). 2015. 34:1940–8. doi:10.1377/hlthaff.2015.0434 26526253 | Intervention/Exposure; Outcome
596 | Doo, EY, Jun, DW, Yang, SY, Kim, YS, Lee, SM. The intervention and education of low-sodium diet decreases insulin resistance in obese subjects. Clinical nutrition (edinburgh, scotland). 2015. 34:S210–S211. doi:unavailable | Publication Status
597 | Doo, M, Kim, Y. Sleep duration and dietary macronutrient consumption can modify the cardiovascular disease for Korean women but not for men. Lipids Health Dis. 2016. 15:17. doi:10.1186/s12944-015-0170-7 26819201 | Study Design
598 | Doostvandi, T, Bahadoran, Z, Mozaffari-Khosravi, H, Mirmiran, P, Azizi, F. Food intake patterns are associated with the risk of impaired glucose and insulin homeostasis: a prospective approach in the Tehran Lipid and Glucose Study. Public Health Nutr. 2016. 19:2467–74. doi:10.1017/s1368980016000616 27087273 | Outcome
599 | Doostvandi, T, Bahadoran, Z, Mozaffari-Khosravi, H, Tahmasebinejad, Z, Mirmiran, P, Azizi, F. The association of dietary patterns and the incidence of insulin resistance after a 3-year follow-up: Tehran Lipid and Glucose Study. Asia Pac J Clin Nutr. 2017. 26:531–538. doi:10.6133/apjcn.032016.12 28429920 | Outcome
600 | Dopheide, J, Geleijnse, JM, Bakker, SJL, Brink, EJ, Van Baak, MA. Increased dietary protein intake lowers blood pressure in overweight subjects. Obesity reviews. 2011. 12:275–276. doi:10.1111/j.1467-789X.2011.00889.x | Publication Status
601 | Dopheide, J, Teunissen-Beekman, KFM, Geleijnse, JM, Bakker, SJL, Brink, EJ, Van Baak, MA. Increased dietary protein intake lowers blood pressure in overweight subjects. Annals of nutrition & metabolism. 2013. 62:148. doi:10.1159/000346990 | Publication Status
602 | Dorenbos, E, Drummen, M, Rijks, J, Adam, T, Stouthart, P, Alfredo Martinez, J, Navas-Carretero, S, Stratton, G, Swindell, N, Fogelholm, M, Raben, A, Westerterp-Plantenga, M, Vreugdenhil, A. PREVIEW (Prevention of Diabetes Through Lifestyle Intervention and Population Studies in Europe and Around the World) study in children aged 10 to 17 years: Design, methods and baseline results. Diabetes Obes Metab. 2018. 20:1096–1101. doi:10.1111/dom.13216 29322617 | Study Design
603 | Dorgan, JF, Liu, L, Barton, BA, Deshmukh, S, Snetselaar, LG, Van Horn, L, Stevens, VJ, Robson, AM, Lasser, NL, Himes, JH, Shepherd, JA, Pourfarzib, R, Pettee Gabriel, K, Kriska, A, Kwiterovich, PO, Jr. Adolescent diet and metabolic syndrome in young women: results of the Dietary Intervention Study in Children (DISC) follow-up study. J Clin Endocrinol Metab. 2011. 96:E1999–2008. doi:10.1210/jc.2010-2726 21994964 | Intervention/Exposure
604 | Dorosty, AR, Emmett, PM, Cowin, IS, Reilly, JJ. Factors associated with early adiposity rebound. Pediatrics. 2000. 105:1115–1118. doi:10.1542/peds.105.5.1115 10790472 | AGE: Intervention/Exposure
605 | Dow, CA, Stauffer, BL, Greiner, JJ, DeSouza, CA. Influence of habitual high dietary fat intake on endothelium-dependent vasodilation. Appl Physiol Nutr Metab. 2015. 40:711–5. doi:10.1139/apnm-2015-0006 26058441 | Study Design
606 | Downer, MK, Gea, A, Stampfer, M, Sanchez-Tainta, A, Corella, D, Salas-Salvado, J, Ros, E, Estruch, R, Fito, M, Gomez-Gracia, E, Aros, F, Fiol, M, De-la-Corte, FJ, Serra-Majem, L, Pinto, X, Basora, J, Sorli, JV, Vinyoles, E, Zazpe, I, Martinez-Gonzalez, MA. Predictors of short- and long-term adherence with a Mediterranean-type diet intervention: the PREDIMED randomized trial. Int J Behav Nutr Phys Act. 2016. 13:67. doi:10.1186/s12966-016-0394-6 27297426 | Outcome
607 | Drake, I, Sonestedt, E, Ericson, U, Wallstrom, P, Orho-Melander, M. A Western dietary pattern is prospectively associated with cardio-metabolic traits and incidence of the metabolic syndrome. Br J Nutr. 2018. 119:1168–1176. doi:10.1017/s000711451800079x 29759108 | Outcome
608 | Draper, CF, Vassallo, I, Di Cara, A, Milone, C, Comminetti, O, Monnard, I, Godin, JP, Scherer, M, Su, M, Jia, W, Guiraud, SP, Praplan, F, Guignard, L, Ammon Zufferey, C, Shevlyakova, M, Emami, N, Moco, S, Beaumont, M, Kaput, J, Martin, FP. A 48-Hour Vegan Diet Challenge in Healthy Women and Men Induces a BRANCH-Chain Amino Acid Related, Health Associated, Metabolic Signature. Mol Nutr Food Res. 2018. 62:. doi:10.1002/mnfr.201700703 | Study duration
609 | Drehmer, M, Camey, SA, Nunes, MA, Duncan, BB, Lacerda, M, Pinheiro, AP, Schmidt, MI. Fibre intake and evolution of BMI: from pre-pregnancy to postpartum. Public Health Nutr. 2013. 16:1403–13. doi:10.1017/s1368980012003849 22916703 | Intervention/Exposure; AGE: Intervention/Exposure
610 | Drehmer, M, Odegaard, AO, Schmidt, MI, Duncan, BB, Cardoso, LO, Matos, SMA, Molina, Mdcb, Barreto, SM, Pereira, MA. Brazilian dietary patterns and the dietary approaches to stop hypertension (DASH) diet-relationship with metabolic syndrome and newly diagnosed diabetes in the ELSA-Brasil study. Diabetol Metab Syndr. 2017. 9:13. doi:10.1186/s13098-017-0211-7 28228848 | Study Design
611 | Drenowatz, C, Shook, RP, Hand, GA, Hebert, JR, Blair, SN. The independent association between diet quality and body composition. Sci Rep. 2014. 4:4928. doi:10.1038/srep04928 24816165 | Study Design
612 | Dreon, DM, Fernstrom, HA, Williams, PT, Krauss, RM. Reduced LDL particle size in children consuming a very-low-fat diet is related to parental LDL-subclass patterns. Am J Clin Nutr. 2000. 71:1611–6. doi:10.1093/ajcn/71.6.1611 10837306 | Study duration
613 | Drogan, D, Hoffmann, K, Schulz, M, Bergmann, MM, Boeing, H, Weikert, C. A food pattern predicting prospective weight change is associated with risk of fatal but not with nonfatal cardiovascular disease. J Nutr. 2007. 137:1961–7. doi:10.1093/jn/137.8.1961 17634271 | Intervention/Exposure
614 | Drouin-Chartier, JP, Tremblay, AJ, Lépine, MC, Lemelin, V, Lamarche, B, Couture, P. Substitution of dietary ω-6 polyunsaturated fatty acids for saturated fatty acids decreases LDL apolipoprotein B-100 production rate in men with dyslipidemia associated with insulin resistance: a randomized controlled trial. American journal of clinical nutrition. 2018. 107:26–34. doi:10.1093/ajcn/nqx013 | Intervention/Exposure; Comparator
615 | Drummen, M, Dorenbos, E, Vreugdenhil, ACE, Raben, A, Fogelholm, M, Westerterp-Plantenga, MS, Adam, TC. Long-term effects of increased protein intake after weight loss on intrahepatic lipid content and implications for insulin sensitivity: a PREVIEW study. Am J Physiol Endocrinol Metab. 2018. 315:E885–e891. doi:10.1152/ajpendo.00162.2018 30086649 | Intervention/Exposure; Outcome
616 | Du, H, Dong, CY, Lin, QY. Risk factors of acute myocardial infarction in middle-aged and adolescent people (< 45 years) in Yantai. BMC Cardiovasc Disord. 2015. 15:106. doi:10.1186/s12872-015-0102-5 26419462 | Study Design; Intervention/Exposure
617 | Dubois, L, Carter, MA, Farmer, A, Girard, M, Burnier, D, Tatone-Tokuda, F, Porcherie, M. Higher intakes of energy and grain products at 4 years of age are associated with being overweight at 6 years of age. Journal of Nutrition. 2011. 141:2024–2029. doi:10.3945/jn.111.143347 | Intervention/Exposure
618 | Dubois, L, Diasparra, M, Bogl, LH, Fontaine-Bisson, B, Bedard, B, Tremblay, RE, Kaprio, J, Boivin, M. Dietary Intake at 9 Years and Subsequent Body Mass Index in Adolescent Boys and Girls: A Study of Monozygotic Twin Pairs. Twin Res Hum Genet. 2016. 19:47–59. doi:10.1017/thg.2015.97 26810866 | Intervention/Exposure
619 | Dubois, L, Farmer, AP, Girard, M, Peterson, K. Preschool children’s eating behaviours are related to dietary adequacy and body weight. Eur J Clin Nutr. 2007. 61:846–55. doi:10.1038/sj.ejcn.1602586 17180152 | Study Design; Intervention/Exposure; Outcome
620 | Duckworth, LC, Gately, PJ, Radley, D, Cooke, CB, King, RF, Hill, AJ. RCT of a high-protein diet on hunger motivation and weight-loss in obese children: an extension and replication. Obesity (Silver Spring). 2009. 17:1808–10. doi:10.1038/oby.2009.95 19343014 | Study duration
621 | Dudum, R, Juraschek, SP, Appel, LJ. Dose-dependent effects of lifestyle interventions on blood lipid levels: Results from the PREMIER trial. Patient Educ Couns. 2019. 102:1882–1891. doi:10.1016/j.pec.2019.05.005 31153659 | Intervention/Exposure; Comparator
622 | Due, A, Larsen, TM, Hermansen, K, Stender, S, Holst, JJ, Toubro, S, Martinussen, T, Astrup, A. Comparison of the effects on insulin resistance and glucose tolerance of 6-mo high-monounsaturated-fat, low-fat, and control diets. Am J Clin Nutr. 2008. 87:855–62. doi:10.1093/ajcn/87.4.855 18400707 | Power/Size
623 | Due, A, Larsen, TM, Mu, H, Hermansen, K, Stender, S, Toubro, S, Allison, DB, Astrup, A. The effect of three different ad libitum diets for weight loss maintenance: a randomized 18-month trial. Eur J Nutr. 2017. 56:727–738. doi:10.1007/s00394-015-1116-6 26659070 | Weight loss/Hypocaloric
624 | Due, A, Toubro, S, Skov, AR, Astrup, A. Effect of normal-fat diets, either medium or high in protein, on body weight in overweight subjects: a randomised 1-year trial. Int J Obes Relat Metab Disord. 2004. 28:1283–90. doi:10.1038/sj.ijo.0802767 15303109 | Intervention/Exposure
625 | Dugas, C, Belanger, M, Perron, J, Weisnagel, SJ, Tchernof, A, Marc, I, Robitaille, J. Is A Healthy Diet Associated with Lower Anthropometric and Glycemic Alterations in Predisposed Children Born from Mothers with Gestational Diabetes Mellitus?. Nutrients. 2019. 11:. doi:10.3390/nu11030570 | Study Design
626 | Duhita, MR, Schutz, Y, Montani, JP, Dulloo, AG, Miles-Chan, JL. Does gender influence dietary protein-induced thermogenesis? A pilot dose response study. Obesity reviews. 2018. 19:103-. doi:10.1111/(ISSN)1467-789X | Publication Status
627 | Duijzer, G, Haveman-Nies, A, Jansen, SC, Beek, JT, van Bruggen, R, Willink, MGJ, Hiddink, GJ, Feskens, EJM. Effect and maintenance of the SLIMMER diabetes prevention lifestyle intervention in Dutch primary healthcare: a randomised controlled trial. Nutr Diabetes. 2017. 7:e268. doi:10.1038/nutd.2017.21 28481335 | Intervention/Exposure
628 | Dujmovic, M, Kresic, G, Mandic, ML, Kenjeric, D, Cvijanovic, O. Changes in dietary intake and body weight in lactating and non-lactating women: prospective study in northern coastal Croatia. Coll Antropol. 2014. 38:179–87. doi:unavailable24851615 | Participants
629 | Dulloo, AG, Antic, V, Yang, Z, Montani, JP. Propellers of growth trajectories to obesity and the metabolic syndrome. Int J Obes (Lond). 2006. 30 Suppl 4:S1–3. doi:10.1038/sj.ijo.0803512 | Publication Status
630 | Dumesnil, JG, Turgeon, J, Tremblay, A, Poirier, P, Gilbert, M, Gagnon, L, St-Pierra, S, Garneau, C, Lemieux, I, Pascot, A, Bergeron, J, Deapés, JP. Effect of a low-glycaemic index-low-fat-high protein diet on the atherogenic metabolic risk profile of abdominally obese men. British Journal of Nutrition. 2001. 86:557–568. doi:unavailable | Study duration
631 | Dumesnil, JG, Turgeon, J, Tremblay, A, Poirier, P, Gilbert, M, Gagnon, L, St-Pierre, S, Garneau, C, Lemieux, I, Pascot, A, Bergeron, J, Despres, JP. Effect of a low-glycaemic index--low-fat--high protein diet on the atherogenic metabolic risk profile of abdominally obese men. Br J Nutr. 2001. 86:557–68. doi:10.1079/bjn2001427 11737954 | Study duration
632 | Dunlap, BS, Bailes, JR, Jr. Unlimited energy, restricted carbohydrate diet improves lipid parameters in obese children. Metab Syndr Relat Disord. 2008. 6:32–6. doi:10.1089/met.2007.0023 18370834 | Study Design
633 | Dunn, SL, Siu, W, Freund, J, Boutcher, SH. The effect of a lifestyle intervention on metabolic health in young women. Diabetes Metab Syndr Obes. 2014. 7:437–44. doi:10.2147/dmso.S67845 25278771 | Intervention/Exposure
634 | Durao, C, Oliveira, A, Santos, AC, Severo, M, Guerra, A, Barros, H, Lopes, C. Protein intake and dietary glycemic load of 4-year-olds and association with adiposity and serum insulin at 7 years of age: sex-nutrient and nutrient-nutrient interactions. Int J Obes (Lond). 2017. 41:533–541. doi:10.1038/ijo.2016.240 28028320 | Intervention/Exposure
635 | Durkalec-Michalski, K, Zawieja, EE, Zawieja, BE, Jurkowska, D, Buchowski, MS, Jeszka, J. Effects of Low Versus Moderate Glycemic Index Diets on Aerobic Capacity in Endurance Runners: Three-Week Randomized Controlled Crossover Trial. Nutrients. 2018. 10:. doi:10.3390/nu10030370 | Study duration
636 | Durrer, C, Lewis, N, Wan, Z, Ainslie, PN, Jenkins, NT, Little, JP. Short-Term Low-Carbohydrate High-Fat Diet in Healthy Young Males Renders the Endothelium Susceptible to Hyperglycemia-Induced Damage, An Exploratory Analysis. Nutrients. 2019. 11:. doi:10.3390/nu11030489 | Study duration
637 | Durward, CM, Zack, MK, Shlisky, JD, Campbell, JK, Jonnalagadda, SS, Nickols-Richardson, SM. Predictors of early weight loss in a diet and exercise weight loss trial. FASEB journal. 2011. 25:. doi:unavailable | Publication Status
638 | Dyson, PA, Beatty, S, Matthews, DR. A low-carbohydrate diet is more effective in reducing body weight than healthy eating in both diabetic and non-diabetic subjects. Diabet Med. 2007. 24:1430–5. doi:10.1111/j.1464-5491.2007.02290.x 17971178 | Weight loss/Hypocaloric
639 | Dyson, PA, Beatty, S, Matthews, DR. An assessment of low-carbohydrate or low-fat diets for weight loss at 2 year’s follow-up. Diabetic medicine. 2010. 27:363–364. doi:10.1111/j.1464-5491.2010.02926.x 20536502 | Publication Status
640 | Earnest, CP, Church, TS. Evaluation of a Voluntary Worksite Weight Loss Program on Metabolic Syndrome. Metab Syndr Relat Disord. 2015. 13:406–14. doi:10.1089/met.2015.0075 26302220 | Study Design
641 | Ebbeling, CB, Feldman, HA, Klein, GL, Wong, JMW, Bielak, L, Steltz, SK, Luoto, PK, Wolfe, RR, Wong, WW, Ludwig, DS. Effects of a low carbohydrate diet on energy expenditure during weight loss maintenance: randomized trial. Bmj. 2018. 363:k4583. doi:10.1136/bmj.k4583 30429127 | Outcome
642 | Ebbeling, CB, Klein, GL, Luoto, PK, Wong, JMW, Bielak, L, Eddy, RG, Steltz, SK, Devlin, C, Sandman, M, Hron, B, Shimy, K, Heymsfield, SB, Wolfe, RR, Wong, WW, Feldman, HA, Ludwig, DS. A randomized study of dietary composition during weight-loss maintenance: Rationale, study design, intervention, and assessment. Contemp Clin Trials. 2018. 65:76–86. doi:10.1016/j.cct.2017.12.004 29233719 | Study Design
643 | Ebbeling, CB, Leidig, MM, Feldman, HA, Lovesky, MM, Ludwig, DS. Effects of a low-glycemic load vs low-fat diet in obese young adults: a randomized trial. Jama. 2007. 297:2092–102. doi:10.1001/jama.297.19.2092 17507345 | Weight loss/Hypocaloric
644 | Ebbeling, CB, Leidig, MM, Sinclair, KB, Hangen, JP, Ludwig, DS. A reduced-glycemic load diet in the treatment of adolescent obesity. Arch Pediatr Adolesc Med. 2003. 157:773–9. doi:10.1001/archpedi.157.8.773 12912783 | Intervention/Exposure
645 | Ebbeling, CB, Leidig, MM, Sinclair, KB, Seger-Shippee, LG, Feldman, HA, Ludwig, DS. Effects of an ad libitum low-glycemic load diet on cardiovascular disease risk factors in obese young adults. Am J Clin Nutr. 2005. 81:976–82. doi:10.1093/ajcn/81.5.976 15883418 | Intervention/Exposure
646 | Ebbeling, CB, Swain, JF, Feldman, HA, Wong, WW, Hachey, DL, Garcia-Lago, E, Ludwig, DS. Effects of dietary composition on energy expenditure during weight-loss maintenance. Jama. 2012. 307:2627–34. doi:10.1001/jama.2012.6607 22735432 | Study duration
647 | Ebrahimof, S, Hosseini-Esfahani, F, Mirmiran, P, Fallah-Kezabi, M, Azizi, F. Food Patterns and Framingham Risk Score in Iranian Adults: Tehran Lipid and Glucose Study: 2005-2011. Metab Syndr Relat Disord. 2018. 16:64–71. doi:10.1089/met.2017.0125 29293398 | Language
648 | Echeverría, G, Dussaillant, C, McGee, EE, Mena, C, Nitsche, MP, Urquiaga, I, Bitran, M, Pedrals, N, Rigotti, A. Promoting and Implementing the Mediterranean Diet in the Southern Hemisphere: the Chilean Experience. European Journal of Clinical Nutrition. 2018. :. doi:10.1038/s41430-018-0307-7 | Study Design
649 | Eckel, RH, Hernandez, TL, Bell, ML, Weil, KM, Shepard, TY, Grunwald, GK, Sharp, TA, Francis, CC, Hill, JO. Carbohydrate balance predicts weight and fat gain in adults. Am J Clin Nutr. 2006. 83:803–8. doi:10.1093/ajcn/83.4.803 16600931 | Intervention/Exposure; Study duration
650 | Eftekhari, MH, Rajaeifard, AR, Ahmadi, A, Kashfi, SM, Khajeh Rahim, AA. Effect of two isocaloric diets, low fat- high calcium and low fat- high fiber on weight reduction, lipid profile, and blood pressure. Iranian Cardiovascular Research Journal. 2009. 3:200–206. doi:unavailable | Intervention/Exposure; Language
651 | Egert, S, Baxheinrich, A, Lee-Barkey, YH, Tschoepe, D, Stehle, P, Stratmann, B, Wahrburg, U. Effects of a hypoenergetic diet rich in alpha-linolenic acid on fatty acid composition of serum phospholipids in overweight and obese patients with metabolic syndrome. Nutrition. 2018. 49:74–80. doi:10.1016/j.nut.2017.11.002 29500968 | Intervention/Exposure; Outcome
652 | Egert, S, Kratz, M, Kannenberg, F, Fobker, M, Wahrburg, U. Effects of high-fat and low-fat diets rich in monounsaturated fatty acids on serum lipids, LDL size and indices of lipid peroxidation in healthy non-obese men and women when consumed under controlled conditions. Eur J Nutr. 2011. 50:71–9. doi:10.1007/s00394-010-0116-9 20521076 | Study duration
653 | Eilat-Adar, S. Reduce simple carbohydrate and animal protein intake and increase polyunsaturated fatty acid intake in patients with metabolic syndrome and insulin resistance. J Am Diet Assoc. 2008. 108:802–3. doi:10.1016/j.jada.2008.02.013 18442503 | Study Design; Publication Status
654 | Ejlerskov, KT, Larnkjaer, A, Pedersen, D, Ritz, C, Molgaard, C, Michaelsen, KF. IGF-I at 9 and 36 months of age - relations with body composition and diet at 3 years - the SKOT cohort. Growth Horm IGF Res. 2014. 24:239–44. doi:10.1016/j.ghir.2014.10.005 25466908 | Study Design; Intervention/Exposure; Outcome; AGE: Intervention/Exposure
655 | Ek, A, Chamberlain, KL, Ejderhamn, J, Fisher, PA, Marcus, C, Chamberlain, P, Nowicka, P. The More and Less Study: a randomized controlled trial testing different approaches to treat obesity in preschoolers. BMC Public Health. 2015. 15:735. doi:10.1186/s12889-015-1912-1 26231850 | Study Design; Intervention/Exposure
656 | El Ansari, W, Suominen, S, Berg-Beckhoff, G. Mood and food at the University of Turku in Finland: nutritional correlates of perceived stress are most pronounced among overweight students. Int J Public Health. 2015. 60:707–16. doi:10.1007/s00038-015-0717-4 26202822 | Study Design
657 | Elbelt, U, Schuetz, T, Knoll, N, Burkert, S. Self-Directed Weight Loss Strategies: Energy Expenditure Due to Physical Activity Is Not Increased to Achieve Intended Weight Loss. Nutrients. 2015. 7:5868–88. doi:10.3390/nu7075256 26193310 | Study Design; Intervention/Exposure
658 | Ellingsen, I, Hjerkinn, EM, Arnesen, H, Seljeflot, I, Hjermann, I, Tonstad, S. Follow-up of diet and cardiovascular risk factors 20 years after cessation of intervention in the Oslo Diet and Antismoking Study. Eur J Clin Nutr. 2006. 60:378–85. doi:10.1038/sj.ejcn.1602327 16306931 | Intervention/Exposure
659 | Elliott, SA, Truby, H, Lee, A, Harper, C, Abbott, RA, Davies, PS. Associations of body mass index and waist circumference with: energy intake and percentage energy from macronutrients, in a cohort of Australian children. Nutr J. 2011. 10:58. doi:10.1186/1475-2891-10-58 21615883 | Study Design
660 | Ellsworth, DL, Costantino, NS, Blackburn, HL, Engler, RJ, Kashani, M, Vernalis, MN. Lifestyle modification interventions differing in intensity and dietary stringency improve insulin resistance through changes in lipoprotein profiles. Obes Sci Pract. 2016. 2:282–292. doi:10.1002/osp4.54 27708845 | Intervention/Exposure
661 | Eloranta, AM, Schwab, U, Venalainen, T, Kiiskinen, S, Lakka, HM, Laaksonen, DE, Lakka, TA, Lindi, V. Dietary quality indices in relation to cardiometabolic risk among Finnish children aged 6-8 years - The PANIC study. Nutr Metab Cardiovasc Dis. 2016. 26:833–41. doi:10.1016/j.numecd.2016.05.005 27397511 | Study Design
662 | Eloranta, AM, Schwab, U, Venäläinen, T, Kiiskinen, S, Lakka, HM, Laaksonen, DE, Lakka, TA, Lindi, V. Dietary quality indices in relation to cardiometabolic risk among Finnish children aged 6–8 years – The PANIC study. Nutrition, Metabolism and Cardiovascular Diseases. 2016. 26:833–841. doi:10.1016/j.numecd.2016.05.005 | Study Design
663 | Elvevoll, EO, Eilertsen, KE, Brox, J, Dragnes, BT, Falkenberg, P, Olsen, JO, Kirkhus, B, Lamglait, A, Osterud, B. Seafood diets: hypolipidemic and antiatherogenic effects of taurine and n-3 fatty acids. Atherosclerosis. 2008. 200:396–402. doi:10.1016/j.atherosclerosis.2007.12.021 18242615 | Intervention/Exposure; Comparator
664 | Emond, A, Emmett, P, Steer, C, Golding, J. Feeding symptoms, dietary patterns, and growth in young children with autism spectrum disorders. Pediatrics. 2010. 126:e337–e342. doi:10.1542/peds.2009-2391 20643716 | Intervention/Exposure; Health Status
665 | Engberink, MF, Geleijnse, JM, Bakker, SJ, Larsen, TM, Handjieva-Darlesnka, T, Kafatos, A, Martinez, JA, Pfeiffer, AF, Kunesova, M, Jebb, SA, Holst, C, Astrup, A, Saris, WH, Brink, EJ, van Baak, MA. Effect of a high-protein diet on maintenance of blood pressure levels achieved after initial weight loss: the DiOGenes randomized study. J Hum Hypertens. 2015. 29:58–63. doi:10.1038/jhh.2014.30 24759040 | Intervention/Exposure
666 | Engel, S, Tholstrup, T. Butter increased total and LDL cholesterol compared with olive oil but resulted in higher HDL cholesterol compared with a habitual diet. Am J Clin Nutr. 2015. 102:309–15. doi:10.3945/ajcn.115.112227 26135349 | Study duration
667 | Entezari, MH, Salehi, R, Kazemi, M, Janghorbani, M, Kafeshani, M. Comparison of the effect of the Dietary Approaches to Stop Hypertension diet with usual dietary advice on expression of peroxisome proliferators-activated receptor gamma gene in women: A randomized controlled clinical trial. ARYA Atheroscler. 2018. 14:24–31. doi:10.22122/arya.v14i1.1565 29942335 | Power/Size
668 | Erber, E, Hopping, BN, Grandinetti, A, Park, SY, Kolonel, LN, Maskarinec, G. Dietary patterns and risk for diabetes: The multiethnic cohort. Diabetes Care. 2010. 33:532–538. doi:10.2337/dc09-1621 20007939 | Intervention/Exposure; Publication Date Overlaps with Existing Review
669 | Ericson, U, Hellstrand, S, Brunkwall, L, Schulz, CA, Sonestedt, E, Wallstrom, P, Gullberg, B, Wirfalt, E, Orho-Melander, M. Food sources of fat may clarify the inconsistent role of dietary fat intake for incidence of type 2 diabetes. Am J Clin Nutr. 2015. 101:1065–80. doi:10.3945/ajcn.114.103010 25832335 | Intervention/Exposure
670 | Ericson, U, Rukh, G, Stojkovic, I, Sonestedt, E, Gullberg, B, Wirfalt, E, Wallstrom, P, Orho-Melander, M. Sex-specific interactions between the IRS1 polymorphism and intakes of carbohydrates and fat on incident type 2 diabetes. Am J Clin Nutr. 2013. 97:208–16. doi:10.3945/ajcn.112.046474 23221578 | Intervention/Exposure
671 | Erlinger, TP, Miller, ER, 3rd, Charleston, J, Appel, LJ. Inflammation modifies the effects of a reduced-fat low-cholesterol diet on lipids: results from the DASH-sodium trial. Circulation. 2003. 108:150–4. doi:10.1161/01.Cir.0000080288.30567.86 12847067 | Study Design; Intervention/Exposure
672 | Ertas Ozturk, Y, Bozbulut, R, Doger, E, Bideci, A, Koksal, E. The relationship between diet quality and insulin resistance in obese children: adaptation of the Healthy Lifestyle-Diet Index in Turkey. J Pediatr Endocrinol Metab. 2018. 31:391–398. doi:10.1515/jpem-2017-0271 29494339 | Study Design
673 | Escurriol, V, Cofan, M, Serra, M, Bullo, M, Basora, J, Salas-Salvado, J, Corella, D, Zazpe, I, Martinez-Gonzalez, MA, Ruiz-Gutierrez, V, Estruch, R, Ros, E. Serum sterol responses to increasing plant sterol intake from natural foods in the Mediterranean diet. Eur J Nutr. 2009. 48:373–82. doi:10.1007/s00394-009-0024-z 19412676 | Outcome; Publication Date Overlaps with Existing Review
674 | Esfandiari, S, Bahadoran, Z, Mirmiran, P, Tohidi, M, Azizi, F. Adherence to the dietary approaches to stop hypertension trial (DASH) diet is inversely associated with incidence of insulin resistance in adults: the Tehran lipid and glucose study. J Clin Biochem Nutr. 2017. 61:123–129. doi:10.3164/jcbn.16-95 28955129 | Power/Size
675 | Eshriqui, I, Vilela, AA, Rebelo, F, Farias, DR, Castro, MB, Kac, G. Gestational dietary patterns are not associated with blood pressure changes during pregnancy and early postpartum in a Brazilian prospective cohort. Eur J Nutr. 2016. 55:21–32. doi:10.1007/s00394-014-0819-4 25526968 | Outcome; Participants
676 | Eslamian, G, Mirmiran, P, Asghari, G, Hosseini-Esfahani, F, Yuzbashian, E, Azizi, F. Low carbohydrate diet score does not predict metabolic syndrome in children and adolescents: Tehran Lipid and Glucose Study. Arch Iran Med. 2014. 17:417–22. doi:24916527 | Power/Size
677 | Esmaeili, SS, Fallahi, F, Gholami Fesharaki, M, Noormohammadi, G. A Randomized Trial on the Effect of Razavi’s Dietary Pattern on the Components of Metabolic Syndrome. Iran Red Crescent Med J. 2014. 16:e14601. doi:10.5812/ircmj.14601 24829773 | Intervention/Exposure
678 | Esposito, K, Marfella, R, Ciotola, M, Di Palo, C, Giugliano, F, Giugliano, G, D’Armiento, M, D’Andrea, F, Giugliano, D. Effect of a Mediterranean-style diet on endothelial dysfunction and markers of vascular inflammation in the metabolic syndrome: A randomized trial. Journal of the American Medical Association. 2004. 292:1440–1446. doi:10.1001/jama.292.12.1440 15383514 | Intervention/Exposure; Publication Date Overlaps with Existing Review
679 | Essah, PA, Levy, JR, Sistrun, SN, Kelly, SM, Nestler, JE. Effect of weight loss by a low-fat diet and a low-carbohydrate diet on peptide YY levels. Int J Obes (Lond). 2010. 34:1239–42. doi:10.1038/ijo.2010.48 20351741 | Intervention/Exposure
680 | Esser, D, van Dijk, SJ, Oosterink, E, Muller, M, Afman, LA. A high-fat SFA, MUFA, or n3 PUFA challenge affects the vascular response and initiates an activated state of cellular adherence in lean and obese middle-aged men. J Nutr. 2013. 143:843–51. doi:10.3945/jn.113.174540 23616512 | Study duration
681 | Estrada-Reyes, C, Tlatempa-Sotelo, P, Valdes-Ramos, R, Cabanas-Armesilla, M, Manjarrez-Montes-de-Oca, R. Dietary Patterns and Fitness Level in Mexican Teenagers. J Nutr Metab. 2018. 2018:7159216. doi:10.1155/2018/7159216 29854442 | Study Design; Outcome
682 | Estruch, R, Casas, R, Sacanella, E, Urpi-Sarda, M, Corella, C, Cataner, O, Salas-Salvado, J, Martinez-Gonzalez, MA, Lamuela-Raventos, RM. Mediterranean diet and inflammatory biomarkers. Annals of nutrition and metabolism. 2015. 67:41–42. doi:10.1159/000440895 | Publication Status
683 | Estruch, R, Martinez-Gonzalez, MA, Corella, D, Basora-Gallisa, J, Ruiz-Gutierrez, V, Covas, MI, Fiol, M, Gomez-Gracia, E, Lopez-Sabater, MC, Escoda, R, Pena, MA, Diez-Espino, J, Lahoz, C, Lapetra, J, Saez, G, Ros, E. Effects of dietary fibre intake on risk factors for cardiovascular disease in subjects at high risk. J Epidemiol Community Health. 2009. 63:582–8. doi:10.1136/jech.2008.082214 19289389 | Intervention/Exposure
684 | Estruch, R, Martinez-Gonzalez, MA, Corella, D, Salas-Salvado, J, Fito, M, Chiva-Blanch, G, Fiol, M, Gomez-Gracia, E, Aros, F, Lapetra, J, Serra-Majem, L, Pinto, X, Buil-Cosiales, P, Sorli, JV, Munoz, MA, Basora-Gallisa, J, Lamuela-Raventos, RM, Serra-Mir, M, Ros, E. Retracted: Effect of a high-fat Mediterranean diet on bodyweight and waist circumference: a prespecified secondary outcomes analysis of the PREDIMED randomised controlled trial. Lancet Diabetes Endocrinol. 2016. 4:666–676. doi:10.1016/s2213-8587(16)30085-7 27283479 | Publication Status
685 | Estruch, R, Martínez-González, MA, Corella, D, Salas-Salvadó, J, Fitó, M, Chiva-Blanch, G, Fiol, M, Gómez-Gracia, E, Arós, F, Lapetra, J, Serra-Majem, L, Pintó, X, Buil-Cosiales, P, Sorlí, JV, Muñoz, MA, Basora-Gallisá, J, Lamuela-Raventós, RM, Serra-Mir, M, Ros, E. Effect of a high-fat Mediterranean diet on bodyweight and waist circumference: a prespecified secondary outcomes analysis of the PREDIMED randomised controlled trial. The Lancet Diabetes and Endocrinology. 2016. 4:666–676. doi:10.1016/S2213-8587(16)30085-7 27283479 | Publication Status
686 | Estruch, R, Martinez-Gonzalez, MA, Corella, D, Salas-Salvado, J, Ruiz-Gutierrez, V, Covas, MI, Fiol, M, Gomez-Gracia, E, Lopez-Sabater, MC, Vinyoles, E, Aros, F, Conde, M, Lahoz, C, Lapetra, J, Saez, G, Ros, E. Effects of a Mediterranean-style diet on cardiovascular risk factors: a randomized trial. Ann Intern Med. 2006. 145:1–11. doi:10.7326/0003-4819-145-1-200607040-00004 16818923 | Intervention/Exposure; Publication Date Overlaps with Existing Review
687 | Estruch, R, Martínez-González, MA. Mediterranean diets reduced cardiovascular events more than a low-fat diet in high-risk persons. Annals of Internal Medicine. 2013. 158:JC3. doi:10.7326/0003-4819-158-12-201306180-02003 | Publication Status
688 | Estruch, R, Ros, E, Salas-Salvadó, J, Covas, MI, Corella, D, Arós, F, Gómez-Gracia, E, Ruiz-Gutiérrez, V, Fiol, M, Lapetra, J, Lamuela-Raventos, RM, Serra-Majem, L, Pintó, X, Basora, J, Muñoz, MA, Sorlí, JV, Martínez, JA, Martínez-González, MA. Primary prevention of cardiovascular disease with a Mediterranean diet. New England Journal of Medicine. 2013. 368:1279–1290. doi:10.1056/NEJMoa1200303 | Study Design; Publication Status
689 | Estruch, R. Anti-inflammatory effects of the Mediterranean diet: the experience of the PREDIMED study. Proc Nutr Soc. 2010. 69:333–40. doi:10.1017/s0029665110001539 20515519 | Publication Status
690 | Estruch, R. Cardiovascular mortality: how can it be prevented?. Nefrologia. 2014. 34:561–9. doi:10.3265/Nefrologia.pre2014.Apr.12481 25036262 | Study Design; Publication Status
691 | Evans, EM, Mojtahedi, MC, Thorpe, MP, Valentine, RJ, Kris-Etherton, PM, Layman, DK. Effects of protein intake and gender on body composition changes: a randomized clinical weight loss trial. Nutr Metab (Lond). 2012. 9:55. doi:10.1186/1743-7075-9-55 22691622 | Weight loss/Hypocaloric
692 | Fagherazzi, G, Gusto, G, Mancini, FR, Dow, C, Rajaobelina, K, Balkau, B, Boutron-Ruault, MC, Bonnet, F. Determinants of 20-year non-progression to Type 2 diabetes in women at very high risk: the E3N cohort study. Diabet Med. 2018. 35:1716–1721. doi:10.1111/dme.13774 29978499 | Power/Size
693 | Faghihnia, N, Tsimikas, S, Miller, ER, Witztum, JL, Krauss, RM. Changes in lipoprotein(a), oxidized phospholipids, and LDL subclasses with a low-fat high-carbohydrate diet. J Lipid Res. 2010. 51:3324–30. doi:10.1194/jlr.M005769 20713651 | Intervention/Exposure
694 | Fajcsak, Z, Gabor, A, Kovacs, V, Martos, E. The effects of 6-week low glycemic load diet based on low glycemic index foods in overweight/obese children--pilot study. J Am Coll Nutr. 2008. 27:12–21. doi:10.1080/07315724.2008.10719670 18460477 | Study Design
695 | Fallaize, R, Livingstone, KM, Celis-Morales, C, Macready, AL, San-Cristobal, R, Navas-Carretero, S, Marsaux, CFM, O’Donovan, CB, Kolossa, S, Moschonis, G, Walsh, MC, Gibney, ER, Brennan, L, Bouwman, J, Manios, Y, Jarosz, M, Martinez, JA, Daniel, H, Saris, WHM, Gundersen, TE, Drevon, CA, Gibney, MJ, Mathers, JC, Lovegrove, JA. Association between Diet-Quality Scores, Adiposity, Total Cholesterol and Markers of Nutritional Status in European Adults: Findings from the Food4Me Study. Nutrients. 2018. 10:. doi:10.3390/nu10010049 | Study Design
696 | Farhadnejad, H, Asghari, G, Mirmiran, P, Azizi, F. Dietary approach to stop hypertension diet and cardiovascular risk factors among 10- to 18-year-old individuals. Pediatr Obes. 2018. 13:185–194. doi:10.1111/ijpo.12268 29363277 | Power/Size
697 | Farhangi, MA, Jahangiry, L. Dietary diversity score is associated with cardiovascular risk factors and serum adiponectin concentrations in patients with metabolic syndrome. BMC Cardiovasc Disord. 2018. 18:68. doi:10.1186/s12872-018-0807-3 29665770 | Power/Size
698 | Farnsworth, E, Luscombe, ND, Noakes, M, Wittert, G, Argyiou, E, Clifton, PM. Effect of a high-protein, energy-restricted diet on body composition, glycemic control, and lipid concentrations in overweight and obese hyperinsulinemic men and women. Am J Clin Nutr. 2003. 78:31–9. doi:10.1093/ajcn/78.1.31 12816768 | Power/Size
699 | Farrell, P, Negin, J, Awoke, M, Thow, AM, Taua, M, Faumuina, T, Mihrshahi, S, Vizintin, P, Richards, J. Associations between sociodemographic and behaviour factors, and dietary risk factors for overweight and obesity, in Samoan women. Appetite. 2019. 134:155–161. doi:10.1016/j.appet.2018.12.037 30593836 | Study Design
700 | Farvid, MS, Malekshah, AF, Pourshams, A, Poustchi, H, Sepanlou, SG, Sharafkhah, M, Khoshnia, M, Farvid, M, Abnet, CC, Kamangar, F, Dawsey, SM, Brennan, P, Pharoah, PD, Boffetta, P, Willett, WC, Malekzadeh, R. Dietary Protein Sources and All-Cause and Cause-Specific Mortality: The Golestan Cohort Study in Iran. Am J Prev Med. 2017. 52:237–248. doi:10.1016/j.amepre.2016.10.041 28109460 | Intervention/Exposure; Country
701 | Fatemi, MJ, Fararouei, M, Moravej, H, Dianatinasab, M. Stunting and its associated factors among 6-7-year-old children in southern Iran: a nested case-control study. Public Health Nutr. 2018. :1–8. doi:10.1017/s136898001800263x | Study Design; Intervention/Exposure
702 | Fava, F, Gitau, R, Griffin, BA, Gibson, GR, Tuohy, KM, Lovegrove, JA. The type and quantity of dietary fat and carbohydrate alter faecal microbiome and short-chain fatty acid excretion in a metabolic syndrome ‘at-risk’ population. Int J Obes (Lond). 2013. 37:216–23. doi:10.1038/ijo.2012.33 22410962 | Power/Size
703 | Fearnbach, SN, Masterson, TD, Schlechter, HA, Ross, AJ, Rykaczewski, MJ, Loken, E, Downs, DS, Thivel, D, Keller, KL. Impact of imposed exercise on energy intake in children at risk for overweight. Nutrition Journal. 2016. 15:. doi:10.1186/s12937-016-0206-5 | Intervention/Exposure; Study duration
704 | Feart, C, Jutand, MA, Larrieu, S, Letenneur, L, Delcourt, C, Combe, N, Barberger-Gateau, P. Energy, macronutrient and fatty acid intake of French elderly community dwellers and association with socio-demographic characteristics: data from the Bordeaux sample of the Three-City Study. Br J Nutr. 2007. 98:1046–57. doi:10.1017/s0007114507756520 17532868 | Study Design
705 | Fechner, E, Bilet, L, Peters, HPF, Hiemstra, H, Schrauwen, P, Mensink, RP. Investigating The Effectiveness Of A Healthy Diet On Cardiovascular Risk Markers - A Challenge-Based Human Trial. Atherosclerosis. 2019. 287:e148-. doi:10.1016/j.atherosclerosis.2019.06.441 | Publication Status
706 | Feng, R, Du, S, Chen, Y, Zheng, S, Zhang, W, Na, G, Li, Y, Sun, C. High carbohydrate intake from starchy foods is positively associated with metabolic disorders: a Cohort Study from a Chinese population. Sci Rep. 2015. 5:16919. doi:10.1038/srep16919 26581652 | Country
707 | Feng, R, Sun, G, Zhang, Y, Sun, Q, Ju, L, Sun, C, Wang, C. Short-term high-fat diet exacerbates insulin resistance and glycolipid metabolism disorders in young obese men with hyperlipidemia, as determined by metabolomics analysis using ultra-HPLC-quadrupole time-of-flight mass spectrometry. J Diabetes. 2019. 11:148–160. doi:10.1111/1753-0407.12828 30058212 | Study duration
708 | Ferdowsian, HR, Barnard, ND, Hoover, VJ, Katcher, HI, Levin, SM, Green, AA, Cohen, JL. A multicomponent intervention reduces body weight and cardiovascular risk at a GEICO corporate site. Am J Health Promot. 2010. 24:384–7. doi:10.4278/ajhp.081027-QUAN-255 20594095 | Publication Date Overlaps with Existing Review
709 | Ferland, A, Chateau-Degat, ML, Hernandez, TL, Eckel, RH. Tissue-specific responses of lipoprotein lipase to dietary macronutrient composition as a predictor of weight gain over 4 years. Obesity (Silver Spring). 2012. 20:1006–11. doi:10.1038/oby.2011.372 22262159 | Study duration
710 | Fernandez de la Puebla, RA, Fuentes, F, Perez-Martinez, P, Sanchez, E, Paniagua, JA, Lopez-Miranda, J, Perez-Jimenez, F. A reduction in dietary saturated fat decreases body fat content in overweight, hypercholesterolemic males. Nutr Metab Cardiovasc Dis. 2003. 13:273–7. doi:unavailable14717059 | Study duration
711 | Fernandez, C, Kasper, NM, Miller, AL, Lumeng, JC, Peterson, KE. Association of Dietary Variety and Diversity With Body Mass Index in US Preschool Children. Pediatrics. 2016. 137:e20152307. doi:10.1542/peds.2015-2307 26908657 | Intervention/Exposure
712 | Fernandez, ML. Plant-Based Diet Quality is Associated with Changes in Plasma Adiposity Biomarker Concentrations in Women. J Nutr. 2019. 149:551–552. doi:10.1093/jn/nxy317 30938778 | Study Design; Publication Status
713 | Fernandez-Lazaro, CI, Toledo, E, Salas-Salvado, J, Corella, D, Fito, M, Martinez, JA, Buil-Cosiales, P. PREDIMED-Plus trial: one-year changes in the quality of dietary carbohydrate intake and concurrent changes in cardiovascular risk factors. Annals of nutrition & metabolism. 2019. 75:20–21. doi:10.1159/000501441 32564018 | Publication Status
714 | Ferranti, R, Marventano, S, Castellano, S, Giogianni, G, Nolfo, F, Rametta, S, Matalone, M, Mistretta, A. Sleep quality and duration is related with diet and obesity in young adolescent living in Sicily, Southern Italy. Sleep Sci. 2016. 9:117–22. doi:10.1016/j.slsci.2016.04.003 27656277 | Study Design
715 | Ferrara, LA, Innelli, P, Palmieri, V, Limauro, S, De Luca, G, Ferrara, F, Liccardo, E, Celentano, A. Effects of different dietary protein intakes on body composition and vascular reactivity. Eur J Clin Nutr. 2006. 60:643–9. doi:10.1038/sj.ejcn.1602363 16340944 | Intervention/Exposure
716 | Ferreira, AA, Souza-Filho, ZA, Goncalves, MJF, Santos, J, Pierin, AMG. Relationship between alcohol drinking and arterial hypertension in indigenous people of the Mura ethnics, Brazil. PLoS One. 2017. 12:e0182352. doi:10.1371/journal.pone.0182352 28777805 | Study Design
717 | Feuerstein, JS, Bautista, LT, Bjerke, WS. A dietary approach for treating dyslipidemia and hyperglycemia. Current Nutrition and Food Science. 2011. 7:271–274. doi:unavailable | Study Design
718 | Field, AE, Willett, WC, Lissner, L, Colditz, GA. Dietary fat and weight gain among women in the Nurses’ Health Study. Obesity (Silver Spring). 2007. 15:967–76. doi:10.1038/oby.2007.616 17426332 | Intervention/Exposure
719 | Filaire, E, Maso, F, Degoutte, F, Jouanel, P, Lac, G. Food restriction, performance, psychological state and lipid values in judo athletes. Int J Sports Med. 2001. 22:454–9. doi:10.1055/s-2001-16244 11531040 | Study duration
720 | Finelli, C, Crispino, P, Gioia, S, La Sala, N, D’amico, L, La Grotta, M, Miro, O, Colarusso, D. The improvement of large high-density lipoprotein (HDL) particle levels, and presumably HDL metabolism, depend on effects of low-carbohydrate diet and weight loss. EXCLI Journal. 2016. 15:166–176. doi:10.17179/excli2015-642 27103896 | Publication Status
721 | Fito, M, Estruch, R, Salas-Salvado, J, Martinez-Gonzalez, MA, Aros, F, Vila, J, Corella, D, Diaz, O, Saez, G, de la Torre, R, Mitjavila, MT, Munoz, MA, Lamuela-Raventos, RM, Ruiz-Gutierrez, V, Fiol, M, Gomez-Gracia, E, Lapetra, J, Ros, E, Serra-Majem, L, Covas, MI. Effect of the Mediterranean diet on heart failure biomarkers: a randomized sample from the PREDIMED trial. Eur J Heart Fail. 2014. 16:543–50. doi:10.1002/ejhf.61 24574190 | Outcome
722 | Fito, M, Hernaez, A, Olga, C, Pinto, X, Estruch, R, Salas-Salvado, J, Corella, D, Blanchart, G, Gaixas, S, Aros, F, , . Effects of the mediterranean diet on the lipid profile and lipoprotein-related markers. Annals of nutrition & metabolism. 2017. 71:193–194. doi:10.1159/000480486 | Publication Status
723 | Fitzpatrick, SL, Coughlin, JW, Appel, LJ, Tyson, C, Stevens, VJ, Jerome, GJ, Dalcin, A, Brantley, PJ, Hill-Briggs, F. Application of Latent Class Analysis to Identify Behavioral Patterns of Response to Behavioral Lifestyle Interventions in Overweight and Obese Adults. Int J Behav Med. 2015. 22:471–80. doi:10.1007/s12529-014-9446-y 25331853 | Intervention/Exposure
724 | Fleming, J, Kris-Etherton, P, Petersen, K, Baer, D. Effect of mediterranean diet with varying amounts of lean beef on measures of arterial stiffness and central blood pressure. Circulation. 2018. 138:. doi:unavailable | Publication Status
725 | Fleming, J, Kris-Etherton, P, Petersen, K, Baer, D. The dose-response effect of a mediterranean style diet with lean beef on lipids and lipoproteins. Circulation. 2019. 139:. doi:10.1161/circ.139.suppl_1.045 | Publication Status
726 | Fleming, RM. The effect of high-, moderate-, and low-fat diets on weight loss and cardiovascular disease risk factors. Prev Cardiol. 2002. 5:110–8. doi:10.1111/j.1520-037x.2002.01231.x 12091753 | Intervention/Exposure
727 | Fletcher, EA, Lamb, KE, McNaughton, SA, Garnett, SP, Dunstan, DW, Baur, LA, Salmon, J. Cross-sectional and prospective mediating effects of dietary intake on the relationship between sedentary behaviour and body mass index in adolescents. BMC Public Health. 2017. 17:751. doi:10.1186/s12889-017-4771-0 28962606 | Study Design; Intervention/Exposure
728 | Fletcher, ES, Rugg-Gunn, AJ, Matthews, JN, Hackett, A, Moynihan, PJ, Mathers, JC, Adamson, AJ. Changes over 20 years in macronutrient intake and body mass index in 11- to 12-year-old adolescents living in Northumberland. Br J Nutr. 2004. 92:321–33. doi:10.1079/bjn20041199 15333164 | Intervention/Exposure
729 | Fletcher, S, Wright, C, Jones, A, Parkinson, K, Adamson, A. Tracking of toddler fruit and vegetable preferences to intake and adiposity later in childhood. Matern Child Nutr. 2017. 13:. doi:10.1111/mcn.12290 | Intervention/Exposure; Outcome
730 | Flock, MR, Kris-Etherton, PM. Dietary Guidelines for Americans 2010: implications for cardiovascular disease. Curr Atheroscler Rep. 2011. 13:499–507. doi:10.1007/s11883-011-0205-0 21874316 | Study Design
731 | Flood, A, Mai, V, Pfeiffer, R, Kahle, L, Remaley, AT, Rosen, CJ, Lanza, E, Schatzkin, A. The effects of a high-fruit and - vegetable, high-fiber, low-fat dietary intervention on serum concentrations of insulin, glucose, IGF-I and IGFBP-3. Eur J Clin Nutr. 2008. 62:186–96. doi:10.1038/sj.ejcn.1602726 17487212 | Outcome; Publication Date Overlaps with Existing Review
732 | Florencio, TM, Bueno, NB, Clemente, AP, Albuquerque, FC, Britto, RP, Ferriolli, E, Sawaya, AL. Weight gain and reduced energy expenditure in low-income Brazilian women living in slums: a 4-year follow-up study. Br J Nutr. 2015. 114:462–71. doi:10.1017/s0007114515001816 26123236 | Intervention/Exposure
733 | Flores, M, Macias, N, Rivera, M, Lozada, A, Barquera, S, Rivera-Dommarco, J, Tucker, KL. Dietary patterns in Mexican adults are associated with risk of being overweight or obese. J Nutr. 2010. 140:1869–73. doi:10.3945/jn.110.121533 20739452 | Study Design
734 | Fonseca, MJ, Durao, C, Lopes, C, Santos, AC. Weight following birth and childhood dietary intake: A prospective cohort study. Nutrition. 2017. 33:58–64. doi:10.1016/j.nut.2016.08.008 27908552 | Intervention/Exposure; Outcome
735 | Foraker, RE, Pennell, M, Sprangers, P, Vitolins, MZ, DeGraffinreid, C, Paskett, ED. Effect of a low-fat or low-carbohydrate weight-loss diet on markers of cardiovascular risk among premenopausal women: a randomized trial. J Womens Health (Larchmt). 2014. 23:675–80. doi:10.1089/jwh.2013.4638 25029619 | Intervention/Exposure
736 | Ford, CN, Weber, MB, Staimez, LR, Anjana, RM, Lakshmi, K, Mohan, V, Narayan, KMV, Harish, R. Dietary changes in a diabetes prevention intervention among people with prediabetes: the Diabetes Community Lifestyle Improvement Program trial. Acta Diabetologica. 2019. 56:197–209. doi:10.1007/s00592-018-1249-1 30426214 | Intervention/Exposure
737 | Ford, DW, Hartman, TJ, Still, C, Wood, C, Mitchell, DC, Erickson, P, Bailey, R, Smiciklas-Wright, H, Coffman, DL, Jensen, GL. Body mass index, poor diet quality, and health-related quality of life are associated with mortality in rural older adults. J Nutr Gerontol Geriatr. 2014. 33:23–34. doi:10.1080/21551197.2014.875819 24597994 | Outcome
738 | Forouhi, NG, Sharp, SJ, Du, H, van der, Dl A, Halkjaer, J, Schulze, MB, Tjonneland, A, Overvad, K, Jakobsen, MU, Boeing, H, Buijsse, B, Palli, D, Masala, G, Feskens, EJ, Sorensen, TI, Wareham, NJ. Dietary fat intake and subsequent weight change in adults: results from the European Prospective Investigation into Cancer and Nutrition cohorts. Am J Clin Nutr. 2009. 90:1632–41. doi:10.3945/ajcn.2009.27828 19828709 | Intervention/Exposure
739 | Forsythe, CE, French, MA, Goh, YK, Clandinin, MT. Cholesterolaemic influence of palmitic acid in the sn-1, 3 v. the sn-2 position with high or low dietary linoleic acid in healthy young men. Br J Nutr. 2007. 98:337–44. doi:10.1017/s0007114507704993 17391563 | Study duration
740 | Forsythe, CE, Phinney, SD, Feinman, RD, Volk, BM, Freidenreich, D, Quann, E, Ballard, K, Puglisi, MJ, Maresh, CM, Kraemer, WJ, Bibus, DM, Fernandez, ML, Volek, JS. Limited effect of dietary saturated fat on plasma saturated fat in the context of a low carbohydrate diet. Lipids. 2010. 45:947–62. doi:10.1007/s11745-010-3467-3 20820932 | Intervention/Exposure; Comparator
741 | Fortes, C, Forastiere, F, Farchi, S, Rapiti, E, Pastori, G, Perucci, CA. Diet and overall survival in a cohort of very elderly people. Epidemiology. 2000. 11:440–5. doi:10.1097/00001648-200007000-00013 10874552 | Intervention/Exposure; Comparator
742 | Foscolou, A, Georgousopoulou, E, Magriplis, E, Naumovski, N, Rallidis, L, Matalas, AL, Chrysohoou, C, Tousoulis, D, Pitsavos, C, Panagiotakos, D. The mediating role of Mediterranean diet on the association between Lp(a) levels and cardiovascular disease risk: A 10-year follow-up of the ATTICA study. Clin Biochem. 2018. 60:33–37. doi:10.1016/j.clinbiochem.2018.07.011 30055165 | Intervention/Exposure
743 | Foscolou, A, Magriplis, E, Tyrovolas, S, Soulis, G, Bountziouka, V, Mariolis, A, Piscopo, S, Valacchi, G, Anastasiou, F, Gotsis, E, Metallinos, G, Tyrovola, D, Polystipioti, A, Polychronopoulos, E, Matalas, AL, Lionis, C, Zeimbekis, A, Tur, JA, Sidossis, LS, Panagiotakos, D. Lifestyle determinants of healthy ageing in a Mediterranean population: The multinational MEDIS study. Exp Gerontol. 2018. 110:35–41. doi:10.1016/j.exger.2018.05.008 29763722 | Study Design; Outcome
744 | Foscolou, A, Polychronopoulos, E, Paka, E, Tyrovolas, S, Bountziouka, V, Zeimbekis, A, Tyrovola, D, Ural, D, Panagiotakos, D. Lifestyle and health determinants of cardiovascular disease among Greek older adults living in Eastern Aegean Islands: An adventure within the MEDIS study. Hellenic J Cardiol. 2016. 57:407–414. doi:10.1016/j.hjc.2016.11.021 28202216 | Study Design
745 | Foster, GD, Wyatt, HR, Hill, JO, Makris, AP, Rosenbaum, DL, Brill, C, Stein, RI, Mohammed, BS, Miller, B, Rader, DJ, Zemel, B, Wadden, TA, Tenhave, T, Newcomb, CW, Klein, S. Weight and metabolic outcomes after 2 years on a low-carbohydrate versus low-fat diet: a randomized trial. Ann Intern Med. 2010. 153:147–57. doi:10.7326/0003-4819-153-3-201008030-00005 20679559 | Intervention/Exposure
746 | Foster, GD, Wyatt, HR, Hill, JO, Makris, AP, Rosenbaum, DL, Brill, C, Stein, RI, Mohammed, S, Miller, B, Rader, DJ, , . Weight and metabolic outcomes after 2 years on a low-carbohydrate versus low-fat diet. Obstetrical & gynecological survey. 2010. 65:769–770. doi:10.1097/OGX.0b013e31821342ba | Publication Status
747 | Foster, GD, Wyatt, HR, Hill, JO, McGuckin, BG, Brill, C, Mohammed, BS, Szapary, PO, Rader, DJ, Edman, JS, Klein, S. A randomized trial of a low-carbohydrate diet for obesity. N Engl J Med. 2003. 348:2082–90. doi:10.1056/NEJMoa022207 12761365 | Intervention/Exposure
748 | Franklin, KA, Eriksson, M, Larsson, C, Lindahl, B, Mellberg, C, Sahlin, C, Olsson, T, Ryberg, M. Palaeolithic diet and obstructive sleep apnoea in overweight females: a randomised controlled trial. European respiratory journal. 2016. 48:. doi:10.1183/13993003.congress-2016.PA2376 | Publication Status
749 | Frankwich, KA, Egnatios, J, Kenyon, ML, Rutledge, TR, Liao, PS, Gupta, S, Herbst, KL, Zarrinpar, A. Differences in Weight Loss Between Persons on Standard Balanced vs Nutrigenetic Diets in a Randomized Controlled Trial. Clin Gastroenterol Hepatol. 2015. 13:1625–1632.e1. doi:10.1016/j.cgh.2015.02.044 25769412 | Power/Size
750 | Franzini, L, Ardigo, D, Valtuena, S, Pellegrini, N, Del Rio, D, Bianchi, MA, Scazzina, F, Piatti, PM, Brighenti, F, Zavaroni, I. Food selection based on high total antioxidant capacity improves endothelial function in a low cardiovascular risk population. Nutr Metab Cardiovasc Dis. 2012. 22:50–7. doi:10.1016/j.numecd.2010.04.001 20674303 | Study duration
751 | Franzon, K, Byberg, L, Sjogren, P, Zethelius, B, Cederholm, T, Kilander, L. Predictors of Independent Aging and Survival: A 16-Year Follow-Up Report in Octogenarian Men. J Am Geriatr Soc. 2017. 65:1953–1960. doi:10.1111/jgs.14971 28685810 | Outcome
752 | Fraser, D, Bilenko, N, Vardy, H, Abu-Saad, K, Shai, I, Abu-Shareb, H, Shahar, DR. Differences in food intake and disparity in obesity rates between adult Jews and Bedouins in Southern Israel. Ethnicity and Disease. 2008. 18:13–18. doi:unavailable18447093 | Study Design
753 | Freire, RD, Cardoso, MA, Gimeno, SG, Ferreira, SR. Dietary fat is associated with metabolic syndrome in Japanese Brazilians. Diabetes Care. 2005. 28:1779–85. doi:10.2337/diacare.28.7.1779 15983334 | Study Design
754 | Freisling, H, Pisa, PT, Ferrari, P, Byrnes, G, Moskal, A, Dahm, CC, Vergnaud, AC, Boutron-Ruault, MC, Fagherazzi, G, Cadeau, C, Kuhn, T, Neamat-Allah, J, Buijsse, B, Boeing, H, Halkjaer, J, Tjonneland, A, Hansen, CP, Quiros, JR, Travier, N, Molina-Montes, E, Amiano, P, Huerta, JM, Barricarte, A, Khaw, KT, Wareham, N, Key, TJ, Romaguera, D, Lu, Y, Lassale, CM, Naska, A, Orfanos, P, Trichopoulou, A, Masala, G, Pala, V, Berrino, F, Tumino, R, Ricceri, F, de Magistris, MS, Bueno-de-Mesquita, HB, Ocke, MC, Sonestedt, E, Ericson, U, Johansson, M, Skeie, G, Weiderpass, E, Braaten, T, Peeters, PH, Slimani, N. Main nutrient patterns are associated with prospective weight change in adults from 10 European countries. Eur J Nutr. 2016. 55:2093–104. doi:10.1007/s00394-015-1023-x 26303194 | Study Design; Intervention/Exposure
755 | Freitas-Vilela, AA, Smith, AD, Kac, G, Pearson, RM, Heron, J, Emond, A, Hibbeln, JR, Castro, MB, Emmett, PM. Dietary patterns by cluster analysis in pregnant women: relationship with nutrient intakes and dietary patterns in 7-year-old offspring. Matern Child Nutr. 2017. 13:. doi:10.1111/mcn.12353 | Study Design
756 | French, SA, Harnack, L, Jeffery, RW. Fast food restaurant use among women in the Pound of Prevention study: dietary, behavioral and demographic correlates. Int J Obes Relat Metab Disord. 2000. 24:1353–9. doi:10.1038/sj.ijo.0801429 11093299 | Intervention/Exposure
757 | Frisch, S, Zittermann, A, Berthold, HK, Gotting, C, Kuhn, J, Kleesiek, K, Stehle, P, Kortke, H. A randomized controlled trial on the efficacy of carbohydrate-reduced or fat-reduced diets in patients attending a telemedically guided weight loss program. Cardiovasc Diabetol. 2009. 8:36. doi:10.1186/1475-2840-8-36 19615091 | Weight loss/Hypocaloric
758 | Fritzen, AM, Lundsgaard, AM, Jordy, AB, Poulsen, SK, Stender, S, Pilegaard, H, Astrup, A, Larsen, TM, Wojtaszewski, JF, Richter, EA, Kiens, B. New Nordic Diet-Induced Weight Loss Is Accompanied by Changes in Metabolism and AMPK Signaling in Adipose Tissue. J Clin Endocrinol Metab. 2015. 100:3509–19. doi:10.1210/jc.2015-2079 26126206 | Power/Size
759 | Frolich, S, Lehmann, N, Weyers, S, Wahl, S, Dragano, N, Budde, T, Kalsch, H, Mahabadi, AA, Erbel, R, Moebus, S, Jockel, KH, Schmidt, B. Association of dietary patterns with five-year degree and progression of coronary artery calcification in the Heinz Nixdorf Recall study. Nutr Metab Cardiovasc Dis. 2017. 27:999–1007. doi:10.1016/j.numecd.2017.09.002 29074383 | Outcome
760 | Fuehrlein, BS, Rutenberg, MS, Silver, JN, Warren, MW, Theriaque, DW, Duncan, GE, Stacpoole, PW, Brantly, ML. Differential metabolic effects of saturated versus polyunsaturated fats in ketogenic diets. J Clin Endocrinol Metab. 2004. 89:1641–5. doi:10.1210/jc.2003-031796 15070924 | Study duration
761 | Fuentes, F, Lopez-Miranda, J, Perez-Martinez, P, Jimenez, Y, Marin, C, Gomez, P, Fernandez, JM, Caballero, J, Delgado-Lista, J, Perez-Jimenez, F. Chronic effects of a high-fat diet enriched with virgin olive oil and a low-fat diet enriched with alpha-linolenic acid on postprandial endothelial function in healthy men. Br J Nutr. 2008. 100:159–65. doi:10.1017/s0007114508888708 18275619 | Intervention/Exposure; Outcome
762 | Fuentes, F, Lopez-Miranda, J, Sanchez, E, Sanchez, F, Paez, J, Paz-Rojas, E, Marin, C, Gomez, P, Jimenez-Pereperez, J, Ordovas, JM, Perez-Jimenez, F. Mediterranean and low-fat diets improve endothelial function in hypercholesterolemic men. Ann Intern Med. 2001. 134:1115–9. doi:10.7326/0003-4819-134-12-200106190-00011 11412051 | Intervention/Exposure
763 | Fukuda, Y, Umeno, Y, Taniguchi, Y, Marukawa, S, Kurihara, H, Nakajima, H, Yamasaki, T. Analysis of Dietary Factors Affecting Body Mass Index in Elderly Patients With Type 2 Diabetes Mellitus. J Clin Med Res. 2019. 11:563–571. doi:10.14740/jocmr3893 31413768 | Study Design; Health Status
764 | Fung, TT, Chiuve, SE, McCullough, ML, Rexrode, KM, Logroscino, G, Hu, FB. Adherence to a DASH-style diet and risk of coronary heart disease and stroke in women. Arch Intern Med. 2008. 168:713–20. doi:10.1001/archinte.168.7.713 18413553 | Publication Date Overlaps with Existing Review
765 | Fung, TT, Feskanich, D. Dietary patterns and risk of hip fractures in postmenopausal women and men over 50 years. Osteoporos Int. 2015. 26:1825–30. doi:10.1007/s00198-015-3081-6 25731807 | Outcome
766 | Fung, TT, Rimm, EB, Spiegelman, D, Rifai, N, Tofler, GH, Willett, WC, Hu, FB. Association between dietary patterns and plasma biomarkers of obesity and cardiovascular disease risk. Am J Clin Nutr. 2001. 73:61–7. doi:10.1093/ajcn/73.1.61 11124751 | Intervention/Exposure
767 | Fung, TT, Schulze, M, Manson, JE, Willett, WC, Hu, FB. Dietary patterns, meat intake, and the risk of type 2 diabetes in women. Arch Intern Med. 2004. 164:2235–40. doi:10.1001/archinte.164.20.2235 15534160 | Publication Date Overlaps with Existing Review
768 | Fung, TT, Stampfer, MJ, Manson, JE, Rexrode, KM, Willett, WC, Hu, FB. Prospective study of major dietary patterns and stroke risk in women. Stroke. 2004. 35:2014–9. doi:10.1161/01.Str.0000135762.89154.92 15232120 | Publication Date Overlaps with Existing Review
769 | Furber, M, Anton-Solanas, A, Koppe, E, Ashby, C, Roberts, M, Roberts, J. A 7-day high protein hypocaloric diet promotes cellular metabolic adaptations and attenuates lean mass loss in healthy males. Clinical Nutrition Experimental. 2017. 14:13–25. doi:10.1016/j.yclnex.2017.05.002 | Study duration
770 | Furtado, JD, Campos, H, Appel, LJ, Miller, ER, Laranjo, N, Carey, VJ, Sacks, FM. Effect of protein, unsaturated fat, and carbohydrate intakes on plasma apolipoprotein B and VLDL and LDL containing apolipoprotein C-III: results from the OmniHeart Trial. Am J Clin Nutr. 2008. 87:1623–30. doi:10.1093/ajcn/87.6.1623 18541549 | Study duration
771 | Furtado, JD, Campos, H, Sumner, AE, Appel, LJ, Carey, VJ, Sacks, FM. Dietary interventions that lower lipoproteins containing apolipoprotein C-III are more effective in whites than in blacks: results of the OmniHeart trial. Am J Clin Nutr. 2010. 92:714–22. doi:10.3945/ajcn.2009.28532 20826623 | Intervention/Exposure
772 | Gadelha, Pcfp, de Arruda, IKG, Coelho, PBP, Queiroz, PMA, Maio, R, da Silva Diniz, A. Consumption of ultraprocessed foods, nutritional status, and dyslipidemia in schoolchildren: a cohort study. Eur J Clin Nutr. 2019. 73:1194–1199. doi:10.1038/s41430-019-0404-2 30787472 | Study Design
773 | Gadgil, MD, Anderson, CA, Kandula, NR, Kanaya, AM. Dietary patterns in Asian Indians in the United States: an analysis of the metabolic syndrome and atherosclerosis in South Asians Living in America study. J Acad Nutr Diet. 2014. 114:238–43. doi:10.1016/j.jand.2013.09.021 24295929 | Study Design
774 | Gadgil, MD, Appel, LJ, Yeung, E, Anderson, CA, Sacks, FM, Miller, ER, 3rd. The effects of carbohydrate, unsaturated fat, and protein intake on measures of insulin sensitivity: results from the OmniHeart trial. Diabetes Care. 2013. 36:1132–7. doi:10.2337/dc12-0869 23223345 | Outcome; Study duration
775 | Gaeini, Z, Bahadoran, Z, Mirmiran, P, Djazayery, A. The Association between Dietary Fat Pattern and the Risk of Type 2 Diabetes. Prev Nutr Food Sci. 2019. 24:1–7. doi:10.3746/pnf.2019.24.1.1 31008091 | Intervention/Exposure
776 | Gajda, K, Sulich, A, Hamulka, J, Bialkowska, A. Comparing diabetic with non-diabetic overweight subjects through assessing dietary intakes and key parameters of blood biochemistry and haematology. Rocz Panstw Zakl Hig. 2014. 65:133–8. doi:unavailable25272580 | Study Design
777 | Galan-Lopez, P, Ries, F, Gisladottir, T, Dominguez, R, Sanchez-Oliver, AJ. Healthy Lifestyle: Relationship between Mediterranean Diet, Body Composition and Physical Fitness in 13 to 16-Years Old Icelandic Students. Int J Environ Res Public Health. 2018. 15:. doi:10.3390/ijerph15122632 | Study Design
778 | Galan-Lopez, P, Sanchez-Oliver, AJ, Ries, F, Gonzalez-Jurado, JA. Mediterranean Diet, Physical Fitness and Body Composition in Sevillian Adolescents: A Healthy Lifestyle. Nutrients. 2019. 11:. doi:10.3390/nu11092009 | Study Design
779 | Galbreath, M, Campbell, B, LaBounty, P, Bunn, J, Dove, J, Harvey, T, Hudson, G, Gutierrez, JL, Levers, K, Galvan, E, Jagim, A, Greenwood, L, Cooke, MB, Greenwood, M, Rasmussen, C, Kreider, RB. Effects of Adherence to a Higher Protein Diet on Weight Loss, Markers of Health, and Functional Capacity in Older Women Participating in a Resistance-Based Exercise Program. Nutrients. 2018. 10:. doi:10.3390/nu10081070 | Intervention/Exposure
780 | Gao, J, Sun, H, Liang, X, Gao, M, Zhao, H, Qi, Y, Wang, Y, Liu, Y, Li, J, Zhu, Y, Zhao, Y, Wang, W, Ma, L, Wu, S. Ideal cardiovascular health behaviors and factors prevent the development of hypertension in prehypertensive subjects. Clin Exp Hypertens. 2015. 37:650–5. doi:10.3109/10641963.2015.1047938 26114351 | Intervention/Exposure; Country
781 | Garaulet, M, Martinez, A, Victoria, F, Perez-Llamas, F, Ortega, RM, Zamora, S. Difference in dietary intake and activity level between normal-weight and overweight or obese adolescents. J Pediatr Gastroenterol Nutr. 2000. 30:253–8. doi:10.1097/00005176-200003000-00008 10749407 | Study Design; Intervention/Exposure
782 | Garcia Hermoso, A, Saavedra Garcia, JM, Escalante Gonzalez, Y, Dominguez Pachon, AM. Effect of long-term physical exercise program and/or diet on metabolic syndrome in obese boys. Nutr Hosp. 2014. 30:94–103. doi:10.3305/nh.2014.30.1.7448 25137267 | Intervention/Exposure; Comparator
783 | Garcia-Arellano, A, Ramallal, R, Ruiz-Canela, M, Salas-Salvado, J, Corella, D, Shivappa, N, Schroder, H, Hebert, JR, Ros, E, Gomez-Garcia, E, Estruch, R, Lapetra, J, Aros, F, Fiol, M, Serra-Majem, L, Pinto, X, Babio, N, Gonzalez, JI, Fito, M, Martinez, JA, Martinez-Gonzalez, MA. Dietary Inflammatory Index and Incidence of Cardiovascular Disease in the PREDIMED Study. Nutrients. 2015. 7:4124–38. doi:10.3390/nu7064124 26035241 | Intervention/Exposure
784 | Garcia-Calzon, S, Gea, A, Razquin, C, Corella, D, Lamuela-Raventos, RM, Martinez, JA, Martinez-Gonzalez, MA, Zalba, G, Marti, A. Longitudinal association of telomere length and obesity indices in an intervention study with a Mediterranean diet: the PREDIMED-NAVARRA trial. Int J Obes (Lond). 2014. 38:177–82. doi:10.1038/ijo.2013.68 23711776 | Intervention/Exposure
785 | Garcia-Calzon, S, Martinez-Gonzalez, MA, Razquin, C, Corella, D, Salas-Salvado, J, Martinez, JA, Zalba, G, Marti, A. Pro12Ala polymorphism of the PPARgamma2 gene interacts with a mediterranean diet to prevent telomere shortening in the PREDIMED-NAVARRA randomized trial. Circ Cardiovasc Genet. 2015. 8:91–9. doi:10.1161/circgenetics.114.000635 25406242 | Intervention/Exposure; Outcome
786 | Garcia-Calzon, S, Zalba, G, Ruiz-Canela, M, Shivappa, N, Hebert, JR, Martinez, JA, Fito, M, Gomez-Gracia, E, Martinez-Gonzalez, MA, Marti, A. Dietary inflammatory index and telomere length in subjects with a high cardiovascular disease risk from the PREDIMED-NAVARRA study: cross-sectional and longitudinal analyses over 5 y. Am J Clin Nutr. 2015. 102:897–904. doi:10.3945/ajcn.115.116863 26354530 | Intervention/Exposure
787 | García-López, M, Toledo, E, Beunza, JJ, Aros, F, Estruch, R, Salas-Salvadó, J, Corella, D, Ros, E, Covas, MI, Gómez-Gracia, E, , . Mediterranean diet and heart rate: the PREDIMED randomised trial. International journal of cardiology. 2014. 171:299–301. doi:10.1016/j.ijcard.2013.11.074 24369792 | Publication Status
788 | Garcia-Perez, I, Posma, JM, Gibson, R, Chambers, ES, Hansen, TH, Vestergaard, H, Hansen, T, Beckmann, M, Pedersen, O, Elliott, P, Stamler, J, Nicholson, JK, Draper, J, Mathers, JC, Holmes, E, Frost, G. Objective assessment of dietary patterns by use of metabolic phenotyping: a randomised, controlled, crossover trial. Lancet Diabetes Endocrinol. 2017. 5:184–195. doi:10.1016/s2213-8587(16)30419-3 28089709 | Study duration
789 | Garcia-Rios, A, Alcala-Diaz, JF, Gomez-Delgado, F, Delgado-Lista, J, Marin, C, Leon-Acuna, A, Camargo, A, Rodriguez-Cantalejo, F, Blanco-Rojo, R, Quintana-Navarro, G, , . Beneficial effect of CETP gene polymorphism in combination with a Mediterranean diet influencing lipid metabolism in metabolic syndrome patients: CORDIOPREV study. Clinical nutrition. (no pagination), 2016. 2016. Date of Publication: February 15:. doi:10.1016/j.clnu.2016.12.011 | Intervention/Exposure; Health Status
790 | Garcia-Silva, J, Navarrete N N, Peralta-Ramirez, MI, Garcia-Sanchez, A, Ferrer-Gonzalez, MA, Caballo, VE. Efficacy of Cognitive Behavioral Therapy in Adherence to the Mediterranean Diet in Metabolic Syndrome Patients: A Randomized Controlled Trial. J Nutr Educ Behav. 2018. 50:896–904. doi:10.1016/j.jneb.2018.06.003 30100127 | Intervention/Exposure
791 | Garcia-Unciti, M, Martinez, JA, Izquierdo, M, Gorostiaga, EM, Grijalba, A, Ibanez, J. Effect of resistance training and hypocaloric diets with different protein content on body composition and lipid profile in hypercholesterolemic obese women. Nutr Hosp. 2012. 27:1511–20. doi:10.3305/nh.2012.27.5.5921 23478699 | Power/Size
792 | Gardener, H, Wright, CB, Cabral, D, Scarmeas, N, Gu, Y, Cheung, K, Elkind, MS, Sacco, RL, Rundek, T. Mediterranean diet and carotid atherosclerosis in the Northern Manhattan Study. Atherosclerosis. 2014. 234:303–10. doi:10.1016/j.atherosclerosis.2014.03.011 24721190 | Outcome
793 | Gardner, CD, Coulston, A, Chatterjee, L, Rigby, A, Spiller, G, Farquhar, JW. The effect of a plant-based diet on plasma lipids in hypercholesterolemic adults: a randomized trial. Ann Intern Med. 2005. 142:725–33. doi:10.7326/0003-4819-142-9-200505030-00007 15867404 | Intervention/Exposure
794 | Gardner, CD, Hauser, M, Gobbo, LD, Trepanowski, J, Rigdon, J, Ioannidis, J, King, A, Desai, M. Neither insulin secretion nor genotype pattern modify 12-month weight loss effects of healthy low-fat vs. healthy low-carbohydrate diets among adults with obesity. Circulation. 2017. 135:. doi:unavailable | Publication Status
795 | Gardner, CD, Kiazand, A, Alhassan, S, Kim, S, Stafford, RS, Balise, RR, Kraemer, HC, King, AC. Comparison of the Atkins, Zone, Ornish, and LEARN diets for change in weight and related risk factors among overweight premenopausal women: the A TO Z Weight Loss Study: a randomized trial. Jama. 2007. 297:969–77. doi:10.1001/jama.297.9.969 17341711 | Weight loss/Hypocaloric
796 | Gardner, CD, Offringa, LC, Hartle, JC, Kapphahn, K, Cherin, R. Weight loss on low-fat vs. low-carbohydrate diets by insulin resistance status among overweight adults and adults with obesity: A randomized pilot trial. Obesity (Silver Spring). 2016. 24:79–86. doi:10.1002/oby.21331 26638192 | Weight loss/Hypocaloric
797 | Garemo, M, Elamin, A, Gardner, A. Weight status and food habits of preschool children in Abu Dhabi, United Arab Emirates: NOPLAS project. Asia Pac J Clin Nutr. 2018. 27:1302–1314. doi:10.6133/apjcn.201811_27(6).0018 30485930 | Study Design
798 | Garg, R, Sun, B, Williams, J. Effect of low salt diet on insulin resistance in salt-sensitive versus salt-resistant hypertension. Hypertension. 2014. 64:1384–7. doi:10.1161/hypertensionaha.114.03880 25185125 | Intervention/Exposure; Study duration
799 | Garnett, SP, Baur, LA, Noakes, M, Steinbeck, K, Woodhead, HJ, Burrell, S, Chisholm, K, Broderick, CR, Parker, R, De, S, Shrinivasan, S, Hopley, L, Hendrie, G, Ambler, GR, Kohn, MR, Cowell, CT. Researching Effective Strategies to Improve Insulin Sensitivity in Children and Teenagers - RESIST. A randomised control trial investigating the effects of two different diets on insulin sensitivity in young people with insulin resistance and/or pre-diabetes. BMC Public Health. 2010. 10:575. doi:10.1186/1471-2458-10-575 20868506 | Study Design
800 | Garnett, SP, Gow, M, Ho, M, Baur, LA, Noakes, M, Woodhead, HJ, Broderick, CR, Burrell, S, Chisholm, K, Halim, J, De, S, Steinbeck, K, Srinivasan, S, Ambler, GR, Kohn, MR, Cowell, CT. Optimal macronutrient content of the diet for adolescents with prediabetes; RESIST a randomised control trial. J Clin Endocrinol Metab. 2013. 98:2116–25. doi:10.1210/jc.2012-4251 23533232 | Intervention/Exposure
801 | Garnett, SP, Gow, M, Ho, M, Baur, LA, Noakes, M, Woodhead, HJ, Broderick, CR, Chisholm, K, Briody, J, De, S, Steinbeck, K, Srinivasan, S, Ambler, GR, Cowell, CT. Improved insulin sensitivity and body composition, irrespective of macronutrient intake, after a 12 month intervention in adolescents with pre-diabetes; RESIST a randomised control trial. BMC Pediatr. 2014. 14:289. doi:10.1186/s12887-014-0289-0 25422027 | Intervention/Exposure
802 | Garralda-Del-Villar, M, Carlos-Chilleron, S, Diaz-Gutierrez, J, Ruiz-Canela, M, Gea, A, Martinez-Gonzalez, MA, Bes-Rastrollo, M, Ruiz-Estigarribia, L, Kales, SN, Fernandez-Montero, A. Healthy Lifestyle and Incidence of Metabolic Syndrome in the SUN Cohort. Nutrients. 2018. 11:. doi:10.3390/nu11010065 | Intervention/Exposure; Outcome
803 | Gately, PJ, King, NA, Greatwood, HC, Humphrey, LC, Radley, D, Cooke, CB, Hill, AJ. Does a high-protein diet improve weight loss in overweight and obese children?. Obesity (Silver Spring). 2007. 15:1527–34. doi:10.1038/oby.2007.181 17557990 | Intervention/Exposure
804 | Gawęcka, A, Ryterska, K, Wysokiński, P, Ficek, K, Wilk, K, Banaszczak, M, Jakubczak, K, Piotrowki, J, Czerwińska, M, Hołowko, J, , . CHANGES IN BODY MASS AND BLOOD LIPID LEVELS IN PATIENTS UNDERGOING CALORIC RESTRICTION. Annales academiae medicae stetinensis. 2014. 60:29–33. doi:unavailable | Language
805 | Geiker, NRW, Toennesen, LL, Astrup, A, Backer, V. The efficacy of a high protein/low glycemic index diet intervention in non-obese patients with asthma. Eur J Clin Nutr. 2018. 72:511–516. doi:10.1038/s41430-018-0092-3 29410479 | Intervention/Exposure; Comparator
806 | Gemmink, A, Bakker, LE, Guigas, B, Kornips, E, Schaart, G, Meinders, AE, Jazet, IM, Hesselink, MK. Lipid droplet dynamics and insulin sensitivity upon a 5-day high-fat diet in Caucasians and South Asians. Sci Rep. 2017. 7:42393. doi:10.1038/srep42393 28195217 | Intervention/Exposure; Study duration
807 | Genaro Pde, S, Pinheiro Mde, M, Szejnfeld, VL, Martini, LA. Dietary protein intake in elderly women: association with muscle and bone mass. Nutr Clin Pract. 2015. 30:283–9. doi:10.1177/0884533614545404 25107954 | Study Design; Intervention/Exposure
808 | Genoni, A, Lyons-Wall, P, Lo, J, Devine, A. Cardiovascular, Metabolic Effects and Dietary Composition of Ad-Libitum Paleolithic vs. Australian Guide to Healthy Eating Diets: A 4-Week Randomised Trial. Nutrients. 2016. 8:. doi:10.3390/nu8050314 | Study duration
809 | Georgiopoulos, G, Karatzi, K, Euthimiou, E, Laina, A, Kontogiannis, C, Mareti, A, Mavroeidis, I, Kouzoupis, A, Mitrakou, A, Papamichael, C, Stamatelopoulos, K. Association of macronutrient consumption with arterial aging in adults without clinically overt cardiovascular disease: a 5-year prospective cohort study. Eur J Nutr. 2019. 58:2305–2314. doi:10.1007/s00394-018-1781-3 30039435 | Power/Size
810 | Georgoulis, M, Labrou, K, Yiannakouris, N, Mourati, I, Vagiakis, E, Kechribari, I, Kokkinos, A, Kontogianni, M. Effects of a weight-loss Mediterranean lifestyle intervention on obstructive sleep apnea: preliminary results of a randomized controlled clinical trial. Journal of sleep research. 2018. 27:149–150. doi:10.1111/jsr.12751 29516611 | Publication Status
811 | Georgousopoulou, EN, Kouli, GM, Panagiotakos, DB, Kalogeropoulou, A, Zana, A, Chrysohoou, C, Tsigos, C, Tousoulis, D, Stefanadis, C, Pitsavos, C. Anti-inflammatory diet and 10-year (2002-2012) cardiovascular disease incidence: The ATTICA study. Int J Cardiol. 2016. 222:473–478. doi:10.1016/j.ijcard.2016.08.007 27505336 | Intervention/Exposure
812 | Georgousopoulou, EN, Mellor, DD, Naumovski, N, Polychronopoulos, E, Tyrovolas, S, Piscopo, S, Valacchi, G, Anastasiou, F, Zeimbekis, A, Bountziouka, V, Gotsis, E, Metallinos, G, Tyrovola, D, Foscolou, A, Tur, JA, Matalas, AL, Lionis, C, Sidossis, L, Panagiotakos, D. Mediterranean lifestyle and cardiovascular disease prevention. Cardiovasc Diagn Ther. 2017. 7:S39–s47. doi:10.21037/cdt.2017.03.11 28529921 | Study Design
813 | Gepner, Y, Shelef, I, Komy, O, Cohen, N, Schwarzfuchs, D, Bril, N, Rein, M, Serfaty, D, Kenigsbuch, S, Zelicha, H, Yaskolka Meir, A, Tene, L, Bilitzky, A, Tsaban, G, Chassidim, Y, Sarusy, B, Ceglarek, U, Thiery, J, Stumvoll, M, Bluher, M, Stampfer, MJ, Rudich, A, Shai, I. The beneficial effects of Mediterranean diet over low-fat diet may be mediated by decreasing hepatic fat content. J Hepatol. 2019. 71:379–388. doi:10.1016/j.jhep.2019.04.013 31075323 | Intervention/Exposure
814 | Gerhard, GT, Connor, SL, Wander, RC, Connor, WE. Plasma lipid and lipoprotein responsiveness to dietary fat and cholesterol in premenopausal African American and white women. Am J Clin Nutr. 2000. 72:56–63. doi:10.1093/ajcn/72.1.56 10871561 | Study duration
815 | Giacco, R, Lappi, J, Costabile, G, Kolehmainen, M, Schwab, U, Landberg, R, Uusitupa, M, Poutanen, K, Pacini, G, Rivellese, AA, Riccardi, G, Mykkanen, H. Effects of rye and whole wheat versus refined cereal foods on metabolic risk factors: a randomised controlled two-centre intervention study. Clin Nutr. 2013. 32:941–9. doi:10.1016/j.clnu.2013.01.016 23462537 | Intervention/Exposure
816 | Giardina, S, Hernandez-Alonso, P, Diaz-Lopez, A, Salas-Huetos, A, Salas-Salvado, J, Bullo, M. Changes in circulating miRNAs in healthy overweight and obese subjects: Effect of diet composition and weight loss. Clin Nutr. 2019. 38:438–443. doi:10.1016/j.clnu.2017.11.014 29233588 | Intervention/Exposure
817 | Gibas, MK, Gibas, KJ. Induced and controlled dietary ketosis as a regulator of obesity and metabolic syndrome pathologies. Diabetes Metab Syndr. 2017. 11 Suppl 1:S385–s390. doi:10.1016/j.dsx.2017.03.022 28433617 | Intervention/Exposure
818 | Gibbs, BB, Tudorascu, D, Bryce, C, Comer, D, Fischer, G, Hess, R, Huber, K, McTigue, K, Simkin-Silverman, L, Conroy, MB. Dietary habits associated with 6-and 24-month weight loss maintenance in primary care patients. Circulation. 2018. 137:. doi:unavailable | Publication Status
819 | Gilardini, L, Croci, M, Pasqualinotto, L, Caffetto, K, Invitti, C. Dietary Habits and Cardiometabolic Health in Obese Children. Obes Facts. 2015. 8:101–9. doi:10.1159/000381157 26087840 | Study Design; Intervention/Exposure
820 | Gilis-Januszewska, A, Barengo, NC, Lindstrom, J, Wojtowicz, E, Acosta, T, Tuomilehto, J, Schwarz, PEH, Piwonska-Solska, B, Szybinski, Z, Windak, A, Hubalewska-Dydejczyk, A. Predictors of long term weight loss maintenance in patients at high risk of type 2 diabetes participating in a lifestyle intervention program in primary health care: The DE-PLAN study. PLoS One. 2018. 13:e0194589. doi:10.1371/journal.pone.0194589 29570724 | Intervention/Exposure
821 | Gillingham, MB, Purnell, JQ, Jordan, J, Stadler, D, Haqq, AM, Harding, CO. Effects of higher dietary protein intake on energy balance and metabolic control in children with long-chain 3-hydroxy acyl-CoA dehydrogenase (LCHAD) or trifunctional protein (TFP) deficiency. Mol Genet Metab. 2007. 90:64–9. doi:10.1016/j.ymgme.2006.08.002 16996288 | Study duration
822 | Gingras, V, Rifas-Shiman, SL, Taveras, EM, Oken, E, Hivert, MF. Dietary behaviors throughout childhood are associated with adiposity and estimated insulin resistance in early adolescence: a longitudinal study. Int J Behav Nutr Phys Act. 2018. 15:129. doi:10.1186/s12966-018-0759-0 30558613 | Intervention/Exposure
823 | Ginos, BNR, Navarro, SL, Schwarz, Y, Gu, H, Wang, D, Randolph, TW, Shojaie, A, Hullar, MAJ, Lampe, PD, Kratz, M, Neuhouser, ML, Raftery, D, Lampe, JW. Circulating bile acids in healthy adults respond differently to a dietary pattern characterized by whole grains, legumes and fruits and vegetables compared to a diet high in refined grains and added sugars: A randomized, controlled, crossover feeding study. Metabolism. 2018. 83:197–204. doi:10.1016/j.metabol.2018.02.006 29458053 | Outcome
824 | Giontella, A, Bonafini, S, Tagetti, A, Bresadola, I, Minuz, P, Gaudino, R, Cavarzere, P, Ramaroli, DA, Marcon, D, Branz, L, Nicolussi Principe, L, Antoniazzi, F, Maffeis, C, Fava, C. Relation between Dietary Habits, Physical Activity, and Anthropometric and Vascular Parameters in Children Attending the Primary School in the Verona South District. Nutrients. 2019. 11:. doi:10.3390/nu11051070 | Study Design
825 | Glabska, D, Cackowska, K, Guzek, D. Comparison of the Body Composition of Caucasian Young Normal Body Mass Women, Measured in the Follicular Phase, Depending on the Carbohydrate Diet Level. Medicina (Kaunas). 2018. 54:. doi:10.3390/medicina54060104 | Study Design; Intervention/Exposure
826 | Goff, LM, Frost, GS, Hamilton, G, Thomas, EL, Dhillo, WS, Dornhorst, A, Bell, JD. Carbohydrate-induced manipulation of insulin sensitivity independently of intramyocellular lipids. Br J Nutr. 2003. 89:365–75. doi:10.1079/bjn2002789 12628032 | Intervention/Exposure; Study duration
827 | Gogebakan, O, Kohl, A, Osterhoff, MA, van Baak, MA, Jebb, SA, Papadaki, A, Martinez, JA, Handjieva-Darlenska, T, Hlavaty, P, Weickert, MO, Holst, C, Saris, WH, Astrup, A, Pfeiffer, AF. Effects of weight loss and long-term weight maintenance with diets varying in protein and glycemic index on cardiovascular risk factors: the diet, obesity, and genes (DiOGenes) study: a randomized, controlled trial. Circulation. 2011. 124:2829–38. doi:10.1161/circulationaha.111.033274 22104550 | Intervention/Exposure
828 | Gokmen-Ozel, H, Ferguson, C, Evans, S, Daly, A, MacDonald, A. Does a lower carbohydrate protein substitute impact on blood phenylalanine control, growth and appetite in children with PKU?. Mol Genet Metab. 2011. 104 Suppl:S64–7. doi:10.1016/j.ymgme.2011.09.014 21978770 | Health Status
829 | Goldberg, JM, O’Mara, K. Metabolic and anthropometric changes in obese subjects from an unrestricted calorie, high monounsaturated fat, very low carbohydrate diet. Journal of Clinical Ligand Assay. 2000. 23:97–103. doi:unavailable | Study Design
830 | Goldberg, R, Temprosa, M, Otvos, J, Brunzell, J, Marcovina, S, Mather, K, Arakaki, R, Watson, K, Horton, E, Barrett-Connor, E. Lifestyle and metformin treatment favorably influence lipoprotein subfraction distribution in the Diabetes Prevention Program. J Clin Endocrinol Metab. 2013. 98:3989–98. doi:10.1210/jc.2013-1452 23979954 | Intervention/Exposure
831 | Goletzke, J, Herder, C, Joslowski, G, Bolzenius, K, Remer, T, Wudy, SA, Roden, M, Rathmann, W, Buyken, AE. Habitually higher dietary glycemic index during puberty is prospectively related to increased risk markers of type 2 diabetes in younger adulthood. Diabetes Care. 2013. 36:1870–1876. doi:10.2337/dc12-2063 23349549 | Intervention/Exposure; Comparator
832 | Golley, RK, Hendrie, GA. Evaluation of the relative concentration of serum fatty acids C14:0. C15:0 and C17:0 as markers of children’s dairy fat intake. Ann Nutr Metab. 2014. 65:310–6. doi:10.1159/000368325 25402168 | Intervention/Exposure; Outcome
833 | Golzarand, M, Bahadoran, Z, Mirmiran, P, Azizi, F. Protein Foods Group and 3-Year Incidence of Hypertension: A Prospective Study From Tehran Lipid and Glucose Study. J Ren Nutr. 2016. 26:219–25. doi:10.1053/j.jrn.2016.01.017 26908191 | Intervention/Exposure
834 | Golzarand, M, Bahadoran, Z, Mirmiran, P, Sadeghian-Sharif, S, Azizi, F. Dietary phytochemical index is inversely associated with the occurrence of hypertension in adults: a 3-year follow-up (the Tehran Lipid and Glucose Study). Eur J Clin Nutr. 2015. 69:392–8. doi:10.1038/ejcn.2014.233 25387902 | Intervention/Exposure; Outcome
835 | Gomez-Arbelaez, D, Bellido, D, Castro, AI, Ordonez-Mayan, L, Carreira, J, Galban, C, Martinez-Olmos, MA, Crujeiras, AB, Sajoux, I, Casanueva, FF. Body Composition Changes After Very-Low-Calorie Ketogenic Diet in Obesity Evaluated by 3 Standardized Methods. J Clin Endocrinol Metab. 2017. 102:488–498. doi:10.1210/jc.2016-2385 27754807 | Study Design
836 | Gomez-Arbelaez, D, Crujeiras, AB, Castro, AI, Martinez-Olmos, MA, Canton, A, Ordonez-Mayan, L, Sajoux, I, Galban, C, Bellido, D, Casanueva, FF. Resting metabolic rate of obese patients under very low calorie ketogenic diet. Nutr Metab (Lond). 2018. 15:18. doi:10.1186/s12986-018-0249-z 29467800 | Study Design; Intervention/Exposure
837 | Gomez-Delgado, F, Alcala-Diaz, JF, Garcia-Rios, A, Delgado-Lista, J, Ortiz-Morales, A, Rangel-Zuniga, O, Tinahones, FJ, Gonzalez-Guardia, L, Malagon, MM, Bellido-Munoz, E, Ordovas, JM, Perez-Jimenez, F, Lopez-Miranda, J, Perez-Martinez, P. Polymorphism at the TNF-alpha gene interacts with Mediterranean diet to influence triglyceride metabolism and inflammation status in metabolic syndrome patients: From the CORDIOPREV clinical trial. Mol Nutr Food Res. 2014. 58:1519–27. doi:10.1002/mnfr.201300723 24753491 | Intervention/Exposure; Comparator
838 | Gomez-Huelgas, R, Jansen-Chaparro, S, Baca-Osorio, AJ, Mancera-Romero, J, Tinahones, FJ, Bernal-Lopez, MR. Effects of a long-term lifestyle intervention program with Mediterranean diet and exercise for the management of patients with metabolic syndrome in a primary care setting. Eur J Intern Med. 2015. 26:317–23. doi:10.1016/j.ejim.2015.04.007 25907985 | Intervention/Exposure
839 | Gomez-Marin, B, Gomez-Delgado, F, Lopez-Moreno, J, Alcala-Diaz, JF, Jimenez-Lucena, R, Torres-Pena, JD, Garcia-Rios, A, Ortiz-Morales, AM, Yubero-Serrano, EM, Del Mar Malagon, M, Lai, CQ, Delgado-Lista, J, Ordovas, JM, Lopez-Miranda, J, Perez-Martinez, P. Long-term consumption of a Mediterranean diet improves postprandial lipemia in patients with type 2 diabetes: the Cordioprev randomized trial. Am J Clin Nutr. 2018. 108:963–970. doi:10.1093/ajcn/nqy144 30475968 | Health Status
840 | Goni, L, Riezu-Boj, JI, Milagro, FI, Corrales, FJ, Ortiz, L, Cuervo, M, Martinez, JA. Interaction between an ADCY3 Genetic Variant and Two Weight-Lowering Diets Affecting Body Fatness and Body Composition Outcomes Depending on Macronutrient Distribution: A Randomized Trial. Nutrients. 2018. 10:. doi:10.3390/nu10060789 | Weight loss/Hypocaloric
841 | Goni, L, Sun, D, Heianza, Y, Wang, T, Huang, T, Cuervo, M, Martinez, JA, Shang, X, Bray, GA, Sacks, FM, Qi, L. Macronutrient-specific effect of the MTNR1B genotype on lipid levels in response to 2 year weight-loss diets. J Lipid Res. 2018. 59:155–161. doi:10.1194/jlr.P078634 29089366 | Intervention/Exposure
842 | Goni, L, Sun, D, Heianza, Y, Wang, T, Huang, T, Martinez, JA, Shang, X, Bray, GA, Smith, SR, Sacks, FM, Qi, L. A circadian rhythm-related MTNR1B genetic variant modulates the effect of weight-loss diets on changes in adiposity and body composition: the POUNDS Lost trial. Eur J Nutr. 2019. 58:1381–1389. doi:10.1007/s00394-018-1660-y 29516223 | Intervention/Exposure
843 | González Devia, LJ, Monroy Romero, PA, Almonacid Urrego, CC, Orjuela, OL, Huérfano, MJ, Mendieta Zerón, H. Comparative study of risk factors related to cardiovascular disease in children from Bogotá, Colombia and Toluca, Mexico. Revista de la Facultad de Ciencias Médicas (Córdoba, Argentina). 2014. 71:98–105. doi:unavailable | Study Design
844 | Gooding, HC, Shay, CM, Ning, H, Gillman, MW, Chiuve, SE, Reis, JP, Allen, NB, Lloyd-Jones, DM. Optimal Lifestyle Components in Young Adulthood Are Associated With Maintaining the Ideal Cardiovascular Health Profile Into Middle Age. J Am Heart Assoc. 2015. 4:. doi:10.1161/jaha.115.002048 | Intervention/Exposure; Outcome
845 | Gopinath, B, Flood, VM, Rochtchina, E, Baur, LA, Louie, JC, Smith, W, Mitchell, P. Carbohydrate nutrition and development of adiposity during adolescence. Obesity (Silver Spring). 2013. 21:1884–90. doi:10.1002/oby.20405 23519919 | Intervention/Exposure
846 | Gopinath, B, Russell, J, Kifley, A, Flood, VM, Mitchell, P. Adherence to Dietary Guidelines and Successful Aging Over 10 Years. J Gerontol A Biol Sci Med Sci. 2016. 71:349–55. doi:10.1093/gerona/glv189 26503376 | Outcome
847 | Gorczyca, D, Pasciak, M, Szponar, B, Gamian, A, Jankowski, A. An impact of the diet on serum fatty acid and lipid profiles in Polish vegetarian children and children with allergy. Eur J Clin Nutr. 2011. 65:191–5. doi:10.1038/ejcn.2010.231 21048771 | Study Design
848 | Gordon, MM, Bopp, MJ, Easter, L, Miller, GD, Lyles, MF, Houston, DK, Nicklas, BJ, Kritchevsky, SB. Effects of dietary protein on the composition of weight loss in post-menopausal women. J Nutr Health Aging. 2008. 12:505–9. doi:unavailable18810296 | Weight loss/Hypocaloric
849 | Goree, LL, Chandler-Laney, P, Ellis, AC, Casazza, K, Granger, WM, Gower, BA. Dietary macronutrient composition affects beta cell responsiveness but not insulin sensitivity. Am J Clin Nutr. 2011. 94:120–7. doi:10.3945/ajcn.110.002162 21593507 | Outcome; Study duration
850 | Gorna, I, Kowalowka, M, Morawska, A, Kosewski, G, Boleslawska, I, Przyslawskia, J. Influence of the frequency of consumption of foodstuffs on the risk of overweight and obesity in a group of post-menopausal women. Prz Menopauzalny. 2019. 18:39–45. doi:10.5114/pm.2019.84156 31114457 | Study Design; Intervention/Exposure
851 | Gorostegi-Anduaga, I, Corres, P, Jurio-Iriarte, B, Martinez-Aguirre, A, Perez-Asenjo, J, Aispuru, GR, Arenaza, L, Romaratezabala, E, Arratibel-Imaz, I, Mujika, I, Francisco-Terreros, S, Maldonado-Martin, S. Clinical, physical, physiological, and dietary patterns of obese and sedentary adults with primary hypertension characterized by sex and cardiorespiratory fitness: EXERDIET-HTA study. Clin Exp Hypertens. 2018. 40:141–149. doi:10.1080/10641963.2017.1346111 28783384 | Study Design; Outcome
852 | Goss, AM, Goree, LL, Ellis, AC, Chandler-Laney, PC, Casazza, K, Lockhart, ME, Gower, BA. Effects of diet macronutrient composition on body composition and fat distribution during weight maintenance and weight loss. Obesity (Silver Spring). 2013. 21:1139–42. doi:10.1002/oby.20191 | Study duration
853 | Goss, AM, Gower, BA, Soleymani, T, Stewart, M, Fontaine, K. Effects of an egg-based, carbohydraterestricted diet on body composition, fat distribution, and metabolic health in older adults with obesity: preliminary results from a randomized controlled trial. FASEB journal. 2017. 31:. doi:unavailable | Publication Status
854 | Goulet, J, Lamarche, B, Nadeau, G, Lemieux, S. Effect of a nutritional intervention promoting the Mediterranean food pattern on plasma lipids, lipoproteins and body weight in healthy French-Canadian women. Atherosclerosis. 2003. 170:115–24. doi:10.1016/s0021-9150(03)00243-0 12957689 | Study Design
855 | Gower, B, Goss, A, Soleymani, T. Metabolically healthy obese individuals lose more visceral and total body fat with a low-glycemic diet under controlled feeding conditions. Diabetes. 2016. 65:A70-. doi:10.2337/db16-1-381 | Publication Status
856 | Gower, BA, Goree, LL, Chandler-Laney, PC, Ellis, AC, Casazza, K, Granger, WM. A higher-carbohydrate, lower-fat diet reduces fasting glucose concentration and improves beta-cell function in individuals with impaired fasting glucose. Metabolism. 2012. 61:358–65. doi:10.1016/j.metabol.2011.07.011 21944267 | Study duration
857 | Gower, BA, Goss, AM. A lower-carbohydrate, higher-fat diet reduces abdominal and intermuscular fat and increases insulin sensitivity in adults at risk of type 2 diabetes. J Nutr. 2015. 145:177s–83s. doi:10.3945/jn.114.195065 25527677 | Intervention/Exposure; Study duration
858 | Goyenechea, E, Holst, C, van Baak, MA, Saris, WH, Jebb, S, Kafatos, A, Pfeiffer, A, Handjiev, S, Hlavaty, P, Stender, S, Larsen, TM, Astrup, A, Martinez, JA. Effects of different protein content and glycaemic index of ad libitum diets on diabetes risk factors in overweight adults: the DIOGenes multicentre, randomized, dietary intervention trial. Diabetes Metab Res Rev. 2011. 27:705–16. doi:10.1002/dmrr.1218 21591241 | Intervention/Exposure
859 | Grafenauer, SJ, Tapsell, LC, Beck, EJ, Batterham, MJ. Baseline dietary patterns are a significant consideration in correcting dietary exposure for weight loss. Eur J Clin Nutr. 2013. 67:330–6. doi:10.1038/ejcn.2013.26 23403877 | Power/Size
860 | Graffouillere, L, Deschasaux, M, Mariotti, F, Neufcourt, L, Shivappa, N, Hebert, JR, Wirth, MD, Latino-Martel, P, Hercberg, S, Galan, P, Julia, C, Kesse-Guyot, E, Touvier, M. Prospective association between the Dietary Inflammatory Index and mortality: modulation by antioxidant supplementation in the SU.VI.MAX randomized controlled trial. Am J Clin Nutr. 2016. 103:878–85. doi:10.3945/ajcn.115.126243 26864363 | Intervention/Exposure; Outcome
861 | Grandl, G, Straub, L, Rudigier, C, Arnold, M, Wueest, S, Konrad, D, Wolfrum, C. Short-term feeding of a ketogenic diet induces more severe hepatic insulin resistance than an obesogenic high-fat diet. J Physiol. 2018. 596:4597–4609. doi:10.1113/jp275173 30089335 | Participants
862 | Granic, A, Mendonca, N, Sayer, AA, Hill, TR, Davies, K, Siervo, M, Mathers, JC, Jagger, C. Effects of dietary patterns and low protein intake on sarcopenia risk in the very old: The Newcastle 85+ study. Clin Nutr. 2019. :. doi:10.1016/j.clnu.2019.01.009 | Outcome
863 | Grau, K, Tetens, I, Bjornsbo, KS, Heitman, BL. Overall glycaemic index and glycaemic load of habitual diet and risk of heart disease. Public Health Nutr. 2011. 14:109–18. doi:10.1017/s136898001000176x 20576198 | Intervention/Exposure
864 | Gray, A, Smith, C. Fitness, dietary intake, and body mass index in urban Native American youth. J Am Diet Assoc. 2003. 103:1187–91. doi:10.1016/s0002-8223(03)00979-9 12963950 | Study Design
865 | Gray, DL, O’Brien, KD, D’Alessio, DA, Brehm, BJ, Deeg, MA. Plasma glycosylphosphatidylinositol-specific phospholipase D predicts the change in insulin sensitivity in response to a low-fat but not a low-carbohydrate diet in obese women. Metabolism. 2008. 57:473–8. doi:10.1016/j.metabol.2007.11.007 18328347 | Intervention/Exposure; Outcome
866 | Gray-Donald, K, St-Arnaud-McKenzie, D, Gaudreau, P, Morais, JA, Shatenstein, B, Payette, H. Protein intake protects against weight loss in healthy community-dwelling older adults. J Nutr. 2014. 144:321–6. doi:10.3945/jn.113.184705 24357473 | Intervention/Exposure
867 | Greco, M, Chiefari, E, Montalcini, T, Accattato, F, Costanzo, FS, Pujia, A, Foti, D, Brunetti, A, Gulletta, E. Early effects of a hypocaloric, Mediterranean diet on laboratory parameters in obese individuals. Mediators Inflamm. 2014. 2014:750860. doi:10.1155/2014/750860 24729662 | Intervention/Exposure
868 | Green, CA, Yarborough, BJ, Leo, MC, Yarborough, MT, Stumbo, SP, Janoff, SL, Perrin, NA, Nichols, GA, Stevens, VJ. The STRIDE weight loss and lifestyle intervention for individuals taking antipsychotic medications: a randomized trial. Am J Psychiatry. 2015. 172:71–81. doi:10.1176/appi.ajp.2014.14020173 25219423 | Intervention/Exposure
869 | Green, JG, Johnson, NA, Sachinwalla, T, Cunningham, CW, Thompson, MW, Stannard, SR. Low-carbohydrate diet does not affect intramyocellular lipid concentration or insulin sensitivity in lean, physically fit men when protein intake is elevated. Metabolism. 2010. 59:1633–41. doi:10.1016/j.metabol.2010.03.013 20423743 | Study duration
870 | Green, KK, Shea, JL, Vasdev, S, Randell, E, Gulliver, W, Sun, G. Higher Dietary Protein Intake is Associated with Lower Body Fat in the Newfoundland Population. Clin Med Insights Endocrinol Diabetes. 2010. 3:25–35. doi:10.4137/cmed.s4619 22879784 | Study Design; Intervention/Exposure
871 | Greenberg, I, Stampfer, MJ, Schwarzfuchs, D, Shai, I. Adherence and success in long-term weight loss diets: the dietary intervention randomized controlled trial (DIRECT). J Am Coll Nutr. 2009. 28:159–68. doi:10.1080/07315724.2009.10719767 19828901 | Weight loss/Hypocaloric
872 | Greenlee, H, Strizich, G, Lovasi, GS, Kaplan, RC, Biggs, ML, Li, CI, Richardson, J, Burke, GL, Fitzpatrick, AL, Fretts, AM, Psaty, BM, Fried, LP. Concordance With Prevention Guidelines and Subsequent Cancer, Cardiovascular Disease, and Mortality: A Longitudinal Study of Older Adults. Am J Epidemiol. 2017. 186:1168–1179. doi:10.1093/aje/kwx150 29020206 | Intervention/Exposure
873 | Greer, BK, Edsall, KM, Greer, AE. Reliability of BOD POD Measurements Remains High After a Short-Duration Low-Carbohydrate Diet. Int J Sport Nutr Exerc Metab. 2016. 26:145–9. doi:10.1123/ijsnem.2015-0184 26402571 | Study duration
874 | Grieb, P, Klapcinska, B, Smol, E, Pilis, T, Pilis, W, Sadowska-Krepa, E, Sobczak, A, Bartoszewicz, Z, Nauman, J, Stanczak, K, Langfort, J. Long-term consumption of a carbohydrate-restricted diet does not induce deleterious metabolic effects. Nutr Res. 2008. 28:825–33. doi:10.1016/j.nutres.2008.09.011 19083495 | Study Design
875 | Griffin, BA, Walker, CG, Jebb, SA, Moore, C, Frost, GS, Goff, L, Sanders, TAB, Lewis, F, Griffin, M, Gitau, R, Lovegrove, JA. APOE4 Genotype Exerts Greater Benefit in Lowering Plasma Cholesterol and Apolipoprotein B than Wild Type (E3/E3), after Replacement of Dietary Saturated Fats with Low Glycaemic Index Carbohydrates. Nutrients. 2018. 10:. doi:10.3390/nu10101524 | Intervention/Exposure
876 | Griffin, HJ, Cheng, HL, O’Connor, HT, Rooney, KB, Petocz, P, Steinbeck, KS. Higher protein diet for weight management in young overweight women: a 12-month randomized controlled trial. Diabetes Obes Metab. 2013. 15:572–5. doi:10.1111/dom.12056 23279557 | Power/Size
877 | Griffin, HJ, O’Connor, HT, Rooney, KB, Steinbeck, KS, Cheng, HL, Petocz, P. Comparison of higher-protein and higher-carbohydrate diets in overweight and obese young women. Obesity reviews. 2010. 11:823-. doi: | Publication Status
878 | Griffin, LE, Djuric, Z, Angiletta, CJ, Mitchell, CM, Baugh, ME, Davy, KP, Neilson, AP. A Mediterranean diet does not alter plasma trimethylamine N-oxide concentrations in healthy adults at risk for colon cancer. Food Funct. 2019. 10:2138–2147. doi:10.1039/c9fo00333a 30938383 | Outcome
879 | Grimaldi, M, Ciano, O, Manzo, M, Rispoli, M, Guglielmi, M, Limardi, A, Calatola, P, Lucibello, M, Pardo, S, Capaldo, B, Riccardi, G. Intensive dietary intervention promoting the Mediterranean diet in people with high cardiometabolic risk: a non-randomized study. Acta Diabetol. 2018. 55:219–226. doi:10.1007/s00592-017-1078-7 29218417 | Intervention/Exposure; Comparator
880 | Gu, Y, Yu, H, Li, Y, Ma, X, Lu, J, Yu, W, Xiao, Y, Bao, Y, Jia, W. Beneficial effects of an 8-week, very low carbohydrate diet intervention on obese subjects. Evid Based Complement Alternat Med. 2013. 2013:760804. doi:10.1155/2013/760804 23573151 | Study Design
881 | Gu, Y, Zhao, A, Huang, F, Zhang, Y, Liu, J, Wang, C, Jia, W, Xie, G, Jia, W. Very low carbohydrate diet significantly alters the serum metabolic profiles in obese subjects. J Proteome Res. 2013. 12:5801–11. doi:10.1021/pr4008199 24224694 | Study Design
882 | Guasch-Ferre, M, Hruby, A, Salas-Salvado, J, Martinez-Gonzalez, MA, Sun, Q, Willett, WC, Hu, FB. Olive oil consumption and risk of type 2 diabetes in US women. Am J Clin Nutr. 2015. 102:479–86. doi:10.3945/ajcn.115.112029 26156740 | Intervention/Exposure
883 | Guasch-Ferre, M, Hu, FB, Martinez-Gonzalez, MA, Fito, M, Bullo, M, Estruch, R, Ros, E, Corella, D, Recondo, J, Gomez-Gracia, E, Fiol, M, Lapetra, J, Serra-Majem, L, Munoz, MA, Pinto, X, Lamuela-Raventos, RM, Basora, J, Buil-Cosiales, P, Sorli, JV, Ruiz-Gutierrez, V, Martinez, JA, Salas-Salvado, J. Olive oil intake and risk of cardiovascular disease and mortality in the PREDIMED Study. BMC Med. 2014. 12:78. doi:10.1186/1741-7015-12-78 24886626 | Intervention/Exposure
884 | Guay, V, Lamarche, B, Charest, A, Tremblay, AJ, Couture, P. Effect of short-term low- and high-fat diets on low-density lipoprotein particle size in normolipidemic subjects. Metabolism. 2012. 61:76–83. doi:10.1016/j.metabol.2011.06.002 21816443 | Study duration
885 | Guevara-Cruz, M, Tovar, AR, Aguilar-Salinas, CA, Medina-Vera, I, Gil-Zenteno, L, Hernandez-Viveros, I, Lopez-Romero, P, Ordaz-Nava, G, Canizales-Quinteros, S, Guillen Pineda, LE, Torres, N. A dietary pattern including nopal, chia seed, soy protein, and oat reduces serum triglycerides and glucose intolerance in patients with metabolic syndrome. J Nutr. 2012. 142:64–9. doi:10.3945/jn.111.147447 22090467 | Intervention/Exposure
886 | Gulseth, HL, Gjelstad, IM, Tierney, AC, Shaw, DI, Helal, O, Hees, AM, Delgado-Lista, J, Leszczynska-Golabek, I, Karlstrom, B, Lovegrove, J, Defoort, C, Blaak, EE, Lopez-Miranda, J, Dembinska-Kiec, A, Riserus, U, Roche, HM, Birkeland, KI, Drevon, CA. Dietary fat modifications and blood pressure in subjects with the metabolic syndrome in the LIPGENE dietary intervention study. Br J Nutr. 2010. 104:160–3. doi:10.1017/s0007114510000565 20202290 | Intervention/Exposure
887 | Gulseth, HL, Gjelstad, IMF, Tiereny, AC, McCarthy, D, Lovegrove, JA, Defoort, C, Blaak, EE, Lopez-Miranda, J, Dembinska-Kiec, A, Riserus, U, Roche, HM, Drevon, CA, Birkeland, KI. Effects of dietary fat on insulin secretion in subjects with the metabolic syndrome. Eur J Endocrinol. 2019. 180:321–328. doi:10.1530/eje-19-0022 30893645 | Outcome
888 | Gulseth, HL, Gjelstad, IMF, Tierney, AC, Shaw, DI, Helal, O, Hees, AMJV, Delgado-Lista, J, Leszczynska-Golabek, I, Karlström, B, Lovegrove, J, Defoort, C, Blaak, EE, Lopez-Miranda, J, Dembinska-Kiec, A, Risérus, U, Roche, HM, Birkeland, KI, Drevon, CA. Dietary fat modifications and blood pressure in subjects with the metabolic syndrome in the LIPGENE dietary intervention study. British Journal of Nutrition. 2010. 104:160–163. doi:10.1017/S0007114510000565 | Intervention/Exposure
889 | Gungor, S, Celiloglu, OS, Raif, SG, Ozcan, OO, Selimoglu, MA. Malnutrition and Obesity in Children With ADHD. J Atten Disord. 2016. 20:647–52. doi:10.1177/1087054713478465 23475827 | Study Design; Intervention/Exposure
890 | Gunther, AL, Buyken, AE, Kroke, A. The influence of habitual protein intake in early childhood on BMI and age at adiposity rebound: results from the DONALD Study. Int J Obes (Lond). 2006. 30:1072–9. doi:10.1038/sj.ijo.0803288 16520809 | AGE: Intervention/Exposure
891 | Gunther, AL, Karaolis-Danckert, N, Kroke, A, Remer, T, Buyken, AE. Dietary protein intake throughout childhood is associated with the timing of puberty. J Nutr. 2010. 140:565–71. doi:10.3945/jn.109.114934 20042466 | Outcome
892 | Gunther, AL, Remer, T, Kroke, A, Buyken, AE. Early protein intake and later obesity risk: which protein sources at which time points throughout infancy and childhood are important for body mass index and body fat percentage at 7 y of age?. Am J Clin Nutr. 2007. 86:1765–72. doi:10.1093/ajcn/86.5.1765 18065597 | Intervention/Exposure; AGE: Intervention/Exposure
893 | Gunther, AL, Schulze, MB, Kroke, A, Diethelm, K, Joslowski, G, Krupp, D, Wudy, S, Buyken, AE. Early Diet and Later Cancer Risk: Prospective Associations of Dietary Patterns During Critical Periods of Childhood with the GH-IGF Axis, Insulin Resistance and Body Fatness in Younger Adulthood. Nutr Cancer. 2015. 67:877–92. doi:10.1080/01635581.2015.1056313 26226486 | AGE: Intervention/Exposure
894 | Gutierrez-Bedmar, M, Martinez-Gonzalez, MA, Munoz-Bravo, C, Ruiz-Canela, M, Mariscal, A, Salas-Salvado, J, Estruch, R, Corella, D, Aros, F, Fito, M, Lapetra, J, Serra-Majem, L, Pinto, X, Alonso-Gomez, A, Portoles, O, Fiol, M, Bullo, M, Castaner, O, Ros, E, Gomez-Gracia, E. Chromium Exposure and Risk of Cardiovascular Disease in High Cardiovascular Risk Subjects- Nested Case-Control Study in the Prevention With Mediterranean Diet (PREDIMED) Study. Circ J. 2017. 81:1183–1190. doi:10.1253/circj.CJ-17-0032 28392547 | Intervention/Exposure
895 | Gwin, JA, Leidy, HJ. Effects of dietary protein evenly spread throughout the day on sleep and mood in overweight women during sub-chronic energy balance and energy restriction. FASEB journal. 2017. 31:. doi:unavailable | Publication Status
896 | Gwynne, M, Mounsey, A. Mediterranean diet: Higher fat but lower risk. Journal of Family Practice. 2013. 62:745–748. doi:unavailable | Publication Status
897 | Ha, SA, Lee, SY, Kim, KA, Seo, JS, Sohn, CM, Park, HR, Kim, KW. Eating habits, physical activity, nutrition knowledge, and self-efficacy by obesity status in upper-grade elementary school students. Nutr Res Pract. 2016. 10:597–605. doi:10.4162/nrp.2016.10.6.597 27909557 | Study Design; Intervention/Exposure
898 | Haas, MC, Bodner, EV, Brown, CJ, Bryan, D, Buys, DR, Keita, AD, Flagg, LA, Goss, A, Gower, B, Hovater, M, Hunter, G, Ritchie, CS, Roth, DL, Wingo, BC, Ard, J, Locher, JL. Calorie restriction in overweight seniors: response of older adults to a dieting study: the CROSSROADS randomized controlled clinical trial. J Nutr Gerontol Geriatr. 2014. 33:376–400. doi:10.1080/21551197.2014.965993 25424512 | Intervention/Exposure; Comparator
899 | Habowski, S, Ziegenfuss, T, Sandrock, J, Raub, B, Kedia, W, Lopez, H. A prospective evaluation of a commercial weight loss program on body weight and body circumferences in overweight/obese men and women. FASEB journal. 2017. 31:. doi:unavailable | Publication Status
900 | Haghighatdoost, F, Malekahmadi, M, Onvani, S, Ramezani, N, Azadbakht, L. Macronutrient composition and Body Mass Index vary by season in college students. Progress in Nutrition. 2018. 20:483–490. doi:10.23751/pn.v20i3.5313 | Study Design; Comparator
901 | Haire-Joshu, DL, Schwarz, CD, Peskoe, SB, Budd, EL, Brownson, RC, Joshu, CE. A group randomized controlled trial integrating obesity prevention and control for postpartum adolescents in a home visiting program. Int J Behav Nutr Phys Act. 2015. 12:88. doi:10.1186/s12966-015-0247-8 26112041 | Intervention/Exposure
902 | Hajiluian, G, Farhangi, MA, Jahangiry, L. Mediterranean dietary pattern and VEGF +405 G/C gene polymorphisms in patients with metabolic syndrome: An aspect of genenutrient interaction. PLoS ONE. 2017. 12:. doi:10.1371/journal.pone.0171637 | Study Design
903 | Halbesma, N, Bakker, SJ, Jansen, DF, Stolk, RP, De Zeeuw, D, De Jong, PE, Gansevoort, RT. High protein intake associates with cardiovascular events but not with loss of renal function. J Am Soc Nephrol. 2009. 20:1797–804. doi:10.1681/asn.2008060649 19443643 | Intervention/Exposure
904 | Halkjaer, J, Tjonneland, A, Overvad, K, Sorensen, TI. Dietary predictors of 5-year changes in waist circumference. J Am Diet Assoc. 2009. 109:1356–66. doi:10.1016/j.jada.2009.05.015 19631041 | Intervention/Exposure
905 | Halkjaer, J, Tjonneland, A, Thomsen, BL, Overvad, K, Sorensen, TI. Intake of macronutrients as predictors of 5-y changes in waist circumference. Am J Clin Nutr. 2006. 84:789–97. doi:10.1093/ajcn/84.4.789 17023705 | Intervention/Exposure
906 | Hall, KD, Ayuketah, A, Brychta, R, Cai, H, Cassimatis, T, Chen, KY, Chung, ST, Costa, E, Courville, A, Darcey, V, Fletcher, LA, Forde, CG, Gharib, AM, Guo, J, Howard, R, Joseph, PV, McGehee, S, Ouwerkerk, R, Raisinger, K, Rozga, I, Stagliano, M, Walter, M, Walter, PJ, Yang, S, Zhou, M. Ultra-Processed Diets Cause Excess Calorie Intake and Weight Gain: An Inpatient Randomized Controlled Trial of Ad Libitum Food Intake. Cell Metab. 2019. 30:67–77.e3. doi:10.1016/j.cmet.2019.05.008 31105044 | Study duration
907 | Hall, KD, Bemis, T, Brychta, R, Chen, KY, Courville, A, Crayner, EJ, Goodwin, S, Guo, J, Howard, L, Knuth, ND, Miller, BV, 3rd, Prado, CM, Siervo, M, Skarulis, MC, Walter, M, Walter, PJ, Yannai, L. Calorie for Calorie, Dietary Fat Restriction Results in More Body Fat Loss than Carbohydrate Restriction in People with Obesity. Cell Metab. 2015. 22:427–36. doi:10.1016/j.cmet.2015.07.021 26278052 | Study duration
908 | Hall, KD, Chen, KY, Guo, J, Lam, YY, Leibel, RL, Mayer, LE, Reitman, ML, Rosenbaum, M, Smith, SR, Walsh, BT, Ravussin, E. Energy expenditure and body composition changes after an isocaloric ketogenic diet in overweight and obese men. Am J Clin Nutr. 2016. 104:324–33. doi:10.3945/ajcn.116.133561 27385608 | Study Design; Study duration
909 | Hall, WD, Feng, Z, George, VA, Lewis, CE, Oberman, A, Huber, M, Fouad, M, Cutler, JA. Low-fat diet: effect on anthropometrics, blood pressure, glucose, and insulin in older women. Ethn Dis. 2003. 13:337–43. doi:unavailable12894958 | Intervention/Exposure
910 | Hallikainen, M, Toppinen, L, Mykkanen, H, Agren, JJ, Laaksonen, DE, Miettinen, TA, Niskanen, L, Poutanen, KS, Gylling, H. Interaction between cholesterol and glucose metabolism during dietary carbohydrate modification in subjects with the metabolic syndrome. Am J Clin Nutr. 2006. 84:1385–92. doi:10.1093/ajcn/84.6.1385 17158421 | Intervention/Exposure
911 | Hamideh, S, Behzad, M, Ebrahim, G, Hassan, E, Mojtaba, S. Diet, hypertension, hypercholesterolemia and diabetes in ischemic heart diseases. Pakistan Journal of Medical Sciences. 2007. 23:597–601. doi:unavailable | Study Design; Country
912 | Hammons, AJ, Hannon, BA, Teran-Garcia, M, Barragan, M, Villegas, E, Wiley, A, Fiese, B. Effects of Culturally Tailored Nutrition Education on Dietary Quality of Hispanic Mothers: A Randomized Control Trial. J Nutr Educ Behav. 2019. :. doi:10.1016/j.jneb.2019.06.017 | Intervention/Exposure
913 | Hamnvlk, OPR, Saidana, F, Levy, BD, Loscalzo, J. Against the grain. New England Journal of Medicine. 2014. 371:1333–1338. doi:10.1056/NEJMcps1301321 | Study Design
914 | Han, CJ, Korde, L, Reding, S, Reding, K. Impact of a lifestyle intervention on metabolic pathways: results from the diet, exercise, emotional processing, and mindfulness (DEEM) intervention. Molecular cancer research. 2016. 14:. doi:10.1158/1557-3125.METCA15-A34 | Publication Status
915 | Han, JS, Kim, AJ. The Effect of Nutrition and Exercise or Exercise Program alone on Macronutrients, Sodium Intake and Physical Strength in Middle Aged Obese Women. Korean j obes. 2014. 23:187–193. doi:10.7570/kjo.2014.23.3.187 | Language
916 | Han, Y, Kang, D, Lee, SA. Effect of ‘rice’ pattern on high blood pressure by gender and obesity: using the community-based KoGES cohort. Public Health Nutr. 2019. :1–11. doi:10.1017/s136898001900168x | Outcome
917 | Handjieva-Darlenska, T, Holst, C, Grau, K, Blaak, E, Martinez, JA, Oppert, JM, Taylor, MA, Sørensen, TIA, Astrup, A. Clinical correlates of weight loss and attrition during a 10-week dietary intervention study: Results from the NUGENOB project. Obesity Facts. 2015. 5:928–936. doi:10.1159/000345951 | Intervention/Exposure
918 | Hankinson, AL, Daviglus, ML, Van Horn, L, Chan, Q, Brown, I, Holmes, E, Elliott, P, Stamler, J. Diet composition and activity level of at risk and metabolically healthy obese American adults. Obesity (Silver Spring). 2013. 21:637–43. doi:10.1002/oby.20257 23592673 | Study Design
919 | Hansen-Krone, IJ, Enga, KF, Njolstad, I, Hansen, JB, Braekkan, SK. Heart healthy diet and risk of myocardial infarction and venous thromboembolism. The Tromso Study. Thromb Haemost. 2012. 108:554–60. doi:10.1160/th11-11-0818 22739999 | Intervention/Exposure; Publication Date Overlaps with Existing Review
920 | Harber, MP, Schenk, S, Barkan, AL, Horowitz, JF. Alterations in carbohydrate metabolism in response to short-term dietary carbohydrate restriction. Am J Physiol Endocrinol Metab. 2005. 289:E306–12. doi:10.1152/ajpendo.00069.2005 15797987 | Study duration
921 | Harber, MP, Schenk, S, Barkan, AL, Horowitz, JF. Effects of dietary carbohydrate restriction with high protein intake on protein metabolism and the somatotropic axis. J Clin Endocrinol Metab. 2005. 90:5175–81. doi:10.1210/jc.2005-0559 15972575 | Study duration
922 | Hardcastle, SJ, Taylor, AH, Bailey, MP, Harley, RA, Hagger, MS. Effectiveness of a motivational interviewing intervention on weight loss, physical activity and cardiovascular disease risk factors: a randomised controlled trial with a 12-month post-intervention follow-up. Int J Behav Nutr Phys Act. 2013. 10:40. doi:10.1186/1479-5868-10-40 23537492 | Intervention/Exposure
923 | Harding, AH, Day, NE, Khaw, KT, Bingham, S, Luben, R, Welsh, A, Wareham, NJ. Dietary fat and the risk of clinical type 2 diabetes: the European prospective investigation of Cancer-Norfolk study. Am J Epidemiol. 2004. 159:73–82. doi:10.1093/aje/kwh004 14693662 | Intervention/Exposure
924 | Hardy, LL, Mihrshahi, S, Gale, J, Nguyen, B, Baur, LA, O’Hara, BJ. Translational research: are community-based child obesity treatment programs scalable?. BMC Public Health. 2015. 15:652. doi:10.1186/s12889-015-2031-8 26169687 | Study Design; Intervention/Exposure
925 | Hargrove, RL, Etherton, TD, Pearson, TA, Harrison, EH, Kris-Etherton, PM. Low fat and high monounsaturated fat diets decrease human low density lipoprotein oxidative susceptibility in vitro. J Nutr. 2001. 131:1758–63. doi:10.1093/jn/131.6.1758 11385064 | Study duration
926 | Haring, B, von Ballmoos, MC, Appel, LJ, Sacks, FM. Healthy dietary interventions and lipoprotein (a) plasma levels: results from the Omni Heart Trial. PLoS One. 2014. 9:e114859. doi:10.1371/journal.pone.0114859 25506933 | Outcome
927 | Haro, C, Garcia-Carpintero, S, Rangel-Zuniga, OA, Alcala-Diaz, JF, Landa, BB, Clemente, JC, Perez-Martinez, P, Lopez-Miranda, J, Perez-Jimenez, F, Camargo, A. Consumption of Two Healthy Dietary Patterns Restored Microbiota Dysbiosis in Obese Patients with Metabolic Dysfunction. Mol Nutr Food Res. 2017. 61:. doi:10.1002/mnfr.201700300 | Outcome
928 | Harrington, DM, Champagne, CM, Broyles, ST, Johnson, WD, Tudor-Locke, C, Katzmarzyk, PT. Cardiometabolic risk factor response to a lifestyle intervention: a randomized trial. Metab Syndr Relat Disord. 2015. 13:125–31. doi:10.1089/met.2014.0112 25569324 | Intervention/Exposure; Comparator
929 | Harrington, JM, Dahly, DL, Fitzgerald, AP, Gilthorpe, MS, Perry, IJ. Capturing changes in dietary patterns among older adults: a latent class analysis of an ageing Irish cohort. Public Health Nutr. 2014. 17:2674–86. doi:10.1017/s1368980014000111 24564930 | Power/Size
930 | Harris, C, Flexeder, C, Thiering, E, Buyken, A, Berdel, D, Koletzko, S, Bauer, CP, Bruske, I, Koletzko, B, Standl, M. Changes in dietary intake during puberty and their determinants: results from the GINIplus birth cohort study. BMC Public Health. 2015. 15:841. doi:10.1186/s12889-015-2189-0 26329931 | Intervention/Exposure
931 | Harris, KA, West, SG, Vanden Heuvel, JP, Kris-Etherton, PM. A refined carbohydrate diet attenuates weight loss in insulin resistant individuals. Circulation. 2012. 125:. doi:unavailable | Publication Status
932 | Harrison, T, McCullough, D, Lane, KE, Boddy, LM, Stewart, CE, Enright, KJ, Amirabdollahian, F, Schmidt, MA, Davies, IG. Dietary carbohydrate intake, visceral adipose tissue and associated markers of cardiometabolic risk. Proceedings of the nutrition society. 2018. 77:. doi:10.1017/S0029665118001751 | Publication Status
933 | Harsha, DW, Sacks, FM, Obarzanek, E, Svetkey, LP, Lin, PH, Bray, GA, Aickin, M, Conlin, PR, Miller, ER, 3rd, Appel, LJ. Effect of dietary sodium intake on blood lipids: results from the DASH-sodium trial. Hypertension. 2004. 43:393–8. doi:10.1161/01.HYP.0000113046.83819.a2 14707154 | Intervention/Exposure
934 | Hartman, TJ, Albert, PS, Zhang, Z, Bagshaw, D, Kris-Etherton, PM, Ulbrecht, J, Miller, CK, Bobe, G, Colburn, NH, Lanza, E. Consumption of a legume-enriched, low-glycemic index diet is associated with biomarkers of insulin resistance and inflammation among men at risk for colorectal cancer. Journal of Nutrition. 2010. 140:60–67. doi:10.3945/jn.109.114249 | Intervention/Exposure
935 | Harvey, Cjdc, Schofield, GM, Zinn, C, Thornley, SJ, Crofts, C, Merien, FLR. Low-carbohydrate diets differing in carbohydrate restriction improve cardiometabolic and anthropometric markers in healthy adults: A randomised clinical trial. PeerJ. 2019. 7:e6273. doi:10.7717/peerj.6273 30740270 | Intervention/Exposure
936 | Harvie, M, Wright, C, Pegington, M, McMullan, D, Mitchell, E, Martin, B, Cutler, RG, Evans, G, Whiteside, S, Maudsley, S, Camandola, S, Wang, R, Carlson, OD, Egan, JM, Mattson, MP, Howell, A. The effect of intermittent energy and carbohydrate restriction v. daily energy restriction on weight loss and metabolic disease risk markers in overweight women. Br J Nutr. 2013. 110:1534–47. doi:10.1017/s0007114513000792 23591120 | Intervention/Exposure
937 | Hashemian, M, Farvid, MS, Poustchi, H, Murphy, G, Etemadi, A, Hekmatdoost, A, Kamangar, F, Sheikh, M, Pourshams, A, Sepanlou, SG, Fazeltabar Malekshah, A, Khoshnia, M, Gharavi, A, Brennan, PJ, Boffetta, P, Dawsey, SM, Reedy, J, Subar, AF, Abnet, CC, Malekzadeh, R. The application of six dietary scores to a Middle Eastern population: a comparative analysis of mortality in a prospective study. Eur J Epidemiol. 2019. 34:371–382. doi:10.1007/s10654-019-00508-3 30887377 | Country
938 | Hassan, NE, El Shebini, SM, Ahmed, NH. Association between Dietary Patterns, Breakfast Skipping and Familial Obesity among a Sample of Egyptian Families. Open Access Maced J Med Sci. 2016. 4:213–8. doi:10.3889/oamjms.2016.050 27335589 | Study Design
939 | Hassannejad, R, Kazemi, I, Sadeghi, M, Mohammadifard, N, Roohafza, H, Sarrafzadegan, N, Talaei, M, Mansourian, M. Longitudinal association of metabolic syndrome and dietary patterns: A 13-year prospective population-based cohort study. Nutr Metab Cardiovasc Dis. 2018. 28:352–360. doi:10.1016/j.numecd.2017.10.025 29458993 | Country
940 | Hassapidou, M, Tziomalos, K, Lazaridou, S, Pagkalos, I, Papadimitriou, K, Kokkinopoulou, A, Tzotzas, T. The Nutrition Health Alliance (NutriHeAl) Study: A Randomized, Controlled, Nutritional Intervention Based on Mediterranean Diet in Greek Municipalities. J Am Coll Nutr. 2019. :1–7. doi:10.1080/07315724.2019.1660928 | Intervention/Exposure
941 | Hassapidou, MN, Fotiadou, E. Dietary intakes and food habits of adolescents in northern Greece. Int J Food Sci Nutr. 2001. 52:109–16. doi:10.1080/713671767 11303458 | Study Design; Comparator
942 | Haub, MD, Wells, AM, Tarnopolsky, MA, Campbell, WW. Effect of protein source on resistive-training-induced changes in body composition and muscle size in older men. Am J Clin Nutr. 2002. 76:511–7. doi:10.1093/ajcn/76.3.511 12197993 | Intervention/Exposure
943 | Haufe, S, Engeli, S, Kast, P, Bohnke, J, Utz, W, Haas, V, Hermsdorf, M, Mahler, A, Wiesner, S, Birkenfeld, AL, Sell, H, Otto, C, Mehling, H, Luft, FC, Eckel, J, Schulz-Menger, J, Boschmann, M, Jordan, J. Randomized comparison of reduced fat and reduced carbohydrate hypocaloric diets on intrahepatic fat in overweight and obese human subjects. Hepatology. 2011. 53:1504–14. doi:10.1002/hep.24242 21400557 | Weight loss/Hypocaloric
944 | Haugaard, SB, Madsbad, S, Hoy, CE, Vaag, A. Dietary intervention increases n-3 long-chain polyunsaturated fatty acids in skeletal muscle membrane phospholipids of obese subjects. Implications for insulin sensitivity. Clin Endocrinol (Oxf). 2006. 64:169–78. doi:10.1111/j.1365-2265.2006.02444.x 16430716 | Study Design
945 | Haulrik, N, Toubro, S, Dyerberg, J, Stender, S, Skov, AR, Astrup, A. Effect of protein and methionine intakes on plasma homocysteine concentrations: a 6-mo randomized controlled trial in overweight subjects. Am J Clin Nutr. 2002. 76:1202–6. doi:10.1093/ajcn/76.6.1202 12450883 | Outcome
946 | Hauner, H. High-fat mediterranean diet leads to slight weight reduction. Deutsche medizinische wochenschrift (1946). 2016. 141:1278. doi:10.1055/s-0042-111570 27598910 | Publication Status; Language
947 | Hauser, ME, Hartle, J, Qin, F, Rigdon, J, Del Gobbo, L, Shih, C, Gardner, CD. Dietary adherence and dietary quality are associated with weight loss success among those following low-fat and low-carbohydrate diets. Circulation. 2018. 137:. doi:unavailable | Publication Status
948 | Hays, NP, Starling, RD, Liu, X, Sullivan, DH, Trappe, TA, Fluckey, JD, Evans, WJ. Effects of an ad libitum low-fat, high-carbohydrate diet on body weight, body composition, and fat distribution in older men and women: a randomized controlled trial. Arch Intern Med. 2004. 164:210–7. doi:10.1001/archinte.164.2.210 14744846 | Power/Size
949 | He, DH, Yang, M, Zhang, RH, Ma, XG, Huang, LC, Huang, ES, Gu, W, Zhu, YB, Zhao, D, Zhu, XH, Ding, GQ, Zhou, B. Dietary Patterns Associated Metabolic Syndrome in Chinese Adults. Biomed Environ Sci. 2015. 28:370–3. doi:10.3967/bes2015.051 26055564 | Publication Status
950 | He, F, Bixler, EO, Liao, J, Berg, A, Imamura Kawasawa, Y, Fernandez-Mendoza, J, Vgontzas, AN, Liao, D. Habitual sleep variability, mediated by nutrition intake, is associated with abdominal obesity in adolescents. Sleep Med. 2015. 16:1489–94. doi:10.1016/j.sleep.2015.07.028 26611945 | Intervention/Exposure
951 | Heatherly, AJ, Killen, LG, Smith, AF, Waldman, HS, Seltmann, CL, Hollingsworth, A, O’Neal, EK. Effects of Ad libitum Low-Carbohydrate High-Fat Dieting in Middle-Age Male Runners. Med Sci Sports Exerc. 2018. 50:570–579. doi:10.1249/mss.0000000000001477 29112626 | Study duration
952 | Hebestreit, A, Bornhorst, C, Pala, V, Barba, G, Eiben, G, Veidebaum, T, Hadjigergiou, C, Molnar, D, Claessens, M, Fernandez-Alvira, JM, Pigeot, I. Dietary energy density in young children across Europe. Int J Obes (Lond). 2014. 38 Suppl 2:S124–34. doi:10.1038/ijo.2014.143 25376214 | Intervention/Exposure
953 | Heggen, E, Klemsdal, TO, Haugen, F, Holme, I, Tonstad, S. Effect of a low-fat versus a low-gycemic-load diet on inflammatory biomarker and adipokine concentrations. Metab Syndr Relat Disord. 2012. 10:437–42. doi:10.1089/met.2012.0012 22889406 | Weight loss/Hypocaloric
954 | Heggen, E, Svendsen, M, Klemsdal, TO, Tonstad, S. Low Carbohydrate and Moderately Fat-Reduced Diets Similarly Affected Early Weight Gain in Varenicline-Treated Overweight or Obese Smokers. Nicotine Tob Res. 2016. 18:1440–8. doi:10.1093/ntr/ntv164 26242289 | Intervention/Exposure
955 | Heianza, Y, Ma, W, Huang, T, Wang, T, Zheng, Y, Smith, SR, Bray, GA, Sacks, FM, Qi, L. Macronutrient Intake-Associated FGF21 Genotype Modifies Effects of Weight-Loss Diets on 2-Year Changes of Central Adiposity and Body Composition: The POUNDS Lost Trial. Diabetes Care. 2016. 39:1909–1914. doi:10.2337/dc16-1111 27581055 | Intervention/Exposure; Comparator
956 | Heianza, Y, Sun, D, Ma, W, Zheng, Y, Champagne, CM, Bray, GA, Sacks, FM, Qi, L. Gut-microbiome-related LCT genotype and 2-year changes in body composition and fat distribution: the POUNDS Lost Trial. Int J Obes (Lond). 2018. 42:1565–1573. doi:10.1038/s41366-018-0046-9 29568104 | Intervention/Exposure
957 | Heikkilä, HM, Krachler, B, Rauramaa, R, Schwab, US. Diet, insulin secretion and insulin sensitivity - The Dose-Responses to Exercise Training (DR’s EXTRA) Study (ISRCTN45977199). British Journal of Nutrition. 2014. 112:1530–1541. doi:10.1017/S0007114514002426 | Study Design
958 | Heikkila, HM, Krachler, B, Savonen, K, Hassinen, M, Rauramaa, R, Schwab, US. Combined low-saturated fat intake and high fitness may counterbalance diabetogenic effects of obesity: the DR’s EXTRA Study. Eur J Clin Nutr. 2013. 67:1000–2. doi:10.1038/ejcn.2013.138 23900242 | Study Design; Intervention/Exposure
959 | Helge, JW. Prolonged adaptation to fat-rich diet and training; effects on body fat stores and insulin resistance in man. Int J Obes Relat Metab Disord. 2002. 26:1118–24. doi:10.1038/sj.ijo.0802058 12119578 | Study duration
960 | Helms, ER, Zinn, C, Rowlands, DS, Naidoo, R, Cronin, J. High-protein, low-fat, short-term diet results in less stress and fatigue than moderate-protein moderate-fat diet during weight loss in male weightlifters: a pilot study. Int J Sport Nutr Exerc Metab. 2015. 25:163–70. doi:10.1123/ijsnem.2014-0056 25028958 | Study duration
961 | Henderson, M, Benedetti, A, Gray-Donald, K. Dietary composition and its associations with insulin sensitivity and insulin secretion in youth. Br J Nutr. 2014. 111:527–34. doi:10.1017/s0007114513002572 24047611 | Study Design; Intervention/Exposure
962 | Hengeveld, LM, Wijnhoven, HAH, Olthof, MR, Brouwer, IA, Harris, TB, Kritchevsky, SB, Newman, AB, Visser, M. Prospective associations of poor diet quality with long-term incidence of protein-energy malnutrition in community-dwelling older adults: the Health, Aging, and Body Composition (Health ABC) Study. Am J Clin Nutr. 2018. 107:155–164. doi:10.1093/ajcn/nqx020 29529142 | Outcome
963 | Hermanussen, M. Nutritional protein intake is associated with body mass index in young adolescents. Georgian Med News. 2008. :84–8. doi:unavailable18403817 | Publication Status; Country
964 | Hernáez, Á, Castañer, O, Elosua, R, Pintó, X, Estruch, R, Salas-Salvadó, J, Corella, D, Arós, F, Serra-Majem, L, Fiol, M, Ortega-Calvo, M, Ros, E, Martínez-González, Á M, De La Torre, R, López-Sabater, MC, Fitó, M. Mediterranean Diet Improves High-Density Lipoprotein Function in High-Cardiovascular-Risk Individuals. Circulation. 2017. 135:633–643. doi:10.1161/CIRCULATIONAHA.116.023712 28193797 | Study Design; Outcome
965 | Hernaez, A, Castaner, O, Elosua, R, Pinto, X, Estruch, R, Salas-Salvado, J, Corella, D, Aros, F, Serra-Majem, L, Fiol, M, Ortega-Calvo, M, Ros, E, Martinez-Gonzalez, MA, de la Torre, R, Lopez-Sabater, MC, Fito, M. Mediterranean Diet Improves High-Density Lipoprotein Function in High-Cardiovascular-Risk Individuals: A Randomized Controlled Trial. Circulation. 2017. 135:633–643. doi:10.1161/circulationaha.116.023712 28193797 | Outcome
966 | Hernaez, A, Castaner, O, Goday, A, Ros, E, Pinto, X, Estruch, R, Salas-Salvado, J, Corella, D, Aros, F, Serra-Majem, L, Martinez-Gonzalez, MA, Fiol, M, Lapetra, J, de la Torre, R, Lopez-Sabater, MC, Fito, M. The Mediterranean Diet decreases LDL atherogenicity in high cardiovascular risk individuals: a randomized controlled trial. Mol Nutr Food Res. 2017. 61:. doi:10.1002/mnfr.201601015 | Outcome
967 | Hernaez, A, Sanllorente, A, Castaner, O, Martinez-Gonzalez, MA, Ros, E, Pinto, X, Estruch, R, Salas-Salvado, J, Corella, D, Alonso-Gomez, AM, Serra-Majem, L, Fiol, M, Lapetra, J, Gomez-Gracia, E, de la Torre, R, Lamuela-Raventos, RM, Fito, M. Increased Consumption of Virgin Olive Oil, Nuts, Legumes, Whole Grains, and Fish Promotes HDL Functions in Humans. Mol Nutr Food Res. 2019. 63:e1800847. doi:10.1002/mnfr.201800847 30628167 | Intervention/Exposure
968 | Hernandez, JA, Del Valle Laveaga, D, Cano, JM. Sub-patterns of food consumption and hyperglycemia in Mexican young people: a study by factor analysis. Food Nutr Res. 2016. 60:30185. doi:10.3402/fnr.v60.30185 26928049 | Study Design; Intervention/Exposure
969 | Hernandez-Mijares, A, Banuls, C, Rocha, M, Morillas, C, Martinez-Triguero, ML, Victor, VM, Lacomba, R, Alegria, A, Barbera, R, Farre, R, Lagarda, MJ. Effects of phytosterol ester-enriched low-fat milk on serum lipoprotein profile in mildly hypercholesterolaemic patients are not related to dietary cholesterol or saturated fat intake. Br J Nutr. 2010. 104:1018–25. doi:10.1017/s0007114510001686 20456813 | Intervention/Exposure
970 | Herrmann, TS, Bean, ML, Black, TM, Wang, P, Coleman, RA. High glycemic index carbohydrate diet alters the diurnal rhythm of leptin but not insulin concentrations. Exp Biol Med (Maywood). 2001. 226:1037–44. doi:10.1177/153537020122601111 11743140 | Study duration
971 | Hess, AL, Carayol, J, Blaedel, T, Hager, J, Di Cara, A, Astrup, A, Saris, WHM, Larsen, LH, Valsesia, A. Analysis of circulating angiopoietin-like protein 3 and genetic variants in lipid metabolism and liver health: the DiOGenes study. Genes Nutr. 2018. 13:7. doi:10.1186/s12263-018-0597-3 29619113 | Intervention/Exposure; Outcome
972 | Hesselink, AE, Bilo, HJ, Jonkers, R, Martens, M, de Weerdt, I, Rutten, GE. A cluster-randomized controlled trial to study the effectiveness of a protocol-based lifestyle program to prevent type 2 diabetes in people with impaired fasting glucose. BMC Fam Pract. 2013. 14:184. doi:10.1186/1471-2296-14-184 24295397 | Intervention/Exposure
973 | Hickey, JT, Hickey, L, Yancy, WS, Hepburn, J, Westman, EC. Clinical use of a carbohydrate-restricted diet to treat the dyslipidemia of the metabolic syndrome. Metab Syndr Relat Disord. 2003. 1:227–32. doi:10.1089/154041903322716705 18370666 | Intervention/Exposure
974 | Hickling, S, Hung, J, Knuiman, M, Divitini, M, Beilby, J. Are the associations between diet and C-reactive protein independent of obesity?. Prev Med. 2008. 47:71–6. doi:10.1016/j.ypmed.2008.02.007 18329089 | Study Design; Intervention/Exposure
975 | Hickner, RC. Take flight to reduce cardiovascular disease risk in youth. Exerc Sport Sci Rev. 2014. 42:143–4. doi:10.1249/jes.0000000000000028 25185448 | Study Design; Publication Status
976 | Hikmat, F, Appel, LJ. Effects of the DASH diet on blood pressure in patients with and without metabolic syndrome: results from the DASH trial. J Hum Hypertens. 2014. 28:170–5. doi:10.1038/jhh.2013.52 24067348 | Study duration
977 | Hill, AM, Harris Jackson, KA, Roussell, MA, West, SG, Kris-Etherton, PM. Type and amount of dietary protein in the treatment of metabolic syndrome: a randomized controlled trial. Am J Clin Nutr. 2015. 102:757–70. doi:10.3945/ajcn.114.104026 26354540 | Power/Size
978 | Hinderliter, A, Smith, P, Sherwood, A, Blumenthal, J. Lifestyle interventions reduce the need for guideline-directed antihypertensive medication. Hypertension. 2018. 72:. doi:10.1161/hyp.72.suppl_1.P388 | Publication Status
979 | Hinderliter, AL, Sherwood, A, Craighead, LW, Lin, PH, Watkins, L, Babyak, MA, Blumenthal, JA. The long-term effects of lifestyle change on blood pressure: One-year follow-up of the ENCORE study. Am J Hypertens. 2014. 27:734–41. doi:10.1093/ajh/hpt183 24084586 | Intervention/Exposure; Comparator
980 | Hindy, G, Sonestedt, E, Ericson, U, Jing, XJ, Zhou, Y, Hansson, O, Renstrom, E, Wirfalt, E, Orho-Melander, M. Role of TCF7L2 risk variant and dietary fibre intake on incident type 2 diabetes. Diabetologia. 2012. 55:2646–2654. doi:10.1007/s00125-012-2634-x 22782288 | Intervention/Exposure
981 | Hirsch, O, Kluckner, VJ, Brandt, S, Moss, A, Weck, M, Florath, I, Wabitsch, M, Hebebrand, J, Schimmelmann, BG, Christiansen, H. Restrained and external-emotional eating patterns in young overweight children-results of the Ulm Birth Cohort Study. PLoS One. 2014. 9:e105303. doi:10.1371/journal.pone.0105303 25141134 | Intervention/Exposure
982 | Hjartaker, A, Knudsen, MD, Tretli, S, Weiderpass, E. Consumption of berries, fruits and vegetables and mortality among 10,000 Norwegian men followed for four decades. Eur J Nutr. 2015. 54:599–608. doi:10.1007/s00394-014-0741-9 25087093 | Intervention/Exposure
983 | Hjerkinn, EM, Sandvik, L, Hjermann, I, Arnesen, H. Effect of diet intervention on long-term mortality in healthy middle-aged men with combined hyperlipidaemia. Journal of Internal Medicine. 2004. 255:68–73. doi:10.1046/j.0954-6820.2003.01248.x 14687240 | Intervention/Exposure; Outcome
984 | Hjerpsted, J, Leedo, E, Tholstrup, T. Cheese intake in large amounts lowers LDL-cholesterol concentrations compared with butter intake of equal fat content. Am J Clin Nutr. 2011. 94:1479–84. doi:10.3945/ajcn.111.022426 22030228 | Intervention/Exposure
985 | Hjorth, MF, Astrup, A, Zohar, Y, Urban, LE, Sayer, RD, Patterson, BW, Herring, SJ, Klein, S, Zemel, BS, Foster, GD, Wyatt, HR, Hill, JO. Personalized nutrition: pretreatment glucose metabolism determines individual long-term weight loss responsiveness in individuals with obesity on low-carbohydrate versus low-fat diet. Int J Obes (Lond). 2019. 43:2037–2044. doi:10.1038/s41366-018-0298-4 30568260 | Intervention/Exposure
986 | Hlebowicz, J, Persson, M, Gullberg, B, Sonestedt, E, Wallstrom, P, Drake, I, Nilsson, J, Hedblad, B, Wirfalt, E. Food patterns, inflammation markers and incidence of cardiovascular disease: the Malmo Diet and Cancer study. J Intern Med. 2011. 270:365–76. doi:10.1111/j.1365-2796.2011.02382.x 21443679 | Publication Date Overlaps with Existing Review
987 | Ho, CY, Huang, YC, Lo, YT, Wahlqvist, ML, Lee, MS. Breakfast is associated with the metabolic syndrome and school performance among Taiwanese children. Res Dev Disabil. 2015. 43–44:179–88. doi:10.1016/j.ridd.2015.07.003 | Study Design; Intervention/Exposure; Country
988 | Hobbs, M, Green, M, Roberts, K, Griffiths, C, McKenna, J. Reconsidering the relationship between fast-food outlets, area-level deprivation, diet quality and body mass index: an exploratory structural equation modelling approach. J Epidemiol Community Health. 2019. 73:861–866. doi:10.1136/jech-2018-211798 31171581 | Study Design
989 | Hodge, AM, English, DR, O’Dea, K, Giles, GG. Dietary patterns and diabetes incidence in the Melbourne collaborative cohort study. American Journal of Epidemiology. 2007. 165:603–610. doi:10.1093/aje/kwk061 17220476 | Intervention/Exposure; Publication Date Overlaps with Existing Review
990 | Hodge, AM, English, DR, O’Dea, K, Giles, GG. Glycemic index and dietary fiber and the risk of type 2 diabetes. Diabetes Care. 2004. 27:2701–6. doi:10.2337/diacare.27.11.2701 15505008 | Intervention/Exposure; Outcome
991 | Hodge, AM, O’Dea, K, English, DR, Giles, GG, Flicker, L. Dietary patterns as predictors of successful ageing. J Nutr Health Aging. 2014. 18:221–7. doi:10.1007/s12603-013-0405-0 24626747 | Outcome
992 | Hodgson, JM, Burke, V, Beilin, LJ, Puddey, IB. Partial substitution of carbohydrate intake with protein intake from lean red meat lowers blood pressure in hypertensive persons. Am J Clin Nutr. 2006. 83:780–7. doi:10.1093/ajcn/83.4.780 16600928 | Study duration
993 | Hodson, L, Harnden, KE, Roberts, R, Dennis, AL, Frayn, KN. Does the DASH diet lower blood pressure by altering peripheral vascular function?. J Hum Hypertens. 2010. 24:312–9. doi:10.1038/jhh.2009.65 19657359 | Intervention/Exposure; Publication Date Overlaps with Existing Review
994 | Hodson, L, Skeaff, CM, Chisholm, WA. The effect of replacing dietary saturated fat with polyunsaturated or monounsaturated fat on plasma lipids in free-living young adults. Eur J Clin Nutr. 2001. 55:908–15. doi:10.1038/sj.ejcn.1601234 11593354 | Intervention/Exposure; Study duration
995 | Hodson, L, Skeaff, CM, McKenzie, JE. Maximal response to a plasma cholesterol-lowering diet is achieved within two weeks. Nutr Metab Cardiovasc Dis. 2002. 12:291–5. doi:unavailable12616809 | Study duration
996 | Hoevenaar-Blom, MP, Nooyens, ACJ, Kromhout, D, Spijkerman, AMW, Beulens, JWJ, van der Schouw, YT, Bueno-deMesquita, B, Verschuren, WMM. Mediterranean Style Diet and 12-Year Incidence of Cardiovascular Diseases: The EPIC-NL Cohort Study. PLoS ONE. 2012. 7:. doi:10.1371/journal.pone.0045458 | Publication Date Overlaps with Existing Review
997 | Hoffman, JR, Ratamess, NA, Kang, J, Falvo, MJ, Faigenbaum, AD. Effect of protein intake on strength, body composition and endocrine changes in strength/power athletes. J Int Soc Sports Nutr. 2006. 3:12–8. doi:10.1186/1550-2783-3-2-12 18500968 | Power/Size
998 | Hoffmann, K, Schulze, MB, Schienkiewitz, A, Nothlings, U, Boeing, H. Application of a new statistical method to derive dietary patterns in nutritional epidemiology. Am J Epidemiol. 2004. 159:935–44. doi:10.1093/aje/kwh134 15128605 | Intervention/Exposure; Publication Date Overlaps with Existing Review
999 | Holloway, CJ, Cochlin, LE, Emmanuel, Y, Murray, A, Codreanu, I, Edwards, LM, Szmigielski, C, Tyler, DJ, Knight, NS, Saxby, BK, Lambert, B, Thompson, C, Neubauer, S, Clarke, K. A high-fat diet impairs cardiac high-energy phosphate metabolism and cognitive function in healthy human subjects. Am J Clin Nutr. 2011. 93:748–55. doi:10.3945/ajcn.110.002758 21270386 | Study duration
1000 | Holmberg, S, Thelin, A, Stiernstrom, EL. Food choices and coronary heart disease: a population based cohort study of rural Swedish men with 12 years of follow-up. Int J Environ Res Public Health. 2009. 6:2626–38. doi:10.3390/ijerph6102626 20054459 | Intervention/Exposure
1001 | Holme, I. Long-term survival in pre-specified groups at risk in the Oslo Study, 1972-1973. Scand J Public Health. 2015. 43:117–22. doi:10.1177/1403494814558157 25575502 | Intervention/Exposure; Comparator
1002 | Holt, S. Cochrane corner: Mediterranean diet for the prevention of cardiovascular disease. Advances in Integrative Medicine. 2014. 1:61. doi:10.1016/j.aimed.2013.08.009 | Study Design; Publication Status
1003 | Honemann, I, Ranke, C, Austel, A, Jarzemski, S, Deeken, I, Pleyer, I, Renziehausen, F, Pudel, V, Ellrott, T. Changes of cardiovascular risk factors while following one of three currently discussed dietetic weight-reducing strategies. Aktuelle ernahrungsmedizin. 2010. 35:227–235. doi:10.1055/s-0030-1248497 | Language
1004 | Honerlaw, JP, Ho, YL, Nguyen, XT, Cho, K, Vassy, JL, Gagnon, DR, O’Donnell, CJ, Gaziano, JM, Wilson, PWF, Djousse, L. Fried food consumption and risk of coronary artery disease: The Million Veteran Program. Clin Nutr. 2019. :. doi:10.1016/j.clnu.2019.05.008 | Intervention/Exposure
1005 | Hong, K, Kim, K, Lee, S. High percentage of fat intakes, not low fat oxidation, may induce overweight cyclists. J Sports Med Phys Fitness. 2012. 52:405–12. doi:unavailable22828462 | Study Design; Study duration
1006 | Hong, X, Xu, F, Wang, Z, Liang, Y, Li, J. Dietary patterns and the incidence of hyperglyacemia in China. Public Health Nutr. 2016. 19:131–41. doi:10.1017/s1368980015000774 25880390 | Country
1007 | Hooshmand, F, Asghari, G, Yuzbashian, E, Mahdavi, M, Mirmiran, P, Azizi, F. Modified Healthy Eating Index and Incidence of Metabolic Syndrome in Children and Adolescents: Tehran Lipid and Glucose Study. J Pediatr. 2018. 197:134–139.e2. doi:10.1016/j.jpeds.2018.01.080 29631767 | Study Design; Country
1008 | Hoppu, U, Isolauri, E, Koskinen, P, Laitinen, K. Diet and blood lipids in 1-4 year-old children. Nutr Metab Cardiovasc Dis. 2013. 23:980–6. doi:10.1016/j.numecd.2012.10.007 23182924 | Study Design; Intervention/Exposure
1009 | Horan, MK, McGowan, CA, Gibney, ER, Donnelly, JM, McAuliffe, FM. Maternal diet and weight at 3 months postpartum following a pregnancy intervention with a low glycaemic index diet: results from the ROLO randomised control trial. Nutrients. 2014. 6:2946–55. doi:10.3390/nu6072946 25057103 | Outcome; Participants
1010 | Hoscan, Y, Yigit, F, Muderrisoglu, H. Adherence to Mediterranean diet and its relation with cardiovascular diseases in Turkish population. Int J Clin Exp Med. 2015. 8:2860–6. doi:unavailable25932246 | Power/Size
1011 | Hosking, D, Danthiir, V. Retrospective lifetime dietary patterns are associated with demographic and cardiovascular health variables in an older community-dwelling Australian population. Br J Nutr. 2013. 110:2069–83. doi:10.1017/s000711451300144x 23726359 | Publication Date Overlaps with Existing Review
1012 | Hosseini, N, Talaei, M, Dianatkhah, M, Sadeghi, M, Oveisgharan, S, Sarrafzadegan, N. Determinants of Incident Metabolic Syndrome in a Middle Eastern Population: Isfahan Cohort Study. Metab Syndr Relat Disord. 2017. 15:354–362. doi:10.1089/met.2016.0156 28677982 | Country
1013 | Hosseini, Z, Whiting, SJ, Vatanparast, H. Type 2 diabetes prevalence among Canadian adults - dietary habits and sociodemographic risk factors. Appl Physiol Nutr Metab. 2019. 44:1099–1104. doi:10.1139/apnm-2018-0567 31386561 | Study Design
1014 | Hosseini-Esfahani, F, Esfandiar, Z, Mirmiran, P, Daneshpour, MS, Ghanbarian, A, Azizi, F. The interaction of cholesteryl ester transfer protein gene variations and diet on changes in serum lipid profiles. Eur J Clin Nutr. 2019. 73:1291–1298. doi:10.1038/s41430-019-0397-x 30705383 | Intervention/Exposure
1015 | Hosseini-Esfahani, F, Koochakpoor, G, Daneshpour, MS, Sedaghati-Khayat, B, Mirmiran, P, Azizi, F. Mediterranean Dietary Pattern Adherence Modify the Association between FTO Genetic Variations and Obesity Phenotypes. Nutrients. 2017. 9:. doi:10.3390/nu9101064 | Country
1016 | Hosseini-Esfahani, F, Koochakpoor, G, Mirmiran, P, Daneshpour, MS, Azizi, F. Dietary patterns modify the association between fat mass and obesity-associated genetic variants and changes in obesity phenotypes. Br J Nutr. 2019. 121:1247–1254. doi:10.1017/s0007114519000643 30929646 | Intervention/Exposure; Comparator
1017 | Hosseini-Esfahani, F, Mirmiran, P, Daneshpour, MS, Mehrabi, Y, Hedayati, M, Soheilian-Khorzoghi, M, Azizi, F. Dietary patterns interact with APOA1/APOC3 polymorphisms to alter the risk of the metabolic syndrome: the Tehran Lipid and Glucose Study. Br J Nutr. 2015. 113:644–53. doi:10.1017/s0007114514003687 25653052 | Comparator; Outcome
1018 | Hosseini-Esfahani, F, Mirmiran, P, Daneshpour, MS, Mehrabi, Y, Hedayati, M, Zarkesh, M, Azizi, F. Western dietary pattern interaction with APOC3 polymorphism in the risk of metabolic syndrome: Tehran Lipid and Glucose Study. J Nutrigenet Nutrigenomics. 2014. 7:105–17. doi:10.1159/000365445 25301527 | Study Design; Country
1019 | Houston, DK, Nicklas, BJ, Ding, J, Harris, TB, Tylavsky, FA, Newman, AB, Lee, JS, Sahyoun, NR, Visser, M, Kritchevsky, SB. Dietary protein intake is associated with lean mass change in older, community-dwelling adults: the Health, Aging, and Body Composition (Health ABC) Study. Am J Clin Nutr. 2008. 87:150–5. doi:10.1093/ajcn/87.1.150 18175749 | Intervention/Exposure
1020 | Howard, BV, Manson, JE, Stefanick, ML, Beresford, SA, Frank, G, Jones, B, Rodabough, RJ, Snetselaar, L, Thomson, C, Tinker, L, Vitolins, M, Prentice, R. Low-fat dietary pattern and weight change over 7 years: the Women’s Health Initiative Dietary Modification Trial. Jama. 2006. 295:39–49. doi:10.1001/jama.295.1.39 16391215 | Intervention/Exposure
1021 | Howard, BV, Van Horn, L, Hsia, J, Manson, JE, Stefanick, MI, Wassertheil-Smoller, S, Kuller, LH, LaCroix, AZ, Langer, RD, Lasser, NI, , . Low-fat dietary pattern and risk of cardiovascular disease: the women’s health initiative randomized controlled dietary modification trial. Obstetrical & gynecological survey. 2006. 61:451–453. doi:10.1097/01.ogx.0000224659.41638.7d | Publication Status
1022 | Howard, BV, Van Horn, L, Hsia, J, Manson, JE, Stefanick, ML, Wassertheil-Smoller, S, Kuller, LH, LaCroix, AZ, Langer, RD, Lasser, NL, Lewis, CE, Limacher, MC, Margolis, KL, Mysiw, WJ, Ockene, JK, Parker, LM, Perri, MG, Phillips, L, Prentice, RL, Robbins, J, Rossouw, JE, Sarto, GE, Schatz, IJ, Snetselaar, LG, Stevens, VJ, Tinker, LF, Trevisan, M, Vitolins, MZ, Anderson, GL, Assaf, AR, Bassford, T, Beresford, SA, Black, HR, Brunner, RL, Brzyski, RG, Caan, B, Chlebowski, RT, Gass, M, Granek, I, Greenland, P, Hays, J, Heber, D, Heiss, G, Hendrix, SL, Hubbell, FA, Johnson, KC, Kotchen, JM. Low-fat dietary pattern and risk of cardiovascular disease: the Women’s Health Initiative Randomized Controlled Dietary Modification Trial. Jama. 2006. 295:655–66. doi:10.1001/jama.295.6.655 16467234 | Intervention/Exposure
1023 | Howe, AS, Skidmore, PM, Parnell, WR, Wong, JE, Lubransky, AC, Black, KE. Cardiorespiratory fitness is positively associated with a healthy dietary pattern in New Zealand adolescents. Public Health Nutr. 2016. 19:1279–87. doi:10.1017/s1368980015002566 26347042 | Study Design
1024 | Howe, HR, 3rd, Heidal, K, Choi, MD, Kraus, RM, Boyle, K, Hickner, RC. Increased adipose tissue lipolysis after a 2-week high-fat diet in sedentary overweight/obese men. Metabolism. 2011. 60:976–81. doi:10.1016/j.metabol.2010.09.007 21040937 | Study duration
1025 | Hron, BM, Ebbeling, CB, Feldman, HA, Ludwig, DS. Relationship of insulin dynamics to body composition and resting energy expenditure following weight loss. Obesity (Silver Spring). 2015. 23:2216–22. doi:10.1002/oby.21213 26373701 | Study duration
1026 | Hsiao, PY, Mitchell, DC, Wood, GC, Jensen, GL, Still, CD, Hartman, TJ. The association of dietary patterns and weight change in rural older adults 75 years and older. J Nutr Gerontol Geriatr. 2014. 33:357–75. doi:10.1080/21551197.2014.959681 25424511 | Power/Size
1027 | Hsu, WC, Lau, KH, Matsumoto, M, Moghazy, D, Keenan, H, King, GL. Improvement of insulin sensitivity by isoenergy high carbohydrate traditional Asian diet: a randomized controlled pilot feasibility study. PLoS One. 2014. 9:e106851. doi:10.1371/journal.pone.0106851 25226279 | Study duration
1028 | Hu, FB, Rimm, EB, Stampfer, MJ, Ascherio, A, Spiegelman, D, Willett, WC. Prospective study of major dietary patterns and risk of coronary heart disease in men. Am J Clin Nutr. 2000. 72:912–21. doi:10.1093/ajcn/72.4.912 11010931 | Intervention/Exposure
1029 | Hu, M, Li, Z, Fang, DZ. The C-514T polymorphism of hepatic lipase gene modulates the impact of a high carbohydrate diet on lipid profile in healthy Chinese young adults. Asian Biomedicine. 2012. 6:675–682. doi:10.5372/1905-7415.0605.107 | Intervention/Exposure; Study duration
1030 | Hu, T, Reynolds, K, Yao, L, Bunol, C, Liu, Y, Chen, CS, He, J, Bazzano, L. The long-term effect of a low-carbohydrate diet on endothelial dysfunction and insulin resistance: a randomized controlled trial. Circulation. 2013. 127:. doi:unavailable | Publication Status
1031 | Hu, T, Stuchlik, P, Yao, L, Reynolds, K, Whelton, P, He, J, Bazzano, L. Adherence to low carbohydrate and low fat diets in relation to weight loss and cardiovascular risk factor reduction. Circulation. 2015. 131:. doi:unavailable | Publication Status
1032 | Hu, T, Yao, L, Reynolds, K, Niu, T, Li, S, Whelton, PK, He, J, Steffen, LM, Bazzano, LA. Adherence to low-carbohydrate and low-fat diets in relation to weight loss and cardiovascular risk factors. Obes Sci Pract. 2016. 2:24–31. doi:10.1002/osp4.23 27114827 | Intervention/Exposure
1033 | Hu, T, Yao, L, Reynolds, K, Whelton, PK, Niu, T, Li, S, He, J, Bazzano, LA. The Effects of a Low-Carbohydrate Diet vs. a Low-Fat Diet on Novel Cardiovascular Risk Factors: A Randomized Controlled Trial. Nutrients. 2015. 7:7978–94. doi:10.3390/nu7095377 26393645 | Outcome
1034 | Hu, TY, Chen, YC, Lin, P, Shih, CK, Bai, CH, Yuan, KC, Lee, SY, Chang, JS. Testosterone-Associated Dietary Pattern Predicts Low Testosterone Levels and Hypogonadism. Nutrients. 2018. 10:. doi:10.3390/nu10111786 | Study Design
1035 | Hu, TY, Lee, SY, Shih, CK, Chou, MJ, Wu, MC, Teng, IC, Bai, CH, Sabrina, N, Tinkov, AA, Skalny, AV, Chang, JS. Soluble CD163-Associated Dietary Patterns and the Risk of Metabolic Syndrome. Nutrients. 2019. 11:. doi:10.3390/nu11040940 | Study Design
1036 | Huang, JH, Li, RH, Huang, SL, Sia, HK, Hsu, WT, Tang, FC. Health-associated nutrition and exercise behaviors in relation to metabolic risk factors stratified by body mass index. International Journal of Environmental Research and Public Health. 2019. 16:. doi:10.3390/ijerph16050869 | Study Design
1037 | Huang, T, Beaty, T, Li, J, Liu, H, Zhao, W, Wang, Y. Association between dietary fat intake and insulin resistance in Chinese child twins. Br J Nutr. 2017. 117:230–236. doi:10.1017/s0007114516004542 28120734 | Country
1038 | Huang, T, Huang, J, Qi, Q, Li, Y, Bray, GA, Rood, J, Sacks, FM, Qi, L. PCSK7 genotype modifies effect of a weight-loss diet on 2-year changes of insulin resistance: the POUNDS LOST trial. Diabetes Care. 2015. 38:439–44. doi:10.2337/dc14-0473 25504030 | Outcome
1039 | Huang, T, Shen, Y, Zheng, Y, Smith, S, Bray, G, Sacks, F, Qi, L. Dietary fat intake, MC4R genotype and 2-year changes in body composition: the pounds lost trial. Circulation. 2015. 131:. doi:unavailable | Publication Status
1040 | Huang, T, Wang, T, Heianza, Y, Sun, D, Ivey, K, Durst, R, Schwarzfuchs, D, Stampfer, MJ, Bray, GA, Sacks, FM, Shai, I, Qi, L. HNF1A variant, energy-reduced diets and insulin resistance improvement during weight loss: The POUNDS Lost trial and DIRECT. Diabetes Obes Metab. 2018. 20:1445–1452. doi:10.1111/dom.13250 29424957 | Intervention/Exposure
1041 | Huang, T, Wang, T, Heianza, Y, Sun, D, Zheng, Y, Bray, G, Sacks, FM, Qi, L. Genetic susceptibility to obesity, weight-loss diets, and improvement of insulin resistance and beta-cell function: the pounds lost trial. Diabetes. 2016. 65:A391-. doi:10.2337/db16-1375-1656 | Publication Status
1042 | Huang, T, Xu, M, Lee, A, Cho, S, Qi, L. Consumption of whole grains and cereal fiber and total and cause-specific mortality: prospective analysis of 367,442 individuals. BMC Med. 2015. 13:59. doi:10.1186/s12916-015-0294-7 25858689 | Intervention/Exposure
1043 | Huang, T, Zheng, Y, Bray, GA, Sacks, FM, Qi, L. Diabetes genetic score, 2-year changes in insulin sensitivity, and insulin resistance in response to weight loss diets: the pounds lost trial. Diabetes. 2015. 64:A423–A424. doi: | Publication Status
1044 | Huang, X, Gong, R, Lin, J, Li, R, Xiao, L, Duan, W, Fang, D. Effects of lipoprotein lipase gene variations, a highcarbohydrate low-fat diet, and gender on serum lipid profiles in healthy Chinese Han youth. Biosci Trends. 2011. 5:198–204. doi:unavailable22101375 | Study duration; Country
1045 | Huang, Z, Li, N, Hu, YM. Dietary patterns and their effects on postpartum weight retention of lactating women in south central China. Nutrition. 2019. 67–68:110555. doi:10.1016/j.nut.2019.110555 | Study Design; Participants
1046 | Hudson, JL, Kim, JE, Paddon-Jones, D, Campbell, WW. Evenly re-distributing daily dietary protein intake does not augment changes in body composition and cardio-metabolic health indexes. FASEB journal. 2017. 31:. doi:unavailable | Publication Status
1047 | Huete, L, Manzano-Lista, FJ, Aranguez, I, Fernandez-Alfonso, MS. Impact of pharmacist’s intervention on reducing cardiovascular risk in obese patients. Int J Clin Pharm. 2019. 41:1099–1109. doi:10.1007/s11096-019-00856-w 31161498 | Study Design; Intervention/Exposure
1048 | Huffman, KM, Hawk, VH, Henes, ST, Ocampo, CI, Orenduff, MC, Slentz, CA, Johnson, JL, Houmard, JA, Samsa, GP, Kraus, WE, Bales, CW. Exercise effects on lipids in persons with varying dietary patterns - Does diet matter if they exercise? Responses in Studies of a Targeted Risk Reduction Intervention through Defined Exercise I. American Heart Journal. 2012. 164:117–124. doi:10.1016/j.ahj.2012.04.014 22795291 | Intervention/Exposure
1049 | Huisman, MJ, Soedamah-Muthu, SS, Vermeulen, E, Muilwijk, M, Snijder, MB, Nicolaou, MN, van Valkengoed, IGM. Does a High Sugar High Fat Dietary Pattern Explain the Unequal Burden in Prevalence of Type 2 Diabetes in a Multi-Ethnic Population in The Netherlands? The HELIUS Study. Nutrients. 2018. 10:. doi:10.3390/nu10010092 | Study Design
1050 | Hulmi, JJ, Isola, V, Suonpaa, M, Jarvinen, NJ, Kokkonen, M, Wennerstrom, A, Nyman, K, Perola, M, Ahtiainen, JP, Hakkinen, K. The Effects of Intensive Weight Reduction on Body Composition and Serum Hormones in Female Fitness Competitors. Front Physiol. 2016. 7:689. doi:10.3389/fphys.2016.00689 28119632 | Intervention/Exposure
1051 | Hulsegge, G, van der Schouw, YT, Daviglus, ML, Smit, HA, Verschuren, WM. Determinants of attaining and maintaining a low cardiovascular risk profile--the Doetinchem Cohort Study. Eur J Public Health. 2016. 26:135–40. doi:10.1093/eurpub/ckv125 26130798 | Outcome
1052 | Hume, DJ, Kroff, J, Clamp, LD, Lambert, EV. Compensations for Weight Loss in Successful and Unsuccessful Dieters. Am J Health Behav. 2015. 39:589–600. doi:10.5993/ajhb.39.5.1 26248169 | Intervention/Exposure; Outcome
1053 | Hung, CJ, Huang, PC, Li, YH, Lu, SC, Ho, LT, Chou, HF. Taiwanese vegetarians have higher insulin sensitivity than omnivores. British Journal of Nutrition. 2006. 95:129–135. doi:10.1079/BJN20051588 | Study Design; Country
1054 | Hung, JD, Murray, SW, Shaw, MA, Unwin, D. Impact of a low carbohydrate diet on traditional CVD risk factors in people with features of the metabolic syndrome and type 2 diabetes. European journal of preventive cardiology. 2018. 25:S14–S15. doi:unavailable | Publication Status
1055 | Hwalla, N, Torbay, N, Andari, N, Adra, N, Azar, ST, Habbal, Z. Restoration of normal insulinemia and insulin sensitivity in hyperinsulinemic normoglycemic men by a hypoenergetic high monounsaturated fat diet. Journal of Nutritional and Environmental Medicine. 2004. 14:29–38. doi:10.1080/13590840410001695211 | Study duration
1056 | Hwang, JY, Lee, H, Ko, A, Han, CJ, Chung, HW, Chang, N. Dietary changes in Vietnamese marriage immigrant women: The KoGES follow-up study. Nutr Res Pract. 2014. 8:319–26. doi:10.4162/nrp.2014.8.3.319 24944778 | Intervention/Exposure; Comparator
1057 | Hyde, PN, Sapper, TN, Crabtree, CD, LaFountain, RA, Bowling, ML, Buga, A, Fell, B, McSwiney, FT, Dickerson, RM, Miller, VJ, Scandling, D, Simonetti, OP, Phinney, SD, Kraemer, WJ, King, SA, Krauss, RM, Volek, JS. Dietary carbohydrate restriction improves metabolic syndrome independent of weight loss. JCI Insight. 2019. 4:. doi:10.1172/jci.insight.128308 | Study duration
1058 | Iacovides, S, Goble, D, Paterson, B, Meiring, RM. Three consecutive weeks of nutritional ketosis has no effect on cognitive function, sleep, and mood compared with a high-carbohydrate, low-fat diet in healthy individuals: a randomized, crossover, controlled trial. Am J Clin Nutr. 2019. 110:349–357. doi:10.1093/ajcn/nqz073 31098615 | Study duration
1059 | Ibarra-Reynoso Ldel, R, Pisarchyk, L, Perez-Luque, EL, Garay-Sevilla, ME, Malacara, JM. Dietary restriction in obese children and its relation with eating behavior, fibroblast growth factor 21 and leptin: a prospective clinical intervention study. Nutr Metab (Lond). 2015. 12:31. doi:10.1186/s12986-015-0027-0 26379757 | Intervention/Exposure
1060 | Ibe, Y, Takahashi, Y, Sone, H. Food groups and weight gain in Japanese men. Clin Obes. 2014. 4:157–64. doi:10.1111/cob.12056 25826771 | Intervention/Exposure; Comparator
1061 | Ibrahim, M, Bonfiglio, S, Schlogl, M, Vinales, KL, Piaggi, P, Venti, C, Walter, M, Krakoff, J, Thearle, MS. Energy Expenditure and Hormone Responses in Humans After Overeating High-Fructose Corn Syrup Versus Whole-Wheat Foods. Obesity (Silver Spring). 2018. 26:141–149. doi:10.1002/oby.22068 29193741 | Intervention/Exposure; Study duration
1062 | Ibsen, DB, Laursen, ASD, Lauritzen, L, Tjonneland, A, Overvad, K, Jakobsen, MU. Substitutions between dairy product subgroups and risk of type 2 diabetes: the Danish Diet, Cancer and Health cohort. Br J Nutr. 2017. 118:989–997. doi:10.1017/s0007114517002896 29173212 | Intervention/Exposure
1063 | Iglay, HB, Thyfault, JP, Apolzan, JW, Campbell, WW. Resistance training and dietary protein: effects on glucose tolerance and contents of skeletal muscle insulin signaling proteins in older persons. Am J Clin Nutr. 2007. 85:1005–13. doi:10.1093/ajcn/85.4.1005 17413099 | Intervention/Exposure
1064 | Ilich, JZ, Kelly, OJ, Liu, PY, Shin, H, Kim, Y, Chi, Y, Wickrama, Kkas, Colic-Baric, I. Role of Calcium and Low-Fat Dairy Foods in Weight-Loss Outcomes Revisited: Results from the Randomized Trial of Effects on Bone and Body Composition in Overweight/Obese Postmenopausal Women. Nutrients. 2019. 11:. doi:10.3390/nu11051157 | Intervention/Exposure
1065 | Imamura, F, Lemaitre, RN, King, IB, Song, X, Steffen, LM, Folsom, AR, Siscovick, DS, Mozaffarian, D. Long-chain monounsaturated Fatty acids and incidence of congestive heart failure in 2 prospective cohorts. Circulation. 2013. 127:1512–21, 1521e1–18. doi:10.1161/circulationaha.112.001197 23487436 | Intervention/Exposure
1066 | Inelmen, EM, Toffanello, ED, Enzi, G, Sergi, G, Coin, A, Busetto, L, Manzato, E. Differences in dietary patterns between older and younger obese and overweight outpatients. J Nutr Health Aging. 2008. 12:3–8. doi:unavailable18165838 | Publication Date Overlaps with Existing Review
1067 | Isanejad, M, LaCroix, AZ, Thomson, CA, Tinker, L, Larson, JC, Qi, Q, Qi, L, Cooper-DeHoff, RM, Phillips, LS, Prentice, RL, Beasley, JM. Branched-chain amino acid, meat intake and risk of type 2 diabetes in the Women’s Health Initiative. Br J Nutr. 2017. 117:1523–1530. doi:10.1017/s0007114517001568 28721839 | Intervention/Exposure
1068 | Isanejad, M, Mursu, J, Sirola, J, Kroger, H, Rikkonen, T, Tuppurainen, M, Erkkila, AT. Association of protein intake with the change of lean mass among elderly women: The Osteoporosis Risk Factor and Prevention - Fracture Prevention Study (OSTPRE-FPS). J Nutr Sci. 2015. 4:e41. doi:10.1017/jns.2015.31 26793306 | Intervention/Exposure
1069 | Isanejad, M, Mursu, J, Sirola, J, Kroger, H, Rikkonen, T, Tuppurainen, M, Erkkila, AT. Dietary protein intake is associated with better physical function and muscle strength among elderly women. Br J Nutr. 2016. 115:1281–91. doi:10.1017/s000711451600012x 26857389 | Intervention/Exposure; Outcome
1070 | Isanejad, M, Sirola, J, Mursu, J, Rikkonen, T, Kroger, H, Tuppurainen, M, Erkkila, AT. Association of the Baltic Sea and Mediterranean diets with indices of sarcopenia in elderly women, OSPTRE-FPS study. Eur J Nutr. 2018. 57:1435–1448. doi:10.1007/s00394-017-1422-2 28303397 | Power/Size
1071 | Itoh, K, Moriguchi, R, Yamada, Y, Fujita, M, Yamato, T, Oumi, M, Holst, JJ, Seino, Y. High saturated fatty acid intake induces insulin secretion by elevating gastric inhibitory polypeptide levels in healthy individuals. Nutr Res. 2014. 34:653–60. doi:10.1016/j.nutres.2014.07.013 25172378 | Intervention/Exposure; Study duration
1072 | Izadi, V, Esmaillzadeh, A, Hashemipour, M, Surkan, PJ, Azadbakht, L, Kelishadi, R. High protein diets do not affect anthropometric indexes and cardiometabolic risk factors among children with excess weight: A randomized controlled trial. J Cardiovasc Thorac Res. 2018. 10:95–103. doi:10.15171/jcvtr.2018.15 30116508 | Intervention/Exposure
1073 | Izadpanah, A, Barnard, RJ, Almeda, AJ, Baldwin, GC, Bridges, SA, Shellman, ER, Burant, CF, Roberts, CK. A short-term diet and exercise intervention ameliorates inflammation and markers of metabolic health in overweight/obese children. Am J Physiol Endocrinol Metab. 2012. 303:E542–50. doi:10.1152/ajpendo.00190.2012 22713506 | Study duration
1074 | Izaola, O, Primo, D, Gomez Hoyos, E, Lopez Gomez, JJ, Ortola, A, de Luis, D. Association of rs670 variant of APOA1 gene with lipid profile and insulin resistance after 9 months of a high protein/low carbohydrate vs a standard hypocaloric diet. Clinical nutrition (Edinburgh, Scotland). 2019. :. doi:10.1016/j.clnu.2019.04.030 | Study Design; Intervention/Exposure
1075 | Jaacks, LM, Sher, S, Staercke, C, Porkert, M, Alexander, WR, Jones, DP, Vaccarino, V, Ziegler, TR, Quyyumi, AA. Pilot randomized controlled trial of a Mediterranean diet or diet supplemented with fish oil, walnuts, and grape juice in overweight or obese US adults. BMC Nutr. 2018. 4:26. doi:10.1186/s40795-018-0234-y 30271610 | Power/Size
1076 | Jaaskelainen, A, Kaila-Kangas, L, Leino-Arjas, P, Lindbohm, ML, Nevanpera, N, Remes, J, Jarvelin, MR, Laitinen, J. Association between occupational psychosocial factors and waist circumference is modified by diet among men. Eur J Clin Nutr. 2015. 69:1053–9. doi:10.1038/ejcn.2015.59 25898811 | Intervention/Exposure
1077 | Jabekk, PT, Moe, IA, Meen, HD, Tomten, SE, Hostmark, AT. Resistance training in overweight women on a ketogenic diet conserved lean body mass while reducing body fat. Nutr Metab (Lond). 2010. 7:17. doi:10.1186/1743-7075-7-17 20196854 | Study duration
1078 | Jaceldo-Siegl, K, Haddad, E, Knutsen, S, Fan, J, Lloren, J, Bellinger, D, Fraser, GE. Lower C-reactive protein and IL-6 associated with vegetarian diets are mediated by BMI. Nutr Metab Cardiovasc Dis. 2018. 28:787–794. doi:10.1016/j.numecd.2018.03.003 29704951 | Study Design
1079 | Jaceldo-Siegl, K, Lutjohann, D, Sirirat, R, Mashchak, A, Fraser, GE, Haddad, E. Variations in dietary intake and plasma concentrations of plant sterols across plant-based diets among North American adults. Mol Nutr Food Res. 2017. 61:. doi:10.1002/mnfr.201600828 | Study Design; Outcome
1080 | Jacka, FN, Cherbuin, N, Anstey, KJ, Butterworth, P. Dietary patterns and depressive symptoms over time: examining the relationships with socioeconomic position, health behaviours and cardiovascular risk. PLoS One. 2014. 9:e87657. doi:10.1371/journal.pone.0087657 24489946 | Study Design; Outcome
1081 | Jackson, SL, Cunningham, SA. The stability of children’s weight status over time, and the role of television, physical activity, and diet. Prev Med. 2017. 100:229–234. doi:10.1016/j.ypmed.2017.04.026 28450122 | Intervention/Exposure
1082 | Jacobo-Albavera, L, Posadas-Romero, C, Vargas-Alarcon, G, Romero-Hidalgo, S, Posadas-Sanchez, R, Gonzalez-Salazar Mdel, C, Carnevale, A, Canizales-Quinteros, S, Medina-Urrutia, A, Antunez-Arguelles, E, Villarreal-Molina, T. Dietary fat and carbohydrate modulate the effect of the ATP-binding cassette A1 (ABCA1) R230C variant on metabolic risk parameters in premenopausal women from the Genetics of Atherosclerotic Disease (GEA) Study. Nutr Metab (Lond). 2015. 12:45. doi:10.1186/s12986-015-0040-3 26579206 | Study Design; Intervention/Exposure
1083 | Jacobs, B, De Angelis-Schierbaum, G, Egert, S, Assmann, G, Kratz, M. Individual serum triglyceride responses to high-fat and low-fat diets differ in men with modest and severe hypertriglyceridemia. J Nutr. 2004. 134:1400–5. doi:10.1093/jn/134.6.1400 15173403 | Study duration
1084 | Jacques, PF, Cassidy, A, Rogers, G, Peterson, JJ, Dwyer, JT. Dietary flavonoid intakes and CVD incidence in the Framingham Offspring Cohort. Br J Nutr. 2015. 114:1496–503. doi:10.1017/s0007114515003141 26334117 | Intervention/Exposure
1085 | Jagim, A, Byrd, M, Lockard, B, Baetge, C, Levers, K, Galvan, E, Simbo, S, Jung, YP, Oliver, J, Koozehchian, M, , . Adherence to a high protein and low fat energy-restricted diet while participating in a circuit resistance-exercise program promotes positive changes in blood glucose and lipids in postmenopausal women. FASEB journal. 2013. 27:. doi:unavailable | Publication Status
1086 | Jago, R, Baranowski, T, Baranowski, JC, Thompson, D, Greaves, KA. BMI from 3-6y of age is predicted by TV viewing and physical activity, not diet. International Journal of Obesity. 2005. 29:557–564. doi:10.1038/sj.ijo.0802969 15889113 | Intervention/Exposure
1087 | Jakicic, JM, King, WC, Marcus, MD, Davis, KK, Helsel, D, Rickman, AD, Gibbs, BB, Rogers, RJ, Wahed, A, Belle, SH. Short-term weight loss with diet and physical activity in young adults: The IDEA study. Obesity (Silver Spring). 2015. 23:2385–97. doi:10.1002/oby.21241 26538477 | Intervention/Exposure
1088 | Jakobsen, MU, Dethlefsen, C, Due, KM, May, AM, Romaguera, D, Vergnaud, AC, Norat, T, Sorensen, TI, Halkjaer, J, Tjonneland, A, Boutron-Ruault, MC, Clavel-Chapelon, F, Fagherazzi, G, Teucher, B, Kuhn, T, Bergmann, MM, Boeing, H, Naska, A, Orfanos, P, Trichopoulou, A, Palli, D, Santucci De Magistris, M, Sieri, S, Bueno-de-Mesquita, HB, van der, Dl A, Engeset, D, Hjartaker, A, Rodriguez, L, Agudo, A, Molina-Montes, E, Huerta, JM, Barricarte, A, Amiano, P, Manjer, J, Wirfalt, E, Hallmans, G, Johansson, I, Khaw, KT, Wareham, NJ, Key, TJ, Chajes, V, Slimani, N, Riboli, E, Peeters, PH, Overvad, K. Fish consumption and subsequent change in body weight in European women and men. Br J Nutr. 2013. 109:353–62. doi:10.1017/s0007114512001079 22716915 | Intervention/Exposure
1089 | Jakobsen, MU, Dethlefsen, C, Joensen, AM, Stegger, J, Tjonneland, A, Schmidt, EB, Overvad, K. Intake of carbohydrates compared with intake of saturated fatty acids and risk of myocardial infarction: importance of the glycemic index. Am J Clin Nutr. 2010. 91:1764–8. doi:10.3945/ajcn.2009.29099 20375186 | Intervention/Exposure
1090 | Jakobsen, MU, Madsen, L, Dethlefsen, C, Due, KM, Halkjaer, J, Sorensen, TI, Kristiansen, K, Overvad, K. Dietary n-6 PUFA, carbohydrate:protein ratio and change in body weight and waist circumference: a follow-up study. Public Health Nutr. 2015. 18:1317–23. doi:10.1017/s1368980014001578 25160900 | Intervention/Exposure
1091 | Jakobsen, MU, Madsen, L, Skjoth, F, Berentzen, TL, Halkjaer, J, Tjonneland, A, Schmidt, EB, Sorensen, TI, Kristiansen, K, Overvad, K. Dietary intake and adipose tissue content of long-chain n-3 PUFAs and subsequent 5-y change in body weight and waist circumference. Am J Clin Nutr. 2017. 105:1148–1157. doi:10.3945/ajcn.116.140079 28356276 | Intervention/Exposure
1092 | Jakobsen, MU, Overvad, K, Dyerberg, J, Schroll, M, Heitmann, BL. Dietary fat and risk of coronary heart disease: possible effect modification by gender and age. Am J Epidemiol. 2004. 160:141–9. doi:10.1093/aje/kwh193 15234935 | Intervention/Exposure
1093 | Jakse, B, Jakse, B, Pajek, J, Pajek, M. Effects of ad libitum consumed, low-fat, high-fiber plant-based diet supplemented with plant-based meal replacements on cardiovascular risk factors. Food Nutr Res. 2019. 63:. doi:10.29219/fnr.v63.1560 | Study Design; Intervention/Exposure
1094 | Jalali-Farahani, S, Amiri, P, Akbar, HM, Cheraghi, L, Karimi, M, Azizi, F. Effects of a Healthy Lifestyle Education on the Incidence of Metabolic Syndrome in Children during a 13-Year Follow-up. Int J Behav Med. 2018. 25:131–140. doi:10.1007/s12529-017-9680-1 28795355 | Study Design; Intervention/Exposure; Country
1095 | Jamar, G, Pisani, LP, Medeiros, A, Oyama, LM, Masquio, DC, Colantonio, E, Garcia, S, Sanches, RB, dos Santos Moraes, A, Belote, C, Caranti, DA. Effect of Fat Intake on the Inflammatory Process and Cardiometabolic Risk in Obesity After Interdisciplinary Therapy. Horm Metab Res. 2016. 48:106–11. doi:10.1055/s-0035-1548871 26372897 | Study Design; Intervention/Exposure
1096 | James, EL, Stacey, FG, Chapman, K, Boyes, AW, Burrows, T, Girgis, A, Asprey, G, Bisquera, A, Lubans, DR. Impact of a nutrition and physical activity intervention (ENRICH: Exercise and Nutrition Routine Improving Cancer Health) on health behaviors of cancer survivors and carers: a pragmatic randomized controlled trial. BMC Cancer. 2015. 15:710. doi:10.1186/s12885-015-1775-y 26471791 | Intervention/Exposure
1097 | Jancey, JM, Dos Remedios Monteiro, SM, Dhaliwal, SS, Howat, PA, Burns, S, Hills, AP, Anderson, AS. Dietary outcomes of a community based intervention for mothers of young children: a randomised controlled trial. Int J Behav Nutr Phys Act. 2014. 11:120. doi:10.1186/s12966-014-0120-1 25245213 | Outcome
1098 | Janda, J, Veleminsky, M, Sulakova, T, Prochazka, B, Eliasek, J, Stransky, P, Rokyta, R. Effect of the DASH-diet and salt Kardisal® on blood pressure in adolescents with prehypertension (cooperative multicentre interventional study). Neuroendocrinology Letters. 2017. 38:544–548. doi:unavailable | Intervention/Exposure
1099 | Janicke, DM, Lim, CS, Perri, MG, Mathews, AE, Bobroff, LB, Gurka, MJ, Parish, A, Brumback, BA, Dumont-Driscoll, M, Silverstein, JH. Featured Article: Behavior Interventions Addressing Obesity in Rural Settings: The E-FLIP for Kids Trial. J Pediatr Psychol. 2019. 44:889–901. doi:10.1093/jpepsy/jsz029 31039250 | Intervention/Exposure
1100 | Jankovic, N, Geelen, A, Streppel, MT, de Groot, LC, Kiefte-de Jong, JC, Orfanos, P, Bamia, C, Trichopoulou, A, Boffetta, P, Bobak, M, Pikhart, H, Kee, F, O’Doherty, MG, Buckland, G, Woodside, J, Franco, OH, Ikram, MA, Struijk, EA, Pajak, A, Malyutina, S, Kubinova, R, Wennberg, M, Park, Y, Bueno-de-Mesquita, HB, Kampman, E, Feskens, EJ. WHO guidelines for a healthy diet and mortality from cardiovascular disease in European and American elderly: the CHANCES project. Am J Clin Nutr. 2015. 102:745–56. doi:10.3945/ajcn.114.095117 26354545 | Intervention/Exposure
1101 | Jankovic, N, Steppel, MT, Kampman, E, de Groot, LC, Boshuizen, HC, Soedamah-Muthu, SS, Kromhout, D, Feskens, EJ. Stability of dietary patterns assessed with reduced rank regression; the Zutphen Elderly Study. Nutr J. 2014. 13:30. doi:10.1186/1475-2891-13-30 24690194 | Power/Size
1102 | Jansen, EC, Kasper, N, Lumeng, JC, Brophy Herb, HE, Horodynski, MA, Miller, AL, Contreras, D, Peterson, KE. Changes in household food insecurity are related to changes in BMI and diet quality among Michigan Head Start preschoolers in a sex-specific manner. Soc Sci Med. 2017. 181:168–176. doi:10.1016/j.socscimed.2017.04.003 28407601 | Power/Size
1103 | Jansen, S, Lopez-Miranda, J, Castro, P, Lopez-Segura, F, Marin, C, Ordovas, JM, Paz, E, Jimenez-Pereperez, J, Fuentes, F, Perez-Jimenez, F. Low-fat and high-monounsaturated fatty acid diets decrease plasma cholesterol ester transfer protein concentrations in young, healthy, normolipemic men. Am J Clin Nutr. 2000. 72:36–41. doi:10.1093/ajcn/72.1.36 10871558 | Study duration
1104 | Japas, C, Knutsen, S, Dehom, S, Dos Santos, H, Tonstad, S. Body mass index gain between ages 20 and 40 years and lifestyle characteristics of men at ages 40-60 years: the Adventist Health Study-2. Obes Res Clin Pract. 2014. 8:e549–57. doi:10.1016/j.orcp.2013.11.007 25434910 | Study Design; Outcome
1105 | Jarvis, M, McNaughton, L, Seddon, A, Thompson, D. The acute 1-week effects of the Zone diet on body composition, blood lipid levels, and performance in recreational endurance athletes. J Strength Cond Res. 2002. 16:50–7. doi:unavailable11834107 | Study duration
1106 | Jayasinghe, SN, Breier, BH, McNaughton, SA, Russell, AP, Della Gatta, PA, Mason, S, Stonehouse, W, Walsh, DCI, Kruger, R. Dietary Patterns in New Zealand Women: Evaluating Differences in Body Composition and Metabolic Biomarkers. Nutrients. 2019. 11:. doi:10.3390/nu11071643 | Study Design
1107 | Jebb, SA, Lovegrove, JA, Griffin, BA, Frost, GS, Moore, CS, Chatfield, MD, Bluck, LJ, Williams, CM, Sanders, TA. Effect of changing the amount and type of fat and carbohydrate on insulin sensitivity and cardiovascular risk: the RISCK (Reading, Imperial, Surrey, Cambridge, and Kings) trial. Am J Clin Nutr. 2010. 92:748–58. doi:10.3945/ajcn.2009.29096 20739418 | Weight loss/Hypocaloric
1108 | Jen, V, Karagounis, LG, Jaddoe, VWV, Franco, OH, Voortman, T. Dietary protein intake in school-age children and detailed measures of body composition: the Generation R Study. Int J Obes (Lond). 2018. 42:1715–1723. doi:10.1038/s41366-018-0098-x 29777231 | Intervention/Exposure
1109 | Jenkins, DJ, Jones, PJ, Frohlich, J, Lamarche, B, Ireland, C, Nishi, SK, Srichaikul, K, Galange, P, Pellini, C, Faulkner, D, de Souza, RJ, Sievenpiper, JL, Mirrahimi, A, Jayalath, VH, Augustin, LS, Bashyam, B, Leiter, LA, Josse, R, Couture, P, Ramprasath, V, Kendall, CW. The effect of a dietary portfolio compared to a DASH-type diet on blood pressure. Nutr Metab Cardiovasc Dis. 2015. 25:1132–9. doi:10.1016/j.numecd.2015.08.006 26552742 | Health Status
1110 | Jenkins, DJ, Jones, PJ, Lamarche, B, Kendall, CW, Faulkner, D, Cermakova, L, Gigleux, I, Ramprasath, V, de Souza, R, Ireland, C, Patel, D, Srichaikul, K, Abdulnour, S, Bashyam, B, Collier, C, Hoshizaki, S, Josse, RG, Leiter, LA, Connelly, PW, Frohlich, J. Effect of a dietary portfolio of cholesterol-lowering foods given at 2 levels of intensity of dietary advice on serum lipids in hyperlipidemia: a randomized controlled trial. Jama. 2011. 306:831–9. doi:10.1001/jama.2011.1202 21862744 | Intervention/Exposure; Publication Date Overlaps with Existing Review
1111 | Jenkins, DJ, Kendall, CW, Marchie, A, Faulkner, DA, Wong, JM, de Souza, R, Emam, A, Parker, TL, Vidgen, E, Lapsley, KG, Trautwein, EA, Josse, RG, Leiter, LA, Connelly, PW. Effects of a dietary portfolio of cholesterol-lowering foods vs lovastatin on serum lipids and C-reactive protein. Jama. 2003. 290:502–10. doi:10.1001/jama.290.4.502 12876093 | Publication Date Overlaps with Existing Review
1112 | Jenkins, DJ, Kendall, CW, Marchie, A, Faulkner, DA, Wong, JM, de Souza, R, Emam, A, Parker, TL, Vidgen, E, Trautwein, EA, Lapsley, KG, Josse, RG, Leiter, LA, Singer, W, Connelly, PW. Direct comparison of a dietary portfolio of cholesterol-lowering foods with a statin in hypercholesterolemic participants. Am J Clin Nutr. 2005. 81:380–7. doi:10.1093/ajcn.81.2.380 15699225 | Intervention/Exposure
1113 | Jenkins, DJ, Kendall, CW, Nguyen, TH, Teitel, J, Marchie, A, Chiu, M, Taha, AY, Faulkner, DA, Kemp, T, Wong, JM, de Souza, R, Emam, A, Trautwein, EA, Lapsley, KG, Holmes, C, Josse, RG, Leiter, LA, Singer, W. Effect on hematologic risk factors for coronary heart disease of a cholesterol reducing diet. Eur J Clin Nutr. 2007. 61:483–92. doi:10.1038/sj.ejcn.1602551 17136042 | Intervention/Exposure
1114 | Jenkins, DJ, Kendall, CW, Popovich, DG, Vidgen, E, Mehling, CC, Vuksan, V, Ransom, TP, Rao, AV, Rosenberg-Zand, R, Tariq, N, Corey, P, Jones, PJ, Raeini, M, Story, JA, Furumoto, EJ, Illingworth, DR, Pappu, AS, Connelly, PW. Effect of a very-high-fiber vegetable, fruit, and nut diet on serum lipids and colonic function. Metabolism. 2001. 50:494–503. doi:10.1053/meta.2001.21037 11288049 | Intervention/Exposure; Study duration
1115 | Jenkins, DJ, Kendall, CW, Vidgen, E, Mehling, CC, Parker, T, Seyler, H, Faulkner, D, Garsetti, M, Griffin, LC, Agarwal, S, Rao, AV, Cunnane, SC, Ryan, MA, Connelly, PW, Leiter, LA, Vuksan, V, Josse, R. The effect on serum lipids and oxidized low-density lipoprotein of supplementing self-selected low-fat diets with soluble-fiber, soy, and vegetable protein foods. Metabolism. 2000. 49:67–72. doi:10.1016/s0026-0495(00)90738-8 10647066 | Intervention/Exposure
1116 | Jenkins, DJ, Wong, JM, Kendall, CW, Esfahani, A, Ng, VW, Leong, TC, Faulkner, DA, Vidgen, E, Paul, G, Mukherjea, R, Krul, ES, Singer, W. Effect of a 6-month vegan low-carbohydrate (‘Eco-Atkins’) diet on cardiovascular risk factors and body weight in hyperlipidaemic adults: a randomised controlled trial. BMJ Open. 2014. 4:e003505. doi:10.1136/bmjopen-2013-003505 | Power/Size
1117 | Jessri, M, Ng, AP, L’Abbe, MR. Adapting the Healthy Eating Index 2010 for the Canadian Population: Evidence from the Canadian National Nutrition Survey. Nutrients. 2017. 9:. doi:10.3390/nu9080910 | Study Design
1118 | Jessri, M, Nishi, SK, L’Abbe, MR. Assessing the Nutritional Quality of Diets of Canadian Adults Using the 2014 Health Canada Surveillance Tool Tier System. Nutrients. 2015. 7:10447–68. doi:10.3390/nu7125543 26703721 | Study Design; Outcome
1119 | Jiang, J, Liu, M, Troy, LM, Bangalore, S, Hayes, RB, Parekh, N. Concordance with DASH diet and blood pressure change: results from the Framingham Offspring Study (1991-2008). J Hypertens. 2015. 33:2223–30. doi:10.1097/hjh.0000000000000710 26259122 | Outcome
1120 | Jiang, L, Audouze, K, Romero Herrera, JA, Angquist, LH, Kjaerulff, SK, Izarzugaza, JMG, Tjonneland, A, Halkjaer, J, Overvad, K, Sorensen, TIA, Brunak, S. Conflicting associations between dietary patterns and changes of anthropometric traits across subgroups of middle-aged women and men. Clin Nutr. 2019. :. doi:10.1016/j.clnu.2019.02.003 | Intervention/Exposure
1121 | Jiang, L, Huang, H, Johnson, A, Dill, EJ, Beals, J, Manson, SM, Roubideaux, Y. Socioeconomic Disparities in Weight and Behavioral Outcomes Among American Indian and Alaska Native Participants of a Translational Lifestyle Intervention Project. Diabetes Care. 2015. 38:2090–9. doi:10.2337/dc15-0394 26494807 | Intervention/Exposure
1122 | Jimenez Jaime, T, Leiva Balich, L, Barrera Acevedo, G, de la Maza Cave, MP, Hirsch Birn, S, Henriquez Parada, S, Rodriguez Silva, J, Bunout Barnett, D. Effect of calorie restriction on energy expenditure in overweight and obese adult women. Nutr Hosp. 2015. 31:2428–36. doi:10.3305/nh.2015.31.6.8782 26040348 | Study Design; Intervention/Exposure
1123 | Jimenez, AM, Oliva, SL, Vilar, EG, De Cuevillas, B, Morais Moreno, MDC, Gabella De Prado, J, Diaz, EA, Mauro Martin, IS. The Mediterranean diet pattern with intermittent semi-fasting may facilitate weight loss: Randomised controlled trial. Mediterranean Journal of Nutrition and Metabolism. 2019. 12:153–161. doi:10.3233/MNM-180257 | Intervention/Exposure; Study duration
1124 | Jimenez-Gomez, Y, Cruz-Teno, C, Rangel-Zuniga, OA, Peinado, JR, Perez-Martinez, P, Delgado-Lista, J, Garcia-Rios, A, Camargo, A, Vazquez-Martinez, R, Ortega-Bellido, M, Perez-Jimenez, F, Roche, HM, Malagon, MM, Lopez-Miranda, J. Effect of dietary fat modification on subcutaneous white adipose tissue insulin sensitivity in patients with metabolic syndrome. Mol Nutr Food Res. 2014. 58:2177–88. doi:10.1002/mnfr.201300901 25044988 | Intervention/Exposure; Health Status
1125 | Jin, Y, Kanaya, AM, Kandula, NR, Rodriguez, LA, Talegawkar, SA. Vegetarian Diets Are Associated with Selected Cardiometabolic Risk Factors among Middle-Older Aged South Asians in the United States. J Nutr. 2018. 148:1954–1960. doi:10.1093/jn/nxy217 30418560 | Study Design
1126 | Jitnarin, N, Kosulwat, V, Rojroongwasinkul, N, Boonpraderm, A, Haddock, CK, Poston, WS. Risk factors for overweight and obesity among Thai adults: results of the National Thai Food Consumption Survey. Nutrients. 2010. 2:60–74. doi:10.3390/nu20100060 22253992 | Study Design
1127 | Jobs, E, Adamsson, V, Larsson, A, Jobs, M, Nerpin, E, Ingelsson, E, Arnlov, J, Riserus, U. Influence of a prudent diet on circulating cathepsin S in humans. Nutr J. 2014. 13:84. doi:10.1186/1475-2891-13-84 25128296 | Comparator; Outcome
1128 | Johansson-Persson, A, Ulmius, M, Cloetens, L, Karhu, T, Herzig, KH, Onning, G. A high intake of dietary fiber influences C-reactive protein and fibrinogen, but not glucose and lipid metabolism, in mildly hypercholesterolemic subjects. Eur J Nutr. 2014. 53:39–48. doi:10.1007/s00394-013-0496-8 23389112 | Intervention/Exposure
1129 | Johns, DJ, Lindroos, AK, Jebb, SA, Sjostrom, L, Carlsson, LM, Ambrosini, GL. Tracking of a dietary pattern and its components over 10-years in the severely obese. PLoS One. 2014. 9:e97457. doi:10.1371/journal.pone.0097457 24841709 | Outcome
1130 | Johnson, C, Chaput, JP, Rioux, F, Diasparra, M, Richard, C, Dubois, L. An exploration of reported food intake among inmates who gained body weight during incarceration in Canadian federal penitentiaries. PLoS One. 2018. 13:e0208768. doi:10.1371/journal.pone.0208768 30562361 | Study Design; Intervention/Exposure
1131 | Johnson, L, Mander, AP, Jones, LR, Emmett, PM, Jebb, SA. A prospective analysis of dietary energy density at age 5 and 7 years and fatness at 9 years among UK children. Int J Obes (Lond). 2008. 32:586–93. doi:10.1038/sj.ijo.0803746 17912267 | Power/Size
1132 | Johnson, L, Mander, AP, Jones, LR, Emmett, PM, Jebb, SA. Energy-dense, low-fiber, high-fat dietary pattern is associated with increased fatness in childhood. Am J Clin Nutr. 2008. 87:846–54. doi:10.1093/ajcn/87.4.846 18400706 | Power/Size
1133 | Johnson, NA, Stannard, SR, Mehalski, K, Trenell, MI, Sachinwalla, T, Thompson, CH, Thompson, MW. Intramyocellular triacylglycerol in prolonged cycling with high- and low-carbohydrate availability. J Appl Physiol (1985). 2003. 94:1365–72. doi:10.1152/japplphysiol.00833.2002 12626469 | Study duration
1134 | Johnson, NA, Stannard, SR, Rowlands, DS, Chapman, PG, Thompson, CH, O’Connor, H, Sachinwalla, T, Thompson, MW. Effect of short-term starvation versus high-fat diet on intramyocellular triglyceride accumulation and insulin resistance in physically fit men. Exp Physiol. 2006. 91:693–703. doi:10.1113/expphysiol.2006.033399 16627573 | Study duration
1135 | Johnson, NA, Stannard, SR, Rowlands, DS, Chapman, PG, Thompson, CH, Sachinwalla, T, Thompson, MW. Short-term suppression of plasma free fatty acids fails to improve insulin sensitivity when intramyocellular lipid is elevated. Diabet Med. 2006. 23:1061–8. doi:10.1111/j.1464-5491.2006.01952.x 16978369 | Study duration
1136 | Johnston, C, Cosgrove, K. Consistency of adherence to a vegan diet on acid-base balance: a randomized controlled trial in healthy omnivore college students. FASEB journal. 2017. 31:. doi:unavailable | Publication Status
1137 | Johnston, CS, Tjonn, SL, Swan, PD, White, A, Hutchins, H, Sears, B. Ketogenic low-carbohydrate diets have no metabolic advantage over nonketogenic low-carbohydrate diets. Am J Clin Nutr. 2006. 83:1055–61. doi:10.1093/ajcn/83.5.1055 16685046 | Study duration
1138 | Johnston, CS, Tjonn, SL, Swan, PD. High-protein, low-fat diets are effective for weight loss and favorably alter biomarkers in healthy adults. J Nutr. 2004. 134:586–91. doi:10.1093/jn/134.3.586 14988451 | Study duration
1139 | Johnstone, AM, Horgan, GW, Murison, SD, Bremner, DM, Lobley, GE. Effects of a high-protein ketogenic diet on hunger, appetite, and weight loss in obese men feeding ad libitum. Am J Clin Nutr. 2008. 87:44–55. doi:10.1093/ajcn/87.1.44 18175736 | Study duration
1140 | Johnstone, AM, Lobley, GE, Horgan, GW, Bremner, DM, Fyfe, CL, Morrice, PC, Duthie, GG. Effects of a high-protein, low-carbohydrate v. high-protein, moderate-carbohydrate weight-loss diet on antioxidant status, endothelial markers and plasma indices of the cardiometabolic profile. Br J Nutr. 2011. 106:282–91. doi:10.1017/s0007114511000092 21521539 | Study duration
1141 | Jones, JL, Comperatore, M, Barona, J, Calle, MC, Andersen, C, McIntosh, M, Najm, W, Lerman, RH, Fernandez, ML. A Mediterranean-style, low-glycemic-load diet decreases atherogenic lipoproteins and reduces lipoprotein (a) and oxidized low-density lipoprotein in women with metabolic syndrome. Metabolism. 2012. 61:366–72. doi:10.1016/j.metabol.2011.07.013 21944261 | Intervention/Exposure; Comparator
1142 | Jones, JL, Fernandez, ML, McIntosh, MS, Najm, W, Calle, MC, Kalynych, C, Vukich, C, Barona, J, Ackermann, D, Kim, JE, Kumar, V, Lott, M, Volek, JS, Lerman, RH. A Mediterranean-style low-glycemic-load diet improves variables of metabolic syndrome in women, and addition of a phytochemical-rich medical food enhances benefits on lipoprotein metabolism. J Clin Lipidol. 2011. 5:188–196. doi:10.1016/j.jacl.2011.03.002 21600524 | Intervention/Exposure; Comparator
1143 | Jones, RB, Alderete, TL, Kim, JS, Millstein, J, Gilliland, FD, Goran, MI. High intake of dietary fructose in overweight/obese teenagers associated with depletion of Eubacterium and Streptococcus in gut microbiome. Gut Microbes. 2019. :1–8. doi:10.1080/19490976.2019.1592420 | Study Design; Intervention/Exposure
1144 | Joo, NS, Park, YW, Park, KH, Kim, CW, Kim, BT. Application of Protein-Rich Oriental Diet in a community-based obesity control program. Yonsei Med J. 2011. 52:249–56. doi:10.3349/ymj.2011.52.2.249 21319342 | Study duration
1145 | Joost, U, Villa, I, Comasco, E, Oreland, L, Veidebaum, T, Harro, J. Association between Transcription Factor AP-2B genotype, obesity, insulin resistance and dietary intake in a longitudinal birth cohort study. Int J Obes (Lond). 2019. 43:2095–2106. doi:10.1038/s41366-019-0396-y 31209268 | Study Design; Intervention/Exposure
1146 | Josse, AR, Atkinson, SA, Tarnopolsky, MA, Phillips, SM. Consumption of higher dairy and dietary protein during diet- and exercise-induced weight loss promotes a metabolically favourable body composition change in overweight and obese young women. FASEB journal. 2011. 25:. doi:unavailable | Publication Status
1147 | Josse, AR, Atkinson, SA, Tarnopolsky, MA, Phillips, SM. Increased consumption of dairy foods and protein during diet- and exercise-induced weight loss promotes fat mass loss and lean mass gain in overweight and obese premenopausal women. J Nutr. 2011. 141:1626–34. doi:10.3945/jn.111.141028 21775530 | Intervention/Exposure
1148 | Juanola-Falgarona, M, Salas-Salvado, J, Ibarrola-Jurado, N, Rabassa-Soler, A, Bullo, M. Effect of dietary glycemic index and glycemic load on body weight and cardiovascular risk factors: the GLYNDIET Study. Obesity facts. 2013. 6:111. doi:unavailable | Intervention/Exposure
1149 | Juanola-Falgarona, M, Salas-Salvado, J, Ibarrola-Jurado, N, Rabassa-Soler, A, Diaz-Lopez, A, Guasch-Ferre, M, Hernandez-Alonso, P, Balanza, R, Bullo, M. Effect of the glycemic index of the diet on weight loss, modulation of satiety, inflammation, and other metabolic risk factors: a randomized controlled trial. Am J Clin Nutr. 2014. 100:27–35. doi:10.3945/ajcn.113.081216 24787494 | Weight loss/Hypocaloric
1150 | Julia, C, Ducrot, P, Lassale, C, Fezeu, L, Mejean, C, Peneau, S, Touvier, M, Hercberg, S, Kesse-Guyot, E. Prospective associations between a dietary index based on the British Food Standard Agency nutrient profiling system and 13-year weight gain in the SU.VI.MAX cohort. Prev Med. 2015. 81:189–94. doi:10.1016/j.ypmed.2015.08.022 26348449 | Intervention/Exposure
1151 | Julia, C, Fezeu, LK, Ducrot, P, Mejean, C, Peneau, S, Touvier, M, Hercberg, S, Kesse-Guyot, E. The Nutrient Profile of Foods Consumed Using the British Food Standards Agency Nutrient Profiling System Is Associated with Metabolic Syndrome in the SU.VI.MAX Cohort. J Nutr. 2015. 145:2355–61. doi:10.3945/jn.115.213629 26290007 | Intervention/Exposure
1152 | Julibert, A, Bibiloni, MDM, Bouzas, C, Martinez-Gonzalez, MA, Salas-Salvado, J, Corella, D, Zomeno, MD, Romaguera, D, Vioque, J, Alonso-Gomez, AM, Warnberg, J, Martinez, JA, Serra-Majem, L, Estruch, R, Tinahones, FJ, Lapetra, J, Pinto, X, Lopez-Miranda, J, Garcia-Molina, L, Gaforio, JJ, Matia-Martin, P, Daimiel, L, Martin-Sanchez, V, Vidal, J, Vazquez, C, Ros, E, Toledo, E, Becerra-Tomas, N, Portoles, O, Perez-Vega, KA, Fiol, M, Torres-Collado, L, Tojal-Sierra, L, Carabano-Moral, R, Abete, I, Sanchez-Villegas, A, Casas, R, Bernal-Lopez, MR, Santos-Lozano, JM, Galera, A, Ugarriza, L, Ruiz-Canela, M, Babio, N, Coltell, O, Schroder, H, Konieczna, J, Orozco-Beltran, D, Sorto-Sanchez, C, Eguaras, S, Barrubes, L, Fito, M, Tur, JA, Investigators, PP. Total and Subtypes of Dietary Fat Intake and Its Association with Components of the Metabolic Syndrome in a Mediterranean Population at High Cardiovascular Risk. Nutrients. 2019. 11:. doi:10.3390/nu11071493 | Study Design; Intervention/Exposure
1153 | Jung, YP, Byrd, M, Baetge, C, Lockard, B, Levers, K, Galvan, E, Jagim, A, Simbo, S, Oliver, JM, Koozehchian, M, , . Adherence to a high protein and low fat energy-restricted diet while participating in a circuit resistance-exercise program promotes fat loss with no loss in fat free mass in postmenopausal women. FASEB journal. 2013. 27:. doi:unavailable | Publication Status
1154 | Jurado-Fasoli, L, De-la, OA, Castillo, MJ, Amaro-Gahete, FJ. Dietary differences between metabolically healthy overweight-obese and metabolically unhealthy overweight-obese adults. Br J Nutr. 2019. :1–21. doi:10.1017/s0007114519002071 | Study Design; Intervention/Exposure
1155 | Juraschek, SP, Appel, LJ, Anderson, CA, Miller, ER, 3rd. Effect of a high-protein diet on kidney function in healthy adults: results from the OmniHeart trial. Am J Kidney Dis. 2013. 61:547–54. doi:10.1053/j.ajkd.2012.10.017 23219108 | Study duration
1156 | Juraschek, SP, Gelber, AC, Choi, HK, Appel, LJ, Miller, ER, 3rd. Effects of the Dietary Approaches to Stop Hypertension (DASH) Diet and Sodium Intake on Serum Uric Acid. Arthritis Rheumatol. 2016. 68:3002–3009. doi:10.1002/art.39813 27523583 | Outcome
1157 | Juraschek, SP, Miller, ER, 3rd, Selvin, E, Carey, VJ, Appel, LJ, Christenson, RH, Sacks, FM. Effect of type and amount of dietary carbohydrate on biomarkers of glucose homeostasis and C reactive protein in overweight or obese adults: results from the OmniCarb trial. BMJ Open Diabetes Res Care. 2016. 4:e000276. doi:10.1136/bmjdrc-2016-000276 | Study duration
1158 | Juraschek, SP, Miller, ER, 3rd, Weaver, CM, Appel, LJ. Effects of Sodium Reduction and the DASH Diet in Relation to Baseline Blood Pressure. J Am Coll Cardiol. 2017. 70:2841–2848. doi:10.1016/j.jacc.2017.10.011 29141784 | Study duration
1159 | Juraschek, SP, Woodward, M, Sacks, FM, Carey, VJ, Miller, ER, 3rd, Appel, LJ. Time Course of Change in Blood Pressure From Sodium Reduction and the DASH Diet. Hypertension. 2017. 70:923–929. doi:10.1161/hypertensionaha.117.10017 28993451 | Study duration
1160 | Kahleova, H, Fleeman, R, Hlozkova, A, Holubkov, R, Barnard, ND. A plant-based diet in overweight individuals in a 16-week randomized clinical trial: metabolic benefits of plant protein. Nutr Diabetes. 2018. 8:58. doi:10.1038/s41387-018-0067-4 30405108 | Data overlap with included article
1161 | Kahleova, H, Hlozkova, A, Fleeman, R, Fletcher, K, Holubkov, R, Barnard, ND. Fat Quantity and Quality, as Part of a Low-Fat, Vegan Diet, Are Associated with Changes in Body Composition, Insulin Resistance, and Insulin Secretion. A 16-Week Randomized Controlled Trial. Nutrients. 2019. 11:. doi:10.3390/nu11030615 | Data overlap with included article
1162 | Kahleova, H, Tura, A, Hill, M, Holubkov, R, Barnard, N. A plant-based diet improves beta-cell function and insulin resistance in overweight adults-a 16-week randomized clinical trial. Diabetes. 2018. 67:A78-. doi:unavailable | Publication Status
1163 | Kahleova, H, Tura, A, Hill, M, Holubkov, R, Barnard, ND. A Plant-Based Dietary Intervention Improves Beta-Cell Function and Insulin Resistance in Overweight Adults: A 16-Week Randomized Clinical Trial. Nutrients. 2018. 10:. doi:10.3390/nu10020189 | Data overlap with included article
1164 | Kaippert, VC, Dos Santos Lopes, MCO, De Carvalho, PD, Rosado, EL. Effects of unsaturated fatty acids on weight loss, body composition and obesity related biomarkers. Diabetology & metabolic syndrome. 2015. 7:59-. doi:unavailable26146523 | Publication Status
1165 | Kaitosaari, T, Ronnemaa, T, Viikari, J, Raitakari, O, Arffman, M, Marniemi, J, Kallio, K, Pahkala, K, Jokinen, E, Simell, O. Low-saturated fat dietary counseling starting in infancy improves insulin sensitivity in 9-year-old healthy children: the Special Turku Coronary Risk Factor Intervention Project for Children (STRIP) study. Diabetes Care. 2006. 29:781–5. doi:10.2337/diacare.29.04.06.dc05-1523 16567815 | Intervention/Exposure
1166 | Kalantarian, S, Rimm, EB, Herrington, DM, Mozaffarian, D. Dietary macronutrients, genetic variation, and progression of coronary atherosclerosis among women. Am Heart J. 2014. 167:627–635.e1. doi:10.1016/j.ahj.2014.01.001 24655714 | Intervention/Exposure
1167 | Kanamori, K, Ihana-Sugiyama, N, Yamamoto-Honda, R, Nakamura, T, Sobe, C, Kamiya, S, Kishimoto, M, Kajio, H, Kawano, K, Noda, M. Postprandial Glucose Surges after Extremely Low Carbohydrate Diet in Healthy Adults. Tohoku J Exp Med. 2017. 243:35–39. doi:10.1620/tjem.243.35 28924074 | Study duration
1168 | Kang, HJ, Jun, DW, Lee, SM, Jang, EC, Cho, YK. Low salt and low calorie diet does not reduce more body fat than same calorie diet: a randomized controlled study. Oncotarget. 2018. 9:8521–8530. doi:10.18632/oncotarget.23959 29492213 | Intervention/Exposure
1169 | Kang, SH, Cho, KH, Do, JY. Association Between the Modified Dietary Approaches to Stop Hypertension and Metabolic Syndrome in Postmenopausal Women Without Diabetes. Metab Syndr Relat Disord. 2018. 16:282–289. doi:10.1089/met.2018.0007 29902116 | Study Design; Intervention/Exposure
1170 | Kanikowska, D, Sikorska, D, Kuczynska, B, Grzymislawski, M, Breborowicz, A, Witowski, J. Do medical students adhere to advice regarding a healthy lifestyle? A pilot study of BMI and some aspects of lifestyle in medical students in Poland. Adv Clin Exp Med. 2017. 26:1391–1398. doi:10.17219/acem/65783 29442460 | Study Design; Intervention/Exposure
1171 | Kant, AK, Graubard, BI. Energy density of diets reported by American adults: association with food group intake, nutrient intake, and body weight. Int J Obes (Lond). 2005. 29:950–6. doi:10.1038/sj.ijo.0802980 15917854 | Study Design
1172 | Kant, AK, Leitzmann, MF, Park, Y, Hollenbeck, A, Schatzkin, A. Patterns of recommended dietary behaviors predict subsequent risk of mortality in a large cohort of men and women in the United States. J Nutr. 2009. 139:1374–80. doi:10.3945/jn.109.104505 19474153 | Publication Date Overlaps with Existing Review
1173 | Kao, HN, Yang, JH, Hsia, CH, Chen, CY, Lim, SY, Chien, YW. The effect of high protein diet on weight reduction and maintenance in overweight adults. FASEB journal. 2013. 27:. doi:unavailable | Publication Status
1174 | Kapelios, CJ, Kyriazis, I, Ioannidis, I, Dimosthenopoulos, C, Hatziagelaki, E, Liatis, S. Diet, life-style and cardiovascular morbidity in the rural, free living population of Elafonisos island. BMC Public Health. 2017. 17:147. doi:10.1186/s12889-017-4053-x 28143598 | Study Design
1175 | Kapetanakis, M, Liuba, P, Odermarsky, M, Lundgren, J, Hallbook, T. Effects of ketogenic diet on vascular function. Eur J Paediatr Neurol. 2014. 18:489–94. doi:10.1016/j.ejpn.2014.03.006 24703903 | Health Status
1176 | Kaplan, RJ, Greenwood, CE, Winocur, G, Wolever, TM. Cognitive performance is associated with glucose regulation in healthy elderly persons and can be enhanced with glucose and dietary carbohydrates. Am J Clin Nutr. 2000. 72:825–36. doi:10.1093/ajcn/72.3.825 10966906 | Study duration
1177 | Kapoor, D, Iqbal, R, Singh, K, Jaacks, LM, Shivashankar, R, Sudha, V, Anjana, RM, Kadir, M, Mohan, V, Ali, MK, Narayan, KM, Tandon, N, Prabhakaran, D, Merchant, AT. Association of dietary patterns and dietary diversity with cardiometabolic disease risk factors among adults in South Asia: The CARRS study. Asia Pac J Clin Nutr. 2018. 27:1332–1343. doi:10.6133/apjcn.201811_27(6).0021 30485933 | Country
1178 | Karanja, N, Erlinger, TP, Pao-Hwa, L, Miller, IiiER, Bray, GA. The DASH diet for high blood pressure: From clinical trial to dinner table. Cleveland Clinic Journal of Medicine. 2004. 71:745–753. doi:10.3949/ccjm.71.9.745 15478706 | Study Design
1179 | Karfopoulou, E, Brikou, D, Mamalaki, E, Bersimis, F, Anastasiou, CA, Hill, JO, Yannakoulia, M. Dietary patterns in weight loss maintenance: results from the MedWeight study. Eur J Nutr. 2017. 56:991–1002. doi:10.1007/s00394-015-1147-z 26744302 | Study Design
1180 | Karl, JP, Roberts, SB, Schaefer, EJ, Gleason, JA, Fuss, P, Rasmussen, H, Saltzman, E, Das, SK. Effects of carbohydrate quantity and glycemic index on resting metabolic rate and body composition during weight loss. Obesity (Silver Spring). 2015. 23:2190–8. doi:10.1002/oby.21268 26530933 | Intervention/Exposure
1181 | Karwacki-Marugg, C, Huddy, K, Bernstein, B, Whitaker, M, Pranitis, L, Morse, B, Colangelo, R, Stuart, M, O’Donnell, M, Kelsey, AM. Support for Women Achieving Cardiovascular Health Through Exercise And Nutrition (SWAN) Study Pilot. Conn Med. 2016. 80:69–74. doi:unavailable27024976 | Study Design
1182 | Kasai, M, Maki, H, Nosaka, N, Aoyama, T, Ooyama, K, Uto, H, Okazaki, M, Igarashi, O, Kondo, K. Effect of medium-chain triglycerides on the postprandial triglyceride concentration in healthy men. Biosci Biotechnol Biochem. 2003. 67:46–53. doi:10.1271/bbb.67.46 12619672 | Study duration
1183 | Kasim-Karakas, SE, Almario, RU, Mueller, WM, Peerson, J. Changes in plasma lipoproteins during low-fat, high-carbohydrate diets: effects of energy intake. Am J Clin Nutr. 2000. 71:1439–47. doi:10.1093/ajcn/71.6.1439 10837283 | Study Design; Intervention/Exposure
1184 | Kasim-Karakas, SE, Tsodikov, A, Singh, U, Jialal, I. Responses of inflammatory markers to a low-fat, high-carbohydrate diet: effects of energy intake. Am J Clin Nutr. 2006. 83:774–9. doi:10.1093/ajcn/83.4.774 16600927 | Study Design; Intervention/Exposure
1185 | Katsa, ME, Ioannidis, A, Zyga, S, Tsironi, M, Koutsovitis, P, Chatzipanagiotou, S, Panagiotakos, D, Sachlas, A, Kolovos, P, Routsi, K, Pistikou, AM, Kougioumtzi Dimoliani, DE, Rojas Gil, AP. The Effect of Nutrition and Sleep Habits on Predisposition for Metabolic Syndrome in Greek Children. J Pediatr Nurs. 2018. 40:e2–e8. doi:10.1016/j.pedn.2018.01.012 29402659 | Study Design; Intervention/Exposure
1186 | Katsiki, N, Mikhailidis, DP. The Mediterranean diet in the primary prevention of CVD. Cardiology Review. 2013. 29:. doi:unavailable | Study Design
1187 | Katzmarzyk, PT, Barreira, TV, Broyles, ST, Champagne, CM, Chaput, JP, Fogelholm, M, Hu, G, Johnson, WD, Kuriyan, R, Kurpad, A, Lambert, EV, Maher, C, Maia, J, Matsudo, V, Olds, T, Onywera, V, Sarmiento, OL, Standage, M, Tremblay, MS, Tudor-Locke, C, Zhao, P, Church, TS. Relationship between lifestyle behaviors and obesity in children ages 9-11: Results from a 12-country study. Obesity (Silver Spring). 2015. 23:1696–702. doi:10.1002/oby.21152 26173093 | Study Design
1188 | Kaur, B, Ranawana, V, Teh, AL, Henry, CJK. The impact of a low glycemic index (GI) breakfast and snack on daily blood glucose profiles and food intake in young Chinese adult males. J Clin Transl Endocrinol. 2015. 2:92–98. doi:10.1016/j.jcte.2015.05.002 29204372 | Intervention/Exposure
1189 | Kawamura, A, Kajiya, K, Kishi, H, Inagaki, J, Mitarai, M, Oda, H, Umemoto, S, Kobayashi, S. Effects of the DASH-JUMP dietary intervention in Japanese participants with high-normal blood pressure and stage 1 hypertension: an open-label single-arm trial. Hypertens Res. 2016. 39:777–785. doi:10.1038/hr.2016.76 27412796 | Study Design; Intervention/Exposure
1190 | Kawamura, A, Kajiya, K, Kishi, H, Inagaki, J, Mitarai, M, Oda, H, Umemoto, S, Kobayashi, S. The Nutritional Characteristics of the Hypotensive WASHOKU-modified DASH Diet: A Sub-analysis of the DASH-JUMP Study. Curr Hypertens Rev. 2018. 14:56–65. doi:10.2174/1573402114666180405100430 29618312 | Study Design
1191 | Ke, Q, Chen, C, He, F, Ye, Y, Bai, X, Cai, L, Xia, M. Association between dietary protein intake and type 2 diabetes varies by dietary pattern. Diabetol Metab Syndr. 2018. 10:48. doi:10.1186/s13098-018-0350-5 29983752 | Study Design; Country
1192 | Kell, KP, Judd, SE, Pearson, KE, Shikany, JM, Fernandez, JR. Associations between socio-economic status and dietary patterns in US black and white adults. Br J Nutr. 2015. 113:1792–9. doi:10.1017/s0007114515000938 25869232 | Study Design; Outcome
1193 | Kent, L, Morton, D, Rankin, P, Ward, E, Grant, R, Gobble, J, Diehl, H. The effect of a low-fat, plant-based lifestyle intervention (CHIP) on serum HDL levels and the implications for metabolic syndrome status - a cohort study. Nutr Metab (Lond). 2013. 10:58. doi:10.1186/1743-7075-10-58 24283215 | Study Design; Intervention/Exposure
1194 | Kent, LM, Grant, RS, Watts, G, Morton, DP, Rankin, PM, Ward, EJ. HDL subfraction changes with a low-fat, plant-based Complete Health Improvement Program (CHIP). Asia Pac J Clin Nutr. 2018. 27:1002–1009. doi:10.6133/apjcn.052018.05 30272848 | Study Design; Comparator
1195 | Keogh, JB, Brinkworth, GD, Clifton, PM. Effects of weight loss on a low-carbohydrate diet on flow-mediated dilatation, adhesion molecules and adiponectin. Br J Nutr. 2007. 98:852–9. doi:10.1017/s0007114507747815 17490508 | Weight loss/Hypocaloric
1196 | Keogh, JB, Brinkworth, GD, Noakes, M, Belobrajdic, DP, Buckley, JD, Clifton, PM. Effects of weight loss from a very-low-carbohydrate diet on endothelial function and markers of cardiovascular disease risk in subjects with abdominal obesity. Am J Clin Nutr. 2008. 87:567–76. doi:10.1093/ajcn/87.3.567 18326593 | Study duration
1197 | Keogh, JB, Grieger, JA, Noakes, M, Clifton, PM. Flow-mediated dilatation is impaired by a high-saturated fat diet but not by a high-carbohydrate diet. Arterioscler Thromb Vasc Biol. 2005. 25:1274–9. doi:10.1161/01.ATV.0000163185.28245.a1 15774905 | Study duration
1198 | Keogh, JB, Luscombe-Marsh, ND, Noakes, M, Wittert, GA, Clifton, PM. Long-term weight maintenance and cardiovascular risk factors are not different following weight loss on carbohydrate-restricted diets high in either monounsaturated fat or protein in obese hyperinsulinaemic men and women. Br J Nutr. 2007. 97:405–10. doi:10.1017/s0007114507252687 17298712 | Weight loss/Hypocaloric
1199 | Kephart, WC, Pledge, CD, Roberson, PA, Mumford, PW, Romero, MA, Mobley, CB, Martin, JS, Young, KC, Lowery, RP, Wilson, JM, Huggins, KW, Roberts, MD. The Three-Month Effects of a Ketogenic Diet on Body Composition, Blood Parameters, and Performance Metrics in CrossFit Trainees: A Pilot Study. Sports (Basel). 2018. 6:. doi:10.3390/sports6010001 | Intervention/Exposure; Comparator
1200 | Kerksick, C, Thomas, A, Campbell, B, Taylor, L, Wilborn, C, Marcello, B, Roberts, M, Pfau, E, Grimstvedt, M, Opusunju, J, Magrans-Courtney, T, Rasmussen, C, Wilson, R, Kreider, RB. Effects of a popular exercise and weight loss program on weight loss, body composition, energy expenditure and health in obese women. Nutr Metab (Lond). 2009. 6:23. doi:10.1186/1743-7075-6-23 19442301 | Intervention/Exposure; Publication Status
1201 | Kerksick, CM, Wismann-Bunn, J, Fogt, D, Thomas, AR, Taylor, L, Campbell, BI, Wilborn, CD, Harvey, T, Roberts, MD, La Bounty, P, Galbreath, M, Marcello, B, Rasmussen, CJ, Kreider, RB. Changes in weight loss, body composition and cardiovascular disease risk after altering macronutrient distributions during a regular exercise program in obese women. Nutr J. 2010. 9:59. doi:10.1186/1475-2891-9-59 21092228 | Study duration
1202 | Kesse-Guyot, E, Bertrais, S, Péneau, S, Estaquio, C, Dauchet, L, Vergnaud, AC, Czernichow, S, Galan, P, Hercberg, S, Bellisle, F. Dietary patterns and their sociodemographic and behavioural correlates in French middle-aged adults from the SU.VI.MAX cohort. European Journal of Clinical Nutrition. 2009. 63:521–528. doi:10.1038/sj.ejcn.1602978 18212801 | Study Design
1203 | Kesse-Guyot, E, Fezeu, L, Galan, P, Hercberg, S, Czernichow, S, Castetbon, K. Adherence to French nutritional guidelines is associated with lower risk of metabolic syndrome. Journal of Nutrition. 2011. 141:1134–1139. doi:10.3945/jn.110.136317 | Outcome; Publication Date Overlaps with Existing Review
1204 | Kesse-Guyot, E, Touvier, M, Henegar, A, Czernichow, S, Galan, P, Hercberg, S, Castetbon, K. Higher adherence to French dietary guidelines and chronic diseases in the prospective SU.VI.MAX cohort. European Journal of Clinical Nutrition. 2011. 65:887–894. doi:10.1038/ejcn.2011.61 21559045 | Publication Date Overlaps with Existing Review
1205 | Kessler, K, Hornemann, S, Petzke, KJ, Kemper, M, Kramer, A, Pfeiffer, AF, Pivovarova, O, Rudovich, N. The effect of diurnal distribution of carbohydrates and fat on glycaemic control in humans: a randomized controlled trial. Sci Rep. 2017. 7:44170. doi:10.1038/srep44170 28272464 | Study duration
1206 | Keyserling, TC, Samuel-Hodge, CD, Pitts, SJ, Garcia, BA, Johnston, LF, Gizlice, Z, Miller, CL, Braxton, DF, Evenson, KR, Smith, JC, Davis, GB, Quenum, EL, Elliott, NT, Gross, MD, Donahue, KE, Halladay, JR, Ammerman, AS. A community-based lifestyle and weight loss intervention promoting a Mediterranean-style diet pattern evaluated in the stroke belt of North Carolina: the Heart Healthy Lenoir Project. BMC Public Health. 2016. 16:732. doi:10.1186/s12889-016-3370-9 27495295 | Intervention/Exposure
1207 | Khakimov, B, Poulsen, SK, Savorani, F, Acar, E, Gurdeniz, G, Larsen, TM, Astrup, A, Dragsted, LO, Engelsen, SB. New Nordic Diet versus Average Danish Diet: A Randomized Controlled Trial Revealed Healthy Long-Term Effects of the New Nordic Diet by GC-MS Blood Plasma Metabolomics. J Proteome Res. 2016. 15:1939–54. doi:10.1021/acs.jproteome.6b00109 27146725 | Intervention/Exposure; Outcome
1208 | Khalil, H, Murrin, C, O’Reilly, M, Viljoen, K, Segurado, R, O’Brien, J, Somerville, R, McGillicuddy, F, Kelleher, CC. Total HDL cholesterol efflux capacity in healthy children - Associations with adiposity and dietary intakes of mother and child. Nutr Metab Cardiovasc Dis. 2017. 27:70–77. doi:10.1016/j.numecd.2016.10.002 27919542 | Intervention/Exposure; Outcome
1209 | Kheirat, F, Merzouk, H, Saidi Merzouk, A, Merzouk, SA, Belarbi, B. One year changes in biochemical and redox markers in training menopausal women with adherence to Mediterranean diet. Science and Sports. 2018. 33:e25–e32. doi:10.1016/j.scispo.2017.07.013 | Study Design; Intervention/Exposure
1210 | Khera, AV, Plutzky, J. Management of low levels of high-density lipoprotein-cholesterol. Circulation. 2013. 128:72–78. doi:10.1161/CIRCULATIONAHA.112.000443 23817482 | Study Design
1211 | Kilinç, FN, Çaǧdaş, D. Evaluation of body compositions, dietary habits and nutritional knowledge of health college students. Turk Pediatri Arsivi. 2012. 47:181–188. doi:10.4274/tpa.842 | Study Design; Language
1212 | Kim, HS, Demyen, MF, Mathew, J, Kothari, N, Feurdean, M, Ahlawat, SK. Obesity, Metabolic Syndrome, and Cardiovascular Risk in Gluten-Free Followers Without Celiac Disease in the United States: Results from the National Health and Nutrition Examination Survey 2009-2014. Dig Dis Sci. 2017. 62:2440–2448. doi:10.1007/s10620-017-4583-1 28451915 | Study Design
1213 | Kim, IY, Schutzler, SE, Azhar, G, Wolfe, RR, Ferrando, AA, Coker, RH. Short term elevation in dietary protein intake does not worsen insulin resistance or lipids in older adults with metabolic syndrome: a randomized-controlled trial. BMC Nutr. 2017. 3:. doi:10.1186/s40795-017-0152-4 | Intervention/Exposure
1214 | Kim, J, Kim, J. Association between Fruit and Vegetable Consumption and Risk of Hypertension in Middle-Aged and Older Korean Adults. J Acad Nutr Diet. 2018. 118:1438–1449.e5. doi:10.1016/j.jand.2017.08.122 29113723 | Intervention/Exposure; Outcome
1215 | Kim, M, Tanaka, K. Non-high-density lipoprotein cholesterol changes in middle-aged obese men with and without metabolic syndrome during weight loss. Metabolic Syndrome and Related Disorders. 2014. 12:464–471. doi:10.1089/met.2014.0032 25247924 | Study Design
1216 | Kim, MH, Bae, YJ. Comparative Study of Serum Leptin and Insulin Resistance Levels Between Korean Postmenopausal Vegetarian and Non-vegetarian Women. Clin Nutr Res. 2015. 4:175–81. doi:10.7762/cnr.2015.4.3.175 26251836 | Study Design; Intervention/Exposure
1217 | Kim, MH, Bae, YJ. Postmenopausal vegetarians’ low serum ferritin level may reduce the risk for metabolic syndrome. Biological Trace Element Research. 2012. 149:34–41. doi:10.1007/s12011-012-9405-x 22528775 | Study Design
1218 | Kim, MK. Effects of low calorie diet-induced weight loss on post-exercise heart rate recovery in obese men. J Exerc Nutrition Biochem. 2014. 18:181–8. doi:10.5717/jenb.2014.18.2.181 | Intervention/Exposure; Outcome
1219 | Kim, N, Seo, DC, King, MH, Lederer, AM, Sovinski, D. Long-term predictors of blood pressure among adolescents during an 18-month school-based obesity prevention intervention. Journal of Adolescent Health. 2014. 55:521–527. doi:10.1016/j.jadohealth.2014.04.011 | Intervention/Exposure
1220 | Kim, SA, Ha, K, Ahn, S, Ham, D, Kim, S, Joung, H. A randomized clinical trial for the effects of rice-based Korean diet on cardiovascular risk factors in Korean adults. FASEB journal. 2017. 31:. doi:unavailable | Publication Status
1221 | Kim, Y, Keogh, JB, Clifton, PM. Consumption of red and processed meat and refined grains for 4weeks decreases insulin sensitivity in insulin-resistant adults: A randomized crossover study. Metabolism. 2017. 68:173–183. doi:10.1016/j.metabol.2016.12.011 28183449 | Study duration
1222 | Kim, Y, Keogh, JB, Clifton, PM. Differential Effects of Red Meat/Refined Grain Diet and Dairy/Chicken/Nuts/Whole Grain Diet on Glucose, Insulin and Triglyceride in a Randomized Crossover Study. Nutrients. 2016. 8:. doi:10.3390/nu8110687 | Study duration
1223 | Kim, Y, Keogh, JB, Clifton, PM. Effects of Two Different Dietary Patterns on Inflammatory Markers, Advanced Glycation End Products and Lipids in Subjects without Type 2 Diabetes: A Randomised Crossover Study. Nutrients. 2017. 9:. doi:10.3390/nu9040336 | Study duration
1224 | Kimokoti, RW, Brown, LS. Dietary management of the metabolic syndrome. Clinical Pharmacology and Therapeutics. 2011. 90:184–187. doi:10.1038/clpt.2011.92 21633342 | Study Design
1225 | Kimokoti, RW, Gona, P, Zhu, L, Newby, PK, Millen, BE, Brown, LS, D’Agostino, RB, Fung, TT. Dietary patterns of women are associated with incident abdominal obesity but not metabolic syndrome. Journal of Nutrition. 2012. 142:1720–1727. doi:10.3945/jn.112.162479 | Intervention/Exposure; Publication Date Overlaps with Existing Review
1226 | Kimokoti, RW, Newby, PK, Gona, P, Zhu, L, Campbell, WR, D’Agostino, RB, Millen, BE. Stability of the Framingham Nutritional Risk Score and its component nutrients over 8 years: The Framingham Nutrition Studies. European Journal of Clinical Nutrition. 2012. 66:336–344. doi:10.1038/ejcn.2011.167 21970940 | Study Design; Intervention/Exposure
1227 | Kimokoti, RW, Newby, PK, Gona, P, Zhu, L, Jasuja, GK, Pencina, MJ, McKeon-O’Malley, C, Fox, CS, D’Agostino, RB, Millen, BE. Diet quality, physical activity, smoking status, and weight fluctuation are associated with weight change in women and men. Journal of Nutrition. 2010. 140:1287–1293. doi:10.3945/jn.109.120808 | Intervention/Exposure
1228 | Kineish, O, Stentz, FB, Kitabchi, AE. Effect of high protein vs high carbohydrate diets on satiety and cardiovascular factors. Journal of investigative medicine. 2013. 61:496. doi: | Publication Status
1229 | Kirk, E, Reeds, DN, Finck, BN, Mayurranjan, SM, Patterson, BW, Klein, S. Dietary fat and carbohydrates differentially alter insulin sensitivity during caloric restriction. Gastroenterology. 2009. 136:1552–60. doi:10.1053/j.gastro.2009.01.048 19208352 | Study duration
1230 | Kirk, S, Brehm, B, Saelens, BE, Woo, JG, Kissel, E, D’Alessio, D, Bolling, C, Daniels, SR. Role of carbohydrate modification in weight management among obese children: a randomized clinical trial. J Pediatr. 2012. 161:320–7.e1. doi:10.1016/j.jpeds.2012.01.041 22381024 | Weight loss/Hypocaloric
1231 | Kirk, S, Woo, JG, Brehm, B, Daniels, SR, Saelens, BE. Changes in Eating Behaviors of Children with Obesity in Response to Carbohydrate-Modified and Portion-Controlled Diets. Child Obes. 2017. 13:377–383. doi:10.1089/chi.2017.0020 28632394 | Intervention/Exposure; Outcome
1232 | Kirk, S, Woo, JG, Jones, MN, Siegel, RM. Increased frequency of dietitian visits is associated with improved body mass index outcomes in obese youth participating in a comprehensive pediatric weight management program. Child Obes. 2015. 11:202–8. doi:10.1089/chi.2014.0079 25710601 | Intervention/Exposure
1233 | Kirkegaard, H, Stovring, H, Rasmussen, KM, Abrams, B, Sørensen, TIA, Nohr, EA. Maternal weight change from prepregnancy to 7 years postpartum - The influence of behavioral factors. Obesity. 2015. 23:870–878. doi:10.1002/oby.21022 25820258 | Participants
1234 | Kirkwood, L, Aldujaili, E, Drummond, S. Effects of advice on dietary intake and/or physical activity on body composition, blood lipids and insulin resistance following a low-fat, sucrose-containing, high-carbohydrate, energy-restricted diet. Int J Food Sci Nutr. 2007. 58:383–97. doi:10.1080/09637480701252336 17558730 | Weight loss/Hypocaloric
1235 | Kistorp, C, Bliddal, H, Goetze, JP, Christensen, R, Faber, J. Cardiac natriuretic peptides in plasma increase after dietary induced weight loss in obesity. BMC Obes. 2014. 1:24. doi:10.1186/s40608-014-0024-2 26217511 | Intervention/Exposure
1236 | Kitabchi, AE, Brewer, A, Wan, J, Sands, C, Stentz, FB. Remission of impaired glucose tolerance (IGT) to normal glucose tolerance (NGT) in obese adults with high protein vs. High carbohydrate diet. Diabetes. 2015. 64:A23–A24. doi: | Publication Status
1237 | Kitabchi, AE, Stentz, FB, Nyenwe, EA, McDaniel, KA, Tylavsky, FA, Wan, JY, Sands, CW. Effect of macronutrients on markers of oxidative stress, proinflammatory cytokines, adipokines, CV risk factors and lipid peroxidation in obese non-diabetic women. Diabetes. 2012. 61:A11. doi:10.2337/db12-1-377 | Intervention/Exposure
1238 | Klass, DM, Buhrmann, K, Sauter, G, Del Puppo, M, Scheibner, J, Fuchs, M, Stange, EF. Biliary lipids, cholesterol and bile synthesis: different adaptive mechanisms to dietary cholesterol in lean and obese subjects. Aliment Pharmacol Ther. 2006. 23:895–905. doi:10.1111/j.1365-2036.2006.02836.x 16573792 | Study duration
1239 | Kleiner, RE, Hutchins, AM, Johnston, CS, Swan, PD. Effects of an 8-week high-protein or high-carbohydrate diet in adults with hyperinsulinemia. MedGenMed. 2006. 8:39. doi:unavailable | Intervention/Exposure
1240 | Klempel, MC, Kroeger, CM, Norkeviciute, E, Goslawski, M, Phillips, SA, Varady, KA. Benefit of a low-fat over high-fat diet on vascular health during alternate day fasting. Nutr Diabetes. 2013. 3:e71. doi:10.1038/nutd.2013.14 23712283 | Intervention/Exposure; Outcome
1241 | Klempel, MC, Kroeger, CM, Varady, KA. Alternate day fasting (ADF) with a high-fat diet produces similar weight loss and cardio-protection as ADF with a low-fat diet. Metabolism. 2013. 62:137–43. doi:10.1016/j.metabol.2012.07.002 22889512 | Intervention/Exposure
1242 | Klemsdal, TO, Holme, I, Nerland, H, Pedersen, TR, Tonstad, S. Effects of a low glycemic load diet versus a low-fat diet in subjects with and without the metabolic syndrome. Nutr Metab Cardiovasc Dis. 2010. 20:195–201. doi:10.1016/j.numecd.2009.03.010 19502017 | Weight loss/Hypocaloric
1243 | Klonizakis, M, Grammatikopoulou, MG, Theodoridis, X, Milner, M, Liu, Y, Chourdakis, M. Effects of Long-Versus Short-Term Exposure to the Mediterranean Diet on Skin Microvascular Function and Quality of Life of Healthy Adults in Greece and the UK. Nutrients. 2019. 11:. doi:10.3390/nu11102487 | Study duration
1244 | Knopp, RH, Paramsothy, P, Retzlaff, BM, Dowdy, A, Fish, B. Undesirable effects of extreme dietary carbohydrate and saturated fat intakes: the search for the middle ground. Curr Atheroscler Rep. 2005. 7:409–11. doi:unavailable16255997 | Study Design; Publication Status
1245 | Knopp, RH, Retzlaff, B, Walden, C, Fish, B, Buck, B, McCann, B. One-year effects of increasingly fat-restricted, carbohydrate-enriched diets on lipoprotein levels in free-living subjects. Proc Soc Exp Biol Med. 2000. 225:191–9. doi:10.1046/j.1525-1373.2000.22524.x 11082213 | Study Design; Intervention/Exposure
1246 | Koebnick, C, Plank-Habibi, S, Wirsam, B, Gruendel, S, Hahn, A, Meyer-Kleine, C, Leitzmann, C, Zunft, HJ. Double-blind, randomized feedback control fails to improve the hypocholesterolemic effect of a plant-based low-fat diet in patients with moderately elevated total cholesterol levels. Eur J Clin Nutr. 2004. 58:1402–9. doi:10.1038/sj.ejcn.1601984 15114376 | Study duration
1247 | Koebnick, C, Plank-Habibi, S, Wirsam, B, Gruendel, S, Hahn, A, Meyer-Kleine, C, Leitzmann, C, Zunft, HJF. Double-blind, randomized feedback controls fails to improve the hypocholesterolemic effect of a plant-based low-fat diet in patients with moderately elevated total cholesterol levels. European Journal of Clinical Nutrition. 2004. 58:1402–1409. doi:10.1038/sj.ejcn.1601984 15114376 | Study duration
1248 | Kohler, B, Andreen, I. Body weight maintenance and levels of mutans streptococci and lactobacilli in a group of Swedish women seven years after completion of a Weight Watchers’ diet. Swed Dent J. 2011. 35:101–9. doi:unavailable22135941 | Intervention/Exposure
1249 | Kokanovic, A, Mandic, ML, Banjari, I. Does individual dietary intervention have any impact on adolescents with cardiovascular health risks?. Med Glas (Zenica). 2014. 11:234–7. doi:unavailable24496370 | Study Design
1250 | Kokkinos, P, Moutsatsos, G. Obesity and cardiovascular disease: The role of diet and physical activity. Journal of Cardiopulmonary Rehabilitation. 2004. 24:197–203. doi:10.1097/00008483-200405000-00011 15235302 | Study Design
1251 | Kolahdooz, F, Nader, F, Daemi, M, Jang, SL, Johnston, N, Sharma, S. Prevalence of Known Risk Factors for Type 2 Diabetes Mellitus in Multiethnic Urban Youth in Edmonton: Findings From the WHY ACT NOW Project. Can J Diabetes. 2019. 43:207–214. doi:10.1016/j.jcjd.2018.10.002 30551935 | Intervention/Exposure
1252 | Kolehmainen, M, Ulven, SM, Paananen, J, de Mello, V, Schwab, U, Carlberg, C, Myhrstad, M, Pihlajamaki, J, Dungner, E, Sjolin, E, Gunnarsdottir, I, Cloetens, L, Landin-Olsson, M, Akesson, B, Rosqvist, F, Hukkanen, J, Herzig, KH, Dragsted, LO, Savolainen, MJ, Brader, L, Hermansen, K, Riserus, U, Thorsdottir, I, Poutanen, KS, Uusitupa, M, Arner, P, Dahlman, I. Healthy Nordic diet downregulates the expression of genes involved in inflammation in subcutaneous adipose tissue in individuals with features of the metabolic syndrome. Am J Clin Nutr. 2015. 101:228–39. doi:10.3945/ajcn.114.092783 25527767 | Outcome
1253 | Komiyama, N, Saito, T, Hosaka, Y, Aida, K, Kaneko, T, Sato, A, Onaya, T, Kobayashi, T, Tawata, M. Effects of a 4-week 70% high carbohydrate/15% low fat diet on glucose tolerance and on lipid profiles. Diabetes Res Clin Pract. 2004. 64:11–8. doi:10.1016/j.diabres.2003.10.002 15036822 | Study duration
1254 | Kong, AP, Choi, KC, Chan, RS, Lok, K, Ozaki, R, Li, AM, Ho, CS, Chan, MH, Sea, M, Henry, CJ, Chan, JC, Woo, J. A randomized controlled trial to investigate the impact of a low glycemic index (GI) diet on body mass index in obese adolescents. BMC Public Health. 2014. 14:180. doi:10.1186/1471-2458-14-180 24552366 | Weight loss/Hypocaloric
1255 | Kong, LC, Holmes, BA, Cotillard, A, Habi-Rachedi, F, Brazeilles, R, Gougis, S, Gausseres, N, Cani, PD, Fellahi, S, Bastard, JP, Kennedy, SP, Dore, J, Ehrlich, SD, Zucker, JD, Rizkalla, SW, Clement, K. Dietary patterns differently associate with inflammation and gut microbiota in overweight and obese subjects. PLoS One. 2014. 9:e109434. doi:10.1371/journal.pone.0109434 25330000 | Study Design
1256 | Koopman, KE, Booij, J, Fliers, E, La Fleur, SE, Serlie, MJ. A hypercaloric high fat high sugar diet decreases diencephalic serotonin transporters in humans. Clinical nutrition, supplement. 2012. 7:30. doi:10.1016/S1744-1161%2812%2970065-0 | Publication Status
1257 | Kouris-Blazos, A, Itsiopoulos, C. Low all-cause mortality despite high cardiovascular risk in elderly Greek-born Australians: attenuating potential of diet?. Asia Pacific journal of clinical nutrition. 2014. 23:532–544. doi:10.6133/apjcn.2014.23.4.16 25516310 | Study Design
1258 | Koutsari, C, Malkova, D, Hardman, AE. Postprandial lipemia after short-term variation in dietary fat and carbohydrate. Metabolism. 2000. 49:1150–5. doi:10.1053/meta.2000.8612 11016896 | Study duration
1259 | Koutsari, C, Sidossis, LS. Effect of isoenergetic low- and high-carbohydrate diets on substrate kinetics and oxidation in healthy men. Br J Nutr. 2003. 90:413–8. doi:10.1079/bjn2003894 12908902 | Study duration
1260 | Kouvari, M, Notara, V, Panagiotakos, DB, Michalopoulou, M, Vassileiou, N, Papataxiarchis, E, Tzanoglou, D, Mantas, Y, Kogias, Y, Stravopodis, P, Papanagnou, G, Zombolos, S, Pitsavos, C. Exclusive olive oil consumption and 10-year (2004-2014) acute coronary syndrome incidence among cardiac patients: the GREECS observational study. J Hum Nutr Diet. 2016. 29:354–62. doi:10.1111/jhn.12324 26109373 | Health Status
1261 | Kovell, LC, Yeung, EH, Miller, ER, 3rd, Appel, LJ, Christenson, RH, Rebuck, H, Schulman, SP, Juraschek, SP. Healthy diet reduces markers of cardiac injury and inflammation regardless of macronutrients: Results from the OmniHeart trial. Int J Cardiol. 2019. :. doi:10.1016/j.ijcard.2019.07.102 | Study duration
1262 | Krajcovicova-Kudlackova, M, Blazicek, P, Babinska, K, Kopcova, J, Klvanova, J, Bederova, A, Magalova, T. Traditional and alternative nutrition--levels of homocysteine and lipid parameters in adults. Scand J Clin Lab Invest. 2000. 60:657–64. doi:10.1080/00365510050216385 11218148 | Study Design
1263 | Kralova Lesna, I, Suchanek, P, Brabcova, E, Kovar, J, Malinska, H, Poledne, R. Effect of different types of dietary fatty acids on subclinical inflammation in humans. Physiol Res. 2013. 62:145–52. doi:unavailable23234408 | Intervention/Exposure; Study duration
1264 | Kramer, CS, Szmidt, MK, Sicinska, E, Brzozowska, A, Santoro, A, Franceschi, C, de Groot, Lcpgm, Berendsen, AAM. The Elderly-Nutrient Rich Food Score Is Associated With Biochemical Markers of Nutritional Status in European Older Adults. Front Nutr. 2019. 6:150. doi:10.3389/fnut.2019.00150 31572729 | Study Design; Outcome
1265 | Krasevec, J, An, X, Kumapley, R, Bégin, F, Frongillo, EA. Diet quality and risk of stunting among infants and young children in low- and middle-income countries. Maternal and Child Nutrition. 2017. 13:. doi:10.1111/mcn.12430 | Country; AGE: Intervention/Exposure
1266 | Kratz, M, Weigle, DS, Breen, PA, Meeuws, KE, Burden, VR, Callahan, HS, Matthys, CC, Purnell, JQ. Exchanging carbohydrate or protein for fat improves lipid-related cardiovascular risk profile in overweight men and women when consumed ad libitum. J Investig Med. 2010. 58:711–9. doi:10.231/JIM.0b013e3181da4d37 | Study Design; Intervention/Exposure
1267 | Krauss, RM, Blanche, PJ, Rawlings, RS, Fernstrom, HS, Williams, PT. Separate effects of reduced carbohydrate intake and weight loss on atherogenic dyslipidemia. Am J Clin Nutr. 2006. 83:1025–31; quiz 1205. doi:10.1093/ajcn/83.5.1025 16685042 | Weight loss/Hypocaloric
1268 | Krebs, NF, Gao, D, Gralla, J, Collins, JS, Johnson, SL. Efficacy and safety of a high protein, low carbohydrate diet for weight loss in severely obese adolescents. J Pediatr. 2010. 157:252–8. doi:10.1016/j.jpeds.2010.02.010 20304413 | Weight loss/Hypocaloric
1269 | Kreider, RB, Rasmussen, C, Kerksick, CM, Wilborn, C, Taylor, th L, Campbell, B, Magrans-Courtney, T, Fogt, D, Ferreira, M, Li, R, Galbreath, M, Iosia, M, Cooke, M, Serra, M, Gutierrez, J, Byrd, M, Kresta, JY, Simbo, S, Oliver, J, Greenwood, M. A carbohydrate-restricted diet during resistance training promotes more favorable changes in body composition and markers of health in obese women with and without insulin resistance. Phys Sportsmed. 2011. 39:27–40. doi:10.3810/psm.2011.05.1893 21673483 | Study duration
1270 | Krieger, JP, Pestoni, G, Cabaset, S, Brombach, C, Sych, J, Schader, C, Faeh, D, Rohrmann, S. Dietary Patterns and Their Sociodemographic and Lifestyle Determinants in Switzerland: Results from the National Nutrition Survey menuCH. Nutrients. 2018. 11:. doi:10.3390/nu11010062 | Study Design
1271 | Krishnan, S, Adams, SH, Allen, LH, Laugero, KD, Newman, JW, Stephensen, CB, Burnett, DJ, Witbracht, M, Welch, LC, Que, ES, Keim, NL. A randomized controlled-feeding trial based on the Dietary Guidelines for Americans on cardiometabolic health indexes. Am J Clin Nutr. 2018. 108:266–278. doi:10.1093/ajcn/nqy113 30101333 | Study duration
1272 | Krishnan, S, Steffen, LM, Paton, CM, Cooper, JA. Impact of dietary fat composition on prediabetes: a 12-year follow-up study. Public Health Nutr. 2017. 20:1617–1626. doi:10.1017/s1368980016003669 28137328 | Intervention/Exposure; Outcome
1273 | Krokstad, S, Ding, D, Grunseit, AC, Sund, ER, Holmen, TL, Rangul, V, Bauman, A. Multiple lifestyle behaviours and mortality, findings from a large population-based Norwegian cohort study - The HUNT Study. BMC Public Health. 2017. 17:58. doi:10.1186/s12889-016-3993-x 28068991 | Intervention/Exposure
1274 | Kromhout, D, Menotti, A, Alberti-Fidanza, A, Puddu, PE, Hollman, P, Kafatos, A, Tolonen, H, Adachi, H, Jacobs, DR, Jr. Comparative ecologic relationships of saturated fat, sucrose, food groups, and a Mediterranean food pattern score to 50-year coronary heart disease mortality rates among 16 cohorts of the Seven Countries Study. Eur J Clin Nutr. 2018. 72:1103–1110. doi:10.1038/s41430-018-0183-1 29769748 | Study Design
1275 | Krzyminiewski, R, Mrozinska, G, Dobosz, B. The impact of Fruit-Vegetable Diet on High Signal Resolution Pulse Wave (HSR-PW) Parameters. J Nutr Health Aging. 2018. 22:420–424. doi:10.1007/s12603-017-0944-x 29484356 | Intervention/Exposure; Study duration
1276 | Kucharska, A, Gajewska, D, Kiedrowski, M, Sinska, B, Juszczyk, G, Czerw, A, Augustynowicz, A, Bobinski, K, Deptala, A, Niegowska, J. The impact of individualised nutritional therapy according to DASH diet on blood pressure, body mass, and selected biochemical parameters in overweight/obese patients with primary arterial hypertension: a prospective randomised study. Kardiol Pol. 2018. 76:158–165. doi:10.5603/KP.a2017.0184 28980293 | Weight loss/Hypocaloric
1277 | Kuchta, A, Lebiedzinska, A, Fijalkowski, M, Galaska, R, Kreft, E, Toton, M, Czaja, K, Kozlowska, A, Cwiklinska, A, Kortas-Stempak, B, Strzelecki, A, Gliwinska, A, Dabkowski, K, Jankowski, M. Impact of plant-based diet on lipid risk factors for atherosclerosis. Cardiol J. 2016. 23:141–8. doi:10.5603/CJ.a2016.0002 26779974 | Study Design
1278 | Kunesova, M, Braunerova, R, Hlavaty, P, Tvrzicka, E, Stankova, B, Skrha, J, Hilgertova, J, Hill, M, Kopecky, J, Wagenknecht, M, Hainer, V, Matoulek, M, Parizkova, J, Zak, A, Svacina, S. The influence of n-3 polyunsaturated fatty acids and very low calorie diet during a short-term weight reducing regimen on weight loss and serum fatty acid composition in severely obese women. Physiol Res. 2006. 55:63–72. doi:unavailable15857162 | Study duration
1279 | Kurihara, A, Okamura, T, Sugiyama, D, Higashiyama, A, Watanabe, M, Okuda, N, Kadota, A, Miyagawa, N, Fujiyoshi, A, Yoshita, K, Ohkubo, T, Okayama, A, Miura, K, Ueshima, H. Vegetable Protein Intake was Inversely Associated with Cardiovascular Mortality in a 15-Year Follow-Up Study of the General Japanese Population. J Atheroscler Thromb. 2019. 26:198–206. doi:10.5551/jat.44172 30089755 | Intervention/Exposure
1280 | Kurka, JM, Buman, MP, Ainsworth, BE. Validity of the Rapid Eating Assessment for Patients for assessing dietary patterns in NCAA athletes. J Int Soc Sports Nutr. 2014. 11:42. doi:10.1186/s12970-014-0042-y 25302055 | Study Design; Outcome
1281 | Kurotani, K, Nanri, A, Goto, A, Mizoue, T, Noda, M, Oba, S, Sawada, N, Tsugane, S. Cholesterol and egg intakes and the risk of type 2 diabetes: the Japan Public Health Center-based Prospective Study. Br J Nutr. 2014. 112:1636–43. doi:10.1017/s000711451400258x 25230771 | Intervention/Exposure
1282 | Kuzawa, CW, Adair, LS, Avila, JL, Cadungog, JH, Le, NA. Atherogenic lipid profiles in Filipino adolescents with low body mass index and low dietary fat intake. Am J Hum Biol. 2003. 15:688–96. doi:10.1002/ajhb.10200 12953181 | Study Design
1283 | Kwagyan, J, Retta, TM, Ketete, M, Bettencourt, CN, Maqbool, AR, Xu, S, Randall, OS. Obesity and Cardiovascular Diseases in a High-Risk Population: Evidence-Based Approach to CHD Risk Reduction. Ethn Dis. 2015. 25:208–13. doi:unavailable26118150 | Intervention/Exposure
1284 | Kwasniewska, M, Pikala, M, Bielecki, W, Aranowska, A, Waskiewicz, A, Kozakiewicz, K, Tykarski, A, Pajak, A, Zdrojewski, T, Drygas, W. Ten-year changes in the prevalence of healthy lifestyle behaviors and factors among Polish Adults. Results of the National Multicenter Health Surveys WOBASZ (2003-2005) and WOBASZ II (2013-2014). European journal of preventive cardiology. 2017. 24:S12-. doi:unavailable | Publication Status
1285 | Kwon, HN, Nam, SS, Park, YK. Effect on 12-week Intensive Dietary and Exercise Program on Weight Reduction and Maintenance in Obese Women with Weight Cycling History. Clin Nutr Res. 2017. 6:183–197. doi:10.7762/cnr.2017.6.3.183 28770181 | Intervention/Exposure
1286 | Kynde, I, Johnsen, NF, Wedderkopp, N, Bygbjerg, IB, Helge, JW, Heitmann, BL. Intake of total dietary sugar and fibre is associated with insulin resistance among Danish 8-10- and 14-16-year-old girls but not boys. European Youth Heart Studies I and II. Public Health Nutr. 2010. 13:1669–74. doi:10.1017/s1368980010000285 20236560 | Intervention/Exposure
1287 | La Spina, P, Savica, R, Ciacciarelli, A, Cotroneo, M, Dell’Aera, C, Grillo, F, Casella, C, Fazio, MC, Trimarchi, G, Musolino, RF. Eating habits in the population of the Aeolian Islands: an observational study. Public Health Nutr. 2018. :1–7. doi:10.1017/s1368980018003397 | Study Design
1288 | La Verde, M, Mule, S, Zappala, G, Privitera, G, Maugeri, G, Pecora, F, Marranzano, M. Higher adherence to the Mediterranean diet is inversely associated with having hypertension: is low salt intake a mediating factor?. Int J Food Sci Nutr. 2018. 69:235–244. doi:10.1080/09637486.2017.1350941 28705075 | Study Design; Outcome
1289 | Labayen Goni, I, Arenaza, L, Medrano, M, Garcia, N, Cadenas-Sanchez, C, Ortega, FB. Associations between the adherence to the Mediterranean diet and cardiorespiratory fitness with total and central obesity in preschool children: the PREFIT project. Eur J Nutr. 2018. 57:2975–2983. doi:10.1007/s00394-017-1571-3 29127475 | Study Design
1290 | Labayen, I, Diez, N, Gonzalez, A, Parra, D, Martinez, JA. Effects of protein vs. carbohydrate-rich diets on fuel utilisation in obese women during weight loss. Forum Nutr. 2003. 56:168–70. doi:unavailable15806847 | Weight loss/Hypocaloric; Study duration
1291 | Labayen, I, Margareto, J, Maldonado-Martin, S, Gorostegi, I, Illera, M, Medrano, M, Barrenechea, L, Larrarte, E. Independent and combined influence of the FTO rs9939609 and MC4Rrs17782313 polymorphisms on hypocaloric diet induced changes in body mass and composition and energy metabolism in non-morbid obese premenopausal women. Nutr Hosp. 2015. 31:2025–32. doi:10.3305/nh.2015.31.5.8666 25929371 | Intervention/Exposure
1292 | Labayen, I, Ruiz, JR, Ortega, FB, Huybrechts, I, Rodriguez, G, Jimenez-Pavon, D, Roccaldo, R, Nova, E, Widhalm, K, Kafatos, A, Molnar, D, Androutsos, O, Moreno, LA. High fat diets are associated with higher abdominal adiposity regardless of physical activity in adolescents; the HELENA study. Clin Nutr. 2014. 33:859–66. doi:10.1016/j.clnu.2013.10.008 24182766 | Study Design
1293 | LaFountain, RA, Miller, VJ, Barnhart, EC, Hyde, PN, Crabtree, CD, McSwiney, FT, Beeler, MK, Buga, A, Sapper, TN, Short, JA, Bowling, ML, Kraemer, WJ, Simonetti, OP, Maresh, CM, Volek, JS. Extended Ketogenic Diet and Physical Training Intervention in Military Personnel. Mil Med. 2019. :. doi:10.1093/milmed/usz046 | Intervention/Exposure
1294 | Lafrenière, J, Carbonneau, É, Laramée, C, Corneau, L, Robitaille, J, Labonté, M, Lamarche, B, Lemieux, S. Is the Canadian Healthy Eating Index 2007 an Appropriate Diet Indicator of Metabolic Health? Insights from Dietary Pattern Analysis in the PREDISE Study. Nutrients. 2019. 11:. doi:10.3390/nu11071597 | Study Design
1295 | Lagerpusch, M, Enderle, J, Eggeling, B, Braun, W, Johannsen, M, Pape, D, Muller, MJ, Bosy-Westphal, A. Carbohydrate quality and quantity affect glucose and lipid metabolism during weight regain in healthy men. J Nutr. 2013. 143:1593–601. doi:10.3945/jn.113.179390 23946346 | Study duration
1296 | Lagerpusch, M, Enderle, J, Later, W, Eggeling, B, Pape, D, Muller, MJ, Bosy-Westphal, A. Impact of glycaemic index and dietary fibre on insulin sensitivity during the refeeding phase of a weight cycle in young healthy men. Br J Nutr. 2013. 109:1606–16. doi:10.1017/s000711451200462x 23191994 | Study duration
1297 | Lagiou, P, Sandin, S, Lof, M, Trichopoulos, D, Adami, HO, Weiderpass, E. Low carbohydrate-high protein diet and incidence of cardiovascular diseases in Swedish women: prospective cohort study. Bmj. 2012. 344:e4026. doi:10.1136/bmj.e4026 22735105 | Intervention/Exposure
1298 | Lagiou, P, Sandin, S, Weiderpass, E, Lagiou, A, Mucci, L, Trichopoulos, D, Adami, HO. Low carbohydrate-high protein diet and mortality in a cohort of Swedish women. J Intern Med. 2007. 261:366–74. doi:10.1111/j.1365-2796.2007.01774.x 17391111 | Intervention/Exposure
1299 | Lai, HT, Threapleton, DE, Day, AJ, Williamson, G, Cade, JE, Burley, VJ. Fruit intake and cardiovascular disease mortality in the UK Women’s Cohort Study. Eur J Epidemiol. 2015. 30:1035–48. doi:10.1007/s10654-015-0050-5 26076918 | Intervention/Exposure
1300 | Laitinen, TT, Nuotio, J, Juonala, M, Niinikoski, H, Rovio, S, Viikari, JSA, Ronnemaa, T, Magnussen, CG, Jokinen, E, Lagstrom, H, Jula, A, Simell, O, Raitakari, OT, Pahkala, K. Success in Achieving the Targets of the 20-Year Infancy-Onset Dietary Intervention: Association With Insulin Sensitivity and Serum Lipids. Diabetes Care. 2018. 41:2236–2244. doi:10.2337/dc18-0869 30072407 | Intervention/Exposure; AGE: Intervention/Exposure
1301 | Lamarche, B. Dietary sources of saturated fat may influence cardiovascular disease risk. Can Nurse. 2013. 109:19. doi:unavailable23556349 | Study Design; Publication Status
1302 | Lambert, EA, Phillips, S, Belski, R, Tursunalieva, A, Eikelis, N, Sari, CI, Dixon, JB, Straznicky, N, Grima, M, Head, GA, Schlaich, M, Lambert, GW. Endothelial Function in Healthy Young Individuals Is Associated with Dietary Consumption of Saturated Fat. Front Physiol. 2017. 8:876. doi:10.3389/fphys.2017.00876 29170641 | Study Design
1303 | Lammert, O, Grunnet, N, Faber, P, Bjornsbo, KS, Dich, J, Larsen, LO, Neese, RA, Hellerstein, MK, Quistorff, B. Effects of isoenergetic overfeeding of either carbohydrate or fat in young men. Br J Nutr. 2000. 84:233–45. doi:unavailable11029975 | Study duration
1304 | Lamri, A, Bonnefond, A, Meyre, D, Balkau, B, Roussel, R, Marre, M, Froguel, P, Fumeron, F. Interaction between GPR120 p.R270H loss-of-function variant and dietary fat intake on incident type 2 diabetes risk in the D.E.S.I.R. study. Nutr Metab Cardiovasc Dis. 2016. 26:931–6. doi:10.1016/j.numecd.2016.04.010 27212621 | Intervention/Exposure
1305 | Lamri-Senhadji, MY, El Kebir, B, Belleville, J, Bouchenak, M. Assessment of dietary consumption and time-course of changes in serum lipids and lipoproteins before, during and after Ramadan in young Algerian adults. Singapore Med J. 2009. 50:288–94. doi:unavailable19352573 | Intervention/Exposure
1306 | Landers, P, Wolfe, MM, Glore, S, Guild, R, Phillips, L. Effect of weight loss plans on body composition and diet duration. J Okla State Med Assoc. 2002. 95:329–31. doi:unavailable12043107 | Intervention/Exposure
1307 | Langsetmo, L, Barr, SI, Berger, C, Kreiger, N, Rahme, E, Adachi, JD, Papaioannou, A, Kaiser, SM, Prior, JC, Hanley, DA, Kovacs, CS, Josse, RG, Goltzman, D. Associations of Protein Intake and Protein Source with Bone Mineral Density and Fracture Risk: A Population-Based Cohort Study. J Nutr Health Aging. 2015. 19:861–8. doi:10.1007/s12603-015-0544-6 26412291 | Intervention/Exposure
1308 | Langsetmo, L, Barr, SI, Dasgupta, K, Berger, C, Kovacs, CS, Josse, RG, Adachi, JD, Hanley, DA, Prior, JC, Brown, JP, Morin, SN, Davison, KS, Goltzman, D, Kreiger, N. Dietary patterns in men and women are simultaneously determinants of altered glucose metabolism and bone metabolism. Nutr Res. 2016. 36:328–336. doi:10.1016/j.nutres.2015.12.010 27001278 | Outcome
1309 | Lankinen, M, Schwab, U, Kolehmainen, M, Paananen, J, Nygren, H, Seppanen-Laakso, T, Poutanen, K, Hyotylainen, T, Riserus, U, Savolainen, MJ, Hukkanen, J, Brader, L, Marklund, M, Rosqvist, F, Hermansen, K, Cloetens, L, Onning, G, Thorsdottir, I, Gunnarsdottir, I, Akesson, B, Dragsted, LO, Uusitupa, M, Oresic, M. A Healthy Nordic Diet Alters the Plasma Lipidomic Profile in Adults with Features of Metabolic Syndrome in a Multicenter Randomized Dietary Intervention. J Nutr. 2016. :. doi:10.3945/jn.115.220459 | Outcome
1310 | Lapetra, J, Lozano-Rodriguez, JM, Miro-Moriano, L, Ortega-Calvo, M, Santos-Lozano, JM, Garcia-Corte, FJ, Caballero-Valderrama, MR, Dominguez-Espinaco, C, Vaquero-Diaz, S, Santos-Calonge, A. Effect of a mediterranean diet on the primary prevention of atrial fibrillation and major cardiovascular events in hypertensive patients with high cardiovascular risk: results of ICFAMED randomized trial. European journal of clinical investigation. 2018. 48:182–183. doi:10.1111/eci.12926 | Publication Status
1312 | Lappalainen, T, Lindstrom, J, Paananen, J, Eriksson, JG, Karhunen, L, Tuomilehto, J, Uusitupa, M. Association of the fat mass and obesity-associated (FTO) gene variant (rs9939609) with dietary intake in the Finnish Diabetes Prevention Study. Br J Nutr. 2012. 108:1859–65. doi:10.1017/s0007114511007410 22265018 | Intervention/Exposure
1311 | Lapointe, A, Weisnagel, SJ, Provencher, V, Begin, C, Dufour-Bouchard, AA, Trudeau, C, Lemieux, S. Comparison of a dietary intervention promoting high intakes of fruits and vegetables with a low-fat approach: long-term effects on dietary intakes, eating behaviours and body weight in postmenopausal women. Br J Nutr. 2010. 104:1080–90. doi:10.1017/s0007114510001716 20482930 | Intervention/Exposure; Comparator
1313 | Larsen, TM. Nordic diet in obese subjects: results from the SHOPUS study. Annals of nutrition and metabolism. Conference: 12th european nutrition conference, FENS 2015. Berlin germany. Conference start: 20151020. Conference end: 20151023. Conference publication: (var.pagings). 2015. 67:52. doi:10.1159/000440895 | Publication Status
1314 | Larsen, TM. The nordic diet. Obesity facts. 2014. 7:13–14. doi:10.1159/000363668 24853347 | Publication Status
1315 | Larson-Meyer, DE, Borkhsenious, ON, Gullett, JC, Russell, RR, Devries, MC, Smith, SR, Ravussin, E. Effect of dietary fat on serum and intramyocellular lipids and running performance. Med Sci Sports Exerc. 2008. 40:892–902. doi:10.1249/MSS.0b013e318164cb33 18408608 | Study duration
1316 | Larsson, SC, Akesson, A, Wolk, A. Primary prevention of stroke by a healthy lifestyle in a high-risk group. Neurology. 2015. 84:2224–8. doi:10.1212/wnl.0000000000001637 25934859 | Intervention/Exposure
1317 | Larsson, SC, Wolk, A. Dietary fiber intake is inversely associated with stroke incidence in healthy Swedish adults. J Nutr. 2014. 144:1952–5. doi:10.3945/jn.114.200634 25411032 | Intervention/Exposure
1318 | Lasker, DA, Evans, EM, Layman, DK. Moderate carbohydrate, moderate protein weight loss diet reduces cardiovascular disease risk compared to high carbohydrate, low protein diet in obese adults: A randomized clinical trial. Nutr Metab (Lond). 2008. 5:30. doi:10.1186/1743-7075-5-30 18990242 | Weight loss/Hypocaloric
1319 | Lau, C, Toft, U, Tetens, I, Carstensen, B, Jorgensen, T, Pedersen, O, Borch-Johnsen, K. Dietary patterns predict changes in two-hour post-oral glucose tolerance test plasma glucose concentrations in middle-aged adults. J Nutr. 2009. 139:588–93. doi:10.3945/jn.108.100339 19158222 | Outcome
1320 | Laupsa Borge, J, Veum, VL, Eng, Ø, Rostrup, E, Larsen, TH, Nordrehaug, J, Nygård, OK, Sagen, JV, Gudbrandsen, OA, Dankel, SN, , . Very-high-fat and low-fat isocaloric diets exert similar metabolic benefits but different temporal effects on cardiometabolic risk markers. Obesity facts. 2016. 9:185–186. doi:10.1159/000446744 | Publication Status
1321 | Lauria, F, Siani, A, Picó, C, Ahrens, W, Bammann, K, De Henauw, S, Foraita, R, Iacoviello, L, Kourides, Y, Marild, S, Molnar, D, Moreno, LA, Pitsiladis, Y, Sánchez, J, Veidebaum, T, Wang, G, Russo, P. A common variant and the transcript levels of MC4R gene are associated with adiposity in children: The IDEFICS study. Journal of Clinical Endocrinology and Metabolism. 2016. 101:4229–4236. doi:10.1210/jc.2016-1992 27583473 | Intervention/Exposure
1322 | Layman, DK, Boileau, RA, Erickson, DJ, Painter, JE, Shiue, H, Sather, C, Christou, DD. A reduced ratio of dietary carbohydrate to protein improves body composition and blood lipid profiles during weight loss in adult women. J Nutr. 2003. 133:411–7. doi:10.1093/jn/133.2.411 12566476 | Power/Size
1323 | Layman, DK, Evans, E, Baum, JI, Seyler, J, Erickson, DJ, Boileau, RA. Dietary protein and exercise have additive effects on body composition during weight loss in adult women. J Nutr. 2005. 135:1903–10. doi:10.1093/jn/135.8.1903 16046715 | Power/Size
1324 | Layman, DK, Evans, EM, Erickson, D, Seyler, J, Weber, J, Bagshaw, D, Griel, A, Psota, T, Kris-Etherton, P. A moderate-protein diet produces sustained weight loss and long-term changes in body composition and blood lipids in obese adults. J Nutr. 2009. 139:514–21. doi:10.3945/jn.108.099440 19158228 | Weight loss/Hypocaloric
1325 | Layman, DK, Shiue, H, Sather, C, Erickson, DJ, Baum, J. Increased dietary protein modifies glucose and insulin homeostasis in adult women during weight loss. J Nutr. 2003. 133:405–10. doi:10.1093/jn/133.2.405 12566475 | Study duration
1326 | Lazarou, C, Karaolis, M, Matalas, AL, Panagiotakos, DB. Dietary patterns analysis using data mining method. An application to data from the CYKIDS study. Computer Methods and Programs in Biomedicine. 2012. 108:706–714. doi:10.1016/j.cmpb.2011.12.011 22296977 | Study Design; Outcome
1327 | Le, T, Flatt, SW, Natarajan, L, Pakiz, B, Quintana, EL, Heath, DD, Rana, BK, Rock, CL. Effects of Diet Composition and Insulin Resistance Status on Plasma Lipid Levels in a Weight Loss Intervention in Women. J Am Heart Assoc. 2016. 5:. doi:10.1161/jaha.115.002771 | Intervention/Exposure
1328 | Leblanc, V, Begin, C, Hudon, AM, Royer, MM, Corneau, L, Dodin, S, Lemieux, S. Gender differences in the long-term effects of a nutritional intervention program promoting the Mediterranean diet: changes in dietary intakes, eating behaviors, anthropometric and metabolic variables. Nutr J. 2014. 13:107. doi:10.1186/1475-2891-13-107 25416917 | Intervention/Exposure
1329 | Leblanc, V, Hudon, AM, Royer, MM, Corneau, L, Dodin, S, Begin, C, Lemieux, S. Differences between men and women in dietary intakes and metabolic profile in response to a 12-week nutritional intervention promoting the Mediterranean diet. J Nutr Sci. 2015. 4:e13. doi:10.1017/jns.2015.2 26090094 | Study Design; Intervention/Exposure
1330 | Lecheminant, JD, Gibson, CA, Sullivan, DK, Hall, S, Washburn, R, Vernon, MC, Curry, C, Stewart, E, Westman, EC, Donnelly, JE. Comparison of a low carbohydrate and low fat diet for weight maintenance in overweight or obese adults enrolled in a clinical weight management program. Nutr J. 2007. 6:36. doi:10.1186/1475-2891-6-36 17976244 | Power/Size
1331 | LeCheminant, JD, Smith, BK, Westman, EC, Vernon, MC, Donnelly, JE. Comparison of a reduced carbohydrate and reduced fat diet for LDL, HDL, and VLDL subclasses during 9-months of weight maintenance subsequent to weight loss. Lipids Health Dis. 2010. 9:54. doi:10.1186/1476-511x-9-54 20515484 | Power/Size
1332 | Lee, A, Cheung, CK, Lo, K, Keung, VM, Mui, LW, Tam, WWS. Studying Impact of Nutrition on Growth (SING): a prospective cohort for comparing the health outcomes of young children with the dietary quality score. BMJ Open. 2017. 7:e018380. doi:10.1136/bmjopen-2017-018380 | Study Design; AGE: Intervention/Exposure
1333 | Lee, A, Jeon, KJ, Kim, HK, Han, SN. Effect of a 12-week weight management program on the clinical characteristics and dietary intake of the young obese and the contributing factors to the successful weight loss. Nutr Res Pract. 2014. 8:571–9. doi:10.4162/nrp.2014.8.5.571 25324939 | Intervention/Exposure
1334 | Lee, BR, Ko, YM, Cho, MH, Yoon, YR, Kye, SH, Park, YK. Effects of 12-week Vegetarian Diet on the Nutritional Status, Stress Status and Bowel Habits in Middle School Students and Teachers. Clin Nutr Res. 2016. 5:102–11. doi:10.7762/cnr.2016.5.2.102 27152300 | Study Design; Intervention/Exposure
1335 | Lee, CJ, Kim, JY, Shim, E, Hong, SH, Lee, M, Jeon, JY, Park, S. The Effects of Diet Alone or in Combination with Exercise in Patients with Prehypertension and Hypertension: a Randomized Controlled Trial. Korean Circ J. 2018. 48:637–651. doi:10.4070/kcj.2017.0349 29968437 | Intervention/Exposure
1336 | Lee, CJ, Youn, JC, Lee, SH, Park, S, Kang, SM, Choi, D. Randomized study to determine the effect of unmonitored diet and exercise education on blood pressure (the LSM study). European heart journal. 2015. 36:1184. doi:10.1093/eurheartj/ehv401 | Publication Status
1337 | Lee, E, Choi, J, Ahn, A, Oh, E, Kweon, H, Cho, D. Acceptable macronutrient distribution ranges and hypertension. Clin Exp Hypertens. 2015. 37:463–7. doi:10.3109/10641963.2015.1013116 25815800 | Study Design
1338 | Lee, HA, Hwang, HJ, Oh, SY, Park, EA, Cho, SJ, Kim, HS, Park, H. The differential effects of changes in individual macronutrient intake on changes in lipid concentrations during childhood: From the Ewha Birth & Growth Cohort. Clin Nutr. 2018. 37:1027–1033. doi:10.1016/j.clnu.2017.04.017 28506448 | Intervention/Exposure
1339 | Lee, HA, Hwang, HJ, Oh, SY, Park, EA, Cho, SJ, Kim, HS, Park, H. Which Diet-Related Behaviors in Childhood Influence a Healthier Dietary Pattern? From the Ewha Birth and Growth Cohort. Nutrients. 2016. 9:. doi:10.3390/nu9010004 | Study Design
1340 | Lee, HH, Park, HA, Kang, JH, Cho, YG, Park, JK, Lee, R, Yoon, JY, Kim, OH. Factors related to body mass index and body mass index change in korean children: preliminary results from the obesity and metabolic disorders cohort in childhood. Korean J Fam Med. 2012. 33:134–43. doi:10.4082/kjfm.2012.33.3.134 22787535 | Intervention/Exposure
1341 | Lee, J, Kim, J. Association between Dietary Pattern and Incidence of Cholesterolemia in Korean Adults: The Korean Genome and Epidemiology Study. Nutrients. 2018. 10:. doi:10.3390/nu10010053 | Study Design; Outcome
1342 | Lee, J, Pase, M, Pipingas, A, Raubenheimer, J, Thurgood, M, Villalon, L, Macpherson, H, Gibbs, A, Scholey, A. Switching to a 10-day Mediterranean-style diet improves mood and cardiovascular function in a controlled crossover study. Nutrition. 2015. 31:647–52. doi:10.1016/j.nut.2014.10.008 25837207 | Study duration
1343 | Lee, JK, Kim, H. Effects of the lifestyle modification program to reduce serum lipoprotein(a) and other cardiovascular risk factors in Korean college women. Gazzetta Medica Italiana Archivio per le Scienze Mediche. 2018. 177:468–474. doi:10.23736/S0393-3660.17.03592-6 | Intervention/Exposure; Study duration
1344 | Lee, KW, Lyu, J, Park, JK, Jo, C, Kim, SS. Dietary carbohydrate quality and quantity in relation to the incidence of type 2 diabetes: A prospective cohort study of middle-aged and older Korean adults. Nutrition. 2019. 57:245–251. doi:10.1016/j.nut.2018.04.011 30195245 | Intervention/Exposure
1345 | Lee, KW, Woo, HD, Cho, MJ, Park, JK, Kim, SS. Identification of Dietary Patterns Associated with Incidence of Hyperglycemia in Middle-Aged and Older Korean Adults. Nutrients. 2019. 11:. doi:10.3390/nu11081801 | Outcome
1346 | Lee, SK, Novotny, R, Daida, YG, Vijayadeva, V, Gittelsohn, J. Dietary patterns of adolescent girls in Hawaii over a 2-year period. J Am Diet Assoc. 2007. 107:956–61. doi:10.1016/j.jada.2007.03.009 17524716 | Study Design; Publication Date Overlaps with Existing Review
1347 | Lee, TA, Li, Z, Zerlin, A, Heber, D. Effects of dihydrocapsiate on adaptive and diet-induced thermogenesis with a high protein very low calorie diet: a randomized control trial. Nutr Metab (Lond). 2010. 7:78. doi:10.1186/1743-7075-7-78 20925950 | Intervention/Exposure; Study duration
1348 | Lee, Y, Mitchell, DC, Smiciklas-Wright, H, Birch, LL. Diet quality, nutrient intake, weight status, and feeding environments of girls meeting or exceeding recommendations for total dietary fat of the American Academy of Pediatrics. Pediatrics. 2001. 107:E95. doi:10.1542/peds.107.6.e95 11389293 | Intervention/Exposure; Outcome
1349 | Lee, YY, Wan Muda, WAM. Dietary intakes and obesity of Malaysian adults. Nutr Res Pract. 2019. 13:159–168. doi:10.4162/nrp.2019.13.2.159 30984360 | Study Design
1350 | Leech, RM, McNaughton, SA, Timperio, A. Clustering of diet, physical activity and sedentary behaviour among Australian children: cross-sectional and longitudinal associations with overweight and obesity. Int J Obes (Lond). 2015. 39:1079–85. doi:10.1038/ijo.2015.66 25907316 | Intervention/Exposure
1351 | Lefevre, M, Champagne, CM, Tulley, RT, Rood, JC, Most, MM. Individual variability in cardiovascular disease risk factor responses to low-fat and low-saturated-fat diets in men: body mass index, adiposity, and insulin resistance predict changes in LDL cholesterol. Am J Clin Nutr. 2005. 82:957–63; quiz 1145-6. doi:10.1093/ajcn/82.5.957 16280425 | Study duration
1352 | Leichtle, AB, Helmschrodt, C, Ceglarek, U, Shai, I, Henkin, Y, Schwarzfuchs, D, Golan, R, Gepner, Y, Stampfer, MJ, Bluher, M, Stumvoll, M, Thiery, J, Fiedler, GM. Effects of a 2-y dietary weight-loss intervention on cholesterol metabolism in moderately obese men. Am J Clin Nutr. 2011. 94:1189–95. doi:10.3945/ajcn.111.018119 21940598 | Outcome
1353 | Leidy, HJ, Carnell, NS, Mattes, RD, Campbell, WW. Higher protein intake preserves lean mass and satiety with weight loss in pre-obese and obese women. Obesity (Silver Spring). 2007. 15:421–9. doi:10.1038/oby.2007.531 17299116 | Weight loss/Hypocaloric
1354 | Leidy, HJ, Hoertel, HA, Douglas, SM, Higgins, KA, Shafer, RS. A high-protein breakfast prevents body fat gain, through reductions in daily intake and hunger, in “Breakfast skipping” adolescents. Obesity (Silver Spring). 2015. 23:1761–4. doi:10.1002/oby.21185 26239831 | Intervention/Exposure
1355 | Leidy, HJ, Mattes, RD, Campbell, WW. Effects of acute and chronic protein intake on metabolism, appetite, and ghrelin during weight loss. Obesity (Silver Spring). 2007. 15:1215–25. doi:10.1038/oby.2007.143 17495198 | Study duration
1356 | Lelong, H, Blacher, J, Baudry, J, Adriouch, S, Galan, P, Fezeu, L, Hercberg, S, Kesse-Guyot, E. Individual and Combined Effects of Dietary Factors on Risk of Incident Hypertension: Prospective Analysis From the NutriNet-Sante Cohort. Hypertension. 2017. 70:712–720. doi:10.1161/hypertensionaha.117.09622 28760943 | Outcome
1357 | Leme, AC, Philippi, ST. The “Healthy Habits, Healthy Girls” randomized controlled trial for girls: study design, protocol, and baseline results. Cad Saude Publica. 2015. 31:1381–94. doi:10.1590/0102-311x00136014 26248094 | Study Design; Intervention/Exposure
1358 | Leonetti, F, Liguori, A, Petti, F, Rughini, S, Silli, L, Liguori, S, Bangrazi, S. Effects of basic traditional Chinese diet on body mass index, lean body mass, and eating and hunger behaviours in overweight or obese individuals. J Tradit Chin Med. 2016. 36:456–63. doi:unavailable28459509 | Study duration
1359 | León-Muñoz, LM, Guallar-Castillón, P, López-García, E, Rodríguez-Artalejo, F. Mediterranean Diet and Risk of Frailty in Community-Dwelling Older Adults. Journal of the American Medical Directors Association. 2014. 15:899–903. doi:10.1016/j.jamda.2014.06.013 25127502 | Outcome
1360 | Letois, F, Mura, T, Scali, J, Gutierrez, LA, Féart, C, Berr, C. Nutrition and mortality in the elderly over 10 years of follow-up: The Three-City study. British Journal of Nutrition. 2016. 116:882–889. doi:10.1017/S000711451600266X | Intervention/Exposure; Outcome
1361 | Levitan, EB, Mittleman, MA, Wolk, A. Dietary glycemic index, dietary glycemic load, and incidence of heart failure events: a prospective study of middle-aged and elderly women. J Am Coll Nutr. 2010. 29:65–71. doi:10.1080/07315724.2010.10719818 20595647 | Intervention/Exposure
1362 | Lewis, AS, McCourt, HJ, Ennis, CN, Bell, PM, Courtney, CH, McKinley, MC, Young, IS, Hunter, SJ. Comparison of 5% versus 15% sucrose intakes as part of a eucaloric diet in overweight and obese subjects: effects on insulin sensitivity, glucose metabolism, vascular compliance, body composition and lipid profile. A randomised controlled trial. Metabolism. 2013. 62:694–702. doi:10.1016/j.metabol.2012.11.008 23363580 | Intervention/Exposure; Study duration
1363 | Ley, SJ, Metcalf, PA, Scragg, RK, Swinburn, BA. Long-term effects of a reduced fat diet intervention on cardiovascular disease risk factors in individuals with glucose intolerance. Diabetes Res Clin Pract. 2004. 63:103–12. doi:10.1016/j.diabres.2003.09.001 14739050 | Intervention/Exposure
1364 | Li, J, Armstrong, C, Campbell, W. Effects of dietary protein quantity and source in appetite responses in energy-restricted overweight and obese adults. FASEB journal. 2015. 29:. doi:unavailable | Publication Status
1365 | Li, J, Armstrong, CL, Campbell, WW. Effects of Dietary Protein Source and Quantity during Weight Loss on Appetite, Energy Expenditure, and Cardio-Metabolic Responses. Nutrients. 2016. 8:63. doi:10.3390/nu8020063 26821042 | Intervention/Exposure; Study duration
1366 | Li, J, Wang, Y. Tracking of dietary intake patterns is associated with baseline characteristics of urban low-income African-American adolescents. J Nutr. 2008. 138:94–100. doi:10.1093/jn/138.1.94 18156410 | Publication Date Overlaps with Existing Review
1367 | Li, M, Shi, Z. Dietary Pattern during 1991-2011 and Its Association with Cardio Metabolic Risks in Chinese Adults: The China Health and Nutrition Survey. Nutrients. 2017. 9:. doi:10.3390/nu9111218 | Country
1368 | Li, S, Flint, A, Pai, JK, Forman, JP, Hu, FB, Willett, WC, Rexrode, KM, Mukamal, KJ, Rimm, EB. Low carbohydrate diet from plant or animal sources and mortality among myocardial infarction survivors. J Am Heart Assoc. 2014. 3:e001169. doi:10.1161/jaha.114.001169 25246449 | Health Status
1369 | Li, S, Zhu, Y, Chavarro, JE, Bao, W, Tobias, DK, Ley, SH, Forman, JP, Liu, A, Mills, J, Bowers, K, Strom, M, Hansen, S, Hu, FB, Zhang, C. Healthful Dietary Patterns and the Risk of Hypertension Among Women With a History of Gestational Diabetes Mellitus: A Prospective Cohort Study. Hypertension. 2016. 67:1157–65. doi:10.1161/hypertensionaha.115.06747 27091899 | Outcome
1370 | Li, SX, Imamura, F, Schulze, MB, Zheng, J, Ye, Z, Agudo, A, Ardanaz, E, Aune, D, Boeing, H, Dorronsoro, M, Dow, C, Fagherazzi, G, Grioni, S, Gunter, MJ, Huerta, JM, Ibsen, DB, Jakobsen, MU, Kaaks, R, Key, TJ, Khaw, KT, Kyro, C, Mancini, FR, Molina-Portillo, E, Murphy, N, Nilsson, PM, Onland-Moret, NC, Palli, D, Panico, S, Poveda, A, Quiros, JR, Ricceri, F, Sluijs, I, Spijkerman, AMW, Tjonneland, A, Tumino, R, Winkvist, A, Langenberg, C, Sharp, SJ, Riboli, E, Scott, RA, Forouhi, NG, Wareham, NJ. Interplay between genetic predisposition, macronutrient intake and type 2 diabetes incidence: analysis within EPIC-InterAct across eight European countries. Diabetologia. 2018. 61:1325–1332. doi:10.1007/s00125-018-4586-2 29549418 | Study Design; Intervention/Exposure
1371 | Li, XS, Pinto-Martin, JA, Thompson, A, Chittams, J, Kral, TVE. Weight status, diet quality, perceived stress, and functional health of caregivers of children with autism spectrum disorder. J Spec Pediatr Nurs. 2018. 23:. doi:10.1111/jspn.12205 | Study Design; Outcome
1372 | Li, Y, Ley, SH, Tobias, DK, Chiuve, SE, VanderWeele, TJ, Rich-Edwards, JW, Curhan, GC, Willett, WC, Manson, JE, Hu, FB, Qi, L. Birth weight and later life adherence to unhealthy lifestyles in predicting type 2 diabetes: prospective cohort study. Bmj. 2015. 351:h3672. doi:10.1136/bmj.h3672 26199273 | Intervention/Exposure
1373 | Li, Y, Ley, SH, VanderWeele, TJ, Curhan, GC, Rich-Edwards, JW, Willett, WC, Forman, JP, Hu, FB, Qi, L. Joint association between birth weight at term and later life adherence to a healthy lifestyle with risk of hypertension: a prospective cohort study. BMC Med. 2015. 13:175. doi:10.1186/s12916-015-0409-1 26228391 | Intervention/Exposure
1374 | Li, Z, Tseng, CH, Li, Q, Deng, ML, Wang, M, Heber, D. Clinical efficacy of a medically supervised outpatient high-protein, low-calorie diet program is equivalent in prediabetic, diabetic and normoglycemic obese patients. Nutrition and Diabetes. 2014. 4:. doi:10.1038/nutd.2014.1 | Intervention/Exposure
1375 | Li, ZK, Tang, H, Gong, RR, Lin, J, Gan, CF, Huang, X, Li, RH, Fang, DZ. No decrease of HDL cholesterol after 6 days of low fat and high carbohydrate diets in a young Chinese Han population. Sichuan Da Xue Xue Bao Yi Xue Ban. 2008. 39:595–600. doi:unavailable18798502 | Language; Study duration
1376 | Liao, CM, Lin, CM. Life Course Effects of Socioeconomic and Lifestyle Factors on Metabolic Syndrome and 10-Year Risk of Cardiovascular Disease: A Longitudinal Study in Taiwan Adults. Int J Environ Res Public Health. 2018. 15:. doi:10.3390/ijerph15102178 | Intervention/Exposure; Country
1377 | Liao, D, Asberry, PJ, Shofer, JB, Callahan, H, Matthys, C, Boyko, EJ, Leonetti, D, Kahn, SE, Austin, M, Newell, L, Schwartz, RS, Fujimoto, WY. Improvement of BMI, body composition, and body fat distribution with lifestyle modification in Japanese Americans with impaired glucose tolerance. Diabetes Care. 2002. 25:1504–1510. doi:10.2337/diacare.25.9.1504 12196418 | Intervention/Exposure; Comparator
1378 | Lichtenstein, AH, Ausman, LM, Jalbert, SM, Vilella-Bach, M, Jauhiainen, M, McGladdery, S, Erkkila, AT, Ehnholm, C, Frohlich, J, Schaefer, EJ. Efficacy of a Therapeutic Lifestyle Change/Step 2 diet in moderately hypercholesterolemic middle-aged and elderly female and male subjects. J Lipid Res. 2002. 43:264–73. doi:unavailable11861668 | Study duration
1379 | Liese, AD, Nichols, M, Sun, X, D’Agostino, RB, Jr, Haffner, SM. Adherence to the DASH Diet is inversely associated with incidence of type 2 diabetes: the insulin resistance atherosclerosis study. Diabetes Care. 2009. 32:1434–6. doi:10.2337/dc09-0228 19487638 | Publication Date Overlaps with Existing Review
1380 | Lim, CC, Hayes, RB, Ahn, J, Shao, Y, Silverman, DT, Jones, RR, Thurston, GD. Mediterranean Diet and the Association Between Air Pollution and Cardiovascular Disease Mortality Risk. Circulation. 2019. 139:1766–1775. doi:10.1161/circulationaha.118.035742 30700142 | Intervention/Exposure; Outcome
1381 | Lim, GB. Hypertension: Low sodium and DASH diet to lower blood pressure. Nat Rev Cardiol. 2018. 15:68. doi:10.1038/nrcardio.2017.214 | Publication Status
1382 | Lim, H, Kim, SY, Wang, Y, Lee, SJ, Oh, K, Sohn, CY, Moon, YM, Jee, SH. Preservation of a traditional Korean dietary pattern and emergence of a fruit and dairy dietary pattern among adults in South Korea: secular transitions in dietary patterns of a prospective study from 1998 to 2010. Nutr Res. 2014. 34:760–70. doi:10.1016/j.nutres.2014.08.002 25262419 | Study Design; Outcome
1383 | Lim, J, Lee, Y, Shin, S, Lee, HW, Kim, CE, Lee, JK, Lee, SA, Kang, D. An association between diet quality index for Koreans (DQI-K) and total mortality in Health Examinees Gem (HEXA-G) study. Nutr Res Pract. 2018. 12:258–264. doi:10.4162/nrp.2018.12.3.258 29854332 | Outcome
1384 | Lim, S, Kim, SS. Impact of repeated overnutrition intake: randomized controlled trial. Free radical biology & medicine. 2010. 49:S222-. doi:10.1016/j.freeradbiomed.2010.10.647 | Publication Status
1385 | Lim, SS, Noakes, M, Keogh, JB, Clifton, PM. Long-term effects of a low carbohydrate, low fat or high unsaturated fat diet compared to a no-intervention control. Nutr Metab Cardiovasc Dis. 2010. 20:599–607. doi:10.1016/j.numecd.2009.05.003 19692216 | Power/Size
1386 | Lima, ST, Souza, BS, Franca, AK, Salgado, JV, Salgado-Filho, N, Sichieri, R. Reductions in glycemic and lipid profiles in hypertensive patients undergoing the Brazilian Dietary Approach to Break Hypertension: a randomized clinical trial. Nutr Res. 2014. 34:682–7. doi:10.1016/j.nutres.2014.07.009 25172379 | Comparator
1387 | Lin, J, Fang, DZ, Du, J, Shigdar, S, Xiao, LY, Zhou, XD, Duan, W. Elevated levels of triglyceride and triglyceride-rich lipoprotein triglyceride induced by a high-carbohydrate diet is associated with polymorphisms of APOA5-1131T>C and APOC3-482C>T in Chinese healthy young adults. Ann Nutr Metab. 2011. 58:150–7. doi:10.1159/000327913 21646779 | Study duration; Country
1388 | Lin, P, Chang, CC, Yuan, KC, Yeh, HJ, Fang, SU, Cheng, T, Teng, KT, Chao, KC, Tang, JH, Kao, WY, Lin, PY, Liu, JS, Chang, JS. Red Blood Cell Aggregation-Associated Dietary Pattern Predicts Hyperlipidemia and Metabolic Syndrome. Nutrients. 2018. 10:. doi:10.3390/nu10081127 | Study Design
1389 | Lin, PH, Wang, Y, Grambow, SC, Goggins, W, Almirall, D. Dietary saturated fat intake is negatively associated with weight maintenance among the PREMIER participants. Obesity (Silver Spring). 2012. 20:571–5. doi:10.1038/oby.2011.17 21331065 | Intervention/Exposure
1390 | Lin, TJ, Tang, SC, Liao, PY, Dongoran, RA, Yang, JH, Liu, CH. A comparison of L-carnitine and several cardiovascular-related biomarkers between healthy vegetarians and omnivores. Nutrition. 2019. 66:29–37. doi:10.1016/j.nut.2019.03.019 31202134 | Intervention/Exposure
1391 | Lin, TY, Liao, PJ, Ting, MK, Hsu, KH. Lifestyle characteristics as moderators of the effectiveness of weight control interventions among semiconductor workers. Biomed J. 2018. 41:376–384. doi:10.1016/j.bj.2018.09.002 30709580 | Intervention/Exposure
1392 | Lin, X, Racette, SB, Lefevre, M, Ma, L, Spearie, CA, Steger-May, K, Ostlund, RE, Jr. Combined effects of ezetimibe and phytosterols on cholesterol metabolism: a randomized, controlled feeding study in humans. Circulation. 2011. 124:596–601. doi:10.1161/circulationaha.110.006692 21768544 | Study duration
1393 | Linde, JA, Utter, J, Jeffery, RW, Sherwood, NE, Pronk, NP, Boyle, RG. Specific food intake, fat and fiber intake, and behavioral correlates of BMI among overweight and obese members of a managed care organization. Int J Behav Nutr Phys Act. 2006. 3:42. doi:10.1186/1479-5868-3-42 17125525 | Intervention/Exposure
1394 | Lindquist, CH, Gower, BA, Goran, MI. Role of dietary factors in ethnic differences in early risk of cardiovascular disease and type 2 diabetes. Am J Clin Nutr. 2000. 71:725–32. doi:10.1093/ajcn/71.3.725 10702165 | Study Design; Intervention/Exposure
1395 | Lindqvist, HM, Radjursoga, M, Malmodin, D, Winkvist, A, Ellegard, L. Serum metabolite profiles of habitual diet: evaluation by 1H-nuclear magnetic resonance analysis. Am J Clin Nutr. 2019. :. doi:10.1093/ajcn/nqz032 | Study Design
1396 | Lindstrom, J, Peltonen, M, Eriksson, JG, Louheranta, A, Fogelholm, M, Uusitupa, M, Tuomilehto, J. High-fibre, low-fat diet predicts long-term weight loss and decreased type 2 diabetes risk: the Finnish Diabetes Prevention Study. Diabetologia. 2006. 49:912–20. doi:10.1007/s00125-006-0198-3 16541277 | Weight loss/Hypocaloric
1397 | Lingenhel, A, Eder, C, Zwiauer, K, Stangl, H, Kronenberg, F, Patsch, W, Strobl, W. Decrease of plasma apolipoprotein A-IV during weight reduction in obese adolescents on a low fat diet. Int J Obes Relat Metab Disord. 2004. 28:1509–13. doi:10.1038/sj.ijo.0802789 15356672 | Study duration
1398 | Lingfors, H, Persson, LG. All-cause mortality among young men 24-26 years after a lifestyle health dialogue in a Swedish primary care setting: A longitudinal follow-up register study. BMJ Open. 2019. 9:. doi:10.1136/bmjopen-2018-022474 | Intervention/Exposure; Outcome
1399 | Lioret, S, McNaughton, SA, Cameron, AJ, Crawford, D, Campbell, KJ, Cleland, VJ, Ball, K. Three-year change in diet quality and associated changes in BMI among schoolchildren living in socio-economically disadvantaged neighbourhoods. Br J Nutr. 2014. 112:260–8. doi:10.1017/s0007114514000749 24775601 | Power/Size
1400 | Lipscomb, ER, Caffrey, HM, Hays, LM, Finch, EA, Saha, CK, Ackermann, RT. Lower fat intake is associated with lower weight and cholesterol at 4 months in adults with impaired glucose metabolism. Diabetes Spectrum. 2012. 25:49–55. doi:10.2337/diaspect.25.1.49 | Intervention/Exposure
1401 | Lipsky, LM, Haynie, DL, Liu, D, Chaurasia, A, Gee, B, Li, K, Iannotti, RJ, Simons-Morton, B. Trajectories of eating behaviors in a nationally representative cohort of U.S. adolescents during the transition to young adulthood. Int J Behav Nutr Phys Act. 2015. 12:138. doi:10.1186/s12966-015-0298-x 26537771 | Intervention/Exposure
1402 | Lipsky, LM, Nansel, TR, Haynie, DL, Liu, D, Li, K, Pratt, CA, Iannotti, RJ, Dempster, KW, Simons-Morton, B. Diet quality of US adolescents during the transition to adulthood: changes and predictors. Am J Clin Nutr. 2017. 105:1424–1432. doi:10.3945/ajcn.116.150029 28446498 | Outcome
1403 | Liu, CW. Healthy dietary pattern with daily egg consumption might be the true factor associated with decreased risks of cardiovascular diseases and mortality. Heart. 2018. 104:1804. doi:10.1136/heartjnl-2018-313774 | Publication Status
1404 | Liu, H, Lin, J, Zhu, X, Li, Y, Fan, M, Zhang, R, Fang, D. Effects of R219K polymorphism of ATP-binding cassette transporter 1 gene on serum lipids ratios induced by a high-carbohydrate and low-fat diet in healthy youth. Biol Res. 2014. 47:4. doi:10.1186/0717-6287-47-4 25027185 | Study duration
1405 | Liu, X, Li, Y, Tobias, DK, Wang, DD, Manson, JE, Willett, WC, Hu, FB. Changes in Types of Dietary Fats Influence Long-term Weight Change in US Women and Men. J Nutr. 2018. 148:1821–1829. doi:10.1093/jn/nxy183 30247611 | Intervention/Exposure
1406 | Liu, X, Zhang, G, Ye, X, Li, H, Chen, X, Tang, L, Feng, Y, Shai, I, Stampfer, MJ, Hu, FB, Lin, X. Effects of a low-carbohydrate diet on weight loss and cardiometabolic profile in Chinese women: a randomised controlled feeding trial. Br J Nutr. 2013. 110:1444–53. doi:10.1017/s0007114513000640 23522432 | Weight loss/Hypocaloric
1407 | Liu, Y, Milner, M, Klonizakis, M. Physiological effects of a short-term lifestyle intervention based on the Mediterranean diet: comparison between older and younger healthy, sedentary adults. Nutrition. 2018. 55–56:185–191. doi:10.1016/j.nut.2018.05.006 | Study Design; Outcome
1408 | Liu, Z, Li, Q, Maddison, R, Ni Mhurchu, C, Jiang, Y, Wei, DM, Cheng, L, Cheng, Y, Wang, D, Wang, HJ. A School-Based Comprehensive Intervention for Childhood Obesity in China: A Cluster Randomized Controlled Trial. Child Obes. 2019. 15:105–115. doi:10.1089/chi.2018.0251 30565955 | Intervention/Exposure
1409 | Livingstone, KM, Celis-Morales, C, Lara, J, Woolhead, C, O’Donovan, CB, Forster, H, Marsaux, CF, Macready, AL, Fallaize, R, Navas-Carretero, S, San-Cristobal, R, Kolossa, S, Tsirigoti, L, Lambrinou, CP, Moschonis, G, Surwillo, A, Drevon, CA, Manios, Y, Traczyk, I, Gibney, ER, Brennan, L, Walsh, MC, Lovegrove, JA, Martinez, JA, Saris, WH, Daniel, H, Gibney, M, Mathers, JC. Clustering of adherence to personalised dietary recommendations and changes in healthy eating index within the Food4Me study. Public Health Nutr. 2016. 19:3296–3305. doi:10.1017/s1368980016001932 27499187 | Outcome
1410 | Livingstone, KM, Celis-Morales, C, Navas-Carretero, S, San-Cristobal, R, Macready, AL, Fallaize, R, Forster, H, Woolhead, C, O’Donovan, CB, Marsaux, CF, Kolossa, S, Tsirigoti, L, Lambrinou, CP, Moschonis, G, Godlewska, M, Surwillo, A, Drevon, CA, Manios, Y, Traczyk, I, Gibney, ER, Brennan, L, Walsh, MC, Lovegrove, JA, Saris, WH, Daniel, H, Gibney, M, Martinez, JA, Mathers, JC. Effect of an Internet-based, personalized nutrition randomized trial on dietary changes associated with the Mediterranean diet: the Food4Me Study. Am J Clin Nutr. 2016. 104:288–97. doi:10.3945/ajcn.115.129049 27357094 | Comparator; Outcome
1411 | Livingstone, KM, Givens, DI, Cockcroft, JR, Pickering, JE, Lovegrove, JA. Is fatty acid intake a predictor of arterial stiffness and blood pressure in men? Evidence from the Caerphilly Prospective Study. Nutr Metab Cardiovasc Dis. 2013. 23:1079–85. doi:10.1016/j.numecd.2012.12.002 23415455 | Intervention/Exposure; Outcome
1412 | Llanos, AA, Krok, JL, Peng, J, Pennell, ML, Olivo-Marston, S, Vitolins, MZ, Degraffinreid, CR, Paskett, ED. Favorable effects of low-fat and low-carbohydrate dietary patterns on serum leptin, but not adiponectin, among overweight and obese premenopausal women: a randomized trial. Springerplus. 2014. 3:175. doi:10.1186/2193-1801-3-175 24790820 | Outcome
1413 | Llanos, AAM, Krok, JL, Peng, J, Pennell, ML, Olivo-Marston, SE, Vitolins, MZ, Degraffinreid, CR, Paskett, ED. Effects of low-fat and low-carbohydrate dietary patterns combined with physical activity on serum adipokine concentrations among premenopausal women: a randomized trial. Cancer prevention research (philadelphia, pa.). 2013. 6:. doi:unavailable | Outcome; Publication Status
1414 | Lockyer, S, Tzanetou, M, Carvalho-Wells, AL, Jackson, KG, Minihane, AM, Lovegrove, JA. SATgenε dietary model to implement diets of differing fat composition in prospectively genotyped groups (apoE) using commercially available foods. British Journal of Nutrition. 2012. 108:1705–1713. doi:10.1017/S0007114511007082 | Outcome
1415 | Lofley, AC, Root, MM. Macronutrients Association with Change in Waist and Hip Circumference Over 9 Years. J Am Coll Nutr. 2017. 36:57–63. doi:10.1080/07315724.2016.1183241 27797648 | Intervention/Exposure
1416 | Lojko, D, Stelmach-Mardas, M, Suwalska, A. Diet quality and eating patterns in euthymic bipolar patients. Eur Rev Med Pharmacol Sci. 2019. 23:1221–1238. doi:10.26355/eurrev_201902_17016 30779092 | Study Design; Comparator
1417 | Loktionov, A, Scollen, S, McKeown, N, Bingham, SA. Gene-nutrient interactions: dietary behaviour associated with high coronary heart disease risk particularly affects serum LDL cholesterol in apolipoprotein E epsilon4-carrying free-living individuals. Br J Nutr. 2000. 84:885–90. doi:unavailable11177205 | Study Design; Intervention/Exposure
1418 | Longland, TM, Oikawa, SY, Mitchell, CJ, Devries, MC, Phillips, SM. Higher compared with lower dietary protein during an energy deficit combined with intense exercise promotes greater lean mass gain and fat mass loss: a randomized trial. Am J Clin Nutr. 2016. 103:738–46. doi:10.3945/ajcn.115.119339 26817506 | Study duration
1419 | Loo, RL, Zou, X, Appel, LJ, Nicholson, JK, Holmes, E. Characterization of metabolic responses to healthy diets and association with blood pressure: application to the Optimal Macronutrient Intake Trial for Heart Health (OmniHeart), a randomized controlled study. Am J Clin Nutr. 2018. 107:323–334. doi:10.1093/ajcn/nqx072 29506183 | Study duration
1420 | Looman, M, Feskens, EJ, de Rijk, M, Meijboom, S, Biesbroek, S, Temme, EH, de Vries, J, Geelen, A. Development and evaluation of the Dutch Healthy Diet index 2015. Public Health Nutr. 2017. 20:2289–2299. doi:10.1017/s136898001700091x 28625202 | Outcome
1421 | Looney, S, Raynor, H. Are changes in consumption of “healthy” foods related to changes in consumption of “unhealthy” foods during pediatric obesity treatment?. Obesity. 2011. 19:S104–S105. doi:10.1038/oby.2011.226 | Publication Status
1422 | López, CPR, Ramos-Terrones, I, Lazarevich, I, García-López, S, Arriaga, RV, Valverde, LF, Cervera, EG, Nájera-Medina, O. Metabolic syndrome, physical activity and eating habits in school children of the south of Mexico city. Investigacion Clinica (Venezuela). 2019. 60:7–19. doi:10.22209/IC.v60n1a01 | Study Design; Intervention/Exposure
1423 | Lopez-Garcia, E, Rodriguez-Artalejo, F, Li, TY, Fung, TT, Li, S, Willett, WC, Rimm, EB, Hu, FB. The Mediterranean-style dietary pattern and mortality among men and women with cardiovascular disease. Am J Clin Nutr. 2014. 99:172–80. doi:10.3945/ajcn.113.068106 24172306 | Health Status
1424 | Lopez-Legarrea, P, De La Iglesia, R, Abete, I, Bondia-Pons, I, Navas-Carretero, S, Forga, L, Martinez, JA, Zulet, MA. Short-term role of the dietary total antioxidant capacity in two hypocaloric regimes on obese with metabolic syndrome symptoms: The RESMENA randomized controlled trial. Nutrition and Metabolism. 2013. 10:. doi:10.1186/1743-7075-10-22 | Study duration
1425 | Lopez-Legarrea, P, De la Iglesia, R, Abete, I, Ibanez-Melo, A, Navas-Carretero, S, Bondia-Pons, I, Forga, L, Zulet, M, Martinez, A. The resmena diet: a new effective dietary strategy for reducing metabolic syndrome. Obesity facts. 2012. 5:230–231. doi:10.1159/000258190 | Publication Status
1426 | Lopez-Legarrea, P, de la Iglesia, R, Abete, I, Navas-Carretero, S, Martinez, JA, Zulet, MA. The protein type within a hypocaloric diet affects obesity-related inflammation: the RESMENA project. Nutrition. 2014. 30:424–9. doi:10.1016/j.nut.2013.09.009 24607301 | Study duration
1427 | Lopez-Moreno, J, Quintana-Navarro, GM, Camargo, A, Jimenez-Lucena, R, Delgado-Lista, J, Marin, C, Tinahones, FJ, Striker, GE, Roche, HM, Perez-Martinez, P, Lopez-Miranda, J, Yubero-Serrano, EM. Dietary fat quantity and quality modifies advanced glycation end products metabolism in patients with metabolic syndrome. Mol Nutr Food Res. 2017. 61:. doi:10.1002/mnfr.201601029 | Study Design; Intervention/Exposure; Outcome
1428 | Lopez-Sanchez, GF, Radziminski, L, Skalska, M, Jastrzebska, J, Smith, L, Wakuluk, D, Jastrzebski, Z. Body Composition, Physical Fitness, Physical Activity and Nutrition in Polish and Spanish Male Students of Sports Sciences: Differences and Correlations. Int J Environ Res Public Health. 2019. 16:. doi:10.3390/ijerph16071148 | Study Design; Intervention/Exposure
1429 | Loprinzi, PD, Nooe, A. Health characteristics and predicted 10-year risk for a first atherosclerotic cardiovascular disease (ASCVD) event using the Pooled Cohort Risk Equations among US adults who are free of cardiovascular disease. Physiol Behav. 2015. 151:591–5. doi:10.1016/j.physbeh.2015.08.031 26340856 | Study Design; Intervention/Exposure
1430 | Lotrean, LM, Stan, O, Codruta, L, Laza, V. Dietary patterns, physical activity, body mass index, weight-related behaviours and their interrelationship among Romanian university students-trends from 2003 to 2016. Nutr Hosp. 2018. 35:375–383. doi:10.20960/nh.1296 29756972 | Study Design; Intervention/Exposure
1431 | Louie, JC, Flood, VM, Burlutsky, G, Rangan, AM, Gill, TP, Mitchell, P. Dairy consumption and the risk of 15-year cardiovascular disease mortality in a cohort of older Australians. Nutrients. 2013. 5:441–54. doi:10.3390/nu5020441 23389303 | Intervention/Exposure
1432 | Lovejoy, JC, Champagne, CM, Smith, SR, de Jonge, L, Xie, H. Ethnic differences in dietary intakes, physical activity, and energy expenditure in middle-aged, premenopausal women: the Healthy Transitions Study. Am J Clin Nutr. 2001. 74:90–5. doi:10.1093/ajcn/74.1.90 11451722 | Study Design
1433 | Lowry, R, Galuska, DA, Fulton, JE, Wechsler, H, Kann, L, Collins, JL. Physical activity, food choice, and weight management goals and practices among US college students. Am J Prev Med. 2000. 18:18–27. doi:10.1016/s0749-3797(99)00107-5 | Study Design
1434 | Lowry, R, Michael, S, Demissie, Z, Kann, L, Galuska, DA. Associations of Physical Activity and Sedentary Behaviors with Dietary Behaviors among US High School Students. J Obes. 2015. 2015:876524. doi:10.1155/2015/876524 26101666 | Intervention/Exposure; Outcome
1435 | Lu, N, Shai, I, Zhang, Y, Curhan, G, Choi, H. High-protein diet (Atkins Diet) and uric acid response. Arthritis & rheumatology. 2014. 66:S71–S72. doi:10.1002/art.38914 | Publication Status
1436 | Lu, S, Yu, H, Han, R, Su, J, Pan, X, Zhang, Y, Zhou, J, Wu, M. Dietary patterns and the risk of cardiovascular diseases in Jiangsu Province, China: a nested case-control study. Lancet. 2016. 388:62-. doi:unavailable27155903 | Publication Status
1437 | Ludy, MJ, Tan, SY, Leone, RJ, Morgan, AL, Tucker, RM. Weight gain in first-semester university students: Positive sleep and diet practices associated with protective effects. Physiol Behav. 2018. 194:132–136. doi:10.1016/j.physbeh.2018.05.009 29753713 | Intervention/Exposure
1438 | Luger, E, Aspalter, R, Luger, M, Longin, R, Rieder, A, Dorner, TE. Changes of dietary patterns during participation in a web-based weight-reduction programme. Public Health Nutr. 2016. 19:1211–21. doi:10.1017/s1368980015002852 26411757 | Study Design
1439 | Luscombe, ND, Noakes, M, Wittert, G, Farnsworth, E, Argyiou, E, Clifton, PM. Effect of a high protein, energy restricted diet on body composition, insulin sensitivity and lipid levels in hyperinsulinemic subjects. Atherosclerosis. 2002. 3:92. doi:unavailable | Publication Status
1440 | Luscombe-Marsh, ND, Noakes, M, Wittert, GA, Keogh, JB, Foster, P, Clifton, PM. Carbohydrate-restricted diets high in either monounsaturated fat or protein are equally effective at promoting fat loss and improving blood lipids. Am J Clin Nutr. 2005. 81:762–72. doi:10.1093/ajcn/81.4.762 15817850 | Weight loss/Hypocaloric
1441 | Lutjohann, D, Meyer, S, von Bergmann, K, Stellaard, F. Cholesterol Absorption and Synthesis in Vegetarians and Omnivores. Mol Nutr Food Res. 2018. 62:e1700689. doi:10.1002/mnfr.201700689 29427539 | Study Design; Outcome
1442 | Lutze, J, Taylor, P, Brinkworth, GD, Wyld, B, Syrette, J, Wilson, CJ, Clifton, PM, Noakes, M. Psychological well-being response to high protein and high carbohydrate weight loss diets in overweight and obese men: Arandomised trial. e-SPEN Journal. 2013. 8:e235–e240. doi:10.1016/j.clnme.2013.08.002 | Weight loss/Hypocaloric
1443 | Lv, J, Yu, C, Guo, Y, Bian, Z, Yang, L, Chen, Y, Hu, X, Hou, W, Chen, J, Chen, Z, Qi, L, Li, L. Adherence to a healthy lifestyle and the risk of type 2 diabetes in Chinese adults. Int J Epidemiol. 2017. 46:1410–1420. doi:10.1093/ije/dyx074 28582543 | Country
1444 | Lv, J, Yu, C, Guo, Y, Bian, Z, Yang, L, Chen, Y, Tang, X, Zhang, W, Qian, Y, Huang, Y, Wang, X, Chen, J, Chen, Z, Qi, L, Li, L. Adherence to Healthy Lifestyle and Cardiovascular Diseases in the Chinese Population. J Am Coll Cardiol. 2017. 69:1116–1125. doi:10.1016/j.jacc.2016.11.076 28254173 | Country
1445 | Lynch, E, Emery-Tiburcio, E, Dugan, S, White, FS, Thomason, C, Jenkins, L, Feit, C, Avery-Mamer, E, Wang, Y, Mack, L, Ragland, A. Results of ALIntervention/Exposure: A Faith-Based Pilot Intervention to Improve Diet Among African American Church Members. Prog Community Health Partnersh. 2019. 13:19–30. doi:10.1353/cpr.2019.0005 30956244 | Study Design; Comparator
1446 | Ma, W, Hagan, KA, Heianza, Y, Sun, Q, Rimm, EB, Qi, L. Adult height, dietary patterns, and healthy aging. Am J Clin Nutr. 2017. 106:589–596. doi:10.3945/ajcn.116.147256 28592610 | Outcome
1447 | Ma, Y, Li, Y, Chiriboga, DE, Olendzki, BC, Hebert, JR, Li, W, Leung, K, Hafner, AR, Ockene, IS. Association between carbohydrate intake and serum lipids. J Am Coll Nutr. 2006. 25:155–63. doi:10.1080/07315724.2006.10719527 16582033 | Intervention/Exposure
1448 | Ma, Y, Olendzki, B, Chiriboga, D, Hebert, JR, Li, Y, Li, W, Campbell, M, Gendreau, K, Ockene, IS. Association between dietary carbohydrates and body weight. Am J Epidemiol. 2005. 161:359–67. doi:10.1093/aje/kwi051 15692080 | Intervention/Exposure
1449 | Ma, Y, Olendzki, BC, Li, W, Hafner, AR, Chiriboga, D, Hebert, JR, Campbell, M, Sarnie, M, Ockene, IS. Seasonal variation in food intake, physical activity, and body weight in a predominantly overweight population. Eur J Clin Nutr. 2006. 60:519–28. doi:10.1038/sj.ejcn.1602346 16340952 | Intervention/Exposure
1450 | Ma, Y, Olendzki, BC, Wang, J, Persuitte, GM, Li, W, Fang, H, Merriam, PA, Wedick, NM, Ockene, IS, Culver, AL, Schneider, KL, Olendzki, GF, Carmody, J, Ge, T, Zhang, Z, Pagoto, SL. Single-component versus multicomponent dietary goals for the metabolic syndrome: a randomized trial. Ann Intern Med. 2015. 162:248–57. doi:10.7326/m14-0611 25686165 | Intervention/Exposure
1451 | Machado-Rodrigues, AM, Fernandes, RA, Silva, MR, Gama, A, Mourao, I, Nogueira, H, Rosado-Marques, V, Padez, C. Overweight Risk and Food Habits in Portuguese Pre-school Children. J Epidemiol Glob Health. 2018. 8:106–109. doi:10.2991/j.jegh.2017.10.006 30864750 | Study Design; Intervention/Exposure
1452 | Macias-Cervantes, MH, Rodriguez-Soto, JM, Uribarri, J, Diaz-Cisneros, FJ, Cai, W, Garay-Sevilla, ME. Effect of an advanced glycation end product-restricted diet and exercise on metabolic parameters in adult overweight men. Nutrition. 2015. 31:446–51. doi:10.1016/j.nut.2014.10.004 25701333 | Intervention/Exposure
1453 | Maciejewska, D, Michalczyk, M, Czerwinska-Rogowska, M, Banaszczak, M, Ryterska, K, Jakubczyk, K, Piotrwski, J, Holowko, J, Drozd, A, Wysokinki, P, Ficek, K, Wilk, K, Lubkowska, A, Cieszczyk, P, Bertrand, J, Stachowska, E. Seeking Optimal Nutrition for Healthy Body Mass Reduction among Former Athletes. J Hum Kinet. 2017. 60:63–75. doi:10.1515/hukin-2017-0090 29339986 | Intervention/Exposure
1454 | Macknin, M, Kong, T, Weier, A, Worley, S, Tang, AS, Alkhouri, N, Golubic, M. Plant-based, no-added-fat or American Heart Association diets: impact on cardiovascular risk in obese children with hypercholesterolemia and their parents. J Pediatr. 2015. 166:953-9.e1–3. doi:10.1016/j.jpeds.2014.12.058 25684089 | Study duration
1455 | Madero, M, Arriaga, JC, Jalal, D, Rivard, C, McFann, K, Perez-Mendez, O, Vazquez, A, Ruiz, A, Lanaspa, MA, Jimenez, CR, Johnson, RJ, Lozada, LG. The effect of two energy-restricted diets, a low-fructose diet versus a moderate natural fructose diet, on weight loss and metabolic syndrome parameters: a randomized controlled trial. Metabolism. 2011. 60:1551–9. doi:10.1016/j.metabol.2011.04.001 21621801 | Intervention/Exposure; Comparator
1456 | Mady, MA, Kossoff, EH, McGregor, AL, Wheless, JW, Pyzik, PL, Freeman, JM. The ketogenic diet: adolescents can do it, too. Epilepsia. 2003. 44:847–51. doi:10.1046/j.1528-1157.2003.57002.x 12790900 | Study Design; Health Status
1457 | Maekawa, S, Kawahara, T, Nomura, R, Murase, T, Ann, Y, Oeholm, M, Harada, M. Retrospective study on the efficacy of a low-carbohydrate diet for impaired glucose tolerance. Diabetes Metab Syndr Obes. 2014. 7:195–201. doi:10.2147/dmso.S62681 24966689 | Study Design; Intervention/Exposure; Study duration
1458 | Maffeis, C, Maschio, M, Costanzi, S, Tommasi, M, Fasan, I, Morandi, A. Diet macronutrient composition reported before treatment predicts BMI change in obese children: the role of lipids. Eur J Clin Nutr. 2012. 66:1066–8. doi:10.1038/ejcn.2012.97 22828731 | Intervention/Exposure
1459 | Maffiuletti, NA, Agosti, F, Marinone, PG, Silvestri, G, Lafortuna, CL, Sartorio, A. Changes in body composition, physical performance and cardiovascular risk factors after a 3-week integrated body weight reduction program and after 1-y follow-up in severely obese men and women. Eur J Clin Nutr. 2005. 59:685–94. doi:10.1038/sj.ejcn.1602130 15770221 | Study Design; Study duration
1460 | Magnusdottir, OK, Landberg, R, Gunnarsdottir, I, Cloetens, L, Akesson, B, Rosqvist, F, Schwab, U, Herzig, KH, Hukkanen, J, Savolainen, MJ, Brader, L, Hermansen, K, Kolehmainen, M, Poutanen, K, Uusitupa, M, Riserus, U, Thorsdottir, I. Whole grain rye intake, reflected by a biomarker, is associated with favorable blood lipid outcomes in subjects with the metabolic syndrome--a randomized study. PLoS One. 2014. 9:e110827. doi:10.1371/journal.pone.0110827 25340768 | Intervention/Exposure; Outcome
1461 | Magriplis, E, Farajian, P, Risvas, G, Panagiotakos, D, Zampelas, A. Newly derived children-based food index. An index that may detect childhood overweight and obesity. Int J Food Sci Nutr. 2015. 66:623–32. doi:10.3109/09637486.2015.1056109 26186030 | Study Design
1462 | Magriplis, E, Panagiotakos, D, Mitsopoulou, AV, Karageorgou, D, Bakogianni, I, Dimakopoulos, I, Micha, R, Michas, G, Chourdakis, M, Chrousos, GP, Roma, E, Zampelas, A. Prevalence of hyperlipidaemia in adults and its relation to the Mediterranean diet: the Hellenic National Nutrition and Health Survey (HNNHS). Eur J Prev Cardiol. 2019. :2047487319866023. doi:10.1177/2047487319866023 | Study Design
1463 | Magriplis, E, Sialvera, TE, Papadopoulou, A, Efstathiou, SP, Trautwein, EA, Goumas, G, Dimakopoulos, I, Papavasiliou, K, Koutsouri, A, Zampelas, A. Effectiveness and easiness of adherence to behavioural guidelines for diet and lifestyle changes for cholesterol-lowering: the Increasing Adherence of Consumers to Diet & Lifestyle Changes to Lower (LDL) Cholesterol (ACT) randomised controlled trial. J Hum Nutr Diet. 2019. 32:607–618. doi:10.1111/jhn.12667 31134707 | Intervention/Exposure; Outcome
1464 | Mahmoud, AM, Hwang, CL, Szczurek, MR, Bian, JT, Ranieri, C, Gutterman, DD, Phillips, SA. Low-Fat Diet Designed for Weight Loss But Not Weight Maintenance Improves Nitric Oxide-Dependent Arteriolar Vasodilation in Obese Adults. Nutrients. 2019. 11:. doi:10.3390/nu11061339 | Intervention/Exposure; Study duration
1465 | Mahon, AK, Flynn, MG, Stewart, LK, McFarlin, BK, Iglay, HB, Mattes, RD, Lyle, RM, Considine, RV, Campbell, WW. Protein intake during energy restriction: effects on body composition and markers of metabolic and cardiovascular health in postmenopausal women. J Am Coll Nutr. 2007. 26:182–9. doi:10.1080/07315724.2007.10719600 17536130 | Intervention/Exposure
1466 | Maier, IB, Ozel, Y, Wagnerberger, S, Bischoff, SC, Bergheim, I. Dietary pattern and leisure time activity of overweight and normal weight children in Germany: sex-specific differences. Nutr J. 2013. 12:14. doi:10.1186/1475-2891-12-14 23320866 | Study Design
1467 | Maier, JH, Barry, R. Associations among Physical Activity, Diet, and Obesity Measures Change during Adolescence. J Nutr Metab. 2015. 2015:805065. doi:10.1155/2015/805065 26539299 | Intervention/Exposure
1468 | Maijo, M, Ivory, K, Clements, SJ, Dainty, JR, Jennings, A, Gillings, R, Fairweather-Tait, S, Gulisano, M, Santoro, A, Franceschi, C, Carding, SR, Nicoletti, C. One-Year Consumption of a Mediterranean-Like Dietary Pattern With Vitamin D3 Supplements Induced Small Scale but Extensive Changes of Immune Cell Phenotype, Co-receptor Expression and Innate Immune Responses in Healthy Elderly Subjects: Results From the United Kingdom Arm of the NU-AGE Trial. Front Physiol. 2018. 9:997. doi:10.3389/fphys.2018.00997 30093866 | Outcome
1469 | Makarem, N, Scott, M, Quatromoni, P, Jacques, P, Parekh, N. Trends in dietary carbohydrate consumption from 1991 to 2008 in the Framingham Heart Study Offspring Cohort. Br J Nutr. 2014. 111:2010–23. doi:10.1017/s0007114513004443 24661608 | Outcome
1470 | Maki, KC, Lawless, AL, Kelley, KM, Kaden, VN, Geiger, CJ, Dicklin, MR. Corn oil improves the plasma lipoprotein lipid profile compared with extra-virgin olive oil consumption in men and women with elevated cholesterol: results from a randomized controlled feeding trial. J Clin Lipidol. 2015. 9:49–57. doi:10.1016/j.jacl.2014.10.006 25670360 | Intervention/Exposure
1471 | Malin, SK, Kullman, EL, Scelsi, AR, Haus, JM, Filion, J, Pagadala, MR, Godin, JP, Kochhar, S, Ross, AB, Kirwan, JP. A whole-grain diet reduces peripheral insulin resistance and improves glucose kinetics in obese adults: A randomized-controlled trial. Metabolism. 2018. 82:111–117. doi:10.1016/j.metabol.2017.12.011 29305946 | Intervention/Exposure; Study duration
1472 | Mamo, JC, James, AP, Soares, MJ, Griffiths, DG, Purcell, K, Schwenke, JL. A low-protein diet exacerbates postprandial chylomicron concentration in moderately dyslipidaemic subjects in comparison to a lean red meat protein-enriched diet. Eur J Clin Nutr. 2005. 59:1142–8. doi:10.1038/sj.ejcn.1602224 16015257 | Intervention/Exposure; Comparator
1473 | Manco, M, Bertuzzi, A, Salinari, S, Scarfone, A, Calvani, M, Greco, AV, Mingrone, G. The ingestion of saturated fatty acid triacylglycerols acutely affects insulin secretion and insulin sensitivity in human subjects. Br J Nutr. 2004. 92:895–903. doi:10.1079/bjn20041268 15613251 | Study duration
1474 | Manios, Y, Kourlaba, G, Grammatikaki, E, Androutsos, O, Ioannou, E, Roma-Giannikou, E. Comparison of two methods for identifying dietary patterns associated with obesity in preschool children: The GENESIS study. European Journal of Clinical Nutrition. 2010. 64:1407–1414. doi:10.1038/ejcn.2010.168 20808335 | Intervention/Exposure
1475 | Mann, J, Morenga, LT. Carbohydrates in the treatment and prevention of Type 2 diabetes. Diabet Med. 2015. 32:572–5. doi:10.1111/dme.12673 25510817 | Study Design; Publication Status
1476 | Mann, J, Swinburn, B, Beaglehole, R, Ni Mhurchu, C, Jackson, R. Diverging global trends in heart disease and diabetes: implications for dietary guidelines. Lancet Diabetes Endocrinol. 2015. 3:584–5. doi:10.1016/s2213-8587(15)00206-5 26134687 | Study Design
1477 | Mann, JI, De Leeuw, I, Hermansen, K, Karamanos, B, Karlstrom, B, Katsilambros, N, Riccardi, G, Rivellese, AA, Rizkalla, S, Slama, G, Toeller, M, Uusitupa, M, Vessby, B. Evidence-based nutritional approaches to the treatment and prevention of diabetes mellitus. Nutr Metab Cardiovasc Dis. 2004. 14:373–94. doi:unavailable15853122 | Study Design; Publication Status
1478 | Marckmann, P, Raben, A, Astrup, A. Ad libitum intake of low-fat diets rich in either starchy foods or sucrose: effects on blood lipids, factor VII coagulant activity, and fibrinogen. Metabolism. 2000. 49:731–5. doi:10.1053/meta.2000.6237 10877197 | Study duration
1479 | Margolis, LM, Cao, JJ, Whigham, LD, McClung, JP, Combs, GF, Young, AJ, Pasiakos, SM. Dietary protein intake, energy deficit, and nitrogen balance in normal-weight adults: a randomized controlled trial. FASEB journal. 2013. 27:. doi:unavailable | Publication Status
1480 | Marina, A, von Frankenberg, AD, Suvag, S, Callahan, HS, Kratz, M, Richards, TL, Utzschneider, KM. Effects of dietary fat and saturated fat content on liver fat and markers of oxidative stress in overweight/obese men and women under weight-stable conditions. Nutrients. 2014. 6:4678–90. doi:10.3390/nu6114678 25353663 | Study duration
1481 | Marklund, M, Leander, K, Vikstrom, M, Laguzzi, F, Gigante, B, Sjogren, P, Cederholm, T, de Faire, U, Hellenius, ML, Riserus, U. Polyunsaturated Fat Intake Estimated by Circulating Biomarkers and Risk of Cardiovascular Disease and All-Cause Mortality in a Population-Based Cohort of 60-Year-Old Men and Women. Circulation. 2015. 132:586–94. doi:10.1161/circulationaha.115.015607 26085453 | Intervention/Exposure
1482 | Marklund, M, Magnusdottir, OK, Rosqvist, F, Cloetens, L, Landberg, R, Kolehmainen, M, Brader, L, Hermansen, K, Poutanen, KS, Herzig, KH, Hukkanen, J, Savolainen, MJ, Dragsted, LO, Schwab, U, Paananen, J, Uusitupa, M, Akesson, B, Thorsdottir, I, Riserus, U. A dietary biomarker approach captures compliance and cardiometabolic effects of a healthy Nordic diet in individuals with metabolic syndrome. J Nutr. 2014. 144:1642–9. doi:10.3945/jn.114.193771 25080537 | Intervention/Exposure; Comparator
1483 | Marks, J, Barnett, LM, Allender, S. Change of School in Early Adolescence and Adverse Obesity-Related Dietary Behavior: A Longitudinal Cohort Study, Victoria, Australia, 2013-2014. Prev Chronic Dis. 2015. 12:E145. doi:10.5888/pcd12.150042 26355826 | Power/Size
1484 | Marques Rocha, JL, Cristine Anunciacao, P, Vaz Tostes, MG, Thomas Valdes, S, Cardoso Carraro, JC, Galdino Alves, NE, Bressan, J. Human ration does not alter weight and body composition, but improves the lipid profile of overweight woman. Nutr Hosp. 2012. 27:1460–8. doi:10.3305/nh.2012.27.5.5686 23478692 | Study Design; Intervention/Exposure
1485 | Marshall, DA, Vernalis, MN, Remaley, AT, Walizer, EM, Scally, JP, Taylor, AJ. The role of exercise in modulating the impact of an ultralow-fat diet on serum lipids and apolipoproteins in patients with or at risk for coronary artery disease. Am Heart J. 2006. 151:484–91. doi:10.1016/j.ahj.2005.03.065 16442919 | Intervention/Exposure
1486 | Martens, EA, Gatta-Cherifi, B, Gonnissen, HK, Westerterp-Plantenga, MS. The potential of a high protein-low carbohydrate diet to preserve intrahepatic triglyceride content in healthy humans. PLoS One. 2014. 9:e109617. doi:10.1371/journal.pone.0109617 25330327 | Comparator; Outcome
1487 | Martens, EA, Lemmens, SG, Westerterp-Plantenga, MS. Protein leverage affects energy intake of high-protein diets in humans. Am J Clin Nutr. 2013. 97:86–93. doi:10.3945/ajcn.112.046540 23221572 | Intervention/Exposure; Study duration
1488 | Martin, CK, Bray, GA, Ryan, DH, Carey, VJ, Champagne, CM, Williamson, DA, Anton, S, Laranjo, N, Sacks, FM. A high carbohydrate/average protein diet is less efficacious at promoting weight loss among women compared to men: subgroup analysis from POUNDS lost. Obesity (silver spring, md.). 2010. 18:S94-. doi:unavailable | Publication Status
1489 | Martin, CL, Tate, DF, Schaffner, A, Brannen, A, Hatley, KE, Diamond, M, Munoz-Christian, K, Pomeroy, J, Sanchez, T, Mercado, A, Hagobian, T, Phelan, S. Acculturation Influences Postpartum Eating, Activity, and Weight Retention in Low-Income Hispanic Women. J Womens Health (Larchmt). 2017. 26:1333–1339. doi:10.1089/jwh.2016.6154 28816589 | Study Design
1490 | Martin, JC, Moran, LJ, Teede, HJ, Ranasinha, S, Lombard, CB, Harrison, CL. Diet Quality in a Weight Gain Prevention Trial of Reproductive Aged Women: A Secondary Analysis of a Cluster Randomized Controlled Trial. Nutrients. 2018. 11:. doi:10.3390/nu11010049 | Outcome
1491 | Martin, RM, Holly, JMP, Middleton, N, Davey Smith, G, Gunnell, D. Childhood diet and insulin-like growth factors in adulthood: 65-year follow-up of the Boyd Orr Cohort. European Journal of Clinical Nutrition. 2007. 61:1281–1292. doi:10.1038/sj.ejcn.1602616 17299497 | Intervention/Exposure
1492 | Martin-Diener, E, Meyer, J, Braun, J, Tarnutzer, S, Faeh, D, Rohrmann, S, Martin, BW. The combined effect on survival of four main behavioural risk factors for non-communicable diseases. Prev Med. 2014. 65:148–52. doi:10.1016/j.ypmed.2014.05.023 24989976 | Intervention/Exposure
1493 | Martínez-González, MA, Salas-Salvadó, J, Estruch, R, Corella, D, Fitó, M, Ros, E. Benefits of the Mediterranean Diet: Insights From the PREDIMED Study. Progress in Cardiovascular Diseases. 2015. 58:50–60. doi:10.1016/j.pcad.2015.04.003 25940230 | Study Design
1494 | Martínez-González, MA, Sánchez-Tainta, A, Corella, D, Salas-Salvadó, J, Ros, E, Arós, F, Gómez-Gracia, E, Fiol, M, Lamuela-Raventós, RM, Schröder, H, , . A provegetarian food pattern and reduction in total mortality in the Prevención con Dieta Mediterránea (PREDIMED) study. American journal of clinical nutrition. 2014. 100 Suppl 1:320S–8S. doi:10.3945/ajcn.113.071431 | Outcome; Publication Date Overlaps with Existing Review
1495 | Martinez-Gonzalez, MA, Sanchez-Villegas, A. The emerging role of Mediterranean diets in cardiovascular epidemiology: monounsaturated fats, olive oil, red wine or the whole pattern?. Eur J Epidemiol. 2004. 19:9–13. Status doi:10.1023/b:ejep.0000013351.60227.7b 15012018 | Study Design; Publication
1496 | Martinez-Gonzalez, MA, Toledo, E, Aros, F, Fiol, M, Corella, D, Salas-Salvado, J, Ros, E, Covas, MI, Fernandez-Crehuet, J, Lapetra, J, Munoz, MA, Fito, M, Serra-Majem, L, Pinto, X, Lamuela-Raventos, RM, Sorli, JV, Babio, N, Buil-Cosiales, P, Ruiz-Gutierrez, V, Estruch, R, Alonso, A. Extravirgin olive oil consumption reduces risk of atrial fibrillation: the PREDIMED (Prevencion con Dieta Mediterranea) trial. Circulation. 2014. 130:18–26. doi:10.1161/circulationaha.113.006921 24787471 | Outcome
1497 | Martinez-Lapiscina, EH, Clavero, P, Toledo, E, Estruch, R, Salas-Salvado, J, San Julian, B, Sanchez-Tainta, A, Ros, E, Valls-Pedret, C, Martinez-Gonzalez, MA. Mediterranean diet improves cognition: the PREDIMED-NAVARRA randomised trial. J Neurol Neurosurg Psychiatry. 2013. 84:1318–25. doi:10.1136/jnnp-2012-304792 23670794 | Outcome
1498 | Martinez-Lopez, E, Garcia-Garcia, MR, Gonzalez-Avalos, JM, Maldonado-Gonzalez, M, Ruiz-Madrigal, B, Vizmanos, B, Hernandez-Nazara, Z, Roman, S, Panduro, A. Effect of Ala54Thr polymorphism of FABP2 on anthropometric and biochemical variables in response to a moderate-fat diet. Nutrition. 2013. 29:46–51. doi:10.1016/j.nut.2012.03.002 22817827 | Intervention/Exposure
1499 | Martins, MCT, Jaceldo-Siegl, K, Orlich, M, Fan, J, Mashchak, A, Fraser, GE. A New Approach to Assess Lifetime Dietary Patterns Finds Lower Consumption of Animal Foods with Aging in a Longitudinal Analysis of a Health-Oriented Adventist Population. Nutrients. 2017. 9:. doi:10.3390/nu9101118 | Outcome
1500 | Marungruang, N, Tovar, J, Bjorck, I, Hallenius, FF. Improvement in cardiometabolic risk markers following a multifunctional diet is associated with gut microbial taxa in healthy overweight and obese subjects. Eur J Nutr. 2018. 57:2927–2936. doi:10.1007/s00394-017-1563-3 29098426 | Outcome
1501 | Maruyama, C, Nakano, R, Shima, M, Mae, A, Shijo, Y, Nakamura, E, Okabe, Y, Park, S, Kameyama, N, Hirai, S, , . Effects of a Japan Diet intake program on metabolic parameters in middle-aged men: a pilot study. Journal of atherosclerosis and thrombosis. 2017. 24:393–401. doi:10.5551/jat.36780 27667329 | Study Design; Intervention/Exposure
1502 | Masa-Font, R, Fernandez-San-Martin, MI, Martin Lopez, LM, Alba Munoz, AM, Oller Canet, S, Martin Royo, J, San Emeterio Echevarria, L, Olona Tabuena, N, Ibarra Jato, M, Barroso Garcia, A, Gonzalez Tejon, S, Tajada Vitales, C, Diaz Mujica, B, Vinas Cabrera, L, Sanchis Catalan, R, Salvador Barbarroja, T. The effectiveness of a program of physical activity and diet to modify cardiovascular risk factors in patients with severe mental illness after 3-month follow-up: CAPiCOR randomized clinical trial. Eur Psychiatry. 2015. 30:1028–36. doi:10.1016/j.eurpsy.2015.09.006 26521223 | Study Design; Health Status
1503 | Masala, G, Bendinelli, B, Versari, D, Saieva, C, Ceroti, M, Santagiuliana, F, Caini, S, Salvini, S, Sera, F, Taddei, S, Ghiadoni, L, Palli, D. Anthropometric and dietary determinants of blood pressure in over 7000 Mediterranean women: The European Prospective Investigation into Cancer and Nutrition-Florence cohort. Journal of Hypertension. 2008. 26:2112–2120. doi:10.1097/HJH.0b013e32830ef75c 18854749 | Study Design
1504 | Mascherini, G, Petri, C, Cala, P, Bini, V, Galanti, G. Lifestyle and resulting body composition in young athletes. Minerva Pediatr. 2016. :. doi:unavailable | Study Design
1505 | Masset, G, Scarborough, P, Rayner, M, Mishra, G, Brunner, EJ. Can nutrient profiling help to identify foods which diet variety should be encouraged? Results from the Whitehall II cohort. Br J Nutr. 2015. 113:1800–9. doi:10.1017/s000711451500094x 25898932 | Intervention/Exposure
1506 | Mateo-Gallego, R, Lamiquiz-Moneo, I, Perez-Calahorra, S, Marco-Benedi, V, Bea, AM, Baila-Rueda, L, Laclaustra, M, Penalvo, JL, Civeira, F, Cenarro, A. Different protein composition of low-calorie diet differently impacts adipokine profile irrespective of weight loss in overweight and obese women. Nutr Metab Cardiovasc Dis. 2018. 28:133–142. doi:10.1016/j.numecd.2017.10.024 29329923 | Outcome
1507 | Mateo-Gallego, R, Marco-Benedi, V, Perez-Calahorra, S, Bea, AM, Baila-Rueda, L, Lamiquiz-Moneo, I, de Castro-Oros, I, Cenarro, A, Civeira, F. Energy-restricted, high-protein diets more effectively impact cardiometabolic profile in overweight and obese women than lower-protein diets. Clin Nutr. 2017. 36:371–379. doi:10.1016/j.clnu.2016.01.018 26875447 | Power/Size
1508 | Mathers, JC. Impact of nutrition on the ageing process. Br J Nutr. 2015. 113 Suppl:S18–22. doi:10.1017/s0007114514003237 25415221 | Study Design; Publication Status
1509 | Matsumoto, S, Beeson, Weight loss, Shavlik, DJ, Siapco, G, Jaceldo-Siegl, K, Fraser, G, Knutsen, SF. Association between vegetarian diets and cardiovascular risk factors in non-Hispanic white participants of the Adventist Health Study-2. J Nutr Sci. 2019. 8:e6. doi:10.1017/jns.2019.1 30828449 | Study Design
1510 | Mattei, J, Noel, SE, Tucker, KL. A meat, processed meat, and French fries dietary pattern is associated with high allostatic load in Puerto Rican older adults. J Am Diet Assoc. 2011. 111:1498–506. doi:10.1016/j.jada.2011.07.006 21963016 | Study Design
1511 | Mattioli, AV, Coppi, F, Migaldi, M, Scicchitano, P, Ciccone, MM, Farinetti, A. Relationship between Mediterranean diet and asymptomatic peripheral arterial disease in a population of pre-menopausal women. Nutr Metab Cardiovasc Dis. 2017. 27:985–990. doi:10.1016/j.numecd.2017.09.011 29074382 | Study Design; Outcome
1512 | Maukonen, M, Kanerva, N, Partonen, T, Kronholm, E, Konttinen, H, Wennman, H, Mannisto, S. The associations between chronotype, a healthy diet and obesity. Chronobiol Int. 2016. 33:972–81. doi:10.1080/07420528.2016.1183022 27246115 | Intervention/Exposure; Comparator
1513 | May, AM, Struijk, EA, Fransen, HP, Onland-Moret, NC, de Wit, GA, Boer, JM, van der Schouw, YT, Hoekstra, J, Bueno-de-Mesquita, HB, Peeters, PH, Beulens, JW. The impact of a healthy lifestyle on Disability-Adjusted Life Years: a prospective cohort study. BMC Med. 2015. 13:39. doi:10.1186/s12916-015-0287-6 25858161 | Outcome
1514 | Mayneris-Perxachs, J, Sala-Vila, A, Chisaguano, M, Castellote, AI, Estruch, R, Covas, MI, Fito, M, Salas-Salvado, J, Martinez-Gonzalez, MA, Lamuela-Raventos, R, Ros, E, Lopez-Sabater, MC. Effects of 1-year intervention with a Mediterranean diet on plasma fatty acid composition and metabolic syndrome in a population at high cardiovascular risk. PLoS One. 2014. 9:e85202. doi:10.1371/journal.pone.0085202 24651160 | Outcome
1515 | Mayor, S. Low glycaemic index diet fails to reduce cardiovascular risk factors, study shows. BMJ (Online). 2014. 349:. doi:10.1136/bmj.g7719 | Publication Status
1516 | Mazidi, M, Katsiki, N, Mikhailidis, DP, Bartlomiejczyk, MA, Banach, M. Association of Empirical Dietary Atherogenic Indices with All-Cause and Cause-Specific Mortality in a Multi-Ethnic Adult Population of the United States. Nutrients. 2019. 11:. doi:10.3390/nu11102323 | Intervention/Exposure
1517 | Mazidi, M, Wong, ND, Katsiki, N, Mikhailidis, DP, Banach, M. Dietary patterns, plasma vitamins and Trans fatty acids are associated with peripheral artery disease. Lipids Health Dis. 2017. 16:254. doi:10.1186/s12944-017-0635-y 29282129 | Study Design
1518 | Mc Clean, CM, Mc Laughlin, J, Burke, G, Murphy, MH, Trinick, T, Duly, E, Davison, GW. The effect of acute aerobic exercise on pulse wave velocity and oxidative stress following postprandial hypertriglyceridemia in healthy men. Eur J Appl Physiol. 2007. 100:225–34. doi:10.1007/s00421-007-0422-y 17323071 | Study duration
1519 | McAuley, KA, Hopkins, CM, Smith, KJ, McLay, RT, Williams, SM, Taylor, RW, Mann, JI. Comparison of high-fat and high-protein diets with a high-carbohydrate diet in insulin-resistant obese women. Diabetologia. 2005. 48:8–16. doi:10.1007/s00125-004-1603-4 15616799 | Study duration
1520 | McAuley, KA, Smith, KJ, Taylor, RW, McLay, RT, Williams, SM, Mann, JI. Long-term effects of popular dietary approaches on weight loss and features of insulin resistance. Int J Obes (Lond). 2006. 30:342–9. doi:10.1038/sj.ijo.0803075 16158081 | Power/Size
1521 | McCaffery, JM, Poque-Geile, MF, Muldoon, MF, Debski, TT, Wing, RR, Manuck, SB. The nature of the association between diet and serum lipids in the community: a twin study. Health Psychol. 2001. 20:341–50. doi:10.1037//0278-6133.20.5.341 11570648 | Study Design
1522 | McCarter, DF. Low-carbohydrate diet effective for adults. Journal of family practice. 2003. 52:515–516. doi:unavailable | Publication Status
1523 | McClain, AD, Otten, JJ, Hekler, EB, Gardner, CD. Adherence to a low-fat vs. low-carbohydrate diet differs by insulin resistance status. Diabetes, obesity & metabolism. 2013. 15:87–90. doi:10.1111/j.1463-1326.2012.01668.x | Power/Size
1524 | McCourt, HJ, Draffin, CR, Woodside, JV, Cardwell, CR, Young, IS, Hunter, SJ, Murray, LJ, Boreham, CA, Gallagher, AM, Neville, CE, McKinley, MC. Dietary patterns and cardiovascular risk factors in adolescents and young adults: the Northern Ireland Young Hearts Project. Br J Nutr. 2014. 112:1685–98. doi:10.1017/s0007114514002682 25234582 | Power/Size
1525 | McCullough, D, Harrison, T, Lane, KE, Boddy, LM, Stewart, CE, Enright, KJ, Amirabdollahian, F, Schmidt, MA, Davies, IG. The effect of dietary carbohydrate manipulation on low-density lipoprotein-cholesterol and its associated cardiometabolic risk. Proceedings of the nutrition society. 2019. 78:. doi:10.1017/S002966511900020X | Publication Status
1526 | McCullough, ML, Feskanich, D, Rimm, EB, Giovannucci, EL, Ascherio, A, Variyam, JN, Spiegelman, D, Stampfer, MJ, Willett, WC. Adherence to the Dietary Guidelines for Americans and risk of major chronic disease in men. Am J Clin Nutr. 2000. 72:1223–31. doi:10.1093/ajcn/72.5.1223 11063453 | Publication Date Overlaps with Existing Review
1527 | McDougall, J, Thomas, LE, McDougall, C, Moloney, G, Saul, B, Finnell, JS, Richardson, K, Petersen, KM. Effects of 7 days on an ad libitum low-fat vegan diet: the McDougall Program cohort. Nutr J. 2014. 13:99. doi:10.1186/1475-2891-13-99 25311617 | Intervention/Exposure; Study duration
1528 | McEneny, J, McPherson, P, Spence, M, Bradley, U, Blair, S, McKinley, M, Young, I, Hunter, S. Does a diet high or low in fat influence the oxidation potential of VLDL, LDL and HDL subfractions?. Nutr Metab Cardiovasc Dis. 2013. 23:612–8. doi:10.1016/j.numecd.2011.12.007 22405535 | Outcome
1529 | McKay, DL, Eliasziw, M, Chen, CYO, Blumberg, JB. A Pecan-Rich Diet Improves Cardiometabolic Risk Factors in Overweight and Obese Adults: A Randomized Controlled Trial. Nutrients. 2018. 10:. doi:10.3390/nu10030339 | Study duration
1530 | McLaughlin, T, Carter, S, Lamendola, C, Abbasi, F, Yee, G, Schaaf, P, Basina, M, Reaven, G. Effects of moderate variations in macronutrient composition on weight loss and reduction in cardiovascular disease risk in obese, insulin-resistant adults. Am J Clin Nutr. 2006. 84:813–21. doi:10.1093/ajcn/84.4.813 17023708 | Weight loss/Hypocaloric
1531 | McLaughlin, T, Liu, LF, Avery, E, Shen, WJ, Cohen, C, Kraemer, F, Cushman, S, Gardner, CD. Effect of low carbohydrate weight loss diet on adipose cell size. Diabetes. 2016. 65:A443–A444. doi:10.2337/db16-1695-1770 | Publication Status
1532 | McManus, K, Antinoro, L, Sacks, F. A randomized controlled trial of a moderate-fat, low-energy diet compared with a low fat, low-energy diet for weight loss in overweight adults. Int J Obes Relat Metab Disord. 2001. 25:1503–11. doi:10.1038/sj.ijo.0801796 11673773 | Weight loss/Hypocaloric
1533 | McMillan-Price, J, Petocz, P, Atkinson, F, O’Neill, K, Samman, S, Steinbeck, K, Caterson, I, Brand-Miller, J. Comparison of 4 diets of varying glycemic load on weight loss and cardiovascular risk reduction in overweight and obese young adults: a randomized controlled trial. Arch Intern Med. 2006. 166:1466–75. doi:10.1001/archinte.166.14.1466 16864756 | Intervention/Exposure
1534 | McMorrow, AM, O’Reilly, ME, Connaughton, RM, Carolan, E, O’Shea, D, Lithander, FE, McGillicuddy, FC, Roche, HM. Weight status and dietary fat modulate high density lipoprotein particle function in adolescents: results from a cross-sectional analysis and a randomised, placebo-controlled, crossover trial. Proceedings of the nutrition society. 2016. 75:E70-. doi:10.1017/S0029665116000859 | Publication Status
1535 | McNaughton, SA, Ball, K, Mishra, GD, Crawford, DA. Dietary patterns of adolescents and risk of obesity and hypertension. J Nutr. 2008. 138:364–70. doi:10.1093/jn/138.2.364 18203905 | Study Design
1536 | McNaughton, SA, Mishra, GD, Brunner, EJ. Dietary patterns, insulin resistance, and incidence of type 2 diabetes in the Whitehall II Study. Diabetes Care. 2008. 31:1343–8. doi:10.2337/dc07-1946 18390803 | Publication Date Overlaps with Existing Review
1537 | McNeill, SH. Inclusion of red meat in healthful dietary patterns. Meat Sci. 2014. 98:452–60. doi:10.1016/j.meatsci.2014.06.028 25034452 | Study Design
1538 | McSwiney, FT, Wardrop, B, Hyde, PN, Lafountain, RA, Volek, JS, Doyle, L. Keto-adaptation enhances exercise performance and body composition responses to training in endurance athletes. Metabolism. 2018. 81:25–34. doi:10.1016/j.metabol.2017.10.010 29108901 | Power/Size
1539 | McVay, MA, Jeffreys, AS, King, HA, Olsen, MK, Voils, CI, Yancy, WS, Jr. The relationship between pretreatment dietary composition and weight loss during a randomised trial of different diet approaches. J Hum Nutr Diet. 2015. 28 Suppl 2:16–23. doi:10.1111/jhn.12188 | Intervention/Exposure
1540 | McVay, MA, Voils, CI, Geiselman, PJ, Smith, VA, Coffman, CJ, Mayer, S, Yancy, WS, Jr. Food preferences and weight change during low-fat and low-carbohydrate diets. Appetite. 2016. 103:336–343. doi:10.1016/j.appet.2016.04.035 27133551 | Intervention/Exposure; Outcome
1541 | Mebonia, N, Trapaidze, D, Kvanchakhadze, R, Zhizhilashvili, S, Kasradze, N. DIETARY HABITS OF SCHOOL-AGE CHILDREN IN TBILISI. Georgian Med News. 2015. :68–73. doi:unavailable | Study Design
1542 | Meckling, KA, Gauthier, M, Grubb, R, Sanford, J. Effects of a hypocaloric, low-carbohydrate diet on weight loss, blood lipids, blood pressure, glucose tolerance, and body composition in free-living overweight women. Can J Physiol Pharmacol. 2002. 80:1095–105. doi:10.1139/y02-140 12489929 | Study Design
1543 | Meckling, KA, O’Sullivan, C, Saari, D. Comparison of a low-fat diet to a low-carbohydrate diet on weight loss, body composition, and risk factors for diabetes and cardiovascular disease in free-living, overweight men and women. J Clin Endocrinol Metab. 2004. 89:2717–23. doi:10.1210/jc.2003-031606 15181047 | Study duration
1544 | Meckling, KA, Sherfey, R. A randomized trial of a hypocaloric high-protein diet, with and without exercise, on weight loss, fitness, and markers of the Metabolic Syndrome in overweight and obese women. Appl Physiol Nutr Metab. 2007. 32:743–52. doi:10.1139/h07-059 17622289 | Weight loss/Hypocaloric
1545 | Medak, KD, Townsend, LK. Adding more fat to a high-fat diet only exacerbates hepatic insulin resistance. J Physiol. 2019. 597:1435–1436. doi:10.1113/jp277632 30653266 | Study Design; Publication Status
1546 | Medenwald, D, Kluttig, A, Lacruz, ME, Schumann, J. Serum dietary fatty acids and coronary heart disease risk - A nested case-control-study within the CARLA cohort. Nutr Metab Cardiovasc Dis. 2019. 29:152–158. doi:10.1016/j.numecd.2018.10.006 30642791 | Intervention/Exposure
1547 | Medina-Remon, A, Casas, R, Tressserra-Rimbau, A, Ros, E, Martinez-Gonzalez, MA, Fito, M, Corella, D, Salas-Salvado, J, Lamuela-Raventos, RM, Estruch, R. Polyphenol intake from a Mediterranean diet decreases inflammatory biomarkers related to atherosclerosis: a substudy of the PREDIMED trial. British journal of clinical pharmacology. 2017. 83:114–128. doi:10.1111/bcp.12986 27100393 | Study Design; Publication Status
1548 | Medina-Remon, A, Tresserra-Rimbau, A, Pons, A, Tur, JA, Martorell, M, Ros, E, Buil-Cosiales, P, Sacanella, E, Covas, MI, Corella, D, Salas-Salvado, J, Gomez-Gracia, E, Ruiz-Gutierrez, V, Ortega-Calvo, M, Garcia-Valdueza, M, Aros, F, Saez, GT, Serra-Majem, L, Pinto, X, Vinyoles, E, Estruch, R, Lamuela-Raventos, RM. Effects of total dietary polyphenols on plasma nitric oxide and blood pressure in a high cardiovascular risk cohort. The PREDIMED randomized trial. Nutr Metab Cardiovasc Dis. 2015. 25:60–7. doi:10.1016/j.numecd.2014.09.001 25315667 | Intervention/Exposure; Outcome
1549 | Meier, T, Grafe, K, Senn, F, Sur, P, Stangl, GI, Dawczynski, C, Marz, W, Kleber, ME, Lorkowski, S. Cardiovascular mortality attributable to dietary risk factors in 51 countries in the WHO European Region from 1990 to 2016: a systematic analysis of the Global Burden of Disease Study. Eur J Epidemiol. 2019. 34:37–55. doi:10.1007/s10654-018-0473-x 30547256 | Study Design
1550 | Meirelles, C, Candido, T, Gomes, PS. Effects of short-term very low-carbohydrate or conventional diet on strength performance. J Sports Med Phys Fitness. 2010. 50:189–95. doi:unavailable20585297 | Study duration
1551 | Meisinger, C, Rospleszcz, S, Wintermeyer, E, Lorbeer, R, Thorand, B, Bamberg, F, Peters, A, Schlett, CL, Linseisen, J. Isocaloric Substitution of Dietary Carbohydrate Intake with Fat Intake and MRI-Determined Total Volumes of Visceral, Subcutaneous and Hepatic Fat Content in Middle-Aged Adults. Nutrients. 2019. 11:. doi:10.3390/nu11051151 | Study Design
1552 | Mekary, RA, Rimm, EB, Giovannucci, E, Stampfer, MJ, Willett, WC, Ludwig, DS, Hu, FB. Joint association of glycemic load and alcohol intake with type 2 diabetes incidence in women. Am J Clin Nutr. 2011. 94:1525–32. doi:10.3945/ajcn.111.023754 22049168 | Intervention/Exposure
1553 | Meksawan, K, Pendergast, DR, Leddy, JJ, Mason, M, Horvath, PJ, Awad, AB. Effect of low and high fat diets on nutrient intakes and selected cardiovascular risk factors in sedentary men and women. J Am Coll Nutr. 2004. 23:131–40. doi:10.1080/07315724.2004.10719353 15047679 | Study duration
1554 | Meksawan, K, Venkatraman, JT, Awad, AB, Pendergast, DR. Effect of dietary fat intake and exercise on inflammatory mediators of the immune system in sedentary men and women. J Am Coll Nutr. 2004. 23:331–40. doi:10.1080/07315724.2004.10719376 15310737 | Outcome; Study duration
1555 | Mellberg, C, Sandberg, S, Ryberg, M, Eriksson, M, Brage, S, Larsson, C, Olsson, T, Lindahl, B. Long-term effects of a Palaeolithic-type diet in obese postmenopausal women: a 2-year randomized trial. Eur J Clin Nutr. 2014. 68:350–7. doi:10.1038/ejcn.2013.290 24473459 | Power/Size
1556 | Mellendick, K, Shanahan, L, Wideman, L, Calkins, S, Keane, S, Lovelady, C. Diets Rich in Fruits and Vegetables Are Associated with Lower Cardiovascular Disease Risk in Adolescents. Nutrients. 2018. 10:. doi:10.3390/nu10020136 | Study Design; Comparator
1557 | Memelink, R, Verreijen, A, Engberink, M, Weijs, P. Higher than 1.2 G/KG/D protein intake is associated with increased fat mass loss during weight loss in obese older adults. Clinical nutrition. 2014. 33:S110. doi:unavailable | Publication Status
1558 | Mendonca, RD, Carvalho, NC, Martin-Moreno, JM, Pimenta, AM, Lopes, ACS, Gea, A, Martinez-Gonzalez, MA, Bes-Rastrollo, M. Total polyphenol intake, polyphenol subtypes and incidence of cardiovascular disease: The SUN cohort study. Nutr Metab Cardiovasc Dis. 2019. 29:69–78. doi:10.1016/j.numecd.2018.09.012 30459074 | Intervention/Exposure
1559 | Mendonca, RD, Lopes, AC, Pimenta, AM, Gea, A, Martinez-Gonzalez, MA, Bes-Rastrollo, M. Ultra-Processed Food Consumption and the Incidence of Hypertension in a Mediterranean Cohort: The Seguimiento Universidad de Navarra Project. Am J Hypertens. 2017. 30:358–366. doi:10.1093/ajh/hpw137 27927627 | Outcome
1560 | Meneton, P, Kesse-Guyot, E, Fezeu, L, Galan, P, Hercberg, S, Menard, J. Distinctive unhealthy eating pattern in free-living middle-aged hypertensives when compared with dyslipidemic or overweight patients. J Hypertens. 2013. 31:1554–63. doi:10.1097/HJH.0b013e32836130f8 23591702 | Study Design; Intervention/Exposure
1561 | Meng, H, Matthan, NR, Fried, SK, Berciano, S, Walker, ME, Galluccio, JM, Lichtenstein, AH. Effect of Dietary Carbohydrate Type on Serum Cardiometabolic Risk Indicators and Adipose Tissue Inflammatory Markers. J Clin Endocrinol Metab. 2018. 103:3430–3438. doi:10.1210/jc.2018-00667 29982704 | Intervention/Exposure
1562 | Meng, X, Zhu, K, Devine, A, Kerr, DA, Binns, CW, Prince, RL. A 5-year cohort study of the effects of high protein intake on lean mass and BMC in elderly postmenopausal women. J Bone Miner Res. 2009. 24:1827–34. doi:10.1359/jbmr.090513 19419320 | Power/Size
1563 | Mensink, M, Schutte, S, Chatindiara, I, Esser, D, Siebelink, E, Afman, L. Effect of caloric restriction and dietary composition on liver triglyceride content in subjects with abdominal obesity: the wageningen belly fat study. FASEB journal. Conference: experimental biology 2016, EB. San diego, CA united states. Conference start: 20160402. Conference end: 20160406. Conference publication: (var.pagings). 2016. 30:. doi:unavailable | Publication Status
1564 | Mercanligil, SM, Arslan, P, Alasalvar, C, Okut, E, Akgul, E, Pinar, A, Geyik, PO, Tokgozoglu, L, Shahidi, F. Effects of hazelnut-enriched diet on plasma cholesterol and lipoprotein profiles in hypercholesterolemic adult men. Eur J Clin Nutr. 2007. 61:212–20. doi:10.1038/sj.ejcn.1602518 16969381 | Study duration
1565 | Merino, J, Guasch-Ferre, M, Martinez-Gonzalez, MA, Corella, D, Estruch, R, Fito, M, Ros, E, Aros, F, Bullo, M, Gomez-Gracia, E, Monino, M, Lapetra, J, Serra-Majem, L, Razquin, C, Buil-Cosiales, P, Sorli, JV, Munoz, MA, Pinto, X, Masana, L, Salas-Salvado, J. Is complying with the recommendations of sodium intake beneficial for health in individuals at high cardiovascular risk? Findings from the PREDIMED study. Am J Clin Nutr. 2015. 101:440–8. doi:10.3945/ajcn.114.096750 25733627 | Intervention/Exposure, data overlap with included article
1566 | Mero, AA, Huovinen, H, Matintupa, O, Hulmi, JJ, Puurtinen, R, Hohtari, H, Karila, TA. Moderate energy restriction with high protein diet results in healthier outcome in women. J Int Soc Sports Nutr. 2010. 7:4. doi:10.1186/1550-2783-7-4 20205751 | Intervention/Exposure; Study duration
1567 | Merra, G, Gratteri, S, De Lorenzo, A, Barrucco, S, Perrone, MA, Avolio, E, Bernardini, S, Marchetti, M, Di Renzo, L. Effects of very-low-calorie diet on body composition, metabolic state, and genes expression: a randomized double-blind placebo-controlled trial. Eur Rev Med Pharmacol Sci. 2017. 21:329–345. doi:unavailable28165552 | Study duration
1568 | Merra, G, Miranda, R, Barrucco, S, Gualtieri, P, Mazza, M, Moriconi, E, Marchetti, M, Chang, TF, De Lorenzo, A, Di Renzo, L. Very-low-calorie ketogenic diet with aminoacid supplement versus very low restricted-calorie diet for preserving muscle mass during weight loss: a pilot double-blind study. Eur Rev Med Pharmacol Sci. 2016. 20:2613–21. doi:unavailable27383313 | Intervention/Exposure; Study duration
1569 | Merrotsy, A, McCarthy, AL, Flack, J, Lacey, S, Coppinger, T. Project Spraoi: a two-year longitudinal study on the effectiveness of a school-based nutrition and physical activity intervention on dietary intake, nutritional knowledge and markers of health of Irish schoolchildren. Public Health Nutr. 2019. 22:2489–2499. doi:10.1017/s1368980019001368 31203819 | Intervention/Exposure
1570 | Mertens, E, Deforche, B, Mullie, P, Lefevre, J, Charlier, R, Knaeps, S, Huybrechts, I, Clarys, P. Longitudinal study on the association between three dietary indices, anthropometric parameters and blood lipids. Nutr Metab (Lond). 2015. 12:47. doi:10.1186/s12986-015-0042-1 26594230 | Power/Size
1571 | Mesquita de Carvalho, C, Dias Mendonca, D, Haas Piovesan, C, Edler Macagnan, F, Pandolfo Feoli, AM. Nutritional adequacy in subjects with metabolic syndrome. Nutr Hosp. 2014. 31:1147–53. doi:10.3305/nh.2015.31.3.8086 25726206 | Outcome
1572 | Metkus, TS, Dobrosielski, D, Stewart, K. Effect of a low carbohydrate versus a low fat diet on the metabolic syndrome. Journal of the american college of cardiology. 2012. 59:E1753. doi:10.1016/S0735-1097%2812%2961754-9 | Publication Status
1573 | Metro, D, Tardugno, R, Papa, M, Bisignano, C, Manasseri, L, Calabrese, G, Gervasi, T, Dugo, G, Cicero, N. Adherence to the Mediterranean diet in a Sicilian student population. Nat Prod Res. 2018. 32:1775–1781. doi:10.1080/14786419.2017.1402317 29130340 | Study Design; Intervention/Exposure
1574 | Mettler, S, Mitchell, N, Tipton, KD. Increased protein intake reduces lean body mass loss during weight loss in athletes. Med Sci Sports Exerc. 2010. 42:326–37. doi:10.1249/MSS.0b013e3181b2ef8e 19927027 | Study duration
1575 | Mezzano, D, Leighton, F, Strobel, P, Martinez, C, Marshall, G, Cuevas, A, Castillo, O, Panes, O, Munoz, B, Rozowski, J, Pereira, J. Mediterranean diet, but not red wine, is associated with beneficial changes in primary haemostasis. Eur J Clin Nutr. 2003. 57:439–46. doi:10.1038/sj.ejcn.1601558 12627181 | Outcome
1576 | Mia, FB, Vorster, HH. Coronary heart disease risk factors in Indian adolescents the role of diet. Cardiovasc J S Afr. 2000. 11:68–75. doi:unavailable11447466 | Study Design; Country
1577 | Michalczyk, M, Zajac, A, Mikolajec, K, Zydek, G, Langfort, J. No Modification in Blood Lipoprotein Concentration but Changes in Body Composition after 4 Weeks of Low Carbohydrate Diet (LCD) Followed by 7 Days of Carbohydrate Loading in Basketball Players. J Hum Kinet. 2018. 65:125–137. doi:10.2478/hukin-2018-0102 30687425 | Study Design; Study duration
1578 | Michalczyk, MM, Chycki, J, Zajac, A, Maszczyk, A, Zydek, G, Langfort, J. Anaerobic performance after a low-carbohydrate diet (LCD) followed by 7 days of carbohydrate loading in male basketball players. Nutrients. 2019. 11:. doi:10.3390/nu11040778 | Study duration
1579 | Michels, KB, Wolk, A. A prospective study of variety of healthy foods and mortality in women. International Journal of Epidemiology. 2002. 31:847–854. doi:10.1093/ije/31.4.847 12177033 | Publication Date Overlaps with Existing Review
1580 | Michielsen, Ccjr, Hangelbroek, RWJ, Feskens, EJM, Afman, LA. Disentangling the Effects of Monounsaturated Fatty Acids from Other Components of a Mediterranean Diet on Serum Metabolite Profiles: A Randomized Fully Controlled Dietary Intervention in Healthy Subjects at Risk of the Metabolic Syndrome. Mol Nutr Food Res. 2019. 63:e1801095. doi:10.1002/mnfr.201801095 30725537 | Outcome
1581 | Mielgo Ayuso, J, Zourdos, MC, Urdampilleta, A, Calleja Gonzalez, J, Seco, J, Cordova, A. Relationship of long-term macronutrients intake on anabolic-catabolic hormones in female elite volleyball players. Nutr Hosp. 2017. 34:1155–1162. doi:10.20960/nh.763 29130715 | Study Design
1582 | Mielgo-Ayuso, J, Zourdos, MC, Calleja-Gonzalez, J, Urdampilleta, A, Ostojic, SM. Dietary intake habits and controlled training on body composition and strength in elite female volleyball players during the season. Appl Physiol Nutr Metab. 2015. 40:827–34. doi:10.1139/apnm-2015-0100 26224330 | Study Design; Comparator
1583 | Miguet, M, Fillon, A, Masurier, J, Khammassi, M, Julian, V, Boirie, Y, Duclos, M, Blundell, J, Finlayson, G, Thivel, D. Energy intake, appetite and food reward responses to High Intensity Interval Exercise might depend on the degree of obesity in adolescents. Obesity facts. 2018. 11:33-. doi:10.1159/000489691 | Publication Status
1584 | Mihrshahi, S, Ding, D, Gale, J, Allman-Farinelli, M, Banks, E, Bauman, AE. Vegetarian diet and all-cause mortality: Evidence from a large population-based Australian cohort - the 45 and Up Study. Prev Med. 2017. 97:1–7. doi:10.1016/j.ypmed.2016.12.044 28040519 | Outcome
1585 | Miksa, SA, Stadler, D, Karanja, N. Weight loss induced by low carbohydrate or high carbohydrate diets does not improve serum 25(OH)D concentrations. Obesity (silver spring, md.). 2010. 18:S95-. doi:unavailable | Publication Status
1586 | Mildestvedt, T, Meland, E, Eide, GE. No difference in lifestyle changes by adding individual counselling to group-based rehabilitation RCT among coronary heart disease patients. Scandinavian Journal of Public Health. 2007. 35:591–598. doi:10.1080/14034940701349241 17852978 | Health Status
1587 | Millar, L, Rowland, B, Nichols, M, Swinburn, B, Bennett, C, Skouteris, H, Allender, S. Relationship between raised BMI and sugar sweetened beverage and high fat food consumption among children. Obesity (Silver Spring). 2014. 22:E96–103. doi:10.1002/oby.20665 24318968 | Study Design; Intervention/Exposure
1588 | Millen, BE, Quatromoni, PA, Nam, BH, O’Horo, CE, Polak, JF, D’Agostino, RB. Dietary patterns and the odds of carotid atherosclerosis in women: the Framingham Nutrition Studies. Prev Med. 2002. 35:540–7. doi:10.1006/pmed.2002.1116 12460521 | Publication Date Overlaps with Existing Review
1589 | Millen, BE, Quatromoni, PA, Nam, BH, O’Horo, CE, Polak, JF, Wolf, PA, D’Agostino, RB. Dietary patterns, smoking, and subclinical heart disease in women: opportunities for primary prevention from the Framingham Nutrition Studies. J Am Diet Assoc. 2004. 104:208–14. doi:10.1016/j.jada.2003.11.007 14760568 | Study Design; Intervention/Exposure; Outcome; Publication Date Overlaps with Existing Review
1590 | Miller, BV, Bertino, JS, Reed, RG, Burrington, CM, Davidson, LK, Green, A, Gartung, AM, Nafziger, AN. An evaluation of the atkins’ diet. Metab Syndr Relat Disord. 2003. 1:299–309. doi:10.1089/1540419031361426 18370655 | Study duration
1591 | Miller, CK, Ulbrecht, JS, Lyons, J, Parker-Klees, L, Gutschall, MD, Smiciklas-Wright, H, Mitchell, DC, Covasa, M, Hayes, M. A reduced-carbohydrate diet improves outcomes in patients with metabolic syndrome: A translational study. Topics in Clinical Nutrition. 2007. 22:82–91. doi:10.1097/00008486-200701000-00009 | Study Design
1592 | Miller, ER, Cooper, LA, Carson, KA, Wang, NY, Appel, LJ, Gayles, D, Charleston, J, White, K, Dalcin, AT, Martin-Daniels, M, , . A randomized trial of a high potassium dietary intervention to lower blood pressure in urban African Americans with hypertension in the primary care setting: the “five plus nuts and beans” trial. Circulation. 2015. 131:. doi:unavailable | Publication Status
1593 | Miller, GD, Beavers, DP, Hamm, D, Mihalko, SL, Messier, SP. Nutrient Intake During Diet-Induced Weight Loss and Exercise Interventions in a Randomized Trial in Older Overweight and Obese Adults. J Nutr Health Aging. 2017. 21:1216–1224. doi:10.1007/s12603-017-0892-5 29188882 | Study Design; Intervention/Exposure
1594 | Miller, LE, Volpe, JJ, Coleman-Kelly, MD, Gwazdauskas, FC, Nickols-Richardson, SM. Anthropometric and leptin changes in women following different dietary approaches to weight loss. Obesity (Silver Spring). 2009. 17:199–201. doi:10.1038/oby.2008.498 18997680 | Intervention/Exposure
1595 | Miller, M, Beach, V, Sorkin, JD, Mangano, C, Dobmeier, C, Novacic, D, Rhyne, J, Vogel, RA. Comparative effects of three popular diets on lipids, endothelial function, and C-reactive protein during weight maintenance. J Am Diet Assoc. 2009. 109:713–7. doi:10.1016/j.jada.2008.12.023 19328268 | Intervention/Exposure
1596 | Minehira, K, Bettschart, V, Vidal, H, Vega, N, Di Vetta, V, Rey, V, Schneiter, P, Tappy, L. Effect of carbohydrate overfeeding on whole body and adipose tissue metabolism in humans. Obes Res. 2003. 11:1096–103. doi:10.1038/oby.2003.150 12972680 | Study duration
1597 | Minehira, K, Vega, N, Vidal, H, Acheson, K, Tappy, L. Effect of carbohydrate overfeeding on whole body macronutrient metabolism and expression of lipogenic enzymes in adipose tissue of lean and overweight humans. Int J Obes Relat Metab Disord. 2004. 28:1291–8. doi:10.1038/sj.ijo.0802760 15303106 | Study duration
1598 | Ministrini, S, Calzini, L, Nulli Migliola, E, Ricci, MA, Roscini, AR, Siepi, D, Tozzi, G, Daviddi, G, Martorelli, EE, Paganelli, MT, Lupattelli, G. Lysosomal Acid Lipase as a Molecular Target of the Very Low Carbohydrate Ketogenic Diet in Morbidly Obese Patients: The Potential Effects on Liver Steatosis and Cardiovascular Risk Factors. J Clin Med. 2019. 8:. doi:10.3390/jcm8050621 | Study Design; Study duration
1599 | Minoura, A, Wang, DH, Sato, Y, Zou, Y, Sakano, N, Kubo, M, Takemoto, K, Masatomi, C, Ogino, K. Association of dietary fat and carbohydrate consumption and predicted ten-year risk for developing coronary heart disease in a general Japanese population. Acta Med Okayama. 2014. 68:129–35. doi:10.18926/amo/52652 24942790 | Intervention/Exposure
1600 | Mirmiran, P, Asghari, G, Farhadnejad, H, Eslamian, G, Hosseini-Esfahani, F, Azizi, F. Low carbohydrate diet is associated with reduced risk of metabolic syndrome in Tehranian adults. Int J Food Sci Nutr. 2017. 68:358–365. doi:10.1080/09637486.2016.1242119 27718762 | Intervention/Exposure; Outcome
1601 | Mirmiran, P, Bahadoran, Z, Esfandyari, S, Azizi, F. Dietary Protein and Amino Acid Profiles in Relation to Risk of Dysglycemia: Findings from a Prospective Population-Based Study. Nutrients. 2017. 9:. doi:10.3390/nu9090971 | Intervention/Exposure
1602 | Mirmiran, P, Bahadoran, Z, Mirzaei, S, Azizi, F. Dietary Intake, Changes in Lipid Parameters and the Risk of Hypertriglyceridemia: A Prospective Approach in the Tehran Lipid and Glucose Study. Int J Vitam Nutr Res. 2014. 84:269–76. doi:10.1024/0300-9831/a000213 26255548 | Intervention/Exposure
1603 | Mirmiran, P, Noori, N, Azizi, F. A prospective study of determinants of the metabolic syndrome in adults. Nutr Metab Cardiovasc Dis. 2008. 18:567–73. doi:10.1016/j.numecd.2007.06.002 18068961 | Intervention/Exposure; Country
1604 | Mirmiran, P, Ramezankhani, A, Hekmatdoost, A, Azizi, F. Effect of nutrition intervention on non-communicable disease risk factors among Tehranian adults: Tehran Lipid and Glucose Study. Ann Nutr Metab. 2008. 52:91–5. doi:10.1159/000121364 18349527 | Intervention/Exposure; Publication Date Overlaps with Existing Review
1605 | Mirza, NM, Palmer, MG, Sinclair, KB, McCarter, R, He, J, Ebbeling, CB, Ludwig, DS, Yanovski, JA. Effects of a low glycemic load or a low-fat dietary intervention on body weight in obese Hispanic American children and adolescents: a randomized controlled trial. Am J Clin Nutr. 2013. 97:276–85. doi:10.3945/ajcn.112.042630 23255569 | Intervention/Exposure
1606 | Mishra, S, Xu, J, Agarwal, U, Gonzales, J, Levin, S, Barnard, ND. A multicenter randomized controlled trial of a plant-based nutrition program to reduce body weight and cardiovascular risk in the corporate setting: the GEICO study. Eur J Clin Nutr. 2013. 67:718–24. doi:10.1038/ejcn.2013.92 23695207 | Intervention/Exposure; Comparator
1607 | Misirli, G, Benetou, V, Lagiou, P, Bamia, C, Trichopoulos, D, Trichopoulou, A. Relation of the traditional Mediterranean diet to cerebrovascular disease in a Mediterranean population. Am J Epidemiol. 2012. 176:1185–92. doi:10.1093/aje/kws205 23186748 | Publication Date Overlaps with Existing Review
1608 | Misra, A, Wasir, JS, Vikram, NK. Carbohydrate diets, postprandial hyperlipidaemia, abdominal obesity & Asian Indians: A recipe for atherogenic disaster. Indian Journal of Medical Research. 2005. 121:5–8. doi:unavailable | Publication Status
1609 | Mitchell, CJ, Milan, AM, Mitchell, SM, Zeng, N, Ramzan, F, Sharma, P, Knowles, S, Roy, N, Sjodin, A, Wagner, KH, , . Ten weeks of protein consumption at the RDA results: in a loss of appendicular lean mass in healthy older men, a randomized controlled trial. FASEB journal. 2017. 31:. doi:unavailable | Publication Status
1610 | Mitchell, CJ, Milan, AM, Mitchell, SM, Zeng, N, Ramzan, F, Sharma, P, Knowles, SO, Roy, NC, Sjodin, A, Wagner, KH, Cameron-Smith, D. The effects of dietary protein intake on appendicular lean mass and muscle function in elderly men: a 10-wk randomized controlled trial. Am J Clin Nutr. 2017. 106:1375–1383. doi:10.3945/ajcn.117.160325 29092886 | Intervention/Exposure
1611 | Mitchell, SM, Milan, AM, Mitchell, CJ, Gillies, NA, D’Souza, RF, Zeng, N, Ramzan, F, Sharma, P, Knowles, SO, Roy, NC, Sjodin, A, Wagner, KH, Zeisel, SH, Cameron-Smith, D. Protein Intake at Twice the RDA in Older Men Increases Circulatory Concentrations of the Microbiome Metabolite Trimethylamine-N-Oxide (TMAO). Nutrients. 2019. 11:. doi:10.3390/nu11092207 | Intervention/Exposure
1612 | Mitra, SR, Tan, PY. Effect of an individualised high-protein, energy-restricted diet on anthropometric and cardio-metabolic parameters in overweight and obese Malaysian adults: a 6-month randomised controlled study. Br J Nutr. 2019. 121:1002–1017. doi:10.1017/s0007114519000345 30761964 | Weight loss/Hypocaloric
1613 | Mittendorfer, B, Sidossis, LS. Mechanism for the increase in plasma triacylglycerol concentrations after consumption of short-term, high-carbohydrate diets. Am J Clin Nutr. 2001. 73:892–9. doi:10.1093/ajcn/73.5.892 11333842 | Study duration
1614 | Miyagawa, N, Arima, H, Yoshita, K, Okuda, N, Ohkubo, T, Hisamatsu, T, Kondo, K, Miura, K. Feasibility, safety and efficacy of a modified dietary approaches to stop hypertension diet for japanese population. Circulation. 2018. 137:. doi:unavailable | Publication Status
1615 | Mogul, HR, Freeman, R, Scherer, PE, Frey, M, Hantash, FM, Greenbaum, R, Jozak, S, Klein, LA, Tanenbaum, K. Carbohydrate modified diet and insulin sensitizers reduce fasting insulin and body weight, modulate measures of the metabolic syndrome, and improve adipokines in EMPOWIR (enhance the metabolic profile of women with insulin resistance) a randomized clinical trial (NCT00618071) of normoglycemic, hyperinsulinemic women with midlife weight gain. Endocrine reviews. 2012. 33:. doi:unavailable | Publication Status
1616 | Mohammadifard, N, Talaei, M, Sadeghi, M, Oveisegharan, S, Golshahi, J, Esmaillzadeh, A, Sarrafzadegan, N. Dietary patterns and mortality from cardiovascular disease: Isfahan Cohort Study. Eur J Clin Nutr. 2017. 71:252–258. doi:10.1038/ejcn.2016.170 27759064 | Country
1617 | Mohan, V, Spiegelman, D, Sudha, V, Gayathri, R, Hong, B, Praseena, K, Anjana, RM, Wedick, NM, Arumugam, K, Malik, V, Ramachandran, S, Bai, MR, Henry, JK, Hu, FB, Willett, W, Krishnaswamy, K. Effect of brown rice, white rice, and brown rice with legumes on blood glucose and insulin responses in overweight Asian Indians: a randomized controlled trial. Diabetes Technol Ther. 2014. 16:317–25. doi:10.1089/dia.2013.0259 24447043 | Study duration
1618 | Mohler, ER, 3rd, Sibley, AA, Stein, R, Davila-Roman, V, Wyatt, H, Badellino, K, Rader, DJ, Klein, S, Foster, GD. Endothelial function and weight loss: comparison of low-carbohydrate and low-fat diets. Obesity (Silver Spring). 2013. 21:504–9. doi:10.1002/oby.20055 23404949 | Intervention/Exposure; Outcome
1619 | Mohorko, N, Cernelic-Bizjak, M, Poklar-Vatovec, T, Grom, G, Kenig, S, Petelin, A, Jenko-Praznikar, Z. Weight loss, improved physical performance, cognitive function, eating behavior, and metabolic profile in a 12-week ketogenic diet in obese adults. Nutr Res. 2019. 62:64–77. doi:10.1016/j.nutres.2018.11.007 30803508 | Study Design; Comparator
1620 | Mojtahedi, MC, Thorpe, MP, Karampinos, DC, Johnson, CL, Layman, DK, Georgiadis, JG, Evans, EM. The effects of a higher protein intake during energy restriction on changes in body composition and physical function in older women. J Gerontol A Biol Sci Med Sci. 2011. 66:1218–25. doi:10.1093/gerona/glr120 21798863 | Intervention/Exposure
1621 | Monge, A, Lajous, M, Ortiz-Panozo, E, Rodriguez, BL, Gongora, JJ, Lopez-Ridaura, R. Western and Modern Mexican dietary patterns are directly associated with incident hypertension in Mexican women: a prospective follow-up study. Nutr J. 2018. 17:21. doi:10.1186/s12937-018-0332-3 29444692 | Outcome
1622 | Monica Dinu, M, Pagliai, G, Mangino, A, Cesari, F, Giusti, B, Marcucci, R, Casini, A, Sofi, F. Comparison between Mediterranean and Vegetarian diets for cardiovascular prevention: the CARDIntervention/ExposureG study. European journal of preventive cardiology. 2017. 24:S136-. doi:unavailable | Publication Status
1623 | Monjardino, T, Lucas, R, Ramos, E, Barros, H. Associations between a priori-defined dietary patterns and longitudinal changes in bone mineral density in adolescents. Public Health Nutr. 2014. 17:195–205. doi:10.1017/s1368980012004879 23149164 | Outcome
1624 | Monteagudo, C, Mariscal-Arcas, M, Rivas, A, Lorenzo-Tovar, ML, Tur, JA, Olea-Serrano, F. Proposal of a Mediterranean Diet Serving Score. PLoS One. 2015. 10:e0128594. doi:10.1371/journal.pone.0128594 26035442 | Study Design; Intervention/Exposure; Outcome
1625 | Moore, LL, Singer, MR, Bradlee, ML, Daniels, SR. Adolescent dietary intakes predict cardiometabolic risk clustering. Eur J Nutr. 2016. 55:461–468. doi:10.1007/s00394-015-0863-8 25724172 | Intervention/Exposure; Outcome
1626 | Moore, WJ, McGrievy, ME, Turner-McGrievy, GM. Dietary adherence and acceptability of five different diets, including vegan and vegetarian diets, for weight loss: The New DIETs study. Eat Behav. 2015. 19:33–8. doi:10.1016/j.eatbeh.2015.06.011 26164391 | Power/Size
1627 | Moradi, S, Khorrami-Nezhad, L, Ali-Akbar, S, Zare, F, Alipour, T, Dehghani Kari Bozorg, A, Yekaninejad, MS, Maghbooli, Z, Mirzaei, K. The associations between dietary patterns and bone health, according to the TGF-beta1 T869-->C polymorphism, in postmenopausal Iranian women. Aging Clin Exp Res. 2018. 30:563–571. doi:10.1007/s40520-017-0828-2 28918533 | Study Design
1628 | Moraleda, E, Martinez-Argudo, I, Rodriguez-Gomez, I, Ara, I, Aznar, S. Ketogenic diet and physical activity intervention to weight loss analyzing different FTO and AdipoQ polimorfisms. Annals of nutrition & metabolism. 2019. 75:35–36. doi:10.1159/000501441 | Publication Status
1629 | Moran, LJ, Flynn, AC, Louise, J, Deussen, AR, Dodd, JM. The effect of a lifestyle intervention on pregnancy and postpartum dietary patterns determined by factor analysis. Obesity (Silver Spring). 2017. 25:1022–1032. doi:10.1002/oby.21848 28452404 | Outcome; Participants
1630 | Moran, LJ, Noakes, M, Clifton, P, Buckley, J, Brinkworth, G, Thomson, R, Norman, RJ. Predictors of lifestyle intervention attrition or weight loss success in women with polycystic ovary syndrome who are overweight or obese. Nutrients. 2019. 11:. doi:10.3390/nu11030492 | Intervention/Exposure; Health Status
1631 | Moreira, T, Severo, M, Oliveira, A, Ramos, E, Rodrigues, S, Lopes, C. Eating out of home and dietary adequacy in preschool children. Br J Nutr. 2015. 114:297–305. doi:10.1017/s0007114515001713 26082269 | Intervention/Exposure; Outcome
1632 | Morell-Azanza, L, Ochotorena-Elicegui, A, Catalan-Lamban, A, Chueca, M, Marti, A, Julian, CAS. Assessment of adherence to mediterranean diet during a weight loss intervention in children with cardiometabolic risk. Hormone research in paediatrics. 2016. 86:310-. doi:10.1159/000449142 | Publication Status
1633 | Morenga, LT, Williams, S, Brown, R, Mann, J. Effect of a relatively high-protein, high-fiber diet on body composition and metabolic risk factors in overweight women. Eur J Clin Nutr. 2010. 64:1323–31. doi:10.1038/ejcn.2010.163 20842168 | Intervention/Exposure
1634 | Moreno Franco, B, Leon Latre, M, Andres Esteban, EM, Ordovas, JM, Casasnovas, JA, Penalvo, JL. Soluble and insoluble dietary fibre intake and risk factors for metabolic syndrome and cardiovascular disease in middle-aged adults: the AWHS cohort. Nutr Hosp. 2014. 30:1279–88. doi:10.3305/nh.2014.30.6.7778 25433109 | Study Design; Intervention/Exposure
1635 | Moreno, B, Bellido, D, Sajoux, I, Goday, A, Saavedra, D, Crujeiras, AB, Casanueva, FF. Comparison of a very low-calorie-ketogenic diet with a standard low-calorie diet in the treatment of obesity. Endocrine. 2014. 47:793–805. doi:10.1007/s12020-014-0192-3 24584583 | Intervention/Exposure
1636 | Moreno, LA. Effects of diet on growth of children with obesity. J Pediatr Gastroenterol Nutr. 2010. 51 Suppl 3:S147–8. doi:10.1097/MPG.0b013e3181efb1be 21088542 | Study Design
1637 | Moretti, L, Canada, T. A Randomized Study Comparing the Effects of a Low-Carbohydrate Diet and a Conventional Diet on Lipoprotein Subfractions and C-reactive Protein Levels in Patients With Severe Obesity. Nutr Clin Pract. 2006. 21:187–188. doi:10.1177/0115426506021002187 28094672 | Publication Status
1638 | Morgan, LM, Griffin, BA, Millward, DJ, DeLooy, A, Fox, KR, Baic, S, Bonham, MP, Wallace, JM, MacDonald, I, Taylor, MA, Truby, H. Comparison of the effects of four commercially available weight-loss programmes on lipid-based cardiovascular risk factors. Public Health Nutr. 2009. 12:799–807. doi:10.1017/s1368980008003236 18647427 | Weight loss/Hypocaloric
1639 | Morgantini, C, Trifiro, S, Trico, D, Meriwether, D, Baldi, S, Mengozzi, A, Reddy, ST, Natali, A. A short-term increase in dietary cholesterol and fat intake affects high-density lipoprotein composition in healthy subjects. Nutr Metab Cardiovasc Dis. 2018. 28:575–581. doi:10.1016/j.numecd.2018.03.005 29699812 | Study duration
1640 | Morimoto, N, Kasuga, C, Tanaka, A, Kamachi, K, Ai, M, Urayama, KY, Tanaka, A. Association between dietary fibre:carbohydrate intake ratio and insulin resistance in Japanese adults without type 2 diabetes. Br J Nutr. 2018. 119:620–628. doi:10.1017/s0007114517003725 29553029 | Intervention/Exposure
1641 | Morin, E, Michaud-Letourneau, I, Couturier, Y, Roy, M. A whole-food, plant-based nutrition program: Evaluation of cardiovascular outcomes and exploration of food choices determinants. Nutrition. 2019. 66:54–61. doi:10.1016/j.nut.2019.03.020 31207440 | Study Design; Intervention/Exposure
1642 | Morrison, JA, Glueck, CJ, Daniels, S, Wang, P. Determinants of persistent obesity and hyperinsulinemia in a biracial cohort: a 15-year prospective study of schoolgirls. J Pediatr. 2010. 157:559–65. doi:10.1016/j.jpeds.2010.04.030 20553845 | Intervention/Exposure
1643 | Morton, D, Rankin, P, Kent, L, Sokolies, R, Dysinger, W, Gobble, J, Diehl, H. The Complete Health Improvement Program (CHIP) and reduction of chronic disease risk factors in Canada. Can J Diet Pract Res. 2014. 75:72–7. doi:10.3148/75.2.2014.72 24897012 | Study Design
1644 | Mosca, CL, Marshall, JA, Grunwald, GK, Cornier, MA, Baxter, J. Insulin resistance as a modifier of the relationship between dietary fat intake and weight gain. Int J Obes Relat Metab Disord. 2004. 28:803–12. doi:10.1038/sj.ijo.0802621 15146168 | Intervention/Exposure
1645 | Moslehi, N, Ehsani, B, Mirmiran, P, Hojjat, P, Azizi, F. Association of Dietary Proportions of Macronutrients with Visceral Adiposity Index: Non-Substitution and Iso-Energetic Substitution Models in a Prospective Study. Nutrients. 2015. 7:8859–70. doi:10.3390/nu7105436 26516906 | Intervention/Exposure
1646 | Motie, M, Evangelista, LS, Horwich, T, Hamilton, M, Lombardo, D, Cooper, DM, Galassetti, PR, Fonarow, GC. Pro-HEART - a randomized clinical trial to test the effectiveness of a high protein diet targeting obese individuals with heart failure: rationale, design and baseline characteristics. Contemp Clin Trials. 2013. 36:371–81. doi:10.1016/j.cct.2013.08.004 23958597 | Study Design; Health Status
1647 | Moyama, S, Minami, K, Yano, M, Okumura, M, Hayashi, S, Takayama, H, Yorimoto, A. Relationship between dietary patterns and brachial-ankle pulse wave velocity among middle-aged adults in Japan. Asia Pac J Clin Nutr. 2017. 26:539–544. doi:10.6133/apjcn.032016.14 28429921 | Study Design; Outcome
1648 | Mozaffarian, D, Rimm, EB, Herrington, DM. Dietary fats, carbohydrate, and progression of coronary atherosclerosis in postmenopausal women. Am J Clin Nutr. 2004. 80:1175–84. doi:10.1093/ajcn/80.5.1175 15531663 | Intervention/Exposure
1649 | Mozaffarian, D. The great fat debate: taking the focus off of saturated fat. J Am Diet Assoc. 2011. 111:665–6. doi:10.1016/j.jada.2011.03.030 21515109 | Study Design; Publication Status
1650 | Mueller, C, Masri, B, Hogg, J, Mastrogiacomo, M, Chiu, YL. Carbohydrate- vs fat-controlled diet effect on weight loss and coronary artery disease risk: a pilot feeding study. Nutr Clin Pract. 2010. 25:542–7. doi:10.1177/0884533610379854 20962315 | Intervention/Exposure
1651 | Muhammad, HFL, Vink, RG, Roumans, NJT, Arkenbosch, LAJ, Mariman, EC, van Baak, MA. Dietary Intake after Weight Loss and the Risk of Weight Regain: Macronutrient Composition and Inflammatory Properties of the Diet. Nutrients. 2017. 9:. doi:10.3390/nu9111205 | Intervention/Exposure
1652 | Mulla, UZ, Cooper, R, Mishra, GD, Kuh, D, Stephen, AM. Adult macronutrient intake and physical capability in the MRC national survey of health and development. Age and Ageing. 2013. 42:81–87. doi:10.1093/ageing/afs101 22923606 | Outcome
1653 | Mullie, P, Clarys, P. Relation between dietary pattern analysis (principal component analysis) and body mass index: a 5-year follow-up study in a Belgian military population. J R Army Med Corps. 2016. 162:23–9. doi:10.1136/jramc-2014-000356 25712561 | Power/Size
1654 | Munsters, MJ, Geraedts, MC, Saris, WH. Effects of different protein and glycemic index diets on metabolic profiles and substrate partitioning in lean healthy males. Appl Physiol Nutr Metab. 2013. 38:1107–14. doi:10.1139/apnm-2012-0409 24053517 | Intervention/Exposure; Study duration
1655 | Murakami, K, McCaffrey, TA, Gallagher, AM, Neville, CE, Boreham, CA, Livingstone, MB. Dietary glycemic index and glycemic load in relation to changes in body composition measures during adolescence: Northern Ireland Young Hearts Study. Int J Obes (Lond). 2014. 38:252–8. doi:10.1038/ijo.2013.63 23732655 | Intervention/Exposure
1656 | Muraki, I, Wu, H, Imamura, F, Laden, F, Rimm, EB, Hu, FB, Willett, WC, Sun, Q. Rice consumption and risk of cardiovascular disease: results from a pooled analysis of 3 U.S. cohorts. Am J Clin Nutr. 2015. 101:164–72. doi:10.3945/ajcn.114.087551 25527760 | Intervention/Exposure
1657 | Murphy, K, Davis, C, Knight, A, Bryan, J, Wilson, C, Hodgson, J, Woodman, R. Adherence to a mediterranean diet (MEDDIET) results in improved cardiometabolic health measures and maintained cognitive performance in older australians; Results from the mediterranean diet for cognition and cardiovascular health in the elderly (MEDLEY) trial. Revista espanola de nutricion humana y dietetica. 2016. 20:652-. doi:unavailable | Publication Status
1658 | Murphy, KJ, Parker, B, Dyer, KA, Davis, CR, Coates, AM, Buckley, JD, Howe, PR. A comparison of regular consumption of fresh lean pork, beef and chicken on body composition: a randomized cross-over trial. Nutrients. 2014. 6:682–96. doi:10.3390/nu6020682 24534884 | Intervention/Exposure
1659 | Murrin, CM, Heinen, MM, Kelleher, CC. Are Dietary Patterns of Mothers during Pregnancy Related to Children’s Weight Status? Evidence from the Lifeways Cross- Generational Cohort Study. AIMS Public Health. 2015. 2:274–296. doi:10.3934/publichealth.2015.3.274 29546111 | Study Design
1660 | Mursu, J, Virtanen, JK, Rissanen, TH, Tuomainen, TP, Nykanen, I, Laukkanen, JA, Kortelainen, R, Voutilainen, S. Glycemic index, glycemic load, and the risk of acute myocardial infarction in Finnish men: the Kuopio Ischaemic Heart Disease Risk Factor Study. Nutr Metab Cardiovasc Dis. 2011. 21:144–9. doi:10.1016/j.numecd.2009.08.001 19836217 | Intervention/Exposure
1661 | Mursu, J, Virtanen, JK, Tuomainen, TP, Nurmi, T, Voutilainen, S. Intake of fruit, berries, and vegetables and risk of type 2 diabetes in Finnish men: the Kuopio Ischaemic Heart Disease Risk Factor Study. Am J Clin Nutr. 2014. 99:328–33. doi:10.3945/ajcn.113.069641 24257723 | Intervention/Exposure
1662 | Murtaugh, MA, Appel, LJ, Beasley, JM, Guenther, PM, Greene, T, McFadden, ML, Tooze, JA. Higher levels of sodium density (MG/KCAL) are associated with increased blood pressure independent of absolute sodium (MG): the dash sodium trial. Circulation. 2017. 135:. doi:unavailable | Publication Status
1663 | Murtaza, N, Burke, LM, Vlahovich, N, Charlesson, B, O’ Neill H, Ross, ML, Campbell, KL, Krause, L, Morrison, M. The effects of dietary pattern during intensified training on stool microbiota of elite race walkers. Nutrients. 2019. 11:. doi:10.3390/nu11020261 | Study duration
1664 | Muscogiuri, G, Barrea, L, Di Somma, C, Altieri, B, Vecchiarini, M, Orio, F, Spinosa, T, Colao, A, Savastano, S. Patient empowerment and the Mediterranean diet as a possible tool to tackle prediabetes associated with overweight or obesity: a pilot study. Hormones (Athens). 2019. 18:75–84. doi:10.1007/s42000-018-0090-9 30644069 | Study Design
1665 | Mustafa, J, Ellison, RC, Singer, MR, Bradlee, ML, Kalesan, B, Holick, MF, Moore, LL. Dietary Protein and Preservation of Physical Functioning Among Middle-Aged and Older Adults in the Framingham Offspring Study. Am J Epidemiol. 2018. 187:1411–1419. doi:10.1093/aje/kwy014 29590270 | Intervention/Exposure; Outcome
1666 | Muzio, F, Mondazzi, L, Harris, WS, Sommariva, D, Branchi, A. Effects of moderate variations in the macronutrient content of the diet on cardiovascular disease risk factors in obese patients with the metabolic syndrome. Am J Clin Nutr. 2007. 86:946–51. doi:10.1093/ajcn/86.4.946 17921369 | Intervention/Exposure; Publication Date Overlaps with Existing Review
1667 | Muzio, F, Mondazzi, L, Sommariva, D, Branchi, A. Long-term effects of low-calorie diet on the metabolic syndrome in obese nondiabetic patients. Diabetes Care. 2005. 28:1485–6. doi:10.2337/diacare.28.6.1485 15920073 | Study Design
1668 | Muzsik, A, Bajerska, J, Krzyzanowska, P, Walkowiak, J, Chmurzynska, A. The CED-MED project: the effect of a dietary intervention on inflammatory cytokines and lipid metabolism in women with metabolic syndrome: preliminary results. Annals of nutrition and metabolism. Conference: 12th european nutrition conference, FENS 2015. Berlin germany. Conference start: 20151020. Conference end: 20151023. Conference publication: (var.pagings). 2015. 67:231–232. doi:10.1159/000440895 | Publication Status
1669 | Mytton, OT, Forouhi, NG, Scarborough, P, Lentjes, M, Luben, R, Rayner, M, Khaw, KT, Wareham, NJ, Monsivais, P. Association between intake of less-healthy foods defined by the United Kingdom’s nutrient profile model and cardiovascular disease: A population-based cohort study. PLoS Med. 2018. 15:e1002484. doi:10.1371/journal.pmed.1002484 29300725 | Intervention/Exposure
1670 | Na, L, Han, T, Zhang, W, Wu, X, Na, G, Du, S, Li, Y, Sun, C. A Snack Dietary Pattern Increases the Risk of Hypercholesterolemia in Northern Chinese Adults: A Prospective Cohort Study. PLoS One. 2015. 10:e0134294. doi:10.1371/journal.pone.0134294 26244510 | Country
1671 | Na, W, Yu, TY, Sohn, C. Development of a food-based index of dietary inflammatory potential for Koreans and its relationship with metabolic syndrome. Nutr Res Pract. 2019. 13:150–158. doi:10.4162/nrp.2019.13.2.150 30984359 | Study Design; Intervention/Exposure
1672 | Nabuco, HC, Tomeleri, CM, Junior, PS, Fernandes, RR, Cavalcante, EF, Nunes, JP, Cunha, PF, Dos Santos, L, Cyrino, ES. Effects of higher habitual protein intake on resistance-training-induced changes in body composition and muscular strength in untrained older women: A clinical trial study. Nutr Health. 2019. 25:103–112. doi:10.1177/0260106019838365 30909813 | Intervention/Exposure
1673 | Nagai, Y, Kawanabe, S, Fukuda, H, Tanaka, Y. Changes of body composition after replacing dietary carbohydrate with a protein supplement in overweight Japanese subjects. Journal of diabetes investigation. 2018. 9:44-. doi:10.1111/jdi.12938 28593750 | Publication Status
1674 | Nagata, C, Wada, K, Tsuji, M, Kawachi, T, Nakamura, K. Dietary glycaemic index and glycaemic load in relation to all-cause and cause-specific mortality in a Japanese community: the Takayama study. Br J Nutr. 2014. 112:2010–7. doi:10.1017/s0007114514003109 25327340 | Intervention/Exposure
1675 | Nah, EH, Chu, J, Kim, S, Cho, S, Kwon, E. Efficacy of lifestyle interventions in the reversion to normoglycemia in Korean prediabetics: One-year results from a randomised controlled trial. Primary Care Diabetes. 2019. 13:212–220. doi:10.1016/j.pcd.2018.11.017 30583933 | Intervention/Exposure
1676 | Naja, F, Itani, L, Hwalla, N, Sibai, AM, Kharroubi, SA. Identification of dietary patterns associated with elevated blood pressure among Lebanese men: A comparison of principal component analysis with reduced rank regression and partial least square methods. PLoS One. 2019. 14:e0220942. doi:10.1371/journal.pone.0220942 31419246 | Study Design; Outcome
1677 | Naja, F, Shivappa, N, Nasreddine, L, Kharroubi, S, Itani, L, Hwalla, N, Mehio Sibai, A, Hebert, JR. Role of inflammation in the association between the western dietary pattern and metabolic syndrome among Lebanese adults. Int J Food Sci Nutr. 2017. 68:997–1004. doi:10.1080/09637486.2017.1312297 28420273 | Study Design
1678 | Najjar, RS, Moore, CE, Montgomery, BD. A defined, plant-based diet utilized in an outpatient cardiovascular clinic effectively treats hypercholesterolemia and hypertension and reduces medications. Clinical Cardiology. 2018. 41:307–313. doi:10.1002/clc.22863 29575002 | Study Design
1679 | Najjar, RS, Moore, CE, Montgomery, BD. Consumption of a defined, plant-based diet reduces lipoprotein(a), inflammation, and other atherogenic lipoproteins and particles within 4 weeks. Clin Cardiol. 2018. 41:1062–1068. doi:10.1002/clc.23027 30014498 | Study Design; Study duration
1680 | Nakade, M, Lee, JS, Kawakubo, K, Amano, Y, Mori, K, Akabayashi, A. Correlation between food intake change patterns and body weight loss in middle-aged women in Japan. Obes Res Clin Pract. 2007. 1:I–ii. doi:10.1016/j.orcp.2007.01.001 | Publication Date Overlaps with Existing Review
1681 | Nakamura, Y, Ueshima, H, Okuda, N, Higashiyama, A, Kita, Y, Kadowaki, T, Okamura, T, Murakami, Y, Okayama, A, Choudhury, SR, Rodriguez, B, Curb, JD, Stamler, J. Relation of dietary and other lifestyle traits to difference in serum adiponectin concentration of Japanese in Japan and Hawaii: the INTERLIPID Study. Am J Clin Nutr. 2008. 88:424–30. doi:10.1093/ajcn/88.2.424 18689379 | Study Design; Intervention/Exposure
1682 | Nakamura, Y, Ueshima, H, Okuda, N, Miura, K, Kita, Y, Miyagawa, N, Yoshita, K, Nakagawa, H, Sakata, K, Saitoh, S, Okamura, T, Okayama, A, Choudhry, SR, Rodriguez, B, Masaki, KH, Chan, Q, Elliott, P, Stamler, J. Relationship of three different types of low-carbohydrate diet to cardiometabolic risk factors in a Japanese population: the INTERMAP/INTERLIPID Study. Eur J Nutr. 2016. 55:1515–24. doi:10.1007/s00394-015-0969-z 26119583 | Outcome
1683 | Nanri, A, Mizoue, T, Yoshida, D, Takahashi, R, Takayanagi, R. Dietary patterns and A1C in Japanese men and women. Diabetes Care. 2008. 31:1568–73. doi:10.2337/dc08-0297 18443193 | Study Design
1684 | Nasreddine, L, Akika, R, Mailhac, A, Tamim, H, Zgheib, NK. The Interaction between Genetic Polymorphisms in FTO and TCF7L2 Genes and Dietary Intake with Regard to Body Mass and Composition: An Exploratory Study. J Pers Med. 2019. 9:. doi:10.3390/jpm9010011 | Study Design
1685 | Nation, J, Humphrey, M, MacKay, M, Boneh, A. Linear growth of children on a ketogenic diet: does the protein-to-energy ratio matter?. J Child Neurol. 2014. 29:1496–501. doi:10.1177/0883073813508222 24309243 | Intervention/Exposure; Health Status
1686 | Naumann, E, Plat, J, Mensink, RP. Changes in serum concentrations of noncholesterol sterols and lipoproteins in healthy subjects do not depend on the ratio of plant sterols to stanols in the diet. J Nutr. 2003. 133:2741–7. doi:10.1093/jn/133.9.2741 12949359 | Study duration
1687 | Navas-Carretero, S, Holst, C, Saris, WH, van Baak, MA, Jebb, SA, Kafatos, A, Papadaki, A, Pfeiffer, AF, Handjieva-Darlenska, T, Hlavaty, P, Stender, S, Larsen, TM, Astrup, A, Martinez, JA. The Impact of Gender and Protein Intake on the Success of Weight Maintenance and Associated Cardiovascular Risk Benefits, Independent of the Mode of Food Provision: The DiOGenes Randomized Trial. J Am Coll Nutr. 2016. 35:20–30. doi:10.1080/07315724.2014.948642 25826291 | Intervention/Exposure
1688 | Navas-Carretero, S, Perez-Granados, AM, Schoppen, S, Vaquero, MP. An oily fish diet increases insulin sensitivity compared to a red meat diet in young iron-deficient women. Br J Nutr. 2009. 102:546–53. doi:10.1017/s0007114509220794 19210857 | Study duration
1689 | Navas-Carretero, S, San-Cristobal, R, Livingstone, KM, Celis-Morales, C, Marsaux, CF, Macready, AL, Fallaize, R, O’Donovan, CB, Forster, H, Woolhead, C, Moschonis, G, Lambrinou, CP, Jarosz, M, Manios, Y, Daniel, H, Gibney, ER, Brennan, L, Walsh, MC, Drevon, CA, Gibney, M, Saris, WHM, Lovegrove, JA, Mathers, JC, Martinez, JA. Higher vegetable protein consumption, assessed by an isoenergetic macronutrient exchange model, is associated with a lower presence of overweight and obesity in the web-based Food4me European study. Int J Food Sci Nutr. 2019. 70:240–253. doi:10.1080/09637486.2018.1492524 30049236 | Study Design
1690 | Nazare, JA, Smith, J, Borel, AL, Almeras, N, Tremblay, A, Bergeron, J, Poirier, P, Despres, JP. Changes in both global diet quality and physical activity level synergistically reduce visceral adiposity in men with features of metabolic syndrome. J Nutr. 2013. 143:1074–83. doi:10.3945/jn.113.175273 23719226 | Weight loss/Hypocaloric
1691 | Ndanuko, R, Tapsell, L, Charlton, K, Neale, E, Batterham, M. Dietary patterns associated with blood pressure in a clinical sample of overweight adults volunteering for a weight loss trial. Revista espanola de nutricion humana y dietetica. 2016. 20:460–461. doi:unavailable | Publication Status
1692 | Neacsu, M, Fyfe, C, Horgan, G, Johnstone, AM. Appetite control and biomarkers of satiety with vegetarian (soy) and meat-based high-protein diets for weight loss in obese men: a randomized crossover trial. Am J Clin Nutr. 2014. 100:548–58. doi:10.3945/ajcn.113.077503 24944057 | Study duration
1693 | Negele, L, Schneider, B, Ristl, R, Stulnig, TM, Willfort-Ehringer, A, Helk, O, Widhalm, K. Effect of a low-fat diet enriched either with rapeseed oil or sunflower oil on plasma lipoproteins in children and adolescents with familial hypercholesterolaemia. Results of a pilot study. Eur J Clin Nutr. 2015. 69:337–43. doi:10.1038/ejcn.2014.234 25424602 | Intervention/Exposure
1694 | Neri-Sanchez, M, Martinez-Carrillo, BE, Valdes-Ramos, R, Soto-Pina, AE, Vargas-Hernandez, JA, Benitez-Arciniega, AD. Dietary patterns, central obesity and serum lipids concentration in Mexican adults. Nutr Hosp. 2019. 36:109–117. doi:10.20960/nh.2002 30834763 | Power/Size
1695 | Ness, AR, Powles, JW. The role of diet, fruit and vegetables and antioxidants in the Aetiology of stroke. European Journal of Preventive Cardiology. 2014. 6:229–234. doi:10.1177/204748739900600407 | Study Design; Publication Date
1696 | Nettleton, JA, Follis, JL, Ngwa, JS, Smith, CE, Ahmad, S, Tanaka, T, Wojczynski, MK, Voortman, T, Lemaitre, RN, Kristiansson, K, Nuotio, ML, Houston, DK, Perälä, MM, Qi, Q, Sonestedt, E, Manichaikul, A, Kanoni, S, Ganna, A, Mikkilä, V, North, KE, Siscovick, DS, Harald, K, McKeown, NM, Johansson, I, Rissanen, H, Liu, Y, Lahti, J, Hu, FB, Bandinelli, S, Rukh, G, Rich, S, Booij, L, Dmitriou, M, Ax, E, Raitakari, O, Mukamal, K, Männistö, S, Hallmans, G, Jula, A, Ericson, U, Jacobs, DR, J AVanRooijF, Deloukas, P, Sjögren, P, Kähönen, M, Djousse, L, Perola, M, Barroso, I, Hofman, A, Stirrups, K, Viikari, J, Uitterlinden, AG, Kalafati, IP, Franco, OH, Mozaffarian, D, Salomaa, V, Borecki, IB, Knekt, P, Kritchevsky, SB, Eriksson, JG, Dedoussis, GV, Qi, L, Ferrucci, L, Orho-Melander, M, Carola Zillikens, M, Ingelsson, E, Lehtimäki, T, Renström, F, Adrienne Cupples, L, Loos, RJ, Franks, PW. Gene × dietary pattern interactions in obesity: Analysis of up to 68 317 adults of European ancestry. Human Molecular Genetics. 2015. 24:4728–4738. doi:10.1093/hmg/ddv186 25994509 | Study Design; Intervention/Exposure
1697 | Nettleton, JA, Polak, JF, Tracy, R, Burke, GL, Jacobs, DR, Jr. Dietary patterns and incident cardiovascular disease in the Multi-Ethnic Study of Atherosclerosis. Am J Clin Nutr. 2009. 90:647–54. doi:10.3945/ajcn.2009.27597 19625679 | Publication Date Overlaps with Existing Review
1698 | Nettleton, JA, Rock, CL, Wang, Y, Jenny, NS, Jacobs, DR. Associations between dietary macronutrient intake and plasma lipids demonstrate criterion performance of the Multi-Ethnic Study of Atherosclerosis (MESA) food-frequency questionnaire. Br J Nutr. 2009. 102:1220–7. doi:10.1017/s0007114509382161 19454126 | Study Design
1699 | Nettleton, JA, Schulze, MB, Jiang, R, Jenny, NS, Burke, GL, Jacobs Jr, DR. A priori-defined dietary patterns and markers of cardiovascular disease risk in the Multi-Ethnic Study of Atherosclerosis (MESA). American Journal of Clinical Nutrition. 2008. 88:185–194. doi:unavailable | Publication Date Overlaps with Existing Review
1700 | Nettleton, JA, Steffen, LM, Mayer-Davis, EJ, Jenny, NS, Jiang, R, Herrington, DM, Jacobs, DR, Jr. Dietary patterns are associated with biochemical markers of inflammation and endothelial activation in the Multi-Ethnic Study of Atherosclerosis (MESA). Am J Clin Nutr. 2006. 83:1369–79. doi:10.1093/ajcn/83.6.1369 16762949 | Outcome
1701 | Nettleton, JA, Steffen, LM, Ni, H, Liu, K, Jacobs, DR, Jr. Dietary patterns and risk of incident type 2 diabetes in the Multi-Ethnic Study of Atherosclerosis (MESA). Diabetes Care. 2008. 31:1777–82. doi:10.2337/dc08-0760 18544792 | Publication Date Overlaps with Existing Review
1702 | Neuhouser, ML, Howard, B, Lu, J, Tinker, LF, Van Horn, L, Caan, B, Rohan, T, Stefanick, ML, Thomson, CA. A low-fat dietary pattern and risk of metabolic syndrome in postmenopausal women: the Women’s Health Initiative. Metabolism. 2012. 61:1572–81. doi:10.1016/j.metabol.2012.04.007 22633601 | Publication Date Overlaps with Existing Review
1703 | Newton, AL, Hanks, LJ, Ashraf, AP, Williams, E, Davis, M, Casazza, K. Macronutrient intake influences the effect of 25-hydroxy-vitamin d status on metabolic syndrome outcomes in african american girls. Cholesterol. 2012. 2012:581432. doi:10.1155/2012/581432 22792449 | Study duration
1704 | Nguo, K, Bonham, MP, Truby, H, Barber, E, Brown, J, Huggins, CE. Effect of Macronutrient Composition on Appetite Hormone Responses in Adolescents with Obesity. Nutrients. 2019. 11:. doi:10.3390/nu11020340 | Study duration
1705 | Nguyen, BT, Shuval, K, Bertmann, F, Yaroch, AL. The Supplemental Nutrition Assistance Program, Food Insecurity, Dietary Quality, and Obesity Among U.S. Adults. Am J Public Health. 2015. 105:1453–9. doi:10.2105/ajph.2015.302580 25973830 | Study Design
1706 | Nichols, SD, Francis, MP, Dalrymple, N. Sustainability of a Curriculum-based Intervention on Dietary Behaviours and Physical Activity among Primary School Children in Trinidad and Tobago. West Indian Med J. 2014. 63:68–77. doi:10.7727/wimj.2014.011 25303198 | Intervention/Exposure
1707 | Nicklas, J, Sacks, F, Smith, S, LeBoff, M, Rood, J, Bray, G, Ridker, P. Effect of macronutrient composition of weight loss diets on reduction of the inflammatory marker hsCRP. BMC complementary and alternative medicine. 2012. 12:. doi:unavailable | Publication Status
1708 | Nicklas, JM, Sacks, FM, Smith, SR, LeBoff, MS, Rood, JC, Bray, GA, Ridker, PM. Effect of dietary composition of weight loss diets on high-sensitivity c-reactive protein: the Randomized POUNDS LOST trial. Obesity (Silver Spring). 2013. 21:681–9. doi:10.1002/oby.20072 23712970 | Weight loss/Hypocaloric
1709 | Nicklas, TA, Dwyer, J, Feldman, HA, Luepker, RV, Kelder, SH, Nader, PR. Serum cholesterol levels in children are associated with dietary fat and fatty acid intake. J Am Diet Assoc. 2002. 102:511–7. doi:10.1016/s0002-8223(02)90117-3 11985407 | Intervention/Exposure
1710 | Nickols-Richardson, SM, Coleman, MD, Volpe, JJ, Hosig, KW. Perceived hunger is lower and weight loss is greater in overweight premenopausal women consuming a low-carbohydrate/high-protein vs high-carbohydrate/low-fat diet. J Am Diet Assoc. 2005. 105:1433–7. doi:10.1016/j.jada.2005.06.025 16129086 | Outcome; Study duration
1711 | Nickols-Richardson, SM, Piehowski, KE, Metzgar, CJ, Miller, DL, Preston, AG. Changes in body weight, blood pressure and selected metabolic biomarkers with an energy-restricted diet including twice daily sweet snacks and once daily sugar-free beverage. Nutr Res Pract. 2014. 8:695–704. doi:10.4162/nrp.2014.8.6.695 25489410 | Intervention/Exposure
1712 | Niemczyk, NA. Low-carbohydrate versus low-fat diet: A randomized clinical trial. Journal of Midwifery and Women’s Health. 2015. 60:104–105. doi:10.1111/jmwh.12281_1 | Study Design; Publication Status
1713 | Niinikoski, H, Jula, A, Viikari, J, Ronnemaa, T, Heino, P, Lagstrom, H, Jokinen, E, Simell, O. Blood pressure is lower in children and adolescents with a low-saturated-fat diet since infancy: the special turku coronary risk factor intervention project. Hypertension. 2009. 53:918–24. doi:10.1161/hypertensionaha.109.130146 19364991 | Intervention/Exposure
1714 | Niinikoski, H, Pahkala, K, Viikari, J, Ronnemaa, T, Jula, A, Lagstrom, H, Simell, O, Raitakari, OT. The STRIP Study: long-Term Impact of a Low Saturated Fat/Low Cholesterol Diet. Current cardiovascular risk reports. 2014. 8:1–7. doi:10.1007/s12170-014-0410-9 | Study Design; Publication Status
1715 | Nilholm, C, Roth, B, Hoglund, P, Blennow, K, Englund, E, Hansson, O, Zetterberg, H, Ohlsson, B. Dietary intervention with an Okinawan-based Nordic diet in type 2 diabetes renders decreased interleukin-18 concentrations and increased neurofilament light concentrations in plasma. Nutr Res. 2018. 60:13–25. doi:10.1016/j.nutres.2018.08.002 30527256 | Study Design; Study duration; Health Status
1716 | Nilsson, A, Montiel Rojas, D, Kadi, F. Impact of Meeting Different Guidelines for Protein Intake on Muscle Mass and Physical Function in Physically Active Older Women. Nutrients. 2018. 10:. doi:10.3390/nu10091156 | Study Design
1717 | Niswender, K, Piletic, M, Andersen, H, Conradsen Hiort, L, Hollander, P. Weight change upon once-daily initiation of insulin detemir with or without dietary intervention in overweight or obese insulin-naïve individuals with type 2 diabetes: results from the DIET trial. Diabetes, obesity & metabolism. 2014. 16:186–192. doi:10.1111/dom.12218 | Intervention/Exposure; Health Status
1718 | Niswender, KD, Fazio, S, Gower, BA, Silver, HJ. Balanced high fat diet reduces cardiovascular risk in obese women although changes in adipose tissue, lipoproteins, and insulin resistance differ by race. Metabolism. 2018. 82:125–134. doi:10.1016/j.metabol.2018.01.020 29382504 | Study Design; Comparator
1719 | Niu, K, Momma, H, Kobayashi, Y, Guan, L, Chujo, M, Otomo, A, Ouchi, E, Nagatomi, R. The traditional Japanese dietary pattern and longitudinal changes in cardiovascular disease risk factors in apparently healthy Japanese adults. Eur J Nutr. 2016. 55:267–79. doi:10.1007/s00394-015-0844-y 25648737 | Power/Size
1720 | Nizamuddin, J, Turner, Z, Rubenstein, JE, Pyzik, PL, Kossoff, EH. Management and risk factors for dyslipidemia with the ketogenic diet. J Child Neurol. 2008. 23:758–61. doi:10.1177/0883073808318061 18658075 | Health Status
1721 | Njike, VY, Ayettey, R, Petraro, P, Treu, JA, Katz, DL. Walnut ingestion in adults at risk for diabetes: effects on body composition, diet quality, and cardiac risk measures. BMJ Open Diabetes Res Care. 2015. 3:e000115. doi:10.1136/bmjdrc-2015-000115 | Intervention/Exposure
1722 | Noakes, M, Foster, PR, Keogh, JB, James, AP, Mamo, JC, Clifton, PM. Comparison of isocaloric very low carbohydrate/high saturated fat and high carbohydrate/low saturated fat diets on body composition and cardiovascular risk. Nutr Metab (Lond). 2006. 3:7. doi:10.1186/1743-7075-3-7 16403234 | Study duration
1723 | Noakes, M, Keogh, JB, Foster, PR, Clifton, PM. Effect of an energy-restricted, high-protein, low-fat diet relative to a conventional high-carbohydrate, low-fat diet on weight loss, body composition, nutritional status, and markers of cardiovascular health in obese women. Am J Clin Nutr. 2005. 81:1298–306. doi:10.1093/ajcn/81.6.1298 15941879 | Weight loss/Hypocaloric
1724 | Noakes, TD. Low-carbohydrate and high-fat intake can manage obesity and associated conditions: occasional survey. S Afr Med J. 2013. 103:826–30. doi:10.7196/samj.7302 24148165 | Study Design; Publication Status
1725 | Noakes, TD. The Women’s Health Initiative Randomized Controlled Dietary Modification Trial: an inconvenient finding and the diet-heart hypothesis. S Afr Med J. 2013. 103:824–5. doi:10.7196/samj.7343 24148164 | Study Design; Publication Status
1726 | Nobili, V, Liccardo, D, Bedogni, G, Salvatori, G, Gnani, D, Bersani, I, Alisi, A, Valenti, L, Raponi, M. Influence of dietary pattern, physical activity, and I148M PNPLA3 on steatosis severity in at-risk adolescents. Genes Nutr. 2014. 9:392. doi:10.1007/s12263-014-0392-8 24627307 | Study Design; Intervention/Exposure; Outcome
1727 | Noel, SE, Newby, PK, Ordovas, JM, Tucker, KL. Adherence to an (n-3) fatty acid/fish intake pattern is inversely associated with metabolic syndrome among Puerto Rican adults in the Greater Boston area. J Nutr. 2010. 140:1846–54. doi:10.3945/jn.110.124297 20702744 | Intervention/Exposure
1728 | Noll, C, Kunach, M, Frisch, F, Bouffard, L, Dubreuil, S, Jean-Denis, F, Phoenix, S, Cunnane, SC, Guerin, B, Turcotte, EE, Carpentier, AC. Seven-Day Caloric and Saturated Fat Restriction Increases Myocardial Dietary Fatty Acid Partitioning in Impaired Glucose-Tolerant Subjects. Diabetes. 2015. 64:3690–9. doi:10.2337/db15-0337 26224886 | Study duration
1729 | Norman, A, Zeebari, Z, Nyberg, G, Elinder, LS. Parental support in promoting children’s health behaviours and preventing overweight and obesity - a long-term follow-up of the cluster-randomised healthy school start study II trial. BMC Pediatr. 2019. 19:104. doi:10.1186/s12887-019-1467-x 30975106 | Intervention/Exposure; Outcome
1730 | Norouzy, A, Salehi, M, Philippou, E, Arabi, H, Shiva, F, Mehrnoosh, S, Mohajeri, SM, Mohajeri, SA, Motaghedi Larijani, A, Nematy, M. Effect of fasting in Ramadan on body composition and nutritional intake: a prospective study. J Hum Nutr Diet. 2013. 26 Suppl 1:97–104. doi:10.1111/jhn.12042 23679071 | Intervention/Exposure; Comparator
1731 | Nosova, EV, Bartel, K, Chong, KC, Alley, HF, Conte, MS, Owens, CD, Grenon, SM. Analysis of nutritional habits and intake of polyunsaturated fatty acids in veterans with peripheral arterial disease. Vasc Med. 2015. 20:432–8. doi:10.1177/1358863x15591088 26129736 | Study Design; Health Status
1732 | Novotny, R, Nigg, CR, Li, F, Wilkens, LR. Pacific kids DASH for health (PacDASH) randomized, controlled trial with DASH eating plan plus physical activity improves fruit and vegetable intake and diastolic blood pressure in children. Child Obes. 2015. 11:177–86. doi:10.1089/chi.2014.0141 25671796 | Intervention/Exposure
1733 | Nowlin, SY, Cleland, CM, Vadiveloo, M, D’Eramo Melkus, G, Parekh, N, Hagan, H. Explaining Racial/Ethnic Dietary Patterns in Relation to Type 2 Diabetes: An Analysis of NHANES 2007-2012. Ethn Dis. 2016. 26:529–536. doi:10.18865/ed.26.4.529 27773980 | Study Design
1734 | Nowson, CA, Wattanapenpaiboon, N, Pachett, A. Low-sodium Dietary Approaches to Stop Hypertension-type diet including lean red meat lowers blood pressure in postmenopausal women. Nutr Res. 2009. 29:8–18. doi:10.1016/j.nutres.2008.12.002 19185772 | Intervention/Exposure; Publication Date Overlaps with Existing Review
1735 | Nowson, CA, Worsley, A, Margerison, C, Jorna, MK, Frame, AG, Torres, SJ, Godfrey, SJ. Blood pressure response to dietary modifications in free-living individuals. J Nutr. 2004. 134:2322–9. doi:10.1093/jn/134.9.2322 15333723 | Intervention/Exposure
1736 | Nowson, CA, Worsley, A, Margerison, C, Jorna, MK, Godfrey, SJ, Booth, A. Blood pressure change with weight loss is affected by diet type in men. Am J Clin Nutr. 2005. 81:983–9. doi:10.1093/ajcn/81.5.983 15883419 | Intervention/Exposure
1737 | Numao, S, Kawano, H, Endo, N, Yamada, Y, Konishi, M, Takahashi, M, Sakamoto, S. Short-term low carbohydrate/high-fat diet intake increases postprandial plasma glucose and glucagon-like peptide-1 levels during an oral glucose tolerance test in healthy men. Eur J Clin Nutr. 2012. 66:926–31. doi:10.1038/ejcn.2012.58 22669333 | Study duration
1738 | Nurkkala, M, Kaikkonen, K, Vanhala, ML, Karhunen, L, Keranen, AM, Korpelainen, R. Lifestyle intervention has a beneficial effect on eating behavior and long-term weight loss in obese adults. Eat Behav. 2015. 18:179–85. doi:10.1016/j.eatbeh.2015.05.009 26112229 | Intervention/Exposure
1739 | Nykanen, T, Pihlainen, K, Santtila, M, Vasankari, T, Fogelholm, M, Kyrolainen, H. Diet Macronutrient Composition, Physical Activity, and Body Composition in Soldiers During 6 Months Deployment. Mil Med. 2019. 184:e231–e237. doi:10.1093/milmed/usy232 30215796 | Intervention/Exposure
1740 | Nymo, S, Coutinho, SR, Jorgensen, J, Rehfeld, JF, Truby, H, Kulseng, B, Martins, C. Timeline of changes in appetite during weight loss with a ketogenic diet. Int J Obes (Lond). 2017. 41:1224–1231. doi:10.1038/ijo.2017.96 28439092 | Study Design
1741 | Oba, S, Nagata, C, Nakamura, K, Fujii, K, Kawachi, T, Takatsuka, N, Shimizu, H. Dietary glycemic index, glycemic load, and intake of carbohydrate and rice in relation to risk of mortality from stroke and its subtypes in Japanese men and women. Metabolism. 2010. 59:1574–82. doi:10.1016/j.metabol.2010.02.004 20303126 | Intervention/Exposure; Comparator
1742 | Oba, S, Nanri, A, Kurotani, K, Goto, A, Kato, M, Mizoue, T, Noda, M, Inoue, M, Tsugane, S. Dietary glycemic index, glycemic load and incidence of type 2 diabetes in Japanese men and women: the Japan Public Health Center-based Prospective Study. Nutr J. 2013. 12:165. doi:10.1186/1475-2891-12-165 24370346 | Intervention/Exposure
1743 | Obarzanek, E, Sacks, FM, Vollmer, WM, Bray, GA, Miller, ER, 3rd, Lin, PH, Karanja, NM, Most-Windhauser, MM, Moore, TJ, Swain, JF, Bales, CW, Proschan, MA. Effects on blood lipids of a blood pressure-lowering diet: the Dietary Approaches to Stop Hypertension (DASH) Trial. Am J Clin Nutr. 2001. 74:80–9. doi:10.1093/ajcn/74.1.80 11451721 | Publication Date Overlaps with Existing Review
1744 | O’Brien, KD, Brehm, BJ, Seeley, RJ, Bean, J, Wener, MH, Daniels, S, D’Alessio, DA. Diet-induced weight loss is associated with decreases in plasma serum amyloid a and C-reactive protein independent of dietary macronutrient composition in obese subjects. J Clin Endocrinol Metab. 2005. 90:2244–9. doi:10.1210/jc.2004-1011 15671108 | Intervention/Exposure
1745 | O’Brien, KM, Hutchesson, MJ, Jensen, M, Morgan, P, Callister, R, Collins, CE. Participants in an online weight loss program can improve diet quality during weight loss: a randomized controlled trial. Nutr J. 2014. 13:82. doi:10.1186/1475-2891-13-82 25108506 | Intervention/Exposure; Outcome
1746 | O’Connor, LE, Biberstine, SL, Paddon-Jones, D, Schwichtenberg, AJ, Campbell, WW. Adopting a Mediterranean-Style Eating Pattern with Different Amounts of Lean Unprocessed Red Meat Does Not Influence Short-Term Subjective Personal Well-Being in Adults with Overweight or Obesity. J Nutr. 2018. 148:1917–1923. doi:10.1093/jn/nxy235 30517731 | Outcome; Study duration
1747 | O’Connor, LE, Li, J, Sayer, RD, Hennessy, JE, Campbell, WW. Short-Term Effects of Healthy Eating Pattern Cycling on Cardiovascular Disease Risk Factors: Pooled Results from Two Randomized Controlled Trials. Nutrients. 2018. 10:. doi:10.3390/nu10111725 | Study duration
1748 | O’Connor, LE, Paddon-Jones, D, Wright, AJ, Campbell, WW. A Mediterranean-style eating pattern with lean, unprocessed red meat has cardiometabolic benefits for adults who are overweight or obese in a randomized, crossover, controlled feeding trial. Am J Clin Nutr. 2018. 108:33–40. doi:10.1093/ajcn/nqy075 29901710 | Intervention/Exposure; Outcome
1749 | O’Connor, LE, Wright, AJ, Paddon-Jones, D, Campbell, WW. Daily red meat intake does not affect improvements in cardiovascular disease risk factors induced by consuming the USDA’s Healthy Mediterranean-Style Eating Pattern. FASEB journal. 2017. 31:. doi:unavailable | Publication Status
1750 | Oddy, WH, Allen, KL, Trapp, GSA, Ambrosini, GL, Black, LJ, Huang, RC, Rzehak, P, Runions, KC, Pan, F, Beilin, LJ, Mori, TA. Dietary patterns, body mass index and inflammation: Pathways to depression and mental health problems in adolescents. Brain Behav Immun. 2018. 69:428–439. doi:10.1016/j.bbi.2018.01.002 29339318 | Power/Size
1751 | O’Doherty, MG, Skidmore, PM, Young, IS, McKinley, MC, Cardwell, C, Yarnell, JW, Gey, FK, Evans, A, Woodside, JV. Dietary patterns and smoking in Northern Irish men: a population at high risk of coronary heart disease. Int J Vitam Nutr Res. 2011. 81:21–33. doi:10.1024/0300-9831/a000047 22002215 | Study Design
1752 | Oellingrath, IM, Svendsen, MV. BMI-specific associations between health-related behaviours and overweight - a longitudinal study among Norwegian adolescents. Public Health Nutr. 2017. 20:481–491. doi:10.1017/s1368980016002536 27652897 | Power/Size
1753 | Oh, C, No, JK, Kim, HS. Dietary pattern classifications with nutrient intake and body composition changes in Korean elderly. Nutr Res Pract. 2014. 8:192–7. doi:10.4162/nrp.2014.8.2.192 24741404 | Study Design
1754 | Oh, SM, Kim, HC, Rhee, Y, Park, SJ, Lee, HJ, Suh, I, Feskanich, D. Dietary protein in relation to bone stiffness index and fat-free mass in a population consuming relatively low protein diets. J Bone Miner Metab. 2013. 31:433–41. doi:10.1007/s00774-013-0427-z 23420299 | Study Design
1755 | Oh, SY, Ahn, H, Chang, N, Kang, MH, Oh J V. Dietary patterns and weight status associated with behavioural problems in young children. Public Health Nutr. 2014. 17:2563–9. doi:10.1017/s1368980013002917 24182449 | Study Design
1756 | Ojeda Rodriguez, A, Zazpe, I, Morell Azanza, L, Chueca, M, Azcona Sanjulian, M, Marti, A. Improved vitamin D adequacy and its associations with diet quality indices in a lifestyle intervention of children and adolescents with abdominal obesity. Obesity facts. 2019. 12:112-. doi:10.1159/000489691 | Publication Status
1757 | Ojeda-Brito, R, Brito-Ojeda, M, Ruano, C, Nissensonh, M, Ruiz-Caballero, J, Serra-Majem, L. Drinking habits in a sample of university students. Relationship between the adherence to the Mediterranean Diet and BMI. Nutr Hosp. 2015. 32 Suppl 2:10326. doi:10.3305/nh.2015.32.sup2.10326 26615296 | Study Design
1758 | Ojeda-Rodriguez, A, Zazpe, I, Morell-Azanza, L, Chueca, MJ, Azcona-Sanjulian, MC, Marti, A. Improved Diet Quality and Nutrient Adequacy in Children and Adolescents with Abdominal Obesity after a Lifestyle Intervention. Nutrients. 2018. 10:. doi:10.3390/nu10101500 | Intervention/Exposure
1759 | Okekunle, AP, Wu, X, Feng, R, Li, Y, Sun, C. Higher intakes of energy-adjusted dietary amino acids are inversely associated with obesity risk. Amino Acids. 2019. 51:373–382. doi:10.1007/s00726-018-2672-x 30377838 | Study Design
1760 | Okita, K, Takada, S, Kinugawa, S. Very low-carbohydrate diet can effectively reduce weight without deterioration in physical fitness. Journal of the hong kong college of cardiology. 2016. 24:A32-. doi:unavailable | Publication Status
1761 | Okuda, N, Miura, K, Okayama, A, Okamura, T, Abbott, RD, Nishi, N, Fujiyoshi, A, Kita, Y, Nakamura, Y, Miyagawa, N, Hayakawa, T, Ohkubo, T, Kiyohara, Y, Ueshima, H. Fruit and vegetable intake and mortality from cardiovascular disease in Japan: a 24-year follow-up of the NIPPON DATA80 Study. Eur J Clin Nutr. 2015. 69:482–8. doi:10.1038/ejcn.2014.276 25585600 | Intervention/Exposure
1762 | Oliveira, A, Jones, L, de Lauzon-Guillain, B, Emmett, P, Moreira, P, Charles, MA, Lopes, C. Early problematic eating behaviours are associated with lower fruit and vegetable intake and less dietary variety at 4-5 years of age. A prospective analysis of three European birth cohorts. Br J Nutr. 2015. 114:763–71. doi:10.1017/s0007114515002287 26195187 | Study Design
1763 | Oliveira, C, Boule, N, Sharma, AM, Elliott, S, Ghosh, S, Siervo, M, Prado, C. The impact of a high-protein diet on energy expenditure and substrate oxidation: preliminary findings of a randomized, controlled, cross-over trial. Obesity facts. 2018. 11:308-. doi:10.1159/000489691 | Publication Status
1764 | O’Neal, EK, Smith, AF, Heatherly, AJ, Killen, LG, Waldman, HS, Hollingsworth, A, Koh, Y. Effects of a 3-week High-FatLow-Carbohydrate Diet on Lipid and Glucose Profiles in Experienced, Middle-age Male Runners. Int J Exerc Sci. 2019. 12:786–799. doi:unavailable31156745 | Study duration
1765 | O’Neil, A, Shivappa, N, Jacka, FN, Kotowicz, MA, Kibbey, K, Hebert, JR, Pasco, JA. Pro-inflammatory dietary intake as a risk factor for CVD in men: a 5-year longitudinal study. Br J Nutr. 2015. 114:2074–82. doi:10.1017/s0007114515003815 26450630 | Intervention/Exposure
1766 | O’Neil, CE, Nicklas, TA, Fulgoni, VL, 3rd. Nutrient Intake, Diet Quality, and Weight Measures in Breakfast Patterns Consumed by Children Compared with Breakfast Skippers: NHANES 2001-2008. AIMS Public Health. 2015. 2:441–468. doi:10.3934/publichealth.2015.3.441 29546119 | Study Design; Intervention/Exposure
1767 | Ooi, EM, Adams, LA, Zhu, K, Lewis, JR, Kerr, DA, Meng, X, Solah, V, Devine, A, Binns, CW, Prince, RL. Consumption of a whey protein-enriched diet may prevent hepatic steatosis associated with weight gain in elderly women. Nutr Metab Cardiovasc Dis. 2015. 25:388–95. doi:10.1016/j.numecd.2014.11.005 25638597 | Intervention/Exposure
1768 | Ooi, EM, Lichtenstein, AH, Millar, JS, Diffenderfer, MR, Lamon-Fava, S, Rasmussen, H, Welty, FK, Barrett, PH, Schaefer, EJ. Effects of Therapeutic Lifestyle Change diets high and low in dietary fish-derived FAs on lipoprotein metabolism in middle-aged and elderly subjects. J Lipid Res. 2012. 53:1958–67. doi:10.1194/jlr.P024315 22773687 | Intervention/Exposure; Outcome
1769 | Oomen, CM, Feskens, EJ, Rasanen, L, Fidanza, F, Nissinen, AM, Menotti, A, Kok, FJ, Kromhout, D. Fish consumption and coronary heart disease mortality in Finland, Italy, and The Netherlands. Am J Epidemiol. 2000. 151:999–1006. doi:10.1093/oxfordjournals.aje.a010144 10853639 | Intervention/Exposure
1770 | Oppitz, IN, Cesar, JA, Neumann, NA. Overweight among children under five years of age in municipalities of the semiarid region. Rev Bras Epidemiol. 2014. 17:860–72. doi:unavailable25388487 | Study Design; Intervention/Exposure
1771 | Oranta, O, Pahkala, K, Ruottinen, S, Niinikoski, H, Lagstrom, H, Viikari, JS, Jula, A, Loo, BM, Simell, O, Ronnemaa, T, Raitakari, OT. Infancy-onset dietary counseling of low-saturated-fat diet improves insulin sensitivity in healthy adolescents 15-20 years of age: the Special Turku Coronary Risk Factor Intervention Project (STRIP) study. Diabetes Care. 2013. 36:2952–9. doi:10.2337/dc13-0361 23801725 | Intervention/Exposure
1772 | Ortega, JF, Fernandez-Elias, VE, Hamouti, N, Mora-Rodriguez, R. Increased blood cholesterol after a high saturated fat diet is prevented by aerobic exercise training. Appl Physiol Nutr Metab. 2013. 38:42–8. doi:10.1139/apnm-2012-0123 23368827 | Study duration
1773 | Ortega, RM, Rodríguez-Rodríguez, E, Aparicio, A, Marín-Arias, LI, López-Sobaler, AM. Responses to two weight-loss programs based on approximating the diet to the ideal: Differences associated with increased cereal or vegetable consumption. International Journal for Vitamin and Nutrition Research. 2006. 76:367–376. doi:10.1024/0300-9831.76.6.367 17607956 | Intervention/Exposure
1774 | Ortega-Azorin, C, Sorli, JV, Estruch, R, Asensio, EM, Coltell, O, Gonzalez, JI, Martinez-Gonzalez, MA, Ros, E, Salas-Salvado, J, Fito, M, Aros, F, Lapetra, J, Serra-Majem, L, Ruiz-Gutierrez, V, Gomez-Gracia, E, Fiol, M, Flores, G, Pinto, X, Saiz, C, Ordovas, JM, Corella, D. Amino acid change in the carbohydrate response element binding protein is associated with lower triglycerides and myocardial infarction incidence depending on level of adherence to the Mediterranean diet in the PREDIMED trial. Circ Cardiovasc Genet. 2014. 7:49–58. doi:10.1161/circgenetics.113.000301 24448738 | Intervention/Exposure
1775 | Oshakbayev, K, Dukenbayeva, B, Otarbayev, N, Togizbayeva, G, Tabynbayev, N, Gazaliyeva, M, Idrisov, A, Oshakbayev, P. Weight loss therapy for clinical management of patients with some atherosclerotic diseases: a randomized clinical trial. Nutr J. 2015. 14:120. doi:10.1186/s12937-015-0108-y 26608649 | Intervention/Exposure; Health Status
1776 | Osterberg, KL, Boutagy, NE, McMillan, RP, Stevens, JR, Frisard, MI, Kavanaugh, JW, Davy, BM, Davy, KP, Hulver, MW. Probiotic supplementation attenuates increases in body mass and fat mass during high-fat diet in healthy young adults. Obesity (Silver Spring). 2015. 23:2364–70. doi:10.1002/oby.21230 26466123 | Study duration
1777 | Osterdahl, M, Kocturk, T, Koochek, A, Wandell, PE. Effects of a short-term intervention with a paleolithic diet in healthy volunteers. Eur J Clin Nutr. 2008. 62:682–5. doi:10.1038/sj.ejcn.1602790 17522610 | Study duration
1778 | Otten, J, Mellberg, C, Ryberg, M, Sandberg, S, Kullberg, J, Lindahl, B, Larsson, C, Hauksson, J, Olsson, T. Strong and persistent effect on liver fat with a Paleolithic diet during a two-year intervention. Int J Obes (Lond). 2016. 40:747–53. doi:10.1038/ijo.2016.4 26786351 | Intervention/Exposure
1779 | Otten, J, Ryberg, M, Mellberg, C, Lindahl, B, Larsson, C, Juul Holst, J, Olsson, T. Weight loss by two different diets increases the postprandial response of GLP-1 but only the Paleolithic diet increases the postprandial response of GIP. Diabetologia. 2017. 60:S233-. doi:10.1007/s00125-017-4350-z | Publication Status
1780 | Ozawa, M, Yoshida, D, Hata, J, Ohara, T, Mukai, N, Shibata, M, Uchida, K, Nagata, M, Kitazono, T, Kiyohara, Y, Ninomiya, T. Dietary Protein Intake and Stroke Risk in a General Japanese Population: The Hisayama Study. Stroke. 2017. 48:1478–1486. doi:10.1161/strokeaha.116.016059 28487340 | Intervention/Exposure
1781 | Padin, AC, Hebert, JR, Woody, A, Wilson, SJ, Shivappa, N, Belury, MA, Malarkey, WB, Sheridan, JF, Kiecolt-Glaser, JK. A proinflammatory diet is associated with inflammatory gene expression among healthy, non-obese adults: Can social ties protect against the risks?. Brain Behav Immun. 2019. 82:36–44. doi:10.1016/j.bbi.2019.07.031 31356923 | Study Design; Intervention/Exposure
1782 | Padwal, R. The Atkins diet led to more weight loss than the Zone diet in overweight and obese premenopausal women at 12 months. Evidence-based medicine. 2007. 12:138-. doi:10.1136/ebm.12.5.138 17909229 | Publication Status
1783 | Pagliai, G, Dinu, M, Cesari, F, Gori, AM, Giusti, B, Marcucci, R, Casini, A, Sofi, F. Randomized controlled dietary intervention trial comparing mediterranean and vegetarian diets for cardiovascular prevention: preliminary results. European heart journal. 2016. 37:340-. doi:10.1093/eurheartj/ehw432 | Publication Status
1784 | Pagliai, G, Dinu, M, Mangino, A, Cesari, F, Giusti, B, Gori, AM, Marcucci, R, Casini, A, Sofi, F. Comparison between mediterranean and vegetarian diets for cardiovascular prevention: the cardiveg study. Nutrition, metabolism and cardiovascular diseases. 2017. 27:e30–e31. doi:10.1016/j.numecd.2016.11.084 | Study Design; Publication Status
1785 | Pagliai, G, Russo, E, Baldi, S, Dinu, M, Bartolucci, G, Niccolai, E, Nannini, G, Casini, A, Amedei, A, Sofi, F. Impact of mediterranean vs vegetarian diets on gut microbiota and short chain fatty acids: the CARDIntervention/ExposureG study. Nutrition, metabolism and cardiovascular diseases. 2019. 29:879-. doi:10.1016/j.numecd.2019.05.032 | Publication Status
1786 | Paineau, D, Beaufils, F, Boulier, A, Cassuto, DA, Chwalow, J, Combris, P, Couet, C, Jouret, B, Lafay, L, Laville, M, Mahe, S, Ricour, C, Romon, M, Simon, C, Tauber, M, Valensi, P, Chapalain, V, Zourabichvili, O, Bornet, FR. The cumulative effect of small dietary changes may significantly improve nutritional intakes in free-living children and adults. Eur J Clin Nutr. 2010. 64:782–91. doi:10.1038/ejcn.2010.78 20502471 | Intervention/Exposure; Outcome
1787 | Palacios, C, Torres, M, Lopez, D, Trak-Fellermeier, MA, Coccia, C, Perez, CM. Effectiveness of the Nutritional App “MyNutriCart” on Food Choices Related to Purchase and Dietary Behavior: A Pilot Randomized Controlled Trial. Nutrients. 2018. 10:. doi:10.3390/nu10121967 | Intervention/Exposure; Outcome
1788 | Palacios, OM, Maki, KC, Nieman, KM, Lindner, E, Huebner, M, Sorce, J. Replacement of refined carbohydrates with a combination of egg protein and unsaturated fatty acids improves the lipoprotein lipid profile in adults with elevated triglycerides. FASEB journal. 2017. 31:. doi:unavailable | Publication Status
1789 | Paletas, K, Athanasiadou, E, Sarigianni, M, Paschos, P, Kalogirou, A, Hassapidou, M, Tsapas, A. The protective role of the Mediterranean diet on the prevalence of metabolic syndrome in a population of Greek obese subjects. J Am Coll Nutr. 2010. 29:41–5. doi:10.1080/07315724.2010.10719815 20595644 | Study Design
1790 | Pałkowska, E, Bartnikowska, E, Owsiak, D. The use of low-caloric diet with modified fatty acids pool in the therapy of the metabolic syndrome. Roczniki panstwowego zakladu higieny. 2012. 63:163–169. doi:unavailable22928363 | Language
1791 | Pallister, T, Jackson, MA, Martin, TC, Glastonbury, CA, Jennings, A, Beaumont, M, Mohney, RP, Small, KS, MacGregor, A, Steves, CJ, Cassidy, A, Spector, TD, Menni, C, Valdes, AM. Untangling the relationship between diet and visceral fat mass through blood metabolomics and gut microbiome profiling. Int J Obes (Lond). 2017. 41:1106–1113. doi:10.1038/ijo.2017.70 28293020 | Study Design; Intervention/Exposure; Outcome
1792 | Panagiotakos, D, Bountziouka, V, Zeimbekis, A, Vlachou, I, Polychronopoulos, E. Food pattern analysis and prevalence of cardiovascular disease risk factors among elderly people from Mediterranean islands. J Med Food. 2007. 10:615–21. doi:10.1089/jmf.2007.414 18158831 | Study Design
1793 | Panagiotakos, DB, Georgousopoulou, EN, Pitsavos, C, Chrysohoou, C, Metaxa, V, Georgiopoulos, GA, Kalogeropoulou, K, Tousoulis, D, Stefanadis, C. Ten-year (2002-2012) cardiovascular disease incidence and all-cause mortality, in urban Greek population: the ATTICA Study. Int J Cardiol. 2015. 180:178–84. doi:10.1016/j.ijcard.2014.11.206 25463360 | Study Design; Publication Status
1794 | Pandey, A, Clarus, S. The impact of dietary probiotics on estimated global cardiovascular risk in essential hypertensives. Canadian journal of cardiology. 2017. 33:S198-. doi:10.1016/j.cjca.2017.07.389 | Publication Status
1795 | Paniagua, JA, Gallego de la Sacristana, A, Romero, I, Vidal-Puig, A, Latre, JM, Sanchez, E, Perez-Martinez, P, Lopez-Miranda, J, Perez-Jimenez, F. Monounsaturated fat-rich diet prevents central body fat distribution and decreases postprandial adiponectin expression induced by a carbohydrate-rich diet in insulin-resistant subjects. Diabetes Care. 2007. 30:1717–23. doi:10.2337/dc06-2220 17384344 | Outcome; Study duration
1796 | Paniagua, JA, Perez-Martinez, P, Gjelstad, IM, Tierney, AC, Delgado-Lista, J, Defoort, C, Blaak, EE, Riserus, U, Drevon, CA, Kiec-Wilk, B, Lovegrove, JA, Roche, HM, Lopez-Miranda, J. A low-fat high-carbohydrate diet supplemented with long-chain n-3 PUFA reduces the risk of the metabolic syndrome. Atherosclerosis. 2011. 218:443–50. doi:10.1016/j.atherosclerosis.2011.07.003 21839455 | Data overlap with included article
1797 | Paniagua, JA, Romero, MI, Sanchez, ME, Valverde-Estepa, A, Ruano, J, Fuentes, F, Perez-Jimenez, F. Effect of 3 model diets on the glucose and insulin response, lipid profile and endothelial function in insulin-resistant subjects. Clinica e investigacion en arteriosclerosis. 2008. 20:55–63. doi:10.1016/S0214-9168%2808%2972584-1 | Language
1798 | Panizza, CE, Lim, U, Yonemori, KM, Cassel, KD, Wilkens, LR, Harvie, MN, Maskarinec, G, Delp, EJ, Lampe, JW, Shepherd, JA, Le Marchand, L, Boushey, CJ. Effects of Intermittent Energy Restriction Combined with a Mediterranean Diet on Reducing Visceral Adiposity: A Randomized Active Comparator Pilot Study. Nutrients. 2019. 11:. doi:10.3390/nu11061386 | Intervention/Exposure
1799 | Panunzio, MF, Caporizzi, R, Antoniciello, A, Cela, EP, Ferguson, LR, D’Ambrosio, P. Randomized, controlled nutrition education trial promotes a Mediterranean diet and improves anthropometric, dietary, and metabolic parameters in adults. Ann Ig. 2011. 23:13–25. doi:unavailable21736003 | Intervention/Exposure; Publication Date Overlaps with Existing Review
1800 | Paoli, A, Bianco, A, Grimaldi, KA, Lodi, A, Bosco, G. Long term successful weight loss with a combination biphasic ketogenic Mediterranean diet and Mediterranean diet maintenance protocol. Nutrients. 2013. 5:5205–17. doi:10.3390/nu5125205 24352095 | Study Design
1801 | Paoli, A, Cenci, L, Grimaldi, KA. Effect of ketogenic Mediterranean diet with phytoextracts and low carbohydrates/high-protein meals on weight, cardiovascular risk factors, body composition and diet compliance in Italian council employees. Nutr J. 2011. 10:112. doi:10.1186/1475-2891-10-112 21992535 | Study Design; Study duration
1802 | Paoli, A, Grimaldi, K, Bianco, A, Lodi, A, Cenci, L, Parmagnani, A. Medium term effects of a ketogenic diet and a Mediterranean diet on resting energy expenditure and respiratory ratio. BMC proceedings. 2012. 6:. doi:unavailable | Study duration
1803 | Paoli, A, Grimaldi, K, D’Agostino, D, Cenci, L, Moro, T, Bianco, A, Palma, A. Ketogenic diet does not affect strength performance in elite artistic gymnasts. J Int Soc Sports Nutr. 2012. 9:34. doi:10.1186/1550-2783-9-34 22835211 | Study duration
1804 | Papadaki, A, Linardakis, M, Larsen, TM, van Baak, MA, Lindroos, AK, Pfeiffer, AF, Martinez, JA, Handjieva-Darlenska, T, Kunesova, M, Holst, C, Astrup, A, Saris, WH, Kafatos, A. The effect of protein and glycemic index on children’s body composition: the DiOGenes randomized study. Pediatrics. 2010. 126:e1143–52. doi:10.1542/peds.2009-3633 20937657 | Intervention/Exposure
1805 | Papadaki, A, Linardakis, M, Plada, M, Larsen, T, Damsgaard, C, Van Baak, M, Jebb, S, Pfeiffer, A, Martinez, J, Handjieva-Darlenska, T, , . Effect of dietary protein and glycemic index on metabolic syndrome status: the diogenes randomized controlled trial. Annals of nutrition & metabolism. 2013. 63:1189-. doi:10.1159/000354245 | Intervention/Exposure; Publication Status
1806 | Papadaki, A, Linardakis, M, Plada, M, Larsen, TM, Damsgaard, CT, van Baak, MA, Jebb, S, Pfeiffer, AF, Martinez, JA, Handjieva-Darlenska, T, Kunesova, M, Holst, C, Saris, WH, Astrup, A, Kafatos, A. Impact of weight loss and maintenance with ad libitum diets varying in protein and glycemic index content on metabolic syndrome. Nutrition. 2014. 30:410–7. doi:10.1016/j.nut.2013.09.001 24369912 | Intervention/Exposure
1807 | Papadaki, A, Martinez-Gonzalez, MA, Alonso-Gomez, A, Rekondo, J, Salas-Salvado, J, Corella, D, Ros, E, Fito, M, Estruch, R, Lapetra, J, , . Mediterranean diet and risk of heart failure: results from the PREDIMED randomized controlled trial. European journal of heart failure. 2017. (no pagination):. doi:10.1002/ejhf.750 | Publication Status
1808 | Papakonstantinou, E, Zampelas, A. The effect of dietary protein intake on coronary heart disease risk. Nutrition bulletin. 2008. 33:287–297. doi:unavailable | Study Design
1809 | Papandreou, C, Hatzis, CM. Adherence to the Mediterranean Diet in Relation to Obesity Indices before and after a Weight Reduction Program in OSAS Patients. Iran J Public Health. 2014. 43:1454–5. doi:unavailable26060709 | Study Design
1810 | Paradis, AM, Godin, G, Perusse, L, Vohl, MC. Interaction between familial history of obesity and fat intakes on obesity phenotypes. J Nutrigenet Nutrigenomics. 2009. 2:37–42. doi:10.1159/000191281 19776637 | Study Design
1811 | Parcina, M, Brune, M, Kaese, V, Zorn, M, Spiegel, R, Vojvoda, V, Fleming, T, Rudofsky, G, Paul Nawroth, P. No short-term effects of calorie-controlled Mediterranean or fast food dietary interventions on established biomarkers of vascular or metabolic risk in healthy individuals. Nutr Res Pract. 2015. 9:165–73. doi:10.4162/nrp.2015.9.2.165 25861423 | Power/Size
1812 | Parillo, M, Licenziati, MR, Vacca, M, De Marco, D, Iannuzzi, A. Metabolic changes after a hypocaloric, low-glycemic-index diet in obese children. J Endocrinol Invest. 2012. 35:629–33. doi:10.3275/7909 21897113 | Intervention/Exposure
1813 | Park, H, Tserendejid, Z, Song, KH, Lee, J, Lee, Y. Dietary patterns and the association with dietary quality among Mongolian immigrants in South Korea. J Immigr Minor Health. 2015. 17:422–31. doi:10.1007/s10903-014-0047-2 24894430 | Study Design; Outcome
1814 | Park, HA, Lee, JS, Kuller, LH. Relationship between premenopausal dietary intake and postmenopausal subclinical atherosclerosis. Atherosclerosis. 2006. 186:420–7. doi:10.1016/j.atherosclerosis.2005.08.002 16182299 | Intervention/Exposure
1815 | Park, JE, Miller, M, Rhyne, J, Wang, Z, Hazen, SL. Differential effect of short-term popular diets on TMAO and other cardio-metabolic risk markers. Nutr Metab Cardiovasc Dis. 2019. 29:513–517. doi:10.1016/j.numecd.2019.02.003 30940489 | Outcome
1816 | Park, SY, Kang, M, Wilkens, LR, Shvetsov, YB, Harmon, BE, Shivappa, N, Wirth, MD, Hebert, JR, Haiman, CA, Le Marchand, L, Boushey, CJ. The Dietary Inflammatory Index and All-Cause, Cardiovascular Disease, and Cancer Mortality in the Multiethnic Cohort Study. Nutrients. 2018. 10:. doi:10.3390/nu10121844 | Intervention/Exposure
1817 | Park, YM, Choi, MK, Lee, SS, Shivappa, N, Han, K, Steck, SE, Hebert, JR, Merchant, AT, Sandler, DP. Dietary inflammatory potential and risk of mortality in metabolically healthy and unhealthy phenotypes among overweight and obese adults. Clin Nutr. 2019. 38:682–688. doi:10.1016/j.clnu.2018.04.002 29705061 | Intervention/Exposure
1818 | Park, YM, Steck, SE, Fung, TT, Zhang, J, Hazlett, LJ, Han, K, Lee, SH, Kwon, HS, Merchant, AT. Mediterranean diet, Dietary Approaches to Stop Hypertension (DASH) style diet, and metabolic health in U.S. adults. Clin Nutr. 2017. 36:1301–1309. doi:10.1016/j.clnu.2016.08.018 27665232 | Study Design
1819 | Parker, HM, O’Connor, HT, Keating, SE, Cohn, JS, Garg, ML, Caterson, ID, George, J, Johnson, NA. Efficacy of the Omega-3 Index in predicting non-alcoholic fatty liver disease in overweight and obese adults: a pilot study. Br J Nutr. 2015. 114:780–7. doi:10.1017/s0007114515002305 26202539 | Intervention/Exposure
1820 | Parr, EB, Coffey, VG, Cato, LE, Phillips, SM, Burke, LM, Hawley, JA. A randomized trial of high-dairy-protein, variable-carbohydrate diets and exercise on body composition in adults with obesity. Obesity (Silver Spring). 2016. 24:1035–45. doi:10.1002/oby.21451 26931302 | Power/Size
1821 | Partsalaki, I, Karvela, A, Spiliotis, BE. Metabolic impact of a ketogenic diet compared to a hypocaloric diet in obese children and adolescents. J Pediatr Endocrinol Metab. 2012. 25:697–704. doi:10.1515/jpem-2012-0131 23155696 | Intervention/Exposure
1822 | Pasiakos, SM, Cao, JJ, Margolis, LM, Sauter, ER, Whigham, LD, McClung, JP, Rood, JC, Carbone, JW, Combs, GF, Jr, Young, AJ. Effects of high-protein diets on fat-free mass and muscle protein synthesis following weight loss: a randomized controlled trial. Faseb j. 2013. 27:3837–47. doi:10.1096/fj.13-230227 23739654 | Outcome; Study duration
1823 | Pasiakos, SM, Lieberman, HR, Fulgoni, VL, 3rd. Higher-protein diets are associated with higher HDL cholesterol and lower BMI and waist circumference in US adults. J Nutr. 2015. 145:605–14. doi:10.3945/jn.114.205203 25733478 | Study Design
1824 | Pastore, RL, Brooks, JT, Carbone, JW. Paleolithic nutrition improves plasma lipid concentrations of hypercholesterolemic adults to a greater extent than traditional heart-healthy dietary recommendations. Nutr Res. 2015. 35:474–9. doi:10.1016/j.nutres.2015.05.002 26003334 | Power/Size
1825 | Pastori, D, Carnevale, R, Bartimoccia, S, Nocella, C, Tanzilli, G, Cangemi, R, Vicario, T, Catena, M, Violi, F, Pignatelli, P. Does Mediterranean Diet Reduce Cardiovascular Events and Oxidative Stress in Atrial Fibrillation?. Antioxid Redox Signal. 2015. 23:682–7. doi:10.1089/ars.2015.6326 25825798 | Study Design; Health Status
1826 | Pate, RR, Taverno Ross, SE, Liese, AD, Dowda, M. Associations among physical activity, diet quality, and weight status in US adults. Med Sci Sports Exerc. 2015. 47:743–50. doi:10.1249/mss.0000000000000456 25058328 | Study Design
1827 | Patel, L, Alicandro, G, La Vecchia, C. Low-Calorie Beverage Consumption, Diet Quality and Cardiometabolic Risk Factors in British Adults. Nutrients. 2018. 10:. doi:10.3390/nu10091261 | Study Design
1828 | Patino-Alonso, MC, Recio-Rodriguez, JI, Magdalena-Belio, JF, Gine-Garriga, M, Martinez-Vizcaino, V, Fernandez-Alonso, C, Arietaleanizbeaskoa, MS, Galindo-Villardon, MP, Gomez-Marcos, MA, Garcia-Ortiz, L. Clustering of lifestyle characteristics and their association with cardio-metabolic health: the Lifestyles and Endothelial Dysfunction (EVIDENT) study. Br J Nutr. 2015. 114:943–51. doi:10.1017/s0007114515002500 26268844 | Study Design
1829 | Pavic, E, Hadziabdic, MO, Mucalo, I, Martinis, I, Romic, Z, Bozikov, V, Rahelic, D. Effect of the Mediterranean diet in combination with exercise on metabolic syndrome parameters: 1-year randomized controlled trial. Int J Vitam Nutr Res. 2019. 89:132–143. doi:10.1024/0300-9831/a000462 31322480 | Weight loss/Hypocaloric
1830 | Pavicic Zezelj, S, Kendel Jovanovic, G, Dragas Zubalj, N, Micovic, V, Sesar, Z. Associations between Adherence to the Mediterranean Diet and Lifestyle Assessed with the MEDLIFE Index among the Working Population. Int J Environ Res Public Health. 2018. 15:. doi:10.3390/ijerph15102126 | Study Design; Intervention/Exposure
1831 | Pawlak, R. Vegetarian Diets in the Prevention and Management of Diabetes and Its Complications. Diabetes Spectr. 2017. 30:82–88. doi:10.2337/ds16-0057 28588373 | Study Design
1832 | Payab, M, Kelishadi, R, Qorbani, M, Motlagh, ME, Ranjbar, SH, Ardalan, G, Zahedi, H, Chinian, M, Asayesh, H, Larijani, B, Heshmat, R. Association of junk food consumption with high blood pressure and obesity in Iranian children and adolescents: the CASPIAN-IV Study. J Pediatr (Rio J). 2015. 91:196–205. doi:10.1016/j.jped.2014.07.006 25449791 | Study Design
1833 | Peairs, AD, Rankin, JW, Lee, YW. Effects of acute ingestion of different fats on oxidative stress and inflammation in overweight and obese adults. Nutr J. 2011. 10:122. doi:10.1186/1475-2891-10-122 22059644 | Study duration
1834 | Pearce, K, Hatzinikolas, A, Moran, L, de Courten, MPJ, Forbes, J, Scheijen, Jljm, Schalkwijk, CG, Walker, K, de Courten, B. Disparity in the micronutrient content of diets high or low in advanced glycation end products (AGEs) does not explain changes in insulin sensitivity. Int J Food Sci Nutr. 2017. 68:1021–1026. doi:10.1080/09637486.2017.1319468 28460575 | Study duration
1835 | Pehleman, TL, Peters, SJ, Heigenhauser, GJ, Spriet, LL. Enzymatic regulation of glucose disposal in human skeletal muscle after a high-fat, low-carbohydrate diet. J Appl Physiol (1985). 2005. 98:100–7. doi:10.1152/japplphysiol.00686.2004 15310747 | Study duration
1836 | Pelkman, CL, Fishell, VK, Maddox, DH, Pearson, TA, Mauger, DT, Kris-Etherton, PM. Effects of moderate-fat (from monounsaturated fat) and low-fat weight-loss diets on the serum lipid profile in overweight and obese men and women. Am J Clin Nutr. 2004. 79:204–12. doi:10.1093/ajcn/79.2.204 14749224 | Intervention/Exposure
1837 | Penesova, A, Bajer, B, Vlcek, M, Imrich, R. The effect of 8 weeks of weight loss intervention on cardiometabolic parameters (ongoing study). Vnitrni lekarstvi. 2017. 63:2S54-. doi:unavailable | Publication Status
1838 | Pengpid, S, Peltzer, K. Overweight or obesity and related lifestyle and psychosocial factors among adolescents in Brunei Darussalam. Int J Adolesc Med Health. 2018. :. doi:10.1515/ijamh-2018-0019 | Study Design
1839 | Pereira, EV, Costa Jde, A, Alfenas Rde, C. Effect of glycemic index on obesity control. Arch Endocrinol Metab. 2015. 59:245–51. doi:10.1590/2359-3997000000045 26154093 | Study duration
1840 | Pereira, MA, Swain, J, Goldfine, AB, Rifai, N, Ludwig, DS. Effects of a low-glycemic load diet on resting energy expenditure and heart disease risk factors during weight loss. Jama. 2004. 292:2482–90. doi:10.1001/jama.292.20.2482 15562127 | Intervention/Exposure; Study duration
1841 | Perera, MJ, Chirinos, DA, Brintz, CE, Schneiderman, N, Daviglus, M, Talavera, GA, Perreira, KM, Giacinto, RAE, Qi, Q, Llabre, MM. Body Mass of U.S. Hispanics/Latinos From the Hispanic Community Health Study/Study of Latinos (HCHS/SOL): How Do Diet Quality and Sedentary Time Relate?. Hisp Health Care Int. 2019. :1540415319874809. doi:10.1177/1540415319874809 | Study Design
1842 | Perez, LF, Miller, CK, Groner, JA. Adolescents with at-risk eating and lifestyle behaviors are affected by after school schedules across the clinical weight spectrum. Patient Educ Couns. 2017. 100:1511–1518. doi:10.1016/j.pec.2017.03.008 28283217 | Study Design
1843 | Perez-Ferre, N, Del Valle, L, Torrejon, MJ, Barca, I, Calvo, MI, Matia, P, Rubio, MA, Calle-Pascual, AL. Diabetes mellitus and abnormal glucose tolerance development after gestational diabetes: A three-year, prospective, randomized, clinical-based, Mediterranean lifestyle interventional study with parallel groups. Clin Nutr. 2015. 34:579–85. doi:10.1016/j.clnu.2014.09.005 25262459 | Intervention/Exposure; Health Status
1844 | Perez-Guisado, J, Munoz-Serrano, A, Alonso-Moraga, A. Spanish Ketogenic Mediterranean Diet: a healthy cardiovascular diet for weight loss. Nutr J. 2008. 7:30. doi:10.1186/1475-2891-7-30 18950537 | Study Design
1845 | Perez-Guisado, J, Munoz-Serrano, A. A pilot study of the Spanish Ketogenic Mediterranean Diet: an effective therapy for the metabolic syndrome. J Med Food. 2011. 14:681–7. doi:10.1089/jmf.2010.0137 21612461 | Study Design
1846 | Perez-Guisado, J, Munoz-Serrano, A. The effect of the Spanish Ketogenic Mediterranean Diet on nonalcoholic fatty liver disease: a pilot study. J Med Food. 2011. 14:677–80. doi:10.1089/jmf.2011.0075 21688989 | Study Design; Intervention/Exposure
1847 | Perez-Jimenez, F, Lopez-Miranda, J, Pinillos, MD, Gomez, P, Paz-Rojas, E, Montilla, P, Marin, C, Velasco, MJ, Blanco-Molina, A, Jimenez Pereperez, JA, Ordovas, JM. A Mediterranean and a high-carbohydrate diet improve glucose metabolism in healthy young persons. Diabetologia. 2001. 44:2038–43. doi:10.1007/s001250100009 11719836 | Study duration
1848 | Perona, JS, Covas, MI, Fito, M, Cabello-Moruno, R, Aros, F, Corella, D, Ros, E, Garcia, M, Estruch, R, Martinez-Gonzalez, MA, Ruiz-Gutierrez, V. Reduction in systemic and VLDL triacylglycerol concentration after a 3-month Mediterranean-style diet in high-cardiovascular-risk subjects. J Nutr Biochem. 2010. 21:892–8. doi:10.1016/j.jnutbio.2009.07.005 19962297 | Study Design; Outcome
1849 | Perry, ML. Nutrient distribution for type 2 diabetes: what’s a dietetics professional to do?. J Am Diet Assoc. 2005. 105:581–2. doi:10.1016/j.jada.2005.02.036 15800560 | Study Design; Publication Status
1850 | Persson, M, Winkvist, A, Mogren, I. Lifestyle and health status in a sample of Swedish women four years after pregnancy: a comparison of women with a history of normal pregnancy and women with a history of gestational diabetes mellitus. BMC Pregnancy Childbirth. 2015. 15:57. doi:10.1186/s12884-015-0487-2 25884665 | Study Design; Intervention/Exposure
1851 | Petersen, M, Taylor, MA, Saris, WH, Verdich, C, Toubro, S, Macdonald, I, Rossner, S, Stich, V, Guy-Grand, B, Langin, D, Martinez, JA, Pedersen, O, Holst, C, Sorensen, TI, Astrup, A. Randomized, multi-center trial of two hypo-energetic diets in obese subjects: high- versus low-fat content. Int J Obes (Lond). 2006. 30:552–60. doi:10.1038/sj.ijo.0803186 16331300 | Study duration
1852 | Pettitt, C, Liu, J, Kwasnicki, RM, Yang, GZ, Preston, T, Frost, G. A pilot study to determine whether using a lightweight, wearable micro-camera improves dietary assessment accuracy and offers information on macronutrients and eating rate. British Journal of Nutrition. 2016. 115:160–167. doi:10.1017/S0007114515004262 | Study Design; Outcome; Study duration
1853 | Petzke, KJ, Lemke, S, Klaus, S. Increased fat-free body mass and no adverse effects on blood lipid concentrations 4 weeks after additional meat consumption in comparison with an exclusion of meat in the diet of young healthy women. J Nutr Metab. 2011. 2011:210930. doi:10.1155/2011/210930 21773015 | Study duration
1854 | Pfister, R, Michels, G, Sharp, SJ, Luben, R, Wareham, NJ, Khaw, KT. Estimated urinary sodium excretion and risk of heart failure in men and women in the EPIC-Norfolk study. Eur J Heart Fail. 2014. 16:394–402. doi:10.1002/ejhf.56 24464931 | Intervention/Exposure
1855 | Philippou, E, Bovill-Taylor, C, Rajkumar, C, Vampa, ML, Ntatsaki, E, Brynes, AE, Hickson, M, Frost, GS. Preliminary report: the effect of a 6-month dietary glycemic index manipulation in addition to healthy eating advice and weight loss on arterial compliance and 24-hour ambulatory blood pressure in men: a pilot study. Metabolism. 2009. 58:1703–8. doi:10.1016/j.metabol.2009.05.026 19604522 | Intervention/Exposure
1856 | Philippou, E, McGowan, BM, Brynes, AE, Dornhorst, A, Leeds, AR, Frost, GS. The effect of a 12-week low glycaemic index diet on heart disease risk factors and 24 h glycaemic response in healthy middle-aged volunteers at risk of heart disease: a pilot study. Eur J Clin Nutr. 2008. 62:145–9. doi:10.1038/sj.ejcn.1602688 17311054 | Intervention/Exposure
1857 | Phillips, SA, Jurva, JW, Syed, AQ, Syed, AQ, Kulinski, JP, Pleuss, J, Hoffmann, RG, Gutterman, DD. Benefit of low-fat over low-carbohydrate diet on endothelial health in obesity. Hypertension. 2008. 51:376–82. doi:10.1161/hypertensionaha.107.101824 18195164 | Study duration
1858 | Pieke, B, von Eckardstein, A, Gulbahce, E, Chirazi, A, Schulte, H, Assmann, G, Wahrburg, U. Treatment of hypertriglyceridemia by two diets rich either in unsaturated fatty acids or in carbohydrates: effects on lipoprotein subclasses, lipolytic enzymes, lipid transfer proteins, insulin and leptin. Int J Obes Relat Metab Disord. 2000. 24:1286–96. doi:10.1038/sj.ijo.0801440 11093290 | Study duration
1859 | Piernas, C, Wang, D, Du, S, Zhang, B, Wang, Z, Su, C, Popkin, BM. The double burden of under- and overnutrition and nutrient adequacy among Chinese preschool and school-aged children in 2009-2011. Eur J Clin Nutr. 2015. 69:1323–9. doi:10.1038/ejcn.2015.106 26130296 | Study Design; Country
1860 | Piers, LS, Walker, KZ, Stoney, RM, Soares, MJ, O’Dea, K. Substitution of saturated with monounsaturated fat in a 4-week diet affects body weight and composition of overweight and obese men. Br J Nutr. 2003. 90:717–27. doi:10.1079/bjn2003948 13129479 | Intervention/Exposure; Comparator
1861 | Pierucci, P, Misciagna, G, Ventura, MT, Inguaggiato, R, Cisternino, AM, Guerra, VM, Suppressa, P, Resta, F, Sabba, C. Diet and myocardial infarction: a nested case-control study in a cohort of elderly subjects in a Mediterranean area of southern Italy. Nutr Metab Cardiovasc Dis. 2012. 22:727–33. doi:10.1016/j.numecd.2010.12.002 21482083 | Intervention/Exposure
1862 | Pignone, M. High-protein and low-glycemic diets improve weight maintenance among overweight adults. Clinical Diabetes. 2011. 29:73–74. doi:10.2337/diaclin.29.2.73 | Publication Status
1863 | Pikija, S, Trkulja, V, Malojcic, B, Mutzenbach, JS, Sellner, J. A High Burden of Ischemic Stroke in Regions of Eastern/Central Europe is Largely Due to Modifiable Risk Factors. Curr Neurovasc Res. 2015. 12:341–52. doi:unavailable26238468 | Study Design; Intervention/Exposure
1864 | Pilis, K, Pilis, A, Stec, K, Pilis, W, Langfort, J, Letkiewicz, S, Michalski, C, Czuba, M, Zych, M, Chalimoniuk, M. Three-Year Chronic Consumption of Low-Carbohydrate Diet Impairs Exercise Performance and Has a Small Unfavorable Effect on Lipid Profile in Middle-Aged Men. Nutrients. 2018. 10:. doi:10.3390/nu10121914 | Study Design; Outcome; Study duration
1865 | Pilleron, S, Ajana, S, Jutand, MA, Helmer, C, Dartigues, JF, Samieri, C, Féart, C. Dietary Patterns and 12-Year Risk of Frailty: Results From the Three-City Bordeaux Study. Journal of the American Medical Directors Association. 2017. 18:169–175. doi:10.1016/j.jamda.2016.09.014 27847264 | Power/Size
1866 | Pimenta, AM, Toledo, E, Rodriguez-Diez, MC, Gea, A, Lopez-Iracheta, R, Shivappa, N, Hebert, JR, Martinez-Gonzalez, MA. Dietary indexes, food patterns and incidence of metabolic syndrome in a Mediterranean cohort: The SUN project. Clin Nutr. 2015. 34:508–14. doi:10.1016/j.clnu.2014.06.002 24975512 | Outcome
1867 | Pimpin, L, Jebb, S, Johnson, L, Wardle, J, Ambrosini, GL. Dietary protein intake is associated with body mass index and weight up to 5 y of age in a prospective cohort of twins. Am J Clin Nutr. 2016. 103:389–97. doi:10.3945/ajcn.115.118612 26718416 | AGE: Intervention/Exposure
1868 | Pimpin, L, Jebb, SA, Johnson, L, Llewellyn, C, Ambrosini, GL. Sources and pattern of protein intake and risk of overweight or obesity in young UK twins. Br J Nutr. 2018. 120:820–829. doi:10.1017/s0007114518002052 30132433 | AGE: Intervention/Exposure
1869 | Piotrowicz, K, Palkowska, E, Bartnikowska, E, Krzesinski, P, Stanczyk, A, Biecek, P, Skrobowski, A, Gielerak, G. Self-reported health-related behaviors and dietary habits in patients with metabolic syndrome. Cardiol J. 2015. 22:413–20. doi:10.5603/CJ.a2015.0020 26325258 | Study Design; Intervention/Exposure
1870 | Piovesan, CH, Macagnan, FE, Bodanese, LC, Feoli, AM. Dietary quality improvement after a short-term nutritional counseling program in individuals with metabolic syndrome. Arch Latinoam Nutr. 2014. 64:91–8. doi:unavailable25799685 | Study Design; Comparator
1871 | Pisa, PT, Pedro, TM, Kahn, K, Tollman, SM, Pettifor, JM, Norris, SA. Nutrient patterns and their association with socio-demographic, lifestyle factors and obesity risk in rural South African adolescents. Nutrients. 2015. 7:3464–82. doi:10.3390/nu7053464 25984738 | Study Design
1872 | Pivovarova, O, Kessler, K, Hornemann, S, Markova, M, Petzke, KJ, Kemper, M, Rudovich, N, Kramer, A, Pfeiffer, AFH. Time of fat and carbohydrate intake affects substrate oxidation and adipokine secretion in subjects with impaired glucose metabolism. Diabetologia. 2018. 61:S330-. doi:10.1007/s00125-018-4693-0 | Publication Status
1873 | Playdon, MC, Moore, SC, Derkach, A, Reedy, J, Subar, AF, Sampson, JN, Albanes, D, Gu, F, Kontto, J, Lassale, C, Liao, LM, Mannisto, S, Mondul, AM, Weinstein, SJ, Irwin, ML, Mayne, ST, Stolzenberg-Solomon, R. Identifying biomarkers of dietary patterns by using metabolomics. Am J Clin Nutr. 2017. 105:450–465. doi:10.3945/ajcn.116.144501 28031192 | Outcome
1874 | Poirier, P, Hernandez, TL, Weil, KM, Shepard, TJ, Eckel, RH. Impact of diet-induced weight loss on the cardiac autonomic nervous system in severe obesity. Obes Res. 2003. 11:1040–7. doi:10.1038/oby.2003.143 12972673 | Intervention/Exposure
1875 | Poli, VFS, Sanches, RB, Moraes, ADS, Fidalgo, JPN, Nascimento, MA, Bresciani, P, Andrade-Silva, SG, Cipullo, MAT, Clemente, JC, Caranti, DA. The excessive caloric intake and micronutrient deficiencies related to obesity after a long-term interdisciplinary therapy. Nutrition. 2017. 38:113–119. doi:10.1016/j.nut.2017.01.012 28526376 | Study Design; Intervention/Exposure
1876 | Polley, KR, Oswell, NJ, Pegg, RB, Paton, CM, Cooper, JA. A 5-day high-fat diet rich in cottonseed oil improves cholesterol profiles and triglycerides compared to olive oil in healthy men. Nutr Res. 2018. 60:43–53. doi:10.1016/j.nutres.2018.09.001 30527259 | Study duration
1877 | Pontes Torrado, Y, Garcia-Villaraco Velasco, A, Hernandez Galiot, A, Goni Cambrodon, I. A strategy for weight loss based on healthy dietary habits and control of emotional response to food. Nutr Hosp. 2015. 31:2392–9. doi:10.3305/nh.2015.31.6.8736 26040343 | Comparator; Outcome
1878 | Ponzo, V, Goitre, I, Fadda, M, Gambino, R, De Francesco, A, Soldati, L, Gentile, L, Magistroni, P, Cassader, M, Bo, S. Dietary flavonoid intake and cardiovascular risk: a population-based cohort study. J Transl Med. 2015. 13:218. doi:10.1186/s12967-015-0573-2 26152229 | Intervention/Exposure
1879 | Poppitt, SD, Keogh, GF, Mulvey, TB, Phillips, A, McArdle, BH, MacGibbon, AK, Cooper, GJ. Effect of moderate changes in dietary fatty acid profile on postprandial lipaemia, haemostatic and related CVD risk factors in healthy men. Eur J Clin Nutr. 2004. 58:819–27. doi:10.1038/sj.ejcn.1601882 15116086 | Study duration
1880 | Poppitt, SD, Keogh, GF, Prentice, AM, Williams, DE, Sonnemans, HM, Valk, EE, Robinson, E, Wareham, NJ. Long-term effects of ad libitum low-fat, high-carbohydrate diets on body weight and serum lipids in overweight subjects with metabolic syndrome. Am J Clin Nutr. 2002. 75:11–20. doi:10.1093/ajcn/75.1.11 11756055 | Intervention/Exposure
1881 | Pou, SA, Del Pilar Diaz, M, De La Quintana, AG, Forte, CA, Aballay, LR. Identification of dietary patterns in urban population of Argentina: study on diet-obesity relation in population-based prevalence study. Nutr Res Pract. 2016. 10:616–622. doi:10.4162/nrp.2016.10.6.616 27909559 | Study Design
1882 | Pounis, GD, Tyrovolas, S, Antonopoulou, M, Zeimbekis, A, Anastasiou, F, Bountztiouka, V, Metallinos, G, Gotsis, E, Lioliou, E, Polychronopoulos, E, Lionis, C, Panagiotakos, DB. Long-term animal-protein consumption is associated with an increased prevalence of diabetes among the elderly: the Mediterranean Islands (MEDIS) study. Diabetes Metab. 2010. 36:484–90. doi:10.1016/j.diabet.2010.06.007 20888279 | Study Design; Comparator
1883 | Praagman, J, Beulens, JW, Alssema, M, Zock, PL, Wanders, AJ, Sluijs, I, van der Schouw, YT. The association between dietary saturated fatty acids and ischemic heart disease depends on the type and source of fatty acid in the European Prospective Investigation into Cancer and Nutrition-Netherlands cohort. Am J Clin Nutr. 2016. 103:356–65. doi:10.3945/ajcn.115.122671 26791181 | Intervention/Exposure
1884 | Praagman, J, Franco, OH, Ikram, MA, Soedamah-Muthu, SS, Engberink, MF, van Rooij, FJ, Hofman, A, Geleijnse, JM. Dairy products and the risk of stroke and coronary heart disease: the Rotterdam Study. Eur J Nutr. 2015. 54:981–90. doi:10.1007/s00394-014-0774-0 25296885 | Intervention/Exposure
1885 | Prentice, RL, Aragaki, AK, Howard, BV, Chlebowski, RT, Thomson, CA, Van Horn, L, Tinker, LF, Manson, JE, Anderson, GL, Kuller, LE, Neuhouser, ML, Johnson, KC, Snetselaar, L, Rossouw, JE. Low-Fat Dietary Pattern among Postmenopausal Women Influences Long-Term Cancer, Cardiovascular Disease, and Diabetes Outcomes. J Nutr. 2019. 149:1565–1574. doi:10.1093/jn/nxz107 31175807 | Intervention/Exposure
1886 | Prentice, RL, Aragaki, AK, Van Horn, L, Thomson, CA, Beresford, SA, Robinson, J, Snetselaar, L, Anderson, GL, Manson, JE, Allison, MA, Rossouw, JE, Howard, BV. Low-fat dietary pattern and cardiovascular disease: results from the Women’s Health Initiative randomized controlled trial. Am J Clin Nutr. 2017. 106:35–43. doi:10.3945/ajcn.117.153270 28515068 | Intervention/Exposure; Comparator
1887 | Prinelli, F, Adorni, F, Leite, MLC, Pettenati, C, Russo, A, Di Santo, S, Musicco, M. Different Exposures to Risk Factors Do Not Explain the Inverse Relationship of Occurrence Between Cancer and Neurodegenerative Diseases: An Italian Nested Case-control Study. Alzheimer Dis Assoc Disord. 2018. 32:76–82. doi:10.1097/wad.0000000000000204 28796009 | Outcome
1888 | Prinelli, F, Yannakoulia, M, Anastasiou, CA, Adorni, F, Di Santo, SG, Musicco, M, Scarmeas, N, Correa Leite, ML. Mediterranean diet and other lifestyle factors in relation to 20-year all-cause mortality: A cohort study in an Italian population. British Journal of Nutrition. 2015. 113:1003–1011. doi:10.1017/S0007114515000318 | Outcome
1889 | Properzi, C, O’Sullivan, TA, Sherriff, JL, Ching, HL, Jeffrey, GP, Buckley, RF, Tibballs, J, MacQuillan, GC, Garas, G, Adams, LA. Ad Libitum Mediterranean and Low-Fat Diets Both Significantly Reduce Hepatic Steatosis: A Randomized Controlled Trial. Hepatology. 2018. 68:1741–1754. doi:10.1002/hep.30076 29729189 | Health Status
1890 | Psaltopoulou, T, Naska, A, Orfanos, P, Trichopoulos, D, Mountokalakis, T, Trichopoulou, A. Olive oil, the Mediterranean diet, and arterial blood pressure: the Greek European Prospective Investigation into Cancer and Nutrition (EPIC) study. Am J Clin Nutr. 2004. 80:1012–8. doi:10.1093/ajcn/80.4.1012 15447913 | Study Design; Outcome
1891 | Ptomey, LT, Saunders, RR, Saunders, M, Washburn, RA, Mayo, MS, Sullivan, DK, Gibson, CA, Goetz, JR, Honas, JJ, Willis, EA, Danon, JC, Krebill, R, Donnelly, JE. Weight management in adults with intellectual and developmental disabilities: A randomized controlled trial of two dietary approaches. J Appl Res Intellect Disabil. 2018. 31 Suppl 1:82–96. doi:10.1111/jar.12348 | Health Status
1892 | Ptomey, LT, Steger, FL, Lee, J, Sullivan, DK, Goetz, JR, Honas, JJ, Washburn, RA, Gibson, CA, Donnelly, JE. Changes in Energy Intake and Diet Quality during an 18-Month Weight-Management Randomized Controlled Trial in Adults with Intellectual and Developmental Disabilities. J Acad Nutr Diet. 2018. 118:1087–1096. doi:10.1016/j.jand.2017.11.003 29311038 | Health Status
1893 | Ptomey, LT, Willis, EA, Goetz, JR, Lee, J, Szabo-Reed, AN, Sullivan, DK, Donnelly, JE. Portion-controlled meals provide increases in diet quality during weight loss and maintenance. J Hum Nutr Diet. 2016. 29:209–16. doi:10.1111/jhn.12296 25664818 | Study Design
1894 | Puga, GM, Meyer, C, Everman, S, Mandarino, LJ, Katsanos, CS. Postprandial lipemia in the elderly involves increased incorporation of ingested fat in plasma free fatty acids and small (Sf 20-400) triglyceride-rich lipoproteins. Am J Physiol Endocrinol Metab. 2011. 301:E356–61. doi:10.1152/ajpendo.00670.2010 21558545 | Study duration
1895 | Puga, GM, Meyer, C, Mandarino, LJ, Katsanos, CS. Postprandial spillover of dietary lipid into plasma is increased with moderate amounts of ingested fat and is inversely related to adiposity in healthy older men. J Nutr. 2012. 142:1806–11. doi:10.3945/jn.112.162008 22955513 | Study duration
1896 | Purcell, K, Sumithran, P, Prendergast, LA, Bouniu, CJ, Delbridge, E, Proietto, J. The effect of rate of weight loss on longterm weight management: a randomised controlled trial. Lancet Diabetes Endocrinol. 2014. 2:954–62. doi:10.1016/s2213-8587(14)70200-1 25459211 | Intervention/Exposure; Comparator
1897 | Pysz, M, Leszczynska, T, Cieslik, E, Kopec, A, Wielgos, B, Piatkowska, E. Relationship between the intake of energy and basic nutrients and the BMI values in group of children aged 10-12. Rocz Panstw Zakl Hig. 2014. 65:345–52. doi:unavailable25526581 | Study Design
1898 | Qi, Q, Downer, MK, Kilpelainen, TO, Taal, HR, Barton, SJ, Ntalla, I, Standl, M, Boraska, V, Huikari, V, Kiefte-de Jong, JC, Korner, A, Lakka, TA, Liu, G, Magnusson, J, Okuda, M, Raitakari, O, Richmond, R, Scott, RA, Bailey, ME, Scheuermann, K, Holloway, JW, Inskip, H, Isasi, CR, Mossavar-Rahmani, Y, Jaddoe, VW, Laitinen, J, Lindi, V, Melen, E, Pitsiladis, Y, Pitkanen, N, Snieder, H, Heinrich, J, Timpson, NJ, Wang, T, Yuji, H, Zeggini, E, Dedoussis, GV, Kaplan, RC, Wylie-Rosett, J, Loos, RJ, Hu, FB, Qi, L. Dietary Intake, FTO Genetic Variants, and Adiposity: A Combined Analysis of Over 16,000 Children and Adolescents. Diabetes. 2015. 64:2467–76. doi:10.2337/db14-1629 25720386 | Study Design; AGE: Intervention/Exposure
1899 | Qi, Q, Durst, R, Schwarzfuchs, D, Leitersdorf, E, Shpitzen, S, Li, Y, Wu, H, Champagne, CM, Hu, FB, Stampfer, MJ, Bray, GA, Sacks, FM, Shai, I, Qi, L. CETP genotype and changes in lipid levels in response to weight-loss diet intervention in the POUNDS LOST and DIRECT randomized trials. J Lipid Res. 2015. 56:713–21. doi:10.1194/jlr.P055715 25548261 | Intervention/Exposure; Comparator
1900 | Qi, Q, Zheng, Y, Huang, T, Rood, J, Bray, GA, Sacks, FM, Qi, L. Vitamin D metabolism-related genetic variants, dietary protein intake and improvement of insulin resistance in a 2 year weight-loss trial: POUNDS Lost. Diabetologia. 2015. 58:2791–9. doi:10.1007/s00125-015-3750-1 26416604 | Study Design; Intervention/Exposure
1901 | Qin, Y, Melse-Boonstra, A, Pan, X, Zhao, J, Yuan, B, Dai, Y, Zhou, M, Geleijnse, JM, Kok, FJ, Shi, Z. Association of dietary pattern and body weight with blood pressure in Jiangsu Province, China. BMC Public Health. 2014. 14:948. doi:10.1186/1471-2458-14-948 25216777 | Country
1902 | Quatromoni, PA, Copenhafer, DL, D’Agostino, RB, Millen, BE. Dietary patterns predict the development of overweight in women: The Framingham Nutrition Studies. J Am Diet Assoc. 2002. 102:1239–46. doi:10.1016/s0002-8223(02)90275-0 | Power/Size
1903 | Quatromoni, PA, Copenhafer, DL, Demissie, S, D’Agostino, RB, O’Horo, CE, Nam, BH, Millen, BE. The internal validity of a dietary pattern analysis. The Framingham Nutrition Studies. J Epidemiol Community Health. 2002. 56:381–8. doi:10.1136/jech.56.5.381 11964437 | Study Design; Publication Date Overlaps with Existing Review
1904 | Quinteiros Fidalgo, AS, Vollenweider, P, Marques-Vidal, P. No association between dietary markers and incident hypertension in a population-based sample. Clin Nutr ESPEN. 2018. 28:208–213. doi:10.1016/j.clnesp.2018.07.013 30390882 | Outcome
1905 | Raad, N, Rehder, D, Sherma, N, Beezhold, B, Johnston, C, Borges, C, Sweazea, K. Replacing dietary meat with fish increases plasma glucose without affecting protein glycation. FASEB journal. 2015. 29:. doi:unavailable | Publication Status
1906 | Raatz, SK, Young, LR, Picklo, MJ, Sr, Sauter, ER, Qin, W, Kurzer, MS. Total dietary fat and fatty acid content modifies plasma phospholipid fatty acids, desaturase activity indices, and urinary prostaglandin E in women. Nutr Res. 2012. 32:1–7. doi:10.1016/j.nutres.2011.12.006 22260857 | Intervention/Exposure; Outcome
1907 | Rabani, Z, Feizi, A, Najafi, M, Askari, G. Comparison of dietary intake and anthropometric indicators of autistic and non-Autistic children. Annals of Tropical Medicine and Public Health. 2018. :SP30. doi:unavailable | Study Design; Outcome
1908 | Raben, A, Astrup, A, Vasilaras, TH, Prentice, AM, Zunft, HJ, Formiguera, X, Verboeket-van de Venne, WP, Poppitt, SD, Seppelt, B, Johnston, S, , . The CARMEN trial: increased intake of carbohydrates--simple or complex--and unchanged blood lipids in overweight subjects. Ugeskrift for laeger. 2002. 164:627–631. doi:unavailable11871213 | Language
1909 | Raben, A, Holst, JJ, Madsen, J, Astrup, A. Diurnal metabolic profiles after 14 d of an ad libitum high-starch, high-sucrose, or high-fat diet in normal-weight never-obese and postobese women. Am J Clin Nutr. 2001. 73:177–89. doi:10.1093/ajcn/73.2.177 11157312 | Study duration
1910 | Racette, SB, Deusinger, SS, Strube, MJ, Highstein, GR, Deusinger, RH. Weight changes, exercise, and dietary patterns during freshman and sophomore years of college. J Am Coll Health. 2005. 53:245–51. doi:10.3200/jach.53.6.245-251 15900988 | Intervention/Exposure
1911 | Raeini-Sarjaz, M, Vanstone, CA, Papamandjaris, AA, Wykes, LJ, Jones, PJ. Comparison of the effect of dietary fat restriction with that of energy restriction on human lipid metabolism. Am J Clin Nutr. 2001. 73:262–7. doi:10.1093/ajcn/73.2.262 11157322 | Study duration
1912 | Rahi, B, Ajana, S, Tabue-Teguo, M, Dartigues, JF, Peres, K, Feart, C. High adherence to a Mediterranean diet and lower risk of frailty among French older adults community-dwellers: Results from the Three-City-Bordeaux Study. Clinical Nutrition. 2018. 37:1293–1298. doi:10.1016/j.clnu.2017.05.020 28629899 | Power/Size
1913 | Rajaie, S, Azadbakht, L, Khazaei, M, Esmaillzadeh, A. Effects of a moderately-restricted carbohydrate diet on cardiovascular risk factors among women with metabolic syndrome. Journal of isfahan medical school. 2012. 29:. doi:unavailable | Publication Status
1914 | Rajaie, S, Azadbakht, L, Khazaei, M, Sherbafchi, M, Esmaillzadeh, A. Moderate replacement of carbohydrates by dietary fats affects features of metabolic syndrome: a randomized crossover clinical trial. Nutrition. 2014. 30:61–8. doi:10.1016/j.nut.2013.06.011 24290600 | Study duration
1915 | Rajaie, S, Azadbakht, L, Saneei, P, Khazaei, M, Esmaillzadeh, A. The effect of moderate substitution of dietary carbohydrates by fats on serum levels of adipocytokines, inflammatory indices, and biomarkers of endothelial function amongwomen with metabolic syndrome. Journal of zanjan university of medical sciences and health services. 2012. 20:. doi:unavailable | Language
1916 | Rajaobelina, K, Dow, C, Romana Mancini, F, Dartois, L, Boutron-Ruault, MC, Balkau, B, Bonnet, F, Fagherazzi, G. Population attributable fractions of the main type 2 diabetes mellitus risk factors in women: Findings from the French E3N cohort. J Diabetes. 2019. 11:242–253. doi:10.1111/1753-0407.12839 30098121 | Intervention/Exposure
1917 | Rallidis, LS, Lekakis, J, Kolomvotsou, A, Zampelas, A, Vamvakou, G, Efstathiou, S, Dimitriadis, G, Raptis, SA, Kremastinos, DT. Close adherence to a Mediterranean diet improves endothelial function in subjects with abdominal obesity. Am J Clin Nutr. 2009. 90:263–8. doi:10.3945/ajcn.2008.27290 19515732 | Study duration
1918 | Ralston, PA, Lemacks, JL, Wickrama, KK, Young-Clark, I, Coccia, C, Ilich, JZ, Harris, CM, Hart, CB, Battle, AM, O’Neal, CW. Reducing cardiovascular disease risk in mid-life and older African Americans: a church-based longitudinal intervention project at baseline. Contemp Clin Trials. 2014. 38:69–81. doi:10.1016/j.cct.2014.03.003 24685998 | Study Design; Outcome
1919 | Ramallal, R, Toledo, E, Martinez-Gonzalez, MA, Hernandez-Hernandez, A, Garcia-Arellano, A, Shivappa, N, Hebert, JR, Ruiz-Canela, M. Dietary Inflammatory Index and Incidence of Cardiovascular Disease in the SUN Cohort. PLoS One. 2015. 10:e0135221. doi:10.1371/journal.pone.0135221 26340022 | Intervention/Exposure
1920 | Ramon-Krauel, M, Salsberg, SL, Ebbeling, CB, Voss, SD, Mulkern, RV, Apura, MM, Cooke, EA, Sarao, K, Jonas, MM, Ludwig, DS. A low-glycemic-load versus low-fat diet in the treatment of fatty liver in obese children. Child Obes. 2013. 9:252–60. doi:10.1089/chi.2013.0022 23705885 | Intervention/Exposure
1921 | Ramos-Lopez, O, Riezu-Boj, JI, Milagro, FI, Cuervo, M, Goni, L, Alfredo Martinez, J. Models integrating genetic and lifestyle interactions on two adiposity phenotypes for personalized prescription of energy-restricted diets with different macronutrient distribution. Frontiers in Genetics. 2019. 10:. doi:10.3389/fgene.2019.00686 | Intervention/Exposure
1922 | Ramos-Lopez, O, Riezu-Boj, JI, Milagro, FI, Goni, L, Cuervo, M, Martinez, JA. Association of the Gly482Ser PPARGC1A gene variant with different cholesterol outcomes in response to two energy-restricted diets in subjects with excessive weight. Nutrition. 2018. 47:83–89. doi:10.1016/j.nut.2017.10.008 29429541 | Intervention/Exposure
1923 | Rampelli, S, Guenther, K, Turroni, S, Wolters, M, Veidebaum, T, Kourides, Y, Molnar, D, Lissner, L, Benitez-Paez, A, Sanz, Y, Fraterman, A, Michels, N, Brigidi, P, Candela, M, Ahrens, W. Pre-obese children’s dysbiotic gut microbiome and unhealthy diets may predict the development of obesity. Commun Biol. 2018. 1:222. doi:10.1038/s42003-018-0221-5 30534614 | Intervention/Exposure
1924 | Ramprasath, VR, Jenkins, DJ, Lamarche, B, Kendall, CW, Faulkner, D, Cermakova, L, Couture, P, Ireland, C, Abdulnour, S, Patel, D, Bashyam, B, Srichaikul, K, de Souza, RJ, Vidgen, E, Josse, RG, Leiter, LA, Connelly, PW, Frohlich, J, Jones, PJ. Consumption of a dietary portfolio of cholesterol lowering foods improves blood lipids without affecting concentrations of fat soluble compounds. Nutr J. 2014. 13:101. doi:10.1186/1475-2891-13-101 25326876 | Study duration
1925 | Ramprasath, VR, Jones, PJH, Buckley, DD, Woollett, LA, Heubi, JE. Decreased plasma cholesterol concentrations after pufa-rich diets are not due to reduced cholesterol absorption/synthesis. Lipids. 2012. 47:1063–1071. doi:10.1007/s11745-012-3708-8 22965757 | Study duration
1926 | Ramsden, CE, Zamora, D, Leelarthaepin, B, Majchrzak-Hong, SF, Faurot, KR, Suchindran, CM, Ringel, A, Davis, JM, Hibbeln, JR. Use of dietary linoleic acid for secondary prevention of coronary heart disease and death: evaluation of recovered data from the Sydney Diet Heart Study and updated meta-analysis. BMJ (clinical research ed.). 2013. 346:e8707. doi:10.1136/bmj.e8707 | Intervention/Exposure
1927 | Ramya Bai, RM, Anjana, RM, Unnikrishnan, R, Mohan, V. The dietary advance glycation end products (dAGE) of high carbohydrate Indian diets and its effect on inflammatory markers in overweight adults. International journal of diabetes in developing countries. 2018. 38:S122-. doi:10.1007/s13410-018-0702-6 | Study Design; Publication Status
1928 | Randolph, JM, Edirisinghe, I, Masoni, AM, Kappagoda, T, Burton-Freeman, B. Potatoes, glycemic index, and weight loss in free-living individuals: practical implications. J Am Coll Nutr. 2014. 33:375–84. doi:10.1080/07315724.2013.875441 25302575 | Intervention/Exposure
1929 | Rangan, AM, Randall, D, Hector, DJ, Gill, TP, Webb, KL. Consumption of ‘extra’ foods by Australian children: types, quantities and contribution to energy and nutrient intakes. Eur J Clin Nutr. 2008. 62:356–64. doi:10.1038/sj.ejcn.1602720 17356553 | Study Design; Intervention/Exposure
1930 | Rangel-Zuniga, OA, Camargo, A, Marin, C, Pena-Orihuela, P, Perez-Martinez, P, Delgado-Lista, J, Gonzalez-Guardia, L, Yubero-Serrano, EM, Tinahones, FJ, Malagon, MM, Perez-Jimenez, F, Roche, HM, Lopez-Miranda, J. Proteome from patients with metabolic syndrome is regulated by quantity and quality of dietary lipids. BMC Genomics. 2015. 16:509. doi:10.1186/s12864-015-1725-8 26152126 | Intervention/Exposure; Outcome
1931 | Ranjit, N, Wilkinson, AV, Lytle, LM, Evans, AE, Saxton, D, Hoelscher, DM. Socioeconomic inequalities in children’s diet: the role of the home food environment. Int J Behav Nutr Phys Act. 2015. 12 Suppl 1:S4. doi:10.1186/1479-5868-12-s1-s4 26222785 | Study Design
1932 | Rankin, JW, Turpyn, AD. Low carbohydrate, high fat diet increases C-reactive protein during weight loss. J Am Coll Nutr. 2007. 26:163–9. doi:10.1080/07315724.2007.10719598 17536128 | Outcome; Study duration
1933 | Rantala, M, Silaste, ML, Tuominen, A, Kaikkonen, J, Salonen, JT, Alfthan, G, Aro, A, Kesaniemi, YA. Dietary modifications and gene polymorphisms alter serum paraoxonase activity in healthy women. J Nutr. 2002. 132:3012–7. doi:10.1093/jn/131.10.3012 12368388 | Intervention/Exposure
1934 | Ranucci, C, Pippi, R, Buratta, L, Aiello, C, Gianfredi, V, Piana, N, Reginato, E, Tirimagni, A, Chiodini, E, Sbroma Tomaro, E, Gili, A, De Feo, P, Fanelli, C, Mazzeschi, C. Effects of an Intensive Lifestyle Intervention to Treat Overweight/Obese Children and Adolescents. Biomed Res Int. 2017. 2017:8573725. doi:10.1155/2017/8573725 28656151 | Intervention/Exposure; Outcome
1935 | Rašeta, N, Simović, S, Đurić, S, Suzić, N, Prtina, A, Zeljković, N. Eating habits and standard body parameters among students at university of banja luka. Serbian Journal of Experimental and Clinical Research. 2018. 19:41–49. doi:10.1515/SJECR-2017-0014 | Study Design
1936 | Ratliff, J, Mutungi, G, Puglisi, MJ, Volek, JS, Fernandez, ML. Carbohydrate restriction (with or without additional dietary cholesterol provided by eggs) reduces insulin resistance and plasma leptin without modifying appetite hormones in adult men. Nutr Res. 2009. 29:262–8. doi:10.1016/j.nutres.2009.03.007 19410978 | Intervention/Exposure; Comparator
1937 | Ratliff, JC, Mutungi, G, Puglisi, MJ, Volek, JS, Fernandez, ML. Eggs modulate the inflammatory response to carbohydrate restricted diets in overweight men. Nutr Metab (Lond). 2008. 5:6. doi:10.1186/1743-7075-5-6 18289377 | Intervention/Exposure
1938 | Rautiainen, S, Levitan, EB, Mittleman, MA, Wolk, A. Fruit and vegetable intake and rate of heart failure: a population-based prospective cohort of women. Eur J Heart Fail. 2015. 17:20–6. doi:10.1002/ejhf.191 25382356 | Intervention/Exposure
1939 | Rautiainen, S, Wang, L, Lee, IM, Manson, JE, Buring, JE, Sesso, HD. Higher Intake of Fruit, but Not Vegetables or Fiber, at Baseline Is Associated with Lower Risk of Becoming Overweight or Obese in Middle-Aged and Older Women of Normal BMI at Baseline. J Nutr. 2015. 145:960–8. doi:10.3945/jn.114.199158 25934663 | Intervention/Exposure
1940 | Rautio, N, Jokelainen, J, Polonen, A, Oksa, H, Peltonen, M, Vanhala, M, Puolijoki, H, Moilanen, L, Tuomilehto, J, Uusitupa, M, Keinanen-Kiukaanniemi, S, Saaristo, T. Changes in lifestyle modestly reduce the estimated cardiovascular disease risk in one-year follow-up of the Finnish diabetes prevention program (FIN-D2D). Eur J Cardiovasc Nurs. 2015. 14:145–52. doi:10.1177/1474515114521713 24452452 | Intervention/Exposure
1941 | Raynor, H, Looney, S, Steeves, EA, Spence, M, Gorin, A. The effect of a dietary energy density prescription on dietary quality, restriction, and weight loss. Obesity. 2011. 19:S113. doi:10.1038/oby.2011.226 | Publication Status
1942 | Raynor, HA, Anderson, AM, Miller, GD, Reeves, R, Delahanty, LM, Vitolins, MZ, Harper, P, Mobley, C, Konersman, K, Mayer-Davis, E. Partial Meal Replacement Plan and Quality of the Diet at 1 Year: Action for Health in Diabetes (Look AHEAD) Trial. J Acad Nutr Diet. 2015. 115:731–42. doi:10.1016/j.jand.2014.11.003 25573655 | Intervention/Exposure; Outcome
1943 | Raynor, HA, Looney, SM, Steeves, EA, Spence, M, Gorin, AA. The effects of an energy density prescription on diet quality and weight loss: a pilot randomized controlled trial. J Acad Nutr Diet. 2012. 112:1397–1402. doi:10.1016/j.jand.2012.02.020 22575072 | Intervention/Exposure
1944 | Raynor, HA, Osterholt, KM, Hart, CN, Jelalian, E, Vivier, P, Wing, RR. Efficacy of U.S. paediatric obesity primary care guidelines: two randomized trials. Pediatr Obes. 2012. 7:28–38. doi:10.1111/j.2047-6310.2011.00005.x 22434737 | Intervention/Exposure
1945 | Razquin, C, Alfredo Martinez, J, Martinez-Gonzalez, MA, Corella, D, Santos, JM, Marti, A. The Mediterranean diet protects against waist circumference enlargement in 12Ala carriers for the PPARgamma gene: 2 years’ follow-up of 774 subjects at high cardiovascular risk. Br J Nutr. 2009. 102:672–9. doi:10.1017/s0007114509289008 19267951 | Intervention/Exposure
1946 | Razquin, C, Martinez, JA, Martinez-Gonzalez, MA, Bes-Rastrollo, M, Fernandez-Crehuet, J, Marti, A. A 3-year intervention with a Mediterranean diet modified the association between the rs9939609 gene variant in FTO and body weight changes. Int J Obes (Lond). 2010. 34:266–72. doi:10.1038/ijo.2009.233 19918250 | Intervention/Exposure
1947 | Razquin, C, Martinez, JA, Martinez-Gonzalez, MA, Fernandez-Crehuet, J, Santos, JM, Marti, A. A Mediterranean diet rich in virgin olive oil may reverse the effects of the -174G/C IL6 gene variant on 3-year body weight change. Mol Nutr Food Res. 2010. 54 Suppl 1:S75–82. doi:10.1002/mnfr.200900257 20352618 | Intervention/Exposure
1948 | Razquin, C, Martinez, JA, Martinez-Gonzalez, MA, Fernández-Crehuet, J, Santos, JM, Marti, A. A mediterranean diet rich in virgin olive oil may reverse the effects of the-174g/c il6 gene variant on 3-year body weight change. Molecular Nutrition and Food Research. 2010. 54:S75–S82. doi:10.1002/mnfr.200900257 20352618 | Study Design; Intervention/Exposure
1949 | Razquin, C, Martinez, JA, Martinez-Gonzalez, MA, Salas-Salvado, J, Estruch, R, Marti, A. A 3-year Mediterranean-style dietary intervention may modulate the association between adiponectin gene variants and body weight change. Eur J Nutr. 2010. 49:311–9. doi:10.1007/s00394-009-0090-2 20035337 | Intervention/Exposure
1950 | Razquin, C, Sanchez-Tainta, A, Salas-Salvado, J, Buil-Cosiales, P, Corella, D, Fito, M, Ros, E, Estruch, R, Aros, F, Gomez-Gracia, E, Fiol, M, Lapetra, J, Serra-Majem, L, Pinto, X, Schroder, H, Tur, J, Sorli, JV, Lamuela-Raventos, RM, Bullo, M, Bes-Rastrollo, M, Martinez-Gonzalez, MA. Dietary energy density and body weight changes after 3 years in the PREDIMED study. Int J Food Sci Nutr. 2017. 68:865–872. doi:10.1080/09637486.2017.1295028 28276290 | Intervention/Exposure
1951 | Rebollo-Ramos, M, Velazquez-Diaz, D, Corral-Perez, J, Barany-Ruiz, A, Perez-Bey, A, Fernandez-Ponce, C, Garcia-Cozar, FJ, Ponce-Gonzalez, JG, Cuenca-Garcia, M. Aerobic fitness, Mediterranean diet and cardiometabolic risk factors in adults. Endocrinol Diabetes Nutr. 2019. :. doi:10.1016/j.endinu.2019.04.004 | Language
1952 | Receveur, O, Morou, K, Gray-Donald, K, Macaulay, AC. Consumption of key food items is associated with excess weight among elementary-school-aged children in a Canadian first nations community. J Am Diet Assoc. 2008. 108:362–6. doi:10.1016/j.jada.2007.09.002 18237583 | Study Design; Intervention/Exposure
1953 | Recio-Rodriguez, JI, Garcia-Yu, IA, Alonso-Dominguez, R, Maderuelo-Fernandez, JA, Patino-Alonso, MC, Agudo-Conde, C, Sanchez-Aguadero, N, Ramos, R, Marti, R, Rodriguez-Sanchez, E, Gomez-Marcos, MA, Garcia-Ortiz, L. Diet quality and carotid atherosclerosis in intermediate cardiovascular risk individuals. Nutr J. 2017. 16:40. doi:10.1186/s12937-017-0266-1 28673286 | Study Design
1954 | Reeds, J, Mansuri, S, Mamakeesick, M, Harris, SB, Zinman, B, Gittelsohn, J, Wolever, TM, Connelly, PW, Hanley, A. Dietary Patterns and Type 2 Diabetes Mellitus in a First Nations Community. Can J Diabetes. 2016. 40:304–10. doi:10.1016/j.jcjd.2016.05.001 27374251 | Power/Size
1955 | Reichard, A, Saunders, MD, Saunders, RR, Donnelly, JE, Lauer, E, Sullivan, DK, Ptomey, L. A comparison of two weight management programs for adults with mobility impairments. Disabil Health J. 2015. 8:61–9. doi:10.1016/j.dhjo.2014.08.002 25242059 | Intervention/Exposure; Comparator
1956 | Reig Garcia-Galbis, M, Rizo Baeza, M, Cortes Castell, E. INDICATORS OF SUCCESS IN THE DIETARY MANAGEMENT OF OVERWEIGHT AND OBESITY: WEIGHT, BODY FAT LOSS AND QUALITY. Nutr Hosp. 2015. 32:1009–16. doi:10.3305/nh.2015.32.3.9248 26319813 | Intervention/Exposure
1957 | Reinehr, T, Schaefer, A, Winkel, K, Finne, E, Toschke, AM, Kolip, P. An effective lifestyle intervention in overweight children: Findings from a randomized controlled trial on “Obeldicks light”. Clinical Nutrition. 2010. 29:331–336. doi:10.1016/j.clnu.2009.12.010 20106567 | Intervention/Exposure; Comparator
1958 | Renault, KM, Carlsen, EM, Norgaard, K, Nilas, L, Pryds, O, Secher, NJ, Cortes, D, Jensen, JE, Olsen, SF, Halldorsson, TI. Intake of carbohydrates during pregnancy in obese women is associated with fat mass in the newborn offspring. Am J Clin Nutr. 2015. 102:1475–81. doi:10.3945/ajcn.115.110551 26561621 | Participants
1959 | Resch, KL. Dietary Intervention Randomized Controlled Trial (DIRECT) group: weight loss with a low-carbohydrate, Mediterranean, or low-fat diet. Forschende komplementarmedizin (2006). 2008. 15:351–352. doi:unavailable19156970 | Language
1960 | Reseland, JE, Anderssen, SA, Solvoll, K, Hjermann, I, Urdal, P, Holme, I, Drevon, CA. Effect of long-term changes in diet and exercise on plasma leptin concentrations. Am J Clin Nutr. 2001. 73:240–5. doi:10.1093/ajcn/73.2.240 11157319 | Intervention/Exposure
1961 | Retterstol, K, Svendsen, M, Narverud, I, Holven, KB. Effect of low carbohydrate high fat diet on LDL cholesterol and gene expression in normal-weight, young adults: A randomized controlled study. Atherosclerosis. 2018. 279:52–61. doi:10.1016/j.atherosclerosis.2018.10.013 30408717 | Study duration
1962 | Reyes-Castillo, P, Gonzalez-Vazquez, R, Gutierrez-Nava, A, Mendoza-Perez, F, Navarro Gonzalez, MDC, Salgado-Sguayo, A, Torres-Maravilla, E, Mayorga Reyes, L, Azaola-Espinosa, A. Anthropometric measure and adipokine levels of a young undergraduate population with a usual diet. Nutr Hosp. 2019. 36:80–86. doi:10.20960/nh.1894 30836761 | Study Design
1963 | Rhyu, HS, Cho, SY, Roh, HT. The effects of ketogenic diet on oxidative stress and antioxidative capacity markers of Taekwondo athletes. J Exerc Rehabil. 2014. 10:362–6. doi:10.12965/jer.140178 25610820 | Study duration
1964 | Rhyu, HS, Cho, SY. The effect of weight loss by ketogenic diet on the body composition, performance-related physical fitness factors and cytokines of Taekwondo athletes. J Exerc Rehabil. 2014. 10:326–31. doi:10.12965/jer.140160 25426472 | Intervention/Exposure; Study duration
1965 | Ricci, C, Baumgartner, J, Zec, M, Kruger, HS, Smuts, CM. Type of dietary fat intakes in relation to all-cause and cause-specific mortality in US adults: an iso-energetic substitution analysis from the American National Health and Nutrition Examination Survey linked to the US mortality registry. Br J Nutr. 2018. 119:456–463. doi:10.1017/s0007114517003889 29498349 | Intervention/Exposure
1966 | Ricci, G, Canducci, E, Guida, A, Frascari, A, Rossi, A, Bersani, G, Ravani, B, Alvisi, V. The gender-related differences of nutrient intakes in a group of Italian obese patients display the ongoing transition from Mediterranean to western dietary patterns. Obes Surg. 2014. 24:965–7. doi:10.1007/s11695-014-1238-6 24658976 | Study Design; Comparator
1967 | Richard, C, Couture, P, Desroches, S, Lichtenstein, AH, Lamarche, B. Effect of an isoenergetic traditional Mediterranean diet on apolipoprotein A-I kinetic in men with metabolic syndrome. Nutr J. 2013. 12:76. doi:10.1186/1475-2891-12-76 24499022 | Study duration
1968 | Richard, C, Couture, P, Desroches, S, Nehme, B, Bourassa, S, Droit, A, Lamarche, B. Effect of an isoenergetic traditional Mediterranean diet on the high-density lipoprotein proteome in men with the metabolic syndrome. J Nutrigenet Nutrigenomics. 2014. 7:48–60. doi:10.1159/000363137 25011605 | Study Design; Intervention/Exposure
1969 | Richard, C, Couture, P, Ooi, EM, Tremblay, AJ, Desroches, S, Charest, A, Lichtenstein, AH, Lamarche, B. Effect of Mediterranean diet with and without weight loss on apolipoprotein B100 metabolism in men with metabolic syndrome. Arterioscler Thromb Vasc Biol. 2014. 34:433–8. doi:10.1161/atvbaha.113.302185 24265415 | Intervention/Exposure; Comparator
1970 | Ricordi, C, Garcia-Contreras, M, Farnetti, S. Diet and Inflammation: Possible Effects on Immunity, Chronic Diseases, and Life Span. J Am Coll Nutr. 2015. 34 Suppl 1:10–3. doi:10.1080/07315724.2015.1080101 26400428 | Study Design
1971 | Rietman, A, Schwarz, J, Blokker, BA, Siebelink, E, Kok, FJ, Afman, LA, Tome, D, Mensink, M. Increasing protein intake modulates lipid metabolism in healthy young men and women consuming a high-fat hypercaloric diet. J Nutr. 2014. 144:1174–80. doi:10.3945/jn.114.191072 24899158 | Study duration
1972 | Rietman, A, Schwarz, J, Siebelink, E, Kok, F, Tome, D, Mensink, M. High dietary protein intake results in lower intra hepatic lipid content in healthy humans on a hypercaloric high-fat diet. FASEB journal. 2013. 27:. doi:unavailable | Publication Status
1973 | Riggs, AJ, White, BD, Gropper, SS. Changes in energy expenditure associated with ingestion of high protein, high fat versus high protein, low fat meals among underweight, normal weight, and overweight females. Nutr J. 2007. 6:40. doi:10.1186/1475-2891-6-40 17997845 | Intervention/Exposure; Study duration
1974 | Rist, PM, Buring, JE, Kase, CS, Kurth, T. Healthy Lifestyle and Functional Outcomes from Stroke in Women. Am J Med. 2016. 129:715–724.e2. doi:10.1016/j.amjmed.2016.02.002 26899753 | Intervention/Exposure
1975 | Rito, AI, Dinis, A, Rascôa, C, Maia, A, Mendes, S, Stein-Novais, C, Lima, J. Mediterranean Diet Index (KIDMED) Adherence, Socioeconomic Determinants, and Nutritional Status of Portuguese Children: The Eat Mediterranean Program. Portuguese Journal of Public Health. 2018. 36:. doi:10.1159/000495803 | Study Design; Intervention/Exposure
1976 | Rizkalla, SW, Prifti, E, Cotillard, A, Pelloux, V, Rouault, C, Allouche, R, Laromiguiere, M, Kong, L, Darakhshan, F, Massiera, F, Clement, K. Differential effects of macronutrient content in 2 energy-restricted diets on cardiovascular risk factors and adipose tissue cell size in moderately obese individuals: a randomized controlled trial. Am J Clin Nutr. 2012. 95:49–63. doi:10.3945/ajcn.111.017277 22170375 | Study duration
1977 | Ro, A, Osborn, B. Exploring Dietary Factors in the Food Insecurity and Obesity Relationship Among Latinos in California. J Health Care Poor Underserved. 2018. 29:1108–1122. doi:10.1353/hpu.2018.0082 30122686 | Study Design; Intervention/Exposure
1978 | Roberge, JB, Van Hulst, A, Barnett, TA, Drapeau, V, Benedetti, A, Tremblay, A, Henderson, M. Lifestyle Habits, Dietary Factors, and the Metabolically Unhealthy Obese Phenotype in Youth. J Pediatr. 2019. 204:46–52.e1. doi:10.1016/j.jpeds.2018.08.063 30366774 | Intervention/Exposure
1979 | Roberts, CK, Chen, AK, Barnard, RJ. Effect of a short-term diet and exercise intervention in youth on atherosclerotic risk factors. Atherosclerosis. 2007. 191:98–106. doi:10.1016/j.atherosclerosis.2006.09.011 17054960 | Study duration
1980 | Roberts, CK, Izadpanah, A, Angadi, SS, Barnard, RJ. Effects of an intensive short-term diet and exercise intervention: comparison between normal-weight and obese children. Am J Physiol Regul Integr Comp Physiol. 2013. 305:R552–7. doi:10.1152/ajpregu.00131.2013 23883675 | Study duration
1981 | Roberts, CK, Liu, S. Carbohydrate Intake and Obesity: An Association that Needs “Refining”. Journal of the American Dietetic Association. 2009. 109:1163–1164. doi:10.1016/j.jada.2009.04.016 19559131 | Study Design; Publication Status
1982 | Roberts, CK, Ng, C, Hama, S, Eliseo, AJ, Barnard, RJ. Effect of a short-term diet and exercise intervention on inflammatory/anti-inflammatory properties of HDL in overweight/obese men with cardiovascular risk factors. J Appl Physiol (1985). 2006. 101:1727–32. doi:10.1152/japplphysiol.00345.2006 16902063 | Study duration
1983 | Roberts, CK, Ng, C, Hama, S, Eliseo, AJ, Barnard, RJ. Effect of a short-term diet and exercise intervention on inflammatory/antiinflammatory properties of HDL in overweight/obese men with cardiovascular risk factors. Journal of Applied Physiology. 2006. 101:1727–1732. doi:10.1152/japplphysiol.00345.2006 16902063 | Study duration
1984 | Roberts, CK, Vaziri, ND, Barnard, RJ. Effect of diet and exercise intervention on blood pressure, insulin, oxidative stress, and nitric oxide availability. Circulation. 2002. 106:2530–2. doi:10.1161/01.cir.0000040584.91836.0d 12427646 | Study duration
1985 | Roberts, J, Zinchenko, A, Mahbubani, K, Johnstone, J, Smith, L, Merzbach, V, Blacutt, M, Banderas, O, Villasenor, L, Varvik, FT, Henselmans, M. Satiating Effect of High Protein Diets on Resistance-Trained Subjects in Energy Deficit. Nutrients. 2018. 11:. doi:10.3390/nu11010056 | Outcome; Study duration
1986 | Roberts, K, Cade, J, Dawson, J, Holdsworth, M. Empirically Derived Dietary Patterns in UK Adults Are Associated with Sociodemographic Characteristics, Lifestyle, and Diet Quality. Nutrients. 2018. 10:. doi:10.3390/nu10020177 | Outcome
1987 | Roberts, R, Bickerton, AS, Fielding, BA, Blaak, EE, Wagenmakers, AJ, Chong, MF, Gilbert, M, Karpe, F, Frayn, KN. Reduced oxidation of dietary fat after a short term high-carbohydrate diet. Am J Clin Nutr. 2008. 87:824–31. doi:10.1093/ajcn/87.4.824 18400703 | Study duration
1988 | Roberts, SB, Das, SK. One strike against low-carbohydrate diets. Cell Metabolism. 2015. 22:357–358. doi:10.1016/j.cmet.2015.07.022 26278053 | Study Design; Publication Status
1989 | Roberts, WC. The cause of atherosclerosis. Nutr Clin Pract. 2008. 23:464–7. doi:10.1177/0884533608324586 18849550 | Study Design; Publication Status
1990 | Robinson, F, Hackett, AF, Billington, D, Stratton, G. Changing from a mixed to self-selected vegetarian diet--influence on blood lipids. J Hum Nutr Diet. 2002. 15:323–9. doi:10.1046/j.1365-277x.2002.00383.x 12270013 | Study Design; Intervention/Exposure
1991 | Roblin, DW, Robinson, BE, Benjamin, SA. Evaluation of a worksite wellness program designed to reduce cardiovascular risks. J Ambul Care Manage. 2013. 36:272–9. doi:10.1097/JAC.0b013e3182a3e728 24402067 | Intervention/Exposure
1992 | Rock, CL, Flatt, SW, Pakiz, B, Quintana, EL, Heath, DD, Rana, BK, Natarajan, L. Effects of diet composition on weight loss, metabolic factors and biomarkers in a 1-year weight loss intervention in obese women examined by baseline insulin resistance status. Metabolism. 2016. 65:1605–1613. doi:10.1016/j.metabol.2016.07.008 27733248 | Intervention/Exposure
1993 | Rodrigues, SSP, Trichopoulou, A, De Almeida, MDV. Household diet quality in relation to mortality in Portuguese regions: An ecological study. Journal of Public Health. 2008. 16:43–51. doi:10.1007/s10389-007-0113-5 | Study Design; Intervention/Exposure; Outcome
1994 | Rodriguez, JM, Leiva Balich, L, Concha, MJ, Mizon, C, Bunout Barnett, D, Barrera Acevedo, G, Hirsch Birn, S, Jimenez Jaime, T, Henriquez, S, Uribarri, J, de la Maza Cave, MP. Reduction of serum advanced glycation end-products with a low calorie Mediterranean diet. Nutr Hosp. 2015. 31:2511–7. doi:10.3305/nh.2015.31.6.8936 26040359 | Study Design
1995 | Rodriguez-Cano, A, Mier-Cabrera, J, Balas-Nakash, M, Munoz-Manrique, C, Legorreta-Legorreta, J, Perichart-Perera, O. Dietary changes associated with improvement of metabolic syndrome components in postmenopausal women receiving two different nutrition interventions. Menopause. 2015. 22:758–64. doi:10.1097/gme.0000000000000400 25563795 | Intervention/Exposure
1996 | Rodriguez-Garcia, E, Ruiz-Nava, J, Santamaria-Fernandez, S, Fernandez-Garcia, JC, Vargas-Candela, A, Yahyaoui, R, Tinahones, FJ, Bernal-Lopez, MR, Gomez-Huelgas, R. Implications of the Mediterranean diet and physical exercise on the lipid profile of metabolically healthy obese women as measured by nuclear magnetic resonance spectroscopy ((1)H NMR). Chem Phys Lipids. 2018. 213:68–75. doi:10.1016/j.chemphyslip.2018.03.007 29580835 | Intervention/Exposure; Comparator
1997 | Rodriguez-Martin, C, Alonso-Dominguez, R, Patino-Alonso, MC, Gomez-Marcos, MA, Maderuelo-Fernandez, JA, Martin-Cantera, C, Garcia-Ortiz, L, Recio-Rodriguez, JI. The EVIDENT diet quality index is associated with cardiovascular risk and arterial stiffness in adults. BMC Public Health. 2017. 17:305. doi:10.1186/s12889-017-4194-y 28390406 | Study Design
1998 | Rodriguez-Martin, C, Garcia-Ortiz, L, Rodriguez-Sanchez, E, Maderuelo-Fernandez, C, Lugones-Sanchez, A, Martin-Cantera, MS, Soriano-Cano, JF, Arietaleanizbeaskoa, M, Magdalena-Belio, JA, Menendez-Suarez, C, Gomez-Marcos, MA, Recio-Rodriguez, JI, Evident Investigators Group, Obotei. The Relationship of the Atlantic Diet with Cardiovascular Risk Factors and Markers of Arterial Stiffness in Adults without Cardiovascular Disease. Nutrients. 2019. 11:. doi:10.3390/nu11040742 | Study Design
1999 | Rodriguez-Moran, M, Guerrero-Romero, F, Rascon-Pacheco, RA. Dietary factors related to the increase of cardiovascular risk factors in traditional Tepehuanos communities from Mexico. A 10 year follow-up study. Nutr Metab Cardiovasc Dis. 2009. 19:409–16. doi:10.1016/j.numecd.2008.08.005 19150595 | Study Design
2000 | Rodriguez-Rejon, AI, Castro-Quezada, I, Ruano-Rodriguez, C, Ruiz-Lopez, MD, Sanchez-Villegas, A, Toledo, E, Artacho, R, Estruch, R, Salas-Salvado, J, Covas, MI, Corella, D, Gomez-Gracia, E, Lapetra, J, Pinto, X, Aros, F, Fiol, M, Lamuela-Raventos, RM, Ruiz-Gutierrez, V, Schroder, H, Ros, E, Martinez-Gonzalez, MA, Serra-Majem, L. Effect of a Mediterranean Diet Intervention on Dietary Glycemic Load and Dietary Glycemic Index: The PREDIMED Study. J Nutr Metab. 2014. 2014:985373. doi:10.1155/2014/985373 25295183 | Intervention/Exposure; Outcome
2001 | Rogerson, D, Macas, D, Milner, M, Liu, Y, Klonizakis, M. Contrasting Effects of Short-Term Mediterranean and Vegan Diets on Microvascular Function and Cholesterol in Younger Adults: A Comparative Pilot Study. Nutrients. 2018. 10:. doi:10.3390/nu10121897 | Study duration
2002 | Rogerson, D, McNeill, S, Kononen, H, Klonizakis, M. Encouraging effects of a short-term, adapted Nordic diet intervention on skin microvascular function and skin oxygen tension in younger and older adults. Nutrition. 2018. 49:96–101. doi:10.1016/j.nut.2017.11.001 29505921 | Study Design; Study duration
2003 | Rohde, JF, Handel, MN, Stougaard, M, Olsen, NJ, Traerup, M, Mortensen, EL, Heitmann, BL. Relationship between pickiness and subsequent development in body mass index and diet intake in obesity prone normal weight preschool children. PLoS One. 2017. 12:e0172772. doi:10.1371/journal.pone.0172772 28296896 | Intervention/Exposure
2004 | Rohde, JF, Larsen, SC, Angquist, L, Olsen, NJ, Stougaard, M, Mortensen, EL, Heitmann, BL. Effects of the Healthy Start randomized intervention on dietary intake among obesity-prone normal-weight children. Public Health Nutr. 2017. 20:2988–2997. doi:10.1017/s1368980017002026 28879820 | Outcome
2005 | Rolland, C, Broom, J. A randomised controlled trial of a low-carbohydrate vs. a very low calorie diet - A two year follow up. Obesity reviews. 2010. 11:245–246. doi: | Publication Status
2006 | Rolland, C, Hession, M, Murray, S, Wise, A, Broom, I. Randomized clinical trial of standard dietary treatment versus a low-carbohydrate/high-protein diet or the LighterLife Programme in the management of obesity*. J Diabetes. 2009. 1:207–17. doi:10.1111/j.1753-0407.2009.00033.x 20923540 | Intervention/Exposure
2007 | Rolland-Cachera, MF, Thibault, H, Souberbielle, JC, Soulie, D, Carbonel, P, Deheeger, M, Roinsol, D, Longueville, E, Bellisle, F, Serog, P. Massive obesity in adolescents: dietary interventions and behaviours associated with weight regain at 2 y follow-up. Int J Obes Relat Metab Disord. 2004. 28:514–9. doi:10.1038/sj.ijo.0802605 14968129 | Intervention/Exposure; Health Status
2008 | Romero-Moraleda, B, Peinado Lozano, AB, Morencos Martinez, E, Lopez-Plaza, B, Gomez Candela, C, Calderon Montero, FJ. Lipid profile response to weight loss program in overweight and obese patient is related with gender and age. Nutr Hosp. 2015. 31:2455–64. doi:10.3305/nh.2015.31.6.8926 26040352 | Intervention/Exposure
2009 | Roncero-Ramos, I, Alcala-Diaz, JF, Rangel-Zuniga, OA, Gomez-Delgado, F, Jimenez-Lucena, R, Garcia-Rios, A, Vals-Delgado, C, Romero-Baldonado, C, Luque, RM, Ordovas, JM, Perez-Martinez, P, Camargo, A, Lopez-Miranda, J. Prediabetes diagnosis criteria, type 2 diabetes risk and dietary modulation: The CORDIOPREV study. Clin Nutr. 2019. :. doi:10.1016/j.clnu.2019.02.027 | Intervention/Exposure; Health Status
2010 | Rondanelli, M, Klersy, C, Perna, S, Faliva, MA, Montorfano, G, Roderi, P, Colombo, I, Corsetto, PA, Fioravanti, M, Solerte, SB, Rizzo, AM. Effects of two-months balanced diet in metabolically healthy obesity: lipid correlations with gender and BMI-related differences. Lipids Health Dis. 2015. 14:139. doi:10.1186/s12944-015-0131-1 26511930 | Study Design
2011 | Root, MM, Dawson, HR. DASH-like diets high in protein or monounsaturated fats improve metabolic syndrome and calculated vascular risk. International Journal for Vitamin and Nutrition Research. 2014. 83:224–231. doi:10.1024/0300-9831/a000164 | Publication Status
2012 | Rosamond, WD, Ammerman, AS, Holliday, JL, Tawney, KW, Hunt, KJ, Keyserling, TC, Will, JC, Mokdad, AH. Cardiovascular disease risk factor intervention in low-income women: The North Carolina WISEWOMAN project. Preventive Medicine. 2000. 31:370–379. doi:10.1006/pmed.2000.0726 11006062 | Intervention/Exposure
2013 | Rosi, A, Calestani, MV, Parrino, L, Milioli, G, Palla, L, Volta, E, Brighenti, F, Scazzina, F. Weight Status Is Related with Gender and Sleep Duration but Not with Dietary Habits and Physical Activity in Primary School Italian Children. Nutrients. 2017. 9:. doi:10.3390/nu9060579 | Study Design
2014 | Ross, SM. Cardiovascular disease mortality: the deleterious effects of excess dietary sugar intake. Holist Nurs Pract. 2015. 29:53–7. doi:10.1097/hnp.0000000000000066 25470481 | Intervention/Exposure; Publication Status
2015 | Ross, SM. Effects of extra virgin olive oil phenolic compounds and the Mediterranean diet on cardiovascular health. Holist Nurs Pract. 2013. 27:303–7. doi:10.1097/HNP.0b013e3182a0c668 23925351 | Study Design
2016 | Rosvall, M, Persson, M, Ostling, G, Nilsson, PM, Melander, O, Hedblad, B, Engstrom, G. Risk factors for the progression of carotid intima-media thickness over a 16-year follow-up period: the Malmo Diet and Cancer Study. Atherosclerosis. 2015. 239:615–21. doi:10.1016/j.atherosclerosis.2015.01.030 25746169 | Intervention/Exposure
2017 | Rothacker, DQ, Ellis, PK. Elevated intakes of calcium and vitamin D without added calories and fat in overweight adults: A crossover study in Wisconsin. Current Therapeutic Research - Clinical and Experimental. 2002. 63:507–512. doi:10.1016/S0011-393X(02)80056-X | Study duration
2018 | Rouhani, MH, Kelishadi, R, Hashemipour, M, Esmaillzadeh, A, Azadbakht, L. The effect of an energy restricted low glycemic index diet on blood lipids, apolipoproteins and lipoprotein (a) among adolescent girls with excess weight: a randomized clinical trial. Lipids. 2013. 48:1197–205. doi:10.1007/s11745-013-3834-y 24000010 | Intervention/Exposure; Comparator
2019 | Rouhani, MH, Kelishadi, R, Hashemipour, M, Esmaillzadeh, A, Azadbakht, L. The effect of low glycemic index diet on body weight status and blood pressure in overweight adolescent girls: a randomized clinical trial. Nutr Res Pract. 2013. 7:385–92. doi:10.4162/nrp.2013.7.5.385 24133618 | Intervention/Exposure
2020 | Rouillier, MA, David-Riel, S, Brazeau, AS, St-Pierre, DH, Karelis, AD. Effect of an Acute High Carbohydrate Diet on Body Composition Using DXA in Young Men. Ann Nutr Metab. 2015. 66:233–6. doi:10.1159/000435840 26183608 | Study duration
2021 | Roush, K. Diets vs. combinations of fat, protein, and carbohydrates. Am J Nurs. 2009. 109:64. doi:10.1097/01.NAJ.0000363356.61507.fc | Study Design; Publication Status
2022 | Roussell, MA, Hill, AM, Gaugler, TL, West, SG, Ulbrecht, JS, Vanden Heuvel, JP, Gillies, PJ, Kris-Etherton, PM. Effects of a DASH-like diet containing lean beef on vascular health. J Hum Hypertens. 2014. 28:600–5. doi:10.1038/jhh.2014.34 24943285 | Study duration
2023 | Rousset, S, Patureau Mirand, P, Brandolini, M, Martin, JF, Boirie, Y. Daily protein intakes and eating patterns in young and elderly French. Br J Nutr. 2003. 90:1107–15. doi:10.1079/bjn20031004 14641970 | Study Design
2024 | Rowlands, DS, Hopkins, WG. Effects of high-fat and high-carbohydrate diets on metabolism and performance in cycling. Metabolism. 2002. 51:678–90. doi:10.1053/meta.2002.32723 12037719 | Study duration
2025 | Roy, BD, Luttmer, K, Bosman, MJ, Tarnopolsky, MA. The influence of post-exercise macronutrient intake on energy balance and protein metabolism in active females participating in endurance training. Int J Sport Nutr Exerc Metab. 2002. 12:172–88. doi:10.1123/ijsnem.12.2.172 12187617 | Study duration
2026 | Roy, HJ, Most, MM, Sparti, A, Lovejoy, JC, Volaufova, J, Peters, JC, Bray, GA. Effect on body weight of replacing dietary fat with olestra for two or ten weeks in healthy men and women. J Am Coll Nutr. 2002. 21:259–67. doi:10.1080/07315724.2002.10719219 12074254 | Study duration
2027 | Ruan, Y, Huang, Y, Zhang, Q, Qin, S, Du, X, Sun, Y. Association between dietary patterns and hypertension among Han and multi-ethnic population in southwest China. BMC Public Health. 2018. 18:1106. doi:10.1186/s12889-018-6003-7 30200909 | Study Design
2028 | Rubini, A, Bosco, G, Lodi, A, Cenci, L, Parmagnani, A, Grimaldi, K, Zhongjin, Y, Paoli, A. Effects of Twenty Days of the Ketogenic Diet on Metabolic and Respiratory Parameters in Healthy Subjects. Lung. 2015. 193:939–45. doi:10.1007/s00408-015-9806-7 26410589 | Study duration
2029 | Ruiz-Cabello Turmo, P, Aparicio Garcia-Molina, V, Fernandez Martinez Mdel, M, Moratalla Cecilia, N, Gregorio Arenas, E, Aranda Ramirez, P. Mediterranean countries facing the Mediterranean Diet, are we still on track? The example of southern Spain midlife women. Nutr Hosp. 2015. 31:2523–32. doi:10.3305/nh.2015.31.6.8862 26040361 | Study Design
2030 | Ruiz-Canela, M, Guasch-Ferre, M, Toledo, E, Clish, CB, Razquin, C, Liang, L, Wang, DD, Corella, D, Estruch, R, Hernaez, A, Yu, E, Gomez-Gracia, E, Zheng, Y, Aros, F, Romaguera, D, Dennis, C, Ros, E, Lapetra, J, Serra-Majem, L, Papandreou, C, Portoles, O, Fito, M, Salas-Salvado, J, Hu, FB, Martinez-Gonzalez, MA. Plasma branched chain/aromatic amino acids, enriched Mediterranean diet and risk of type 2 diabetes: case-cohort study within the PREDIMED Trial. Diabetologia. 2018. 61:1560–1571. doi:10.1007/s00125-018-4611-5 29663011 | Intervention/Exposure; Comparator
2031 | Ruottinen, S, Ronnemaa, T, Niinikoski, H, Lagstrom, H, Saarinen, M, Pahkala, K, Kaitosaari, T, Viikari, J, Simell, O. Carbohydrate intake, serum lipids and apolipoprotein E phenotype show association in children. Acta Paediatr. 2009. 98:1667–73. doi:10.1111/j.1651-2227.2009.01399.x 19563454 | Intervention/Exposure
2032 | Rush, E, Paterson, J, Obolonkin, V. Food frequency information-relationships to body composition and apparent growth in 4-year-old children in the Pacific Island Family Study. New Zealand Medical Journal. 2008. 121:63–71. doi:unavailable | Study Design
2033 | Rushing, K, Stenhouse, A, Evans, M, Huffman, L, Bowie, V. A low-carbohydrate diet versus a low-calorie diet: Poor retention. Topics in Clinical Nutrition. 2006. 21:251–259. doi:10.1097/00008486-200610000-00002 | Intervention/Exposure
2034 | Russell, JC, Flood, VM, Sadeghpour, A, Gopinath, B, Mitchell, P. Total Diet Score as a valid method of measuring diet quality among older adults. Asia Pac J Clin Nutr. 2017. 26:212–219. doi:10.6133/apjcn.122015.08 28244697 | Intervention/Exposure; Outcome
2035 | Ruth, MR, Port, AM, Shah, M, Bourland, AC, Istfan, NW, Nelson, KP, Gokce, N, Apovian, CM. Consuming a hypocaloric high fat low carbohydrate diet for 12 weeks lowers C-reactive protein, and raises serum adiponectin and high density lipoprotein-cholesterol in obese subjects. Metabolism. 2013. 62:1779–87. doi:10.1016/j.metabol.2013.07.006 24075505 | Power/Size
2036 | Ruth, MR, Shah, M, Bourland, A, Port, AM, Gokce, N, Apovian, C. A 12-week hypocaloric low-carbohydrate diet improves inflammation and cardiovascular risk factors in obese adults. Obesity. 2011. 19:S114. doi:10.1038/oby.2011.226 | Publication Status
2037 | Ryberg, M, Sandberg, S, Mellberg, C, Stegle, O, Lindahl, B, Larsson, C, Hauksson, J, Olsson, T. A Palaeolithic-type diet causes strong tissue-specific effects on ectopic fat deposition in obese postmenopausal women. J Intern Med. 2013. 274:67–76. doi:10.1111/joim.12048 23414424 | Study Design
2038 | Ryman, TK, Boyer, BB, Hopkins, S, Philip, J, Beresford, SA, Thompson, B, Heagerty, PJ, Pomeroy, JJ, Thummel, KE, Austin, MA. Associations between diet and cardiometabolic risk among Yup’ik Alaska Native people using food frequency questionnaire dietary patterns. Nutr Metab Cardiovasc Dis. 2015. 25:1140–5. doi:10.1016/j.numecd.2015.08.003 26607703 | Study Design; Intervention/Exposure
2039 | Sabrina, N, Bai, CH, Chang, CC, Chien, YW, Chen, JR, Chang, JS. Serum Iron:Ferritin Ratio Predicts Healthy Body Composition and Reduced Risk of Severe Fatty Liver in Young Adult Women. Nutrients. 2017. 9:. doi:10.3390/nu9080833 | Study Design
2040 | Sacks, FM, Bray, GA, Carey, VJ, Smith, SR, Ryan, DH, Anton, SD, McManus, K, Champagne, CM, Bishop, LM, Laranjo, N, Leboff, MS, Rood, JC, de Jonge, L, Greenway, FL, Loria, CM, Obarzanek, E, Williamson, DA. Comparison of weight-loss diets with different compositions of fat, protein, and carbohydrates. N Engl J Med. 2009. 360:859–73. doi:10.1056/NEJMoa0804748 19246357 | Weight loss/Hypocaloric
2041 | Sacks, FM, Carey, VJ, Anderson, CA, Miller, ER, 3rd, Copeland, T, Charleston, J, Harshfield, BJ, Laranjo, N, McCarron, P, Swain, J, White, K, Yee, K, Appel, LJ. Effects of high vs low glycemic index of dietary carbohydrate on cardiovascular disease risk factors and insulin sensitivity: the OmniCarb randomized clinical trial. Jama. 2014. 312:2531–41. doi:10.1001/jama.2014.16658 25514303 | Study duration
2042 | Sacks, FM, Svetkey, LP, Vollmer, WM, Appel, LJ, Bray, GA, Harsha, D, Obarzanek, E, Conlin, PR, Miller, ER, 3rd, Simons-Morton, DG, Karanja, N, Lin, PH. Effects on blood pressure of reduced dietary sodium and the Dietary Approaches to Stop Hypertension (DASH) diet. DASH-Sodium Collaborative Research Group. N Engl J Med. 2001. 344:3–10. doi:10.1056/nejm200101043440101 11136953 | Intervention/Exposure; Publication Date
2043 | Sadeghi, M, Talaei, M, Parvaresh Rizi, E, Dianatkhah, M, Oveisgharan, S, Sarrafzadegan, N. Determinants of incident prediabetes and type 2 diabetes in a 7-year cohort in a developing country: The Isfahan Cohort Study. J Diabetes. 2015. 7:633–41. doi:10.1111/1753-0407.12236 25350916 | Country
2044 | Sadov, S, Virtanen, HE, Main, KM, Andersson, AM, Juul, A, Jula, A, Raitakari, OT, Pahkala, K, Niinikoski, H, Toppari, J. Low-saturated-fat and low-cholesterol diet does not alter pubertal development and hormonal status in adolescents. Acta Paediatrica, International Journal of Paediatrics. 2019. 108:321–327. doi:10.1111/apa.14480 | Outcome
2045 | Safaeiyan, A, Pourghassem-Gargari, B, Zarrin, R, Fereidooni, J, Alizadeh, M. Randomized controlled trial on the effects of legumes on cardiovascular risk factors in women with abdominal obesity. ARYA Atheroscler. 2015. 11:117–25. doi:unavailable26405440 | Intervention/Exposure
2046 | Saffari, M, Pakpour, AH, Mohammadi-Zeidi, I, Samadi, M, Chen, H. Long-term effect of motivational interviewing on dietary intake and weight loss in Iranian obese/overweight women. Health Promot Perspect. 2014. 4:206–13. doi:10.5681/hpp.2014.027 25648690 | Intervention/Exposure
2047 | Saha, S, Nordstrom, J, Gerdtham, UG, Mattisson, I, Nilsson, PM, Scarborough, P. Prevention of Cardiovascular Disease and Cancer Mortality by Achieving Healthy Dietary Goals for the Swedish Population: A Macro-Simulation Modelling Study. Int J Environ Res Public Health. 2019. 16:. doi:10.3390/ijerph16050890 | Study Design
2048 | Saha, S, Nordstrom, J, Mattisson, I, Nilsson, PM, Gerdtham, UG. Modelling the Effect of Compliance with Nordic Nutrition Recommendations on Cardiovascular Disease and Cancer Mortality in the Nordic Countries. Nutrients. 2019. 11:. doi:10.3390/nu11061434 | Study Design; Intervention/Exposure
2049 | Said, N, Nor, NM, Sharoni, SKA. A Preliminary study of the evaluation on the dietary pattern among obese school children. Indian Journal of Public Health Research and Development. 2019. 10:1416–1421. doi:10.5958/0976-5506.2019.00912.4 | Study Design
2050 | Saint-Maurice, PF, Coughlan, D, Kelly, SP, Keadle, SK, Cook, MB, Carlson, SA, Fulton, JE, Matthews, CE. Association of Leisure-Time Physical Activity Across the Adult Life Course With All-Cause and Cause-Specific Mortality. JAMA Netw Open. 2019. 2:e190355. doi:10.1001/jamanetworkopen.2019.0355 30848809 | Intervention/Exposure
2051 | Sakae, PN, Bianco, HT, Camargo, LM, Carvalho, JG, Izar, MCO, Ihara, SSM, Fonseca, FAH. Effect of high protein/very low carbohydrate diet and standard hypocaloric diet in obese subjects: nutritional, biochemical and endothelial function evaluations. BBA clinical. Conference: 15th brazilian congress of atherosclerosis. Brazil. Conference start: 20150814. Conference end: 20150815. 2015. 3:S7. doi:10.1016/j.bbacli.2015.05.020 | Publication Status
2052 | Sakurai, Y, Tamura, Y, Takeno, K, Kumashiro, N, Sato, F, Kakehi, S, Ikeda, S, Ogura, Y, Saga, N, Naito, H, Katamoto, S, Fujitani, Y, Hirose, T, Kawamori, R, Watada, H. Determinants of intramyocellular lipid accumulation after dietary fat loading in non-obese men. J Diabetes Investig. 2011. 2:310–7. doi:10.1111/j.2040-1124.2010.00091.x | Study duration
2053 | Salas-Salvado, J, Diaz-Lopez, A, Ruiz-Canela, M, Basora, J, Fito, M, Corella, D, Serra-Majem, L, Warnberg, J, Romaguera, D, Estruch, R, Vidal, J, Martinez, JA, Aros, F, Vazquez, C, Ros, E, Vioque, J, Lopez-Miranda, J, Bueno-Cavanillas, A, Tur, JA, Tinahones, FJ, Martin, V, Lapetra, J, Pinto, X, Daimiel, L, Delgado-Rodriguez, M, Matia, P, Gomez-Gracia, E, Diez-Espino, J, Babio, N, Castaner, O, Sorli, JV, Fiol, M, Zulet, MA, Bullo, M, Goday, A, Martinez-Gonzalez, MA. Effect of a Lifestyle Intervention Program With Energy-Restricted Mediterranean Diet and Exercise on Weight Loss and Cardiovascular Risk Factors: One-Year Results of the PREDIMED-Plus Trial. Diabetes Care. 2019. 42:777–788. doi:10.2337/dc18-0836 30389673 | Intervention/Exposure; Comparator
2054 | Salas-Salvado, J, Fernandez-Ballart, J, Ros, E, Martinez-Gonzalez, MA, Fito, M, Estruch, R, Corella, D, Fiol, M, Gomez-Gracia, E, Aros, F, Flores, G, Lapetra, J, Lamuela-Raventos, R, Ruiz-Gutierrez, V, Bullo, M, Basora, J, Covas, MI. Effect of a Mediterranean diet supplemented with nuts on metabolic syndrome status: one-year results of the PREDIMED randomized trial. Arch Intern Med. 2008. 168:2449–2458. doi:10.1001/archinte.168.22.2449 19064829 | Study Design; Publication Date Overlaps with Existing Review
2055 | Salas-Salvado, J. Weight loss using a healthy diet and exercise promotion to prevent cardiovascular disease: the predimed-plus trial. Annals of nutrition & metabolism. 2017. 71:24-. doi:10.1159/000480486 | Publication Status
2056 | Saldanha-Gomes, C, Heude, B, Charles, MA, de Lauzon-Guillain, B, Botton, J, Carles, S, Forhan, A, Dargent-Molina, P, Lioret, S. Prospective associations between energy balance-related behaviors at 2 years of age and subsequent adiposity: the EDEN mother-child cohort. Int J Obes (Lond). 2017. 41:38–45. doi:10.1038/ijo.2016.138 27528250 | Power/Size
2057 | Sallinen, J, Pakarinen, A, Fogelholm, M, Alen, M, Volek, JS, Kraemer, WJ, Häkkinen, K. Dietary intake, serum hormones, muscle mass and strength during strength training in 49-73-year-old men. International Journal of Sports Medicine. 2007. 28:1070–1076. doi:10.1055/s-2007-965003 17497592 | Intervention/Exposure
2058 | Salmeron, J, Hu, FB, Manson, JE, Stampfer, MJ, Colditz, GA, Rimm, EB, Willett, WC. Dietary fat intake and risk of type 2 diabetes in women. Am J Clin Nutr. 2001. 73:1019–26. doi:10.1093/ajcn/73.6.1019 11382654 | Intervention/Exposure
2059 | Salo, P, Viikari, J, Hamalainen, M, Lapinleimu, H, Routi, T, Niinikoski, H, Rask-Nissila, L, Tammi, A, Ronnemaa, T, Seppanen, R, Jokinen, E, Valimaki, I, Simell, O. Fatty acid composition of serum cholesterol esters as a reflector of low-saturated-fat, low-cholesterol diet in young children: the STRIP project. The Special Turku coronary Risk factor Intervention Project. Acta Paediatr. 2000. 89:399–405. doi:10.1080/080352500750028087 10830449 | Intervention/Exposure
2060 | Salvia, R, D’Amore, S, Graziano, G, Capobianco, C, Sangineto, M, Paparella, D, de Bonfils, P, Palasciano, G, Vacca, M. Short-term benefits of an unrestricted-calorie traditional Mediterranean diet, modified with a reduced consumption of carbohydrates at evening, in overweight-obese patients. Int J Food Sci Nutr. 2017. 68:234–248. doi:10.1080/09637486.2016.1228100 27615385 | Intervention/Exposure
2061 | Samaha, FF, Iqbal, N, Seshadri, P, Chicano, KL, Daily, DA, McGrory, J, Williams, T, Williams, M, Gracely, EJ, Stern, L. A low-carbohydrate as compared with a low-fat diet in severe obesity. N Engl J Med. 2003. 348:2074–81. doi:10.1056/NEJMoa022637 12761364 | Weight loss/Hypocaloric
2062 | Samkani, A, Skytte, MJ, Thomsen, MN, Astrup, A, Deacon, CF, Holst, JJ, Madsbad, S, Rehfeld, JF, Krarup, T, Haugaard, SB. Acute Effects of Dietary Carbohydrate Restriction on Glycemia, Lipemia and Appetite Regulating Hormones in Normal-Weight to Obese Subjects. Nutrients. 2018. 10:. doi:10.3390/nu10091285 | Study Design; Intervention/Exposure; Study duration
2063 | Samman, S, Lai, NT, Sullivan, DR. The effect of a lipid-lowering diet on plasma lipids and lipoproteins in mildly hypercholesterolaemic subjects: A potential role for occasional treats. Journal of Nutritional Biochemistry. 2000. 11:250–254. doi:10.1016/S0955-2863(00)00072-3 | Study Design; Intervention/Exposure
2064 | San Mauro Martin, I, Sanz Rojo, S, Becerra, X, Garicano Vilar, E. Successful Implementation of a Mediterranean Weight Loss Program to Prevent Overweight and Obesity in the Workplace. Journal of Occupational and Environmental Medicine. 2019. 61:E329–E332. doi:10.1097/JOM.0000000000001628 31090674 | Study Design; Intervention/Exposure
2065 | Sanchez-Bayle, M, Soriano-Guillen, L. Influence of dietary intervention on growth in children with hypercholesterolaemia. Acta Paediatr. 2003. 92:1043–6. doi:10.1080/08035250310004775 14599067 | Study Design
2066 | Sanchez-Benito, JL, Sanchez Soriano, E. The excesive intake of macronutrients: does it influence the sports performances of young cyclists?. Nutr Hosp. 2007. 22:461–70. doi:unavailable17650887 | Study Design
2067 | Sanchez-Oliva, D, Grao-Cruces, A, Carbonell-Baeza, A, Cabanas-Sanchez, V, Veiga, OL, Castro-Pinero, J. Lifestyle Clusters in School-Aged Youth and Longitudinal Associations with Fatness: The UP&DOWN Study. J Pediatr. 2018. 203:317–324.e1. doi:10.1016/j.jpeds.2018.07.092 30243538 | Intervention/Exposure; Comparator
2068 | Sanchez-Villegas, A, Bes-Rastrollo, M, Martinez-Gonzalez, MA, Serra-Majem, L. Adherence to a Mediterranean dietary pattern and weight gain in a follow-up study: the SUN cohort. Int J Obes (Lond). 2006. 30:350–8 https://www.ncbi.nlm.nih.gov/pubmed/16231028 16231028 | Data overlap with another included article
2069 | Sanchez-Villegas, A, Ruiz-Canela, M, de la Fuente-Arrillaga, C, Gea, A, Shivappa, N, Hebert, JR, Martinez-Gonzalez, MA. Dietary inflammatory index, cardiometabolic conditions and depression in the Seguimiento Universidad de Navarra cohort study. Br J Nutr. 2015. 114:1471–9. doi:10.1017/s0007114515003074 26344165 | Intervention/Exposure
2070 | San-Cristobal, R, Navas-Carretero, S, Celis-Morales, C, Brennan, L, Walsh, M, Lovegrove, JA, Daniel, H, Saris, WH, Traczyk, I, Manios, Y, Gibney, ER, Gibney, MJ, Mathers, JC, Martinez, JA. Analysis of Dietary Pattern Impact on Weight Status for Personalised Nutrition through On-Line Advice: The Food4Me Spanish Cohort. Nutrients. 2015. 7:9523–37. doi:10.3390/nu7115482 26593942 | Power/Size
2071 | San-Cristobal, R, Navas-Carretero, S, Celis-Morales, C, Livingstone, KM, Stewart-Knox, B, Rankin, A, Macready, AL, Fallaize, R, O’Donovan, CB, Forster, H, Woolhead, C, Walsh, MC, Lambrinou, CP, Moschonis, G, Manios, Y, Jarosz, M, Daniel, H, Gibney, ER, Brennan, L, Gundersen, TE, Drevon, CA, Gibney, M, Marsaux, CFM, Saris, WHM, Lovegrove, JA, Frewer, LJ, Mathers, JC, Martinez, JA. Capturing health and eating status through a nutritional perception screening questionnaire (NPSQ9) in a randomised internet-based personalised nutrition intervention: the Food4Me study. Int J Behav Nutr Phys Act. 2017. 14:168. doi:10.1186/s12966-017-0624-6 29228998 | Study Design
2072 | Sanderlin, AH, Hoscheidt, SM, Hanson, AJ, Baker, LD, Sink, KM, Wittmer, P, Craft, S. THE EFFECTS OF DIET INTERVENTION ON METABOLIC HEALTH AND CEREBRAL SPINAL FLUID ALZHEIMER’S DISEASE BIOMARKERS: a RANDOMIZED TRIAL. Alzheimer’s & dementia. 2018. 14:P1069–P1070. doi:10.1016/j.jalz.2018.06.1374 | Publication Status
2073 | Saneei, P, Hashemipour, M, Kelishadi, R, Esmaillzadeh, A. The Dietary Approaches to Stop Hypertension (DASH) diet affects inflammation in childhood metabolic syndrome: a randomized cross-over clinical trial. Ann Nutr Metab. 2014. 64:20–7. doi:10.1159/000358341 24686130 | Outcome
2074 | Saneei, P, Hashemipour, M, Kelishadi, R, Rajaei, S, Esmaillzadeh, A. Effects of recommendations to follow the Dietary Approaches to Stop Hypertension (DASH) diet v. usual dietary advice on childhood metabolic syndrome: a randomised cross-over clinical trial. Br J Nutr. 2013. 110:2250–9. doi:10.1017/s0007114513001724 23773316 | Intervention/Exposure; Comparator
2075 | Santiago, S, Zazpe, I, Bes-Rastrollo, M, Sanchez-Tainta, A, Sayon-Orea, C, de la Fuente-Arrillaga, C, Benito, S, Martinez, JA, Martinez-Gonzalez, MA. Carbohydrate quality, weight change and incident obesity in a Mediterranean cohort: the SUN Project. Eur J Clin Nutr. 2015. 69:297–302. doi:10.1038/ejcn.2014.187 25226822 | Intervention/Exposure
2076 | Santiago-Torres, M, De Dieu Tapsoba, J, Kratz, M, Lampe, JW, Breymeyer, KL, Levy, L, Song, X, Villasenor, A, Wang, CY, Fejerman, L, Neuhouser, ML, Carlson, CS. Genetic ancestry in relation to the metabolic response to a US versus traditional Mexican diet: a randomized crossover feeding trial among women of Mexican descent. Eur J Clin Nutr. 2017. 71:395–401. doi:10.1038/ejcn.2016.211 27966572 | Study duration
2077 | Santiago-Torres, M, Kratz, M, Lampe, JW, Tapsoba Jde, D, Breymeyer, KL, Levy, L, Villasenor, A, Wang, CY, Song, X, Neuhouser, ML. Metabolic responses to a traditional Mexican diet compared with a commonly consumed US diet in women of Mexican descent: a randomized crossover feeding trial. Am J Clin Nutr. 2016. 103:366–74. doi:10.3945/ajcn.115.119016 26718418 | Study duration
2078 | Santomauro, F, Lorini, C, Tanini, T, Indiani, L, Lastrucci, V, Comodo, N, Bonaccorsi, G. Adherence to Mediterranean diet in a sample of Tuscan adolescents. Nutrition. 2014. 30:1379–83. doi:10.1016/j.nut.2014.04.008 25280416 | Study Design; Outcome
2079 | Santos, LP, Assuncao, MCF, Matijasevich, A, Santos, IS, Barros, AJD. Dietary intake patterns of children aged 6 years and their association with socioeconomic and demographic characteristics, early feeding practices and body mass index. BMC Public Health. 2016. 16:1055. doi:10.1186/s12889-016-3725-2 27716197 | Study Design; Intervention/Exposure
2080 | Santos, LP, Ong, KK, Santos, IS, Matijasevich, A, Barros, AJD. Effects of dietary intake patterns from 1 to 4 years on BMI z-score and body shape at age of 6 years: a prospective birth cohort study from Brazil. Eur J Nutr. 2019. 58:1723–1734. doi:10.1007/s00394-018-1720-3 29774385 | Country
2081 | Santos, RD, Suen, VM, Iannetta, O, Marchini, JS. Climacteric, physically active women ingesting their routine diet oxidize more carbohydrates than lipids. Climacteric. 2008. 11:454–60. doi:10.1080/13697130802398491 18821186 | Study Design
2082 | Saquib, N, Natarajan, L, Rock, CL, Flatt, SW, Madlensky, L, Kealey, S, Pierce, JP. The impact of a long-term reduction in dietary energy density on body weight within a randomized diet trial. Nutr Cancer. 2008. 60:31–8. doi:10.1080/01635580701621320 18444133 | Intervention/Exposure; Publication Date Overlaps with Existing Review
2083 | Saracci, R. The dietary prevention of ischaemic heart disease. IARC Sci Publ. 2002. 156:531–3. doi:unavailable12484252 | Study Design; Publication Status
2084 | Saraf-Bank, S, Esmaillzadeh, A, Faghihimani, E, Azadbakht, L. Effects of Legume-Enriched Diet on Cardiometabolic Risk Factors among Individuals at Risk for Diabetes: A Crossover Study. J Am Coll Nutr. 2016. 35:31–40. doi:10.1080/07315724.2014.931262 25758041 | Study duration
2085 | Sarebanhassanabadi, M, Mirhosseini, SJ, Mirzaei, M, Namayandeh, SM, Soltani, MH, Pakseresht, M, Pedarzadeh, A, Baramesipour, Z, Faraji, R, Salehi-Abargouei, A. Effect of dietary habits on the risk of metabolic syndrome: Yazd Healthy Heart Project. Public Health Nutr. 2018. 21:1139–1146. doi:10.1017/s1368980017003627 29233205 | Intervention/Exposure; Outcome
2086 | Sarebanhassanabadi, M, Mirhosseini, SJ, Mirzaei, M, Namayandeh, SM, Soltani, MH, Salehi-Abargouei, A. The association between a dietary habits score and the risk of metabolic syndrome: A cohort study. Clin Nutr. 2019. :. doi:10.1016/j.clnu.2019.02.005 | Intervention/Exposure; Country
2087 | Sares-Jaske, L, Knekt, P, Lundqvist, A, Heliovaara, M, Mannisto, S. Dieting attempts modify the association between quality of diet and obesity. Nutr Res. 2017. 45:63–72. doi:10.1016/j.nutres.2017.08.001 28967457 | Study Design
2088 | Saris, WH. The fat/carbohydrate ratio in the diet--implications for a healthy diet. Int Dent J. 2001. 51:407. doi:10.1111/j.1875-595x.2001.tb00587.x 11794562 | Publication Status
2089 | Saris, WHM, Astrup, A, Prentice, AM, Zunft, HJF, Formiguera, X, Verboeket-Van De Venne, WPHG, Raben, A, Poppitt, SD, Seppelt, B, Johnston, S, Vasilaras, TH, Keogh, GF. Randomized controlled trial of changes in dietary carbohydrate/fat ratio and simple vs complex carbohydrates on body weight and blood lipids: The CARMEN study. International Journal of Obesity. 2000. 24:1310–1318. doi:10.1038/sj.ijo.0801451 11093293 | Intervention/Exposure
2090 | Sarter, B, Campbell, TC, Fuhrman, J. Effect of a high nutrient density diet on long-term weight loss: a retrospective chart review. Altern Ther Health Med. 2008. 14:48–53. doi:unavailable | Study Design; Intervention/Exposure
2091 | Saslow, LR, Daubenmier, JJ, Moskowitz, JT, Kim, S, Murphy, EJ, Phinney, SD, Ploutz-Snyder, R, Goldman, V, Cox, RM, Mason, AE, Moran, P, Hecht, FM. Twelve-month outcomes of a randomized trial of a moderate-carbohydrate versus very low-carbohydrate diet in overweight adults with type 2 diabetes mellitus or prediabetes. Nutr Diabetes. 2017. 7:304. doi:10.1038/s41387-017-0006-9 29269731 | Intervention/Exposure
2092 | Sauvaget, C, Nagano, J, Allen, N, Grant, EJ, Beral, V. Intake of animal products and stroke mortality in the Hiroshima/Nagasaki Life Span Study. Int J Epidemiol. 2003. 32:536–43. doi:10.1093/ije/dyg151 12913025 | Intervention/Exposure
2093 | Sauvaget, C, Nagano, J, Hayashi, M, Yamada, M. Animal protein, animal fat, and cholesterol intakes and risk of cerebral infarction mortality in the adult health study. Stroke. 2004. 35:1531–7. doi:10.1161/01.Str.0000130426.52064.09 15166397 | Intervention/Exposure
2094 | Sayer, R, Chen, N, Wright, A, Campbell, W. The effects of pork vs. Chicken/fish in a DASH diet on blood pressure control. FASEB journal. Conference: experimental biology 2014, EB. San diego, CA united states. 2014. 28:. doi:unavailable | Publication Status
2095 | Sayer, RD, Speaker, KJ, Pan, Z, Peters, JC, Wyatt, HJ, Hill, JO. Body fat changes in the beef WISE study: beef’s role in weight improvement, satisfaction, and energy. FASEB journal. 2017. 31:. doi:unavailable | Publication Status
2096 | Sayer, RD, Speaker, KJ, Pan, Z, Peters, JC, Wyatt, HR, Hill, JO. Equivalent reductions in body weight during the Beef WISE Study: beef’s role in weight improvement, satisfaction and energy. Obesity Science and Practice. 2017. 3:298–310. doi:10.1002/osp4.118 29071106 | Weight loss/Hypocaloric
2097 | Sayer, RD, Wright, AJ, Chen, N, Campbell, WW. Dietary Approaches to Stop Hypertension diet retains effectiveness to reduce blood pressure when lean pork is substituted for chicken and fish as the predominant source of protein. Am J Clin Nutr. 2015. 102:302–8. doi:10.3945/ajcn.115.111757 26063693 | Study duration
2098 | Scaglioni, S, Agostoni, C, Notaris, RD, Radaelli, G, Radice, N, Valenti, M, Giovannini, M, Riva, E. Early macronutrient intake and overweight at five years of age. Int J Obes Relat Metab Disord. 2000. 24:777–81. doi:10.1038/sj.ijo.0801225 10878686 | Intervention/Exposure
2099 | Scanlan, B, McTigue, KM, Wang, L, Winger, D, Conroy, MB. Association of eating habits with weight loss and diet self monitoring in an online weight loss trial: results from the OCELOT-PC study. Journal of general internal medicine. 2015. 30:S105. doi:unavailable | Publication Status
2100 | Scarapicchia, TM, Sabiston, CM, Faulkner, G. Exploring the prevalence and correlates of meeting health behaviour guidelines among university students. Can J Public Health. 2015. 106:e109–14. doi:10.17269/cjph.106.4784 26125235 | Study Design; Intervention/Exposure
2101 | Scarborough, P, Nnoaham, KE, Clarke, D, Capewell, S, Rayner, M. Modelling the impact of a healthy diet on cardiovascular disease and cancer mortality. J Epidemiol Community Health. 2012. 66:420–6. doi:10.1136/jech.2010.114520 21172796 | Study Design
2102 | Scherr, R, Linnell, J, Smith, M, Nicholson, Y, Spezzano, T, Bergman, J, Brian, K, Briggs, M, Feenstra, G, Hillhouse, C, , . The Shaping Healthy Choices Program results in improved nutrition and health-related outcomes. FASEB journal. 2014. 28:. doi:unavailable | Publication Status
2103 | Schioldan, AG, Gregersen, S, Hald, S, Bjornshave, A, Bohl, M, Hartmann, B, Holst, JJ, Stodkilde-Jorgensen, H, Hermansen, K. Effects of a diet rich in arabinoxylan and resistant starch compared with a diet rich in refined carbohydrates on postprandial metabolism and features of the metabolic syndrome. Eur J Nutr. 2018. 57:795–807. doi:10.1007/s00394-016-1369-8 28070639 | Intervention/Exposure
2104 | Schmedes, M, Balderas, C, Aadland, EK, Jacques, H, Lavigne, C, Graff, IE, Eng, O, Holthe, A, Mellgren, G, Young, JF, Sundekilde, UK, Liaset, B, Bertram, HC. The Effect of Lean-Seafood and Non-Seafood Diets on Fasting and Postprandial Serum Metabolites and Lipid Species: Results from a Randomized Crossover Intervention Study in Healthy Adults. Nutrients. 2018. 10:. doi:10.3390/nu10050598 | Intervention/Exposure; Outcome
2105 | Schnabel, L, Kesse-Guyot, E, Alles, B, Touvier, M, Srour, B, Hercberg, S, Buscail, C, Julia, C. Association Between Ultraprocessed Food Consumption and Risk of Mortality Among Middle-aged Adults in France. JAMA Intern Med. 2019. 179:490–498. doi:10.1001/jamainternmed.2018.7289 30742202 | Outcome
2106 | Schneider, BC, Dumith Sde, C, Lopes, C, Severo, M, Assuncao, MC. How Do Tracking and Changes in Dietary Pattern during Adolescence Relate to the Amount of Body Fat in Early Adulthood?. PLoS One. 2016. 11:e0149299. doi:10.1371/journal.pone.0149299 26907178 | Country
2107 | Schooff, M. Are low-fat diets better than other weight-reducing diets in achieving long-term weight loss?. Am Fam Physician. 2003. 67:507–8. doi:unavailable12588072 | Study Design
2108 | Schrauwen, P, Wagenmakers, AJ, van Marken Lichtenbelt, WD, Saris, WH, Westerterp, KR. Increase in fat oxidation on a high-fat diet is accompanied by an increase in triglyceride-derived fatty acid oxidation. Diabetes. 2000. 49:640–6. doi:10.2337/diabetes.49.4.640 10871203 | Study duration
2109 | Schrauwen-Hinderling, VB, Kooi, ME, Hesselink, MK, Moonen-Kornips, E, Schaart, G, Mustard, KJ, Hardie, DG, Saris, WH, Nicolay, K, Schrauwen, P. Intramyocellular lipid content and molecular adaptations in response to a 1-week high-fat diet. Obes Res. 2005. 13:2088–94. doi:10.1038/oby.2005.259 16421342 | Study duration
2110 | Schrempft, S, van Jaarsveld, CH, Fisher, A, Wardle, J. The Obesogenic Quality of the Home Environment: Associations with Diet, Physical Activity, TV Viewing, and BMI in Preschool Children. PLoS One. 2015. 10:e0134490. doi:10.1371/journal.pone.0134490 26248313 | Intervention/Exposure
2111 | Schrijvers, JK, McNaughton, SA, Beck, KL, Kruger, R. Exploring the Dietary Patterns of Young New Zealand Women and Associations with BMI and Body Fat. Nutrients. 2016. 8:. doi:10.3390/nu8080450 | Power/Size
2112 | Schröder, H, Mendez, MA, Gomez, SF, Fíto, M, Ribas, L, Aranceta, J, Serra-Majem, L. Energy density, diet quality, and central body fat in a nationwide survey of young Spaniards. Nutrition. 2013. 29:1350–1355. doi:10.1016/j.nut.2013.05.019 24103512 | Study Design
2113 | Schroder, H, Salas-Salvado, J, Martinez-Gonzalez, MA, Fito, M, Corella, D, Estruch, R, Ros, E. Baseline adherence to the Mediterranean diet and major cardiovascular events: Prevencion con Dieta Mediterranea trial. JAMA Intern Med. 2014. 174:1690–2. doi:10.1001/jamainternmed.2014.3463 25111658 | Study Design; Publication Status
2114 | Schröder, H, Salas-Salvadó, J, Martínez-González, MA, Fíto, M, Corella, D, Estruch, R, Ros, E. Baseline adherence to the Mediterranean diet and major cardiovascular events: prevención con Dieta Mediterránea trial. JAMA internal medicine. 2014. 174:1690–1692. doi:10.1001/jamainternmed.2014.3463 25111658 | Publication Status
2115 | Schroeder, N, Park, YH, Kang, MS, Kim, Y, Ha, GK, Kim, HR, Yates, AA, Caballero, B. A randomized trial on the effects of 2010 Dietary Guidelines for Americans and Korean diet patterns on cardiovascular risk factors in overweight and obese adults. J Acad Nutr Diet. 2015. 115:1083–92. doi:10.1016/j.jand.2015.03.023 26115560 | Study duration
2116 | Schulz, M, Nothlings, U, Hoffmann, K, Bergmann, MM, Boeing, H. Identification of a food pattern characterized by high-fiber and low-fat food choices associated with low prospective weight change in the EPIC-Potsdam cohort. J Nutr. 2005. 135:1183–9. doi:10.1093/jn/135.5.1183 15867301 | Publication Date Overlaps with Existing Review
2117 | Schulze, MB, Hoffmann, K, Manson, JE, Willett, WC, Meigs, JB, Weikert, C, Heidemann, C, Colditz, GA, Hu, FB. Dietary pattern, inflammation, and incidence of type 2 diabetes in women. Am J Clin Nutr. 2005. 82:675–84; quiz 714–5. doi:10.1093/ajcn.82.3.675 16155283 | Publication Date Overlaps with Existing Review
2118 | Schumacher, TL, Burrows, TL, Cliff, DP, Jones, RA, Okely, AD, Baur, LA, Morgan, PJ, Callister, R, Boggess, MM, Collins, CE. Dietary Intake Is Related to Multifactor Cardiovascular Risk Score in Obese Boys. Healthcare (Basel). 2014. 2:282–98. doi:10.3390/healthcare2030282 27429277 | Intervention/Exposure
2119 | Schwarz, JM, Linfoot, P, Dare, D, Aghajanian, K. Hepatic de novo lipogenesis in normoinsulinemic and hyperinsulinemic subjects consuming high-fat, low-carbohydrate and low-fat, high-carbohydrate isoenergetic diets. Am J Clin Nutr. 2003. 77:43–50. doi:10.1093/ajcn/77.1.43 12499321 | Study duration
2120 | Schwenke, DC. Dietary patterns to mitigate genetic risk of obesity. Curr Opin Lipidol. 2019. 30:351–352. doi:10.1097/mol.0000000000000617 31290812 | Study Design; Publication Status
2121 | Schwingshackl, L, Hoffmann, G. Monounsaturated fatty acids in the primary prevention of cardiovascular disease in overweight / obese patients and diabetics. Aktuelle ernahrungsmedizin. 2011. 36:44–49. doi:10.1055/s-0030-1265978 | Language
2122 | Schwingshackl, L, Knuppel, S, Michels, N, Schwedhelm, C, Hoffmann, G, Iqbal, K, De Henauw, S, Boeing, H, Devleesschauwer, B. Intake of 12 food groups and disability-adjusted life years from coronary heart disease, stroke, type 2 diabetes, and colorectal cancer in 16 European countries. Eur J Epidemiol. 2019. 34:765–775. doi:10.1007/s10654-019-00523-4 31030306 | Intervention/Exposure
2123 | Sciacqua, A, Perticone, M, Falbo, T, Grillo, N, Tassone, EJ, Sinopoli, F, Lo Russo, C, Succurro, E, Andreozzi, F, Sesti, G, Perticone, F. Dietary patterns and 1-h post-load glucose in essential hypertension. Nutr Metab Cardiovasc Dis. 2014. 24:547–53. doi:10.1016/j.numecd.2013.11.005 24462366 | Study Design; Intervention/Exposure
2124 | Scott, D, Blizzard, L, Fell, J, Giles, G, Jones, G. Associations between dietary nutrient intake and muscle mass and strength in community-dwelling older adults: The Tasmanian older adult cohort study. Journal of the American Geriatrics Society. 2010. 58:2129–2134. doi:10.1111/j.1532-5415.2010.03147.x 21054294 | Intervention/Exposure
2125 | Scott, LW, Balasubramanyam, A, Kimball, KT, Aherns, AK, Fordis, CM, Ballantyne, CM. Long-term, randomized clinical trial of two diets in the metabolic syndrome and type 2 diabetes. Diabetes care. 2003. 26:2481–2482. doi:10.2337/diacare.26.8.2481 12882894 | Publication Status
2126 | Scully, A, Neacsu, M, Russell, W, Vaughan, N, Fyfe, C, Hudson, M, Taylor, K, Johnstone, AM. Plant protein influence on appetite and food intake in healthy subjects. Proceedings of the nutrition society. 2017. 76:E44-. doi:10.1017/S0029665117001008 | Publication Status
2127 | Seangpraw, K, Auttama, N, Tonchoy, P, Panta, P. The effect of the behavior modification program Dietary Approaches to Stop Hypertension (DASH) on reducing the risk of hypertension among elderly patients in the rural community of Phayao, Thailand. Journal of Multidisciplinary Healthcare. 2019. 12:109–118. doi:10.2147/JMDH.S185569 30774358 | Intervention/Exposure; Comparator
2128 | Sedaghat, F, Naja, F, Darand, M, Beyzai, B, Rashidkhani, B. Adherence to a Mediterranean dietary pattern and overweight and obesity among female adolescents in Iran. Int J Adolesc Med Health. 2017. 31:. doi:10.1515/ijamh-2016-0160 | Study Design
2129 | Segal-Isaacson, CJ, Johnson, S, Tomuta, V, Cowell, B, Stein, DT. A randomized trial comparing low-fat and low-carbohydrate diets matched for energy and protein. Obes Res. 2004. 12 Suppl 2:130s–40s. doi:10.1038/oby.2004.278 15601961 | Study duration
2130 | Segovia-Siapco, G, Sabaté, J. Health and sustainability outcomes of vegetarian dietary patterns: a revisit of the EPIC-Oxford and the Adventist Health Study-2 cohorts. European Journal of Clinical Nutrition. 2018. :. doi:10.1038/s41430-018-0310-z | Study Design
2131 | Seidelmann, SB, Claggett, B, Cheng, S, Henglin, M, Shah, A, Steffen, LM, Folsom, AR, Rimm, EB, Willett, WC, Solomon, SD. Dietary carbohydrate intake and mortality: a prospective cohort study and meta-analysis. The Lancet Public Health. 2018. 3:e419–e428. doi:10.1016/S2468-2667(18)30135-X 30122560 | Intervention/Exposure; Outcome
2132 | Seip, RL, Volek, JS, Windemuth, A, Kocherla, M, Fernandez, ML, Kraemer, WJ, Ruano, G. Physiogenomic comparison of human fat loss in response to diets restrictive of carbohydrate or fat. Nutr Metab (Lond). 2008. 5:4. doi:10.1186/1743-7075-5-4 18254975 | Power/Size
2133 | Sejda, T, Kovar, J, Pitha, J, Cifkova, R, Svandova, E, Poledne, R. The effect of an acute fat load on endothelial function after different dietary regimens in young healthy volunteers. Physiol Res. 2002. 51:99–105. doi:unavailable12071297 | Study duration
2134 | Selby, LM, Tobin, BS, Conner, BT, Gomez, M, Busch, G, Hauser, J. A quantitative, retrospective inquiry of the impact of a provider-guided low-carbohydrate, high-fat diet on adults in a wellness clinic setting. Diabetes Metab Syndr. 2019. 13:2314–2319. doi:10.1016/j.dsx.2019.05.031 31235173 | Study Design; Intervention/Exposure
2135 | Serra, MC, Beavers, DP, Henderson, RM, Kelleher, JL, Kiel, JR, Beavers, KM. Effects of a hypocaloric, nutritionally complete, higher protein meal plan on regional body fat and cardiometabolic biomarkers in older adults with obesity. Annals of Nutrition and Metabolism. 2019. 74:149–155. doi:10.1159/000497066 30754039 | Intervention/Exposure
2136 | Serra, MC, Treuth, MS, Ryan, AS. Dietary prescription adherence and non-structured physical activity following weight loss with and without aerobic exercise. J Nutr Health Aging. 2014. 18:888–93. doi:10.1007/s12603-014-0481-9 25470804 | Intervention/Exposure; Comparator
2137 | Seshadri, P, Iqbal, N, Stern, L, Williams, M, Chicano, KL, Daily, DA, McGrory, J, Gracely, EJ, Rader, DJ, Samaha, FF. A randomized study comparing the effects of a low-carbohydrate diet and a conventional diet on lipoprotein subfractions and C-reactive protein levels in patients with severe obesity. Am J Med. 2004. 117:398–405. doi:10.1016/j.amjmed.2004.04.009 15380496 | Power/Size; Weight loss/Hypocaloric
2138 | Seshadri, P, Samaha, FF, Stern, L, Ahima, RS, Daily, D, Iqbal, N. Adipocytokine changes caused by low-carbohydrate compared to conventional diets in obesity. Metab Syndr Relat Disord. 2005. 3:66–74. doi:10.1089/met.2005.3.66 18370712 | Power/Size; Weight loss/Hypocaloric
2139 | Setayeshgar, S, Ekwaru, JP, Maximova, K, Majumdar, SR, Storey, KE, McGavock, J, Veugelers, PJ. Dietary intake and prospective changes in cardiometabolic risk factors in children and youth. Appl Physiol Nutr Metab. 2017. 42:39–45. doi:10.1139/apnm-2016-0215 27959641 | Intervention/Exposure
2140 | Setayeshgar, S, Maximova, K, Ekwaru, JP, Gray-Donald, K, Henderson, M, Paradis, G, Tremblay, A, Veugelers, P. Diet quality as measured by the Diet Quality Index-International is associated with prospective changes in body fat among Canadian children. Public Health Nutr. 2017. 20:456–463. doi:10.1017/s1368980016002500 27660199 | Power/Size
2141 | Setayeshgar, S, Whiting, SJ, Pahwa, P, Vatanparast, H. Predicted 10-year risk of cardiovascular disease among Canadian adults using modified Framingham Risk Score in association with dietary intake. Appl Physiol Nutr Metab. 2015. 40:1068–74. doi:10.1139/apnm-2015-0074 26417841 | Study Design
2142 | Sezaki, A, Imai, T, Miyamoto, K, Kawase, F, Shimokata, H. Mediterranean diet score and incidence of IHD: a global comparative study. Public Health Nutr. 2019. 22:1444–1450. doi:10.1017/s1368980018003877 30744723 | Study Design; Intervention/Exposure
2143 | Shah, B, Newman, JD, Woolf, K, Ganguzza, L, Guo, Y, Allen, N, Zhong, J, Fisher, EA, Slater, J. Anti-Inflammatory Effects of a Vegan Diet Versus the American Heart Association-Recommended Diet in Coronary Artery Disease Trial. J Am Heart Assoc. 2018. 7:e011367. doi:10.1161/jaha.118.011367 30571591 | Health Status
2144 | Shah, M, Adams-Huet, B, Grundy, SM, Garg, A. Effect of a high-carbohydrate vs a high-cis-monounsaturated fat diet on lipid and lipoproteins in individuals with and without type 2 diabetes. Nutrition research (new york, N.Y.). 2004. 24:969–979. doi:10.1016/j.nutres.2004.08.001 | Study duration
2145 | Shahnazari, M, Ceresa, C, Foley, S, Fong, A, Zidaru, E, Moody, S. Nutrition-focused wellness coaching promotes a reduction in body weight in overweight US veterans. J Acad Nutr Diet. 2013. 113:928–35. doi:10.1016/j.jand.2013.04.001 23706353 | Intervention/Exposure
2146 | Shai, I, Gepner, Y, Shelef, I, Schwarzfuchs, D, Zelicha, H, Tene, L, Yaskolka Meir, A, Tsaban, G, Wolak, A, Stumvoll, M, , . Precision nutrition. Obesity facts. 2019. 12:1-. doi:10.1159/000489691 30654360 | Publication Status
2147 | Shai, I, Schwarzfuchs, D, Henkin, Y, Shahar, DR, Witkow, S, Greenberg, I, Golan, R, Fraser, D, Bolotin, A, Vardi, H, Tangi-Rozental, O, Zuk-Ramot, R, Sarusi, B, Brickner, D, Schwartz, Z, Sheiner, E, Marko, R, Katorza, E, Thiery, J, Fiedler, GM, Bluher, M, Stumvoll, M, Stampfer, MJ. Weight loss with a low-carbohydrate, Mediterranean, or low-fat diet. N Engl J Med. 2008. 359:229–41. doi:10.1056/NEJMoa0708681 18635428 | Study duration; Health Status
2148 | Shai, I. The effect of low-carb, mediterranean and low-fat diets on renal function; a 2-year dietary intervention randomized controlled trial (direct). Obesity facts. 2012. 5:19-. doi:10.1159/000171026 | Publication Status
2149 | Shang, X, Scott, D, Hodge, A, English, DR, Giles, GG, Ebeling, PR, Sanders, KM. Dietary protein from different food sources, incident metabolic syndrome and changes in its components: An 11-year longitudinal study in healthy community-dwelling adults. Clin Nutr. 2017. 36:1540–1548. doi:10.1016/j.clnu.2016.09.024 27746001 | Intervention/Exposure
2150 | Sharafi, M, Duffy, VB, Miller, RJ, Winchester, SB, Huedo-Medina, TB, Sullivan, MC. Dietary behaviors of adults born prematurely may explain future risk for cardiovascular disease. Appetite. 2016. 99:157–167. doi:10.1016/j.appet.2016.01.007 26792768 | Intervention/Exposure
2151 | Shariff, ZM, Lin, KG, Sariman, S, Siew, CY, Yusof, BN, Mun, CY, Lee, HS, Mohamad, M. Higher Dietary Energy Density is Associated with Stunting but not Overweight and Obesity in a Sample of Urban Malaysian Children. Ecol Food Nutr. 2016. 55:378–89. doi:10.1080/03670244.2016.1181065 27231732 | Study Design; Intervention/Exposure
2152 | Sharman, MJ, Gomez, AL, Kraemer, WJ, Volek, JS. Very low-carbohydrate and low-fat diets affect fasting lipids and postprandial lipemia differently in overweight men. J Nutr. 2004. 134:880–5. doi:10.1093/jn/134.4.880 15051841 | Study duration
2153 | Sharman, MJ, Kraemer, WJ, Love, DM, Avery, NG, Gomez, AL, Scheett, TP, Volek, JS. A ketogenic diet favorably affects serum biomarkers for cardiovascular disease in normal-weight men. J Nutr. 2002. 132:1879–85. doi:10.1093/jn/132.7.1879 12097663 | Study duration
2154 | Sharman, MJ, Volek, JS. Weight loss leads to reductions in inflammatory biomarkers after a very-low-carbohydrate diet and a low-fat diet in overweight men. Clin Sci (Lond). 2004. 107:365–9. doi:10.1042/cs20040111 15265001 | Outcome
2155 | Sharrett, AR, Heiss, G, Chambless, LE, Boerwinkle, E, Coady, SA, Folsom, AR, Patsch, W. Metabolic and lifestyle determinants of postprandial lipemia differ from those of fasting triglycerides: The Atherosclerosis Risk In Communities (ARIC) study. Arterioscler Thromb Vasc Biol. 2001. 21:275–81. doi:10.1161/01.atv.21.2.275 11156865 | Intervention/Exposure
2156 | Shay, CM, Stamler, J, Dyer, AR, Brown, IJ, Chan, Q, Elliott, P, Zhao, L, Okuda, N, Miura, K, Daviglus, ML, Van Horn, L. Nutrient and food intakes of middle-aged adults at low risk of cardiovascular disease: the international study of macro-/micronutrients and blood pressure (INTERMAP). Eur J Nutr. 2012. 51:917–26. doi:10.1007/s00394-011-0268-2 22057680 | Study Design; Outcome
2157 | Sheikh, VK, Raynor, HA. Decreases in High-Fat and/or High-Added-Sugar Food Group Intake Occur when a Hypocaloric, Low-Fat Diet Is Prescribed Within a Lifestyle Intervention: A Secondary Cohort Analysis. J Acad Nutr Diet. 2016. 116:1599–605. doi:10.1016/j.jand.2016.06.007 27436530 | Intervention/Exposure
2158 | Shepard, TY, Weil, KM, Sharp, TA, Grunwald, GK, Bell, ML, Hill, JO, Eckel, RH. Occasional physical inactivity combined with a high-fat diet may be important in the development and maintenance of obesity in human subjects. Am J Clin Nutr. 2001. 73:703–8. doi:10.1093/ajcn/73.4.703 11273843 | Study duration
2159 | Sherafat-Kazemzadeh, R, Egtesadi, S, Mirmiran, P, Gohari, M, Farahani, SJ, Esfahani, FH, Vafa, MR, Hedayati, M, Azizi, F. Dietary patterns by reduced rank regression predicting changes in obesity indices in a cohort study: Tehran Lipid and Glucose Study. Asia Pac J Clin Nutr. 2010. 19:22–32. doi:unavailable20199984 | Country
2160 | Sherwood, NE, Jeffery, RW, French, SA, Hannan, PJ, Murray, DM. Predictors of weight gain in the Pound of Prevention study. Int J Obes Relat Metab Disord. 2000. 24:395–403. doi:10.1038/sj.ijo.0801169 10805494 | Intervention/Exposure
2161 | Shi, L, Brunius, C, Johansson, I, Bergdahl, IA, Lindahl, B, Hanhineva, K, Landberg, R. Plasma metabolites associated with healthy Nordic dietary indexes and risk of type 2 diabetes-a nested case-control study in a Swedish population. Am J Clin Nutr. 2018. 108:564–575. doi:10.1093/ajcn/nqy145 30060042 | Intervention/Exposure
2162 | Shi, Z, Papier, K, Yiengprugsawan, V, Kelly, M, Seubsman, SA, Sleigh, AC. Dietary patterns associated with hypertension risk among adults in Thailand: 8-year findings from the Thai Cohort Study. Public Health Nutr. 2019. 22:307–313. doi:10.1017/s1368980018002203 30187840 | Outcome
2163 | Shi, Z, Zhen, S, Zimmet, PZ, Zhou, Y, Zhou, Y, Magliano, DJ, Taylor, AW. Association of impaired fasting glucose, diabetes and dietary patterns with mortality: a 10-year follow-up cohort in Eastern China. Acta Diabetol. 2016. 53:799–806. doi:10.1007/s00592-016-0875-8 27311686 | Country
2164 | Shih, CW, Hauser, ME, Aronica, L, Rigdon, J, Gardner, CD. Changes in blood lipid concentrations associated with changes in intake of dietary saturated fat in the context of a healthy low-carbohydrate weight-loss diet: a secondary analysis of the Diet Intervention Examining The Factors Interacting with Treatment Success (DIETFITS) trial. Am J Clin Nutr. 2019. 109:433–441. doi:10.1093/ajcn/nqy305 30649213 | Intervention/Exposure
2165 | Shikany, JM, Margolis, KL, Pettinger, M, Jackson, RD, Limacher, MC, Liu, S, Phillips, LS, Tinker, LF. Effects of a low-fat dietary intervention on glucose, insulin, and insulin resistance in the Women’s Health Initiative (WHI) Dietary Modification trial. Am J Clin Nutr. 2011. 94:75–85. doi:10.3945/ajcn.110.010843 21562091 | Intervention/Exposure; Outcome
2166 | Shikany, JM, Phadke, RP, Redden, DT, Gower, BA. Effects of low- and high-glycemic index/glycemic load diets on coronary heart disease risk factors in overweight/obese men. Metabolism. 2009. 58:1793–801. doi:10.1016/j.metabol.2009.06.006 19631353 | Intervention/Exposure; Publication Date Overlaps with Existing Review
2167 | Shikany, JM, Safford, MM, Bryan, J, Newby, PK, Richman, JS, Durant, RW, Brown, TM, Judd, SE. Dietary Patterns and Mediterranean Diet Score and Hazard of Recurrent Coronary Heart Disease Events and All-Cause Mortality in the REGARDS Study. J Am Heart Assoc. 2018. 7:. doi:10.1161/jaha.117.008078 | Health Status
2168 | Shimabukuro, M, Chinen, I, Higa, N, Takasu, N, Yamakawa, K, Ueda, S. Effects of dietary composition on postprandial endothelial function and adiponectin concentrations in healthy humans: a crossover controlled study. Am J Clin Nutr. 2007. 86:923–8. doi:10.1093/ajcn/86.4.923 17921366 | Study duration
2169 | Shimoda, T, Suzuki, T, Takahashi, N, Tsutsumi, K, Samukawa, M, Yoshimachi, S, Goto, T, Enomoto, H, Kise, N, Ogasawara, K, Yoshimura, S. Nutritional Status and Body Composition of Independently Living Older Adults in a Snowy Region of Japan. Gerontol Geriatr Med. 2017. 3:2333721417706854. doi:10.1177/2333721417706854 28516130 | Study Design; Intervention/Exposure
2170 | Shin, D, Lee, KW, Song, WO. Dietary Patterns during Pregnancy Are Associated with Risk of Gestational Diabetes Mellitus. Nutrients. 2015. 7:9369–82. doi:10.3390/nu7115472 26569302 | Outcome; Participants
2171 | Shin, JH, Jung, S, Kim, SA, Kang, MS, Kim, MS, Joung, H, Hwang, GS, Shin, DM. Differential Effects of Typical Korean Versus American-Style Diets on Gut Microbial Composition and Metabolic Profile in Healthy Overweight Koreans: A Randomized Crossover Trial. Nutrients. 2019. 11:. doi:10.3390/nu11102450 | Outcome
2172 | Shin, KO, Oh, SY, Park, HS. Empirically derived major dietary patterns and their associations with overweight in Korean preschool children. Br J Nutr. 2007. 98:416–21. doi:10.1017/s0007114507720226 17433127 | Publication Date Overlaps with Existing Review
2173 | Shin, PK, Kim, MS, Lee, HJ, Park, SJ, Kwon, DY, Choi, SW. A traditional Korean diet reduced total blood cholesterol and increased telomere length of peripheral blood cells in perimenopausal Korean women. FASEB journal. 2017. 31:. doi:unavailable | Publication Status
2174 | Shin, S, Lee, S. Association between Total Diet Quality and Metabolic Syndrome Incidence Risk in a Prospective Cohort of Korean Adults. Clin Nutr Res. 2019. 8:46–54. doi:10.7762/cnr.2019.8.1.46 30746347 | Outcome
2175 | Shinozaki, K, Okuda, M, Sasaki, S, Kunitsugu, I, Shigeta, M. Dietary Fiber Consumption Decreases the Risks of Overweight and Hypercholesterolemia in Japanese Children. Ann Nutr Metab. 2015. 67:58–64. doi:10.1159/000434634 26279290 | Study Design; Intervention/Exposure
2176 | Shintani, TT, Beckham, S, Brown, AC, O’Connor, HK. The Hawaii Diet: ad libitum high carbohydrate, low fat multi-cultural diet for the reduction of chronic disease risk factors: obesity, hypertension, hypercholesterolemia, and hyperglycemia. Hawaii Med J. 2001. 60:69–73. doi:unavailable11320614 | Study Design
2177 | Shirai, K. Ideal body mass index determined by mortality in Europe, and adequate high protein and low carbohydrate diet to maintain bodyweight. J Diabetes Investig. 2011. 2:421–2. doi:10.1111/j.2040-1124.2011.00145.x | Study Design
2178 | Shivappa, N, Steck, SE, Hussey, JR, Ma, Y, Hebert, JR. Inflammatory potential of diet and all-cause, cardiovascular, and cancer mortality in National Health and Nutrition Examination Survey III Study. Eur J Nutr. 2017. 56:683–692. doi:10.1007/s00394-015-1112-x 26644215 | Intervention/Exposure
2179 | Shlisky, JD, Durward, CM, Zack, MK, Gugger, CK, Campbell, JK, Nickols-Richardson, SM. An energy-reduced dietary pattern, including moderate protein and increased nonfat dairy intake combined with walking promotes beneficial body composition and metabolic changes in women with excess adiposity: a randomized comparative trial. Food Sci Nutr. 2015. 3:376–93. doi:10.1002/fsn3.231 26405524 | Intervention/Exposure
2180 | Shmaya, Y, Eilat-Adar, S, Leitner, Y, Reif, S, Gabis, L. Nutritional deficiencies and overweight prevalence among children with autism spectrum disorder. Res Dev Disabil. 2015. 38:1–6. doi:10.1016/j.ridd.2014.11.020 25532026 | Study Design
2181 | Shroff, MR, Perng, W, Baylin, A, Mora-Plazas, M, Marin, C, Villamor, E. Adherence to a snacking dietary pattern and soda intake are related to the development of adiposity: a prospective study in school-age children. Public Health Nutr. 2014. 17:1507–13. doi:10.1017/s136898001300133x 23701749 | Country
2182 | Shu, L, Shen, XM, Li, C, Zhang, XY, Zheng, PF. Dietary patterns are associated with type 2 diabetes mellitus among middle-aged adults in Zhejiang Province, China. Nutr J. 2017. 16:81. doi:10.1186/s12937-017-0303-0 29237454 | Study Design
2183 | Shyam, S, Arshad, F, Abdul Ghani, R, Wahab, NA, Safii, NS, Nisak, MY, Chinna, K, Kamaruddin, NA. Low glycaemic index diets improve glucose tolerance and body weight in women with previous history of gestational diabetes: a six months randomized trial. Nutr J. 2013. 12:68. doi:10.1186/1475-2891-12-68 23705645 | Intervention/Exposure
2184 | Shyam, S, Arshad, F, Ghani, RA, Wahab, NA, Mohd Yusof, BN, Safii, NS, Chinna, K, Kamaruddin, NA. Low glycaemic index diet aids management of fasting blood sugar and body weight in asian women with previous history of gestational diabetes mellitus. Journal of diabetes. 2013. 5:27. doi:10.1111/1753-0407.12032 | Publication Status
2185 | Sichieri, R, Moura, AS, Genelhu, V, Hu, F, Willett, WC. An 18-mo randomized trial of a low-glycemic-index diet and weight change in Brazilian women. Am J Clin Nutr. 2007. 86:707–13. doi:10.1093/ajcn/86.3.707 17823436 | Intervention/Exposure
2186 | Sidell, MA, Ghai, NR, Reynolds, K, Jacobsen, SJ, Scott, R, Van Den Eeden, S, Caan, B, Quinn, VP. Statins as a free pass: Body mass index and other cardiovascular risk factors among lipid-lowering medication users and nonusers in the California Men’s Health Study. Prev Med. 2019. 129:105822. doi:10.1016/j.ypmed.2019.105822 31470024 | Intervention/Exposure
2187 | Siega-Riz, AM, El Ghormli, L, Mobley, C, Gillis, B, Stadler, D, Hartstein, J, Volpe, SL, Virus, A, Bridgman, J. The effects of the HEALTHY study intervention on middle school student dietary intakes. Int J Behav Nutr Phys Act. 2011. 8:7. doi:10.1186/1479-5868-8-7 21294869 | Intervention/Exposure
2188 | Siegel, RM, Rich, W, Joseph, EC, Linhardt, J, Knight, J, Khoury, J, Daniels, SR. A 6-month, office-based, low-carbohydrate diet intervention in obese teens. Clin Pediatr (Phila). 2009. 48:745–9. doi:10.1177/0009922809332585 19264718 | Study Design
2189 | Sieri, S, Brighenti, F, Agnoli, C, Grioni, S, Masala, G, Bendinelli, B, Sacerdote, C, Ricceri, F, Tumino, R, Giurdanella, MC, Pala, V, Berrino, F, Mattiello, A, Chiodini, P, Panico, S, Krogh, V. Dietary glycemic load and glycemic index and risk of cerebrovascular disease in the EPICOR cohort. PLoS One. 2013. 8:e62625. doi:10.1371/journal.pone.0062625 23717392 | Intervention/Exposure
2190 | Sieri, S, Krogh, V, Berrino, F, Evangelista, A, Agnoli, C, Brighenti, F, Pellegrini, N, Palli, D, Masala, G, Sacerdote, C, Veglia, F, Tumino, R, Frasca, G, Grioni, S, Pala, V, Mattiello, A, Chiodini, P, Panico, S. Dietary glycemic load and index and risk of coronary heart disease in a large italian cohort: the EPICOR study. Arch Intern Med. 2010. 170:640–7. doi:10.1001/archinternmed.2010.15 20386010 | Intervention/Exposure
2191 | Sijtsma, FP, Soedamah-Muthu, SS, de Hoon, SE, Jacobs, DR, Jr, Kromhout, D. Healthy eating and survival among elderly men with and without cardiovascular-metabolic diseases. Nutr Metab Cardiovasc Dis. 2015. 25:1117–24. doi:10.1016/j.numecd.2015.08.008 26610653 | Power/Size
2192 | Silaste, ML, Rantala, M, Alfthan, G, Aro, A, Witztum, JL, Kesaniemi, YA, Horkko, S. Changes in dietary fat intake alter plasma levels of oxidized low-density lipoprotein and lipoprotein(a). Arterioscler Thromb Vasc Biol. 2004. 24:498–503. doi:10.1161/01.ATV.0000118012.64932.f4 14739118 | Intervention/Exposure; Comparator
2193 | Silbernagel, G, Kovarova, M, Cegan, A, Machann, J, Schick, F, Lehmann, R, Haring, HU, Stefan, N, Schleicher, E, Fritsche, A, Peter, A. High hepatic SCD1 activity is associated with low liver fat content in healthy subjects under a lipogenic diet. J Clin Endocrinol Metab. 2012. 97:E2288–92. doi:10.1210/jc.2012-2152 23015656 | Study Design; Intervention/Exposure; Outcome
2194 | Silva, FM, Giatti, L, de Figueiredo, RC, Molina, Mdcb, de Oliveira Cardoso, L, Duncan, BB, Barreto, SM. Consumption of ultra-processed food and obesity: cross sectional results from the Brazilian Longitudinal Study of Adult Health (ELSA-Brasil) cohort (2008-2010). Public Health Nutr. 2018. 21:2271–2279. doi:10.1017/s1368980018000861 29642958 | Study Design
2195 | Silva, KF, Prata, A, da Cunha, DF. Frequency of metabolic syndrome and the food intake patterns in adults living in a rural area of Brazil. Revista da Sociedade Brasileira de Medicina Tropical. 2011. 44:425–429. doi:10.1590/S0037-86822011000400005 21860887 | Study Design
2196 | Silveira, BKS, de Novaes, JF, Reis, NA, Lourenco, LP, Capobiango, AHM, Vieira, SA, Hermsdorff, HHM. “Traditional” and “Healthy” Dietary Patterns Are Associated with Low Cardiometabolic Risk in Brazilian Subjects. Cardiol Res Pract. 2018. 2018:4585412. doi:10.1155/2018/4585412 30581607 | Study Design
2197 | Silventoinen, K, Hasselbalch, AL, Lallukka, T, Bogl, L, Pietilainen, KH, Heitmann, BL, Schousboe, K, Rissanen, A, Kyvik, KO, Sorensen, TI, Kaprio, J. Modification effects of physical activity and protein intake on heritability of body size and composition. Am J Clin Nutr. 2009. 90:1096–103. doi:10.3945/ajcn.2009.27689 19710197 | Study Design
2198 | Silver, HJ, Kang, H, Keil, CD, Muldowney, JA, 3rd, Kocalis, H, Fazio, S, Vaughan, DE, Niswender, KD. Consuming a balanced high fat diet for 16 weeks improves body composition, inflammation and vascular function parameters in obese premenopausal women. Metabolism. 2014. 63:562–73. doi:10.1016/j.metabol.2014.01.004 24559846 | Intervention/Exposure; Comparator
2199 | Simila, ME, Kontto, JP, Mannisto, S, Valsta, LM, Virtamo, J. Glycaemic index, carbohydrate substitution for fat and risk of CHD in men. Br J Nutr. 2013. 110:1704–11. doi:10.1017/s0007114513000858 23534456 | Intervention/Exposure
2200 | Simila, ME, Valsta, LM, Kontto, JP, Albanes, D, Virtamo, J. Low-, medium- and high-glycaemic index carbohydrates and risk of type 2 diabetes in men. Br J Nutr. 2011. 105:1258–64. doi:10.1017/s000711451000485x 21114892 | Intervention/Exposure
2201 | Simpson, EJ, Clark, M, Razak, A, Salter, A. Reduced meat consumption and its effect on serum lipid profile; An intervention trial in healthy volunteers. Proceedings of the nutrition society. 2017. 76:E54-. doi:10.1017/S0029665117001276 | Publication Status
2202 | Simpson, EJ, Holdsworth, M, Macdonald, IA. Interstitial glucose profile associated with symptoms attributed to hypoglycemia by otherwise healthy women. Am J Clin Nutr. 2008. 87:354–61. doi:10.1093/ajcn/87.2.354 18258625 | Study duration
2203 | Singh, PN, Clark, RW, Herring, P, Sabate, J, Shavlik, D, Fraser, GE. Obesity and life expectancy among long-lived Black adults. J Gerontol A Biol Sci Med Sci. 2014. 69:63–72. doi:10.1093/gerona/glt049 23682156 | Intervention/Exposure
2204 | Singh-Manoux, A, Fayosse, A, Sabia, S, Tabak, A, Shipley, M, Dugravot, A, Kivimaki, M. Clinical, socioeconomic, and behavioural factors at age 50 years and risk of cardiometabolic multimorbidity and mortality: A cohort study. PLoS Med. 2018. 15:e1002571. doi:10.1371/journal.pmed.1002571 29782486 | Intervention/Exposure
2205 | Siriwoen, R, Chongsuwat, R, Tansakul, S, Siri, S. Effectiveness of a Weight Management Program Applying Mobile Health Technology as a Supporting Tool for Overweight and Obese Working Women. Asia Pac J Public Health. 2018. 30:572–581. doi:10.1177/1010539518800367 30324823 | Study Design
2206 | Sjaarda, LA, Schisterman, EF, Schliep, KC, Plowden, T, Zarek, SM, Yeung, E, Wactawski-Wende, J, Mumford, SL. Dietary Carbohydrate Intake Does Not Impact Insulin Resistance or Androgens in Healthy, Eumenorrheic Women. J Clin Endocrinol Metab. 2015. 100:2979–86. doi:10.1210/jc.2015-1957 26066675 | Study Design; Outcome
2207 | Sjogren, P, Becker, W, Warensjo, E, Olsson, E, Byberg, L, Gustafsson, IB, Karlstrom, B, Cederholm, T. Mediterranean and carbohydrate-restricted diets and mortality among elderly men: a cohort study in Sweden. Am J Clin Nutr. 2010. 92:967–74. doi:10.3945/ajcn.2010.29345 20826627 | Intervention/Exposure; Publication Date Overlaps with Existing Review
2208 | Sjostrom, L, Rissanen, A, Andersen, T, Boldrin, M, Golay, A, Koppeschaar, H, Krempf, M. Randomized placebo-controlled trial of orlistat for weight loss and prevention of weight regain in obese patients. Terapevticheskii arkhiv. 2000. 72:50–54. doi:unavailable | Intervention/Exposure
2209 | Skeaff, CM, Hodson, L, McKenzie, JE. Dietary-induced changes in fatty acid composition of human plasma, platelet, and erythrocyte lipids follow a similar time course. J Nutr. 2006. 136:565–9. doi:10.1093/jn/136.3.565 16484525 | Study duration
2210 | Skeaff, CM, Thoma, C, Mann, J, Chisholm, A, Williams, S, Richmond, K. Isocaloric substitution of plant sterol-enriched fat spread for carbohydrate-rich foods in a low-fat, fibre-rich diet decreases plasma low-density lipoprotein cholesterol and increases high-density lipoprotein concentrations. Nutr Metab Cardiovasc Dis. 2005. 15:337–44. doi:10.1016/j.numecd.2005.03.002 16216719 | Intervention/Exposure
2211 | Skinner, JD, Bounds, W, Carruth, BR, Morris, M, Ziegler, P. Predictors of children’s body mass index: a longitudinal study of diet and growth in children aged 2-8 y. Int J Obes Relat Metab Disord. 2004. 28:476–82. doi:10.1038/sj.ijo.0802405 14993908 | Intervention/Exposure; Comparator
2212 | Skoog, M, Xu, N, Berggren-Soderlund, M, Lovegrove, JA, Nilsson-Ehle, P. ACTH reduces the rise in ApoB-48 levels after fat intake. Atherosclerosis. 2007. 191:433–9. doi:10.1016/j.atherosclerosis.2006.05.012 16839559 | Study duration
2213 | Skov, AR, Haulrik, N, Toubro, S, Molgaard, C, Astrup, A. Effect of protein intake on bone mineralization during weight loss: a 6-month trial. Obes Res. 2002. 10:432–8. doi:10.1038/oby.2002.60 12055318 | Outcome; Weight loss/Hypocaloric; Study duration
2214 | Skreden, M, Hillesund, ER, Wills, AK, Brantsaeter, AL, Bere, E, Overby, NC. Adherence to the New Nordic Diet during pregnancy and subsequent maternal weight development: a study conducted in the Norwegian Mother and Child Cohort Study (MoBa). Br J Nutr. 2018. 119:1286–1294. doi:10.1017/s0007114518000776 29770760 | AGE: Intervention/Exposure; Participants
2215 | Slavicek, J, Kittnar, O, Fraser, GE, Medova, E, Konecna, J, Zizka, R, Dohnalova, A, Novak, V. Lifestyle decreases risk factors for cardiovascular diseases. Cent Eur J Public Health. 2008. 16:161–4. doi:unavailable19256282 | Study duration
2216 | Sloth, B, Due, A, Larsen, TM, Holst, JJ, Heding, A, Astrup, A. The effect of a high-MUFA, low-glycaemic index diet and a low-fat diet on appetite and glucose metabolism during a 6-month weight maintenance period. Br J Nutr. 2009. 101:1846–58. doi:10.1017/s0007114508137710 19079942 | Power/Size
2217 | Sluik, D, Brouwer-Brolsma, EM, Berendsen, AAM, Mikkila, V, Poppitt, SD, Silvestre, MP, Tremblay, A, Perusse, L, Bouchard, C, Raben, A, Feskens, EJM. Protein intake and the incidence of pre-diabetes and diabetes in 4 population-based studies: the PREVIEW project. Am J Clin Nutr. 2019. 109:1310–1318. doi:10.1093/ajcn/nqy388 31051510 | Intervention/Exposure
2218 | Smith, CE, Tucker, KL, Lee, YC, Lai, CQ, Parnell, LD, Ordovas, JM. Low-density lipoprotein receptor-related protein 1 variant interacts with saturated fatty acids in Puerto Ricans. Obesity (Silver Spring). 2013. 21:602–8. doi:10.1002/oby.20001 23404896 | Intervention/Exposure
2219 | Smith, GI, Yoshino, J, Kelly, SC, Reeds, DN, Okunade, A, Patterson, BW, Klein, S, Mittendorfer, B. High-Protein Intake during Weight Loss Therapy Eliminates the Weight-Loss-Induced Improvement in Insulin Action in Obese Postmenopausal Women. Cell Rep. 2016. 17:849–861. doi:10.1016/j.celrep.2016.09.047 27732859 | Intervention/Exposure; Outcome
2220 | Smith, JD, Hou, T, Ludwig, DS, Rimm, EB, Willett, W, Hu, FB, Mozaffarian, D. Changes in intake of protein foods, carbohydrate amount and quality, and long-term weight change: results from 3 prospective cohorts. Am J Clin Nutr. 2015. 101:1216–24. doi:10.3945/ajcn.114.100867 25854882 | Intervention/Exposure
2221 | Smith, R. Are some diets “mass murder”?. Bmj. 2014. 349:g7654. doi:10.1136/bmj.g7654 25510501 | Study Design; Publication Status
2222 | Smith, SR, De Jonge, L, Zachwieja, JJ, Roy, H, Nguyen, T, Rood, JC, Windhauser, MM, Bray, GA. Fat and carbohydrate balances during adaptation to a high-fat diet. American Journal of Clinical Nutrition. 2000. 71:450–457. doi:unavailable | Study duration
2223 | Smith, SR, de Jonge, L, Zachwieja, JJ, Roy, H, Nguyen, T, Rood, JC, Windhauser, MM, Bray, GA. Fat and carbohydrate balances during adaptation to a high-fat. Am J Clin Nutr. 2000. 71:450–7. doi:10.1093/ajcn/71.2.450 10648257 | Study duration
2224 | Snetselaar, L, Stumbo, P, Chenard, C, Ahrens, L, Smith, K, Zimmerman, B. Adolescents eating diets rich in either lean beef or lean poultry and fish reduced fat and saturated fat intake and those eating beef maintained serum ferritin status. J Am Diet Assoc. 2004. 104:424–8. doi:10.1016/j.jada.2003.12.016 14993866 | Intervention/Exposure
2225 | Soare, A, Khazrai, YM, Fontana, L, Del Toro, R, Lazzaro, MC, Di Rosa, C, Buldo, A, Fioriti, E, Maddaloni, E, Angeletti, S, Di Mauro, A, Gesuita, R, Skrami, E, Tuccinardi, D, Fallucca, S, Pianesi, M, Pozzilli, P. Treatment of reactive hypoglycemia with the macrobiotic Ma-pi 2 diet as assessed by continuous glucose monitoring: The MAHYP randomized crossover trial. Metabolism. 2017. 69:148–156. doi:10.1016/j.metabol.2017.01.023 28285645 | Study duration
2226 | Soares, TS, Piovesan, CH, Gustavo Ada, S, Macagnan, FE, Bodanese, LC, Feoli, AM. Alimentary habits, physical activity, and Framingham global risk score in metabolic syndrome. Arq Bras Cardiol. 2014. 102:374–82. doi:10.5935/abc.20140029 24652053 | Intervention/Exposure
2227 | Soderstrom, L, Rosenblad, A, Adolfsson, ET, Wolk, A, Hakansson, N, Bergkvist, L. A high energy intake from dietary fat among middle-aged and older adults is associated with increased risk of malnutrition 10 years later. Br J Nutr. 2015. 114:915–23. doi:10.1017/s0007114515002317 26268629 | Intervention/Exposure; Outcome
2228 | Soenen, S, Bonomi, AG, Lemmens, SG, Scholte, J, Thijssen, MA, van Berkum, F, Westerterp-Plantenga, MS. Relatively high-protein or ‘low-carb’ energy-restricted diets for body weight loss and body weight maintenance?. Physiol Behav. 2012. 107:374–80. doi:10.1016/j.physbeh.2012.08.004 22935440 | Intervention/Exposure
2229 | Soenen, S, Martens, EA, Hochstenbach-Waelen, A, Lemmens, SG, Westerterp-Plantenga, MS. Normal protein intake is required for body weight loss and weight maintenance, and elevated protein intake for additional preservation of resting energy expenditure and fat free mass. J Nutr. 2013. 143:591–6. doi:10.3945/jn.112.167593 23446962 | Intervention/Exposure
2230 | Soenen, S, Westerterp-Plantenga, MS. Changes in body fat percentage during body weight stable conditions of increased daily protein intake vs. control. Physiol Behav. 2010. 101:635–8. doi:10.1016/j.physbeh.2010.09.014 20887742 | Intervention/Exposure
2231 | Sofi, F, Dinu, M, Pagliai, G, Cesari, F, Gori, AM, Sereni, A, Becatti, M, Fiorillo, C, Marcucci, R, Casini, A. Low-Calorie Vegetarian Versus Mediterranean Diets for Reducing Body Weight and Improving Cardiovascular Risk Profile: CARDIntervention/ExposureG Study (Cardiovascular Prevention With Vegetarian Diet). Circulation. 2018. 137:1103–1113. doi:10.1161/circulationaha.117.030088 29483085 | Weight loss/Hypocaloric
2232 | Sofi, F, Giorgi, G, Cesari, F, Gori, AM, Mannini, L, Parisi, G, Casini, A, Abbate, R, Gensini, GF, Poli, BM. The atherosclerotic risk profile is affected differently by fish flesh with a similar EPA and DHA content but different n-6/n-3 ratio. Asia Pac J Clin Nutr. 2013. 22:32–40. doi:10.6133/apjcn.2013.22.1.12 23353608 | Intervention/Exposure
2233 | Somaraki, M, Eli, K, Ek, A, Sandvik, P, Sorjonen, K, Nowicka, P. Changes in parental feeding practices and children’s food intake: a randomized control trial of obesity treatment in preschoolers. Obesity research & clinical practice. 2019. 13:323-. doi:10.1016/j.orcp.2018.11.236 | Publication Status
2234 | Sondike, SB, Copperman, N, Jacobson, MS. Effects of a low-carbohydrate diet on weight loss and cardiovascular risk factor in overweight adolescents. J Pediatr. 2003. 142:253–8. doi:10.1067/mpd.2003.4 12640371 | Power/Size
2235 | Sonestedt, E, Lyssenko, V, Ericson, U, Gullberg, B, Wirfalt, E, Groop, L, Orho-Melander, M. Genetic variation in the glucose-dependent insulinotropic polypeptide receptor modifies the association between carbohydrate and fat intake and risk of type 2 diabetes in the Malmo Diet and Cancer cohort. J Clin Endocrinol Metab. 2012. 97:E810–8. doi:10.1210/jc.2011-2444 22399504 | Intervention/Exposure
2236 | Song, S, Kim, J, Kim, J. Gender Differences in the Association between Dietary Pattern and the Incidence of Hypertension in Middle-Aged and Older Adults. Nutrients. 2018. 10:. doi:10.3390/nu10020252 | Outcome
2237 | Song, S, Song, WO, Song, Y. Dietary carbohydrate and fat intakes are differentially associated with lipid abnormalities in Korean adults. J Clin Lipidol. 2017. 11:338–347.e3. doi:10.1016/j.jacl.2017.01.016 28502489 | Study Design
2238 | Soto Rodríguez, A, García Soidán, JL, de Toro Santos, M, Lagoa Labrador, F, Failde Garrido, JM, Pérez Fernández, MR. Benefits of an educational intervention on diet and anthropometric profile of women with one cardiovascular risk factor. Medicina clinica. 2016. 146:436–439. doi:10.1016/j.medcli.2015.12.013 26897504 | Language
2239 | Soto-Estrada, G, Moreno Altamirano, L, Garcia-Garcia, JJ, Ochoa Moreno, I, Silberman, M. Trends in frequency of type 2 diabetes in Mexico and its relationship to dietary patterns and contextual factors. Gac Sanit. 2018. 32:283–290. doi:10.1016/j.gaceta.2017.08.001 29102307 | Study Design; Country
2240 | Sotos-Prieto, M, Luben, R, Khaw, KT, Wareham, NJ, Forouhi, NG. The association between Mediterranean Diet Score and glucokinase regulatory protein gene variation on the markers of cardiometabolic risk: an analysis in the European Prospective Investigation into Cancer (EPIC)-Norfolk study. Br J Nutr. 2014. 112:122–31. doi:10.1017/s0007114514000580 24804806 | Outcome
2241 | Spengler, S, Mess, F, Schmocker, E, Woll, A. Longitudinal associations of health-related behavior patterns in adolescence with change of weight status and self-rated health over a period of 6 years: results of the MoMo longitudinal study. BMC Pediatr. 2014. 14:242. doi:10.1186/1471-2431-14-242 25270112 | Power/Size
2242 | Spieth, LE, Harnish, JD, Lenders, CM, Raezer, LB, Pereira, MA, Hangen, SJ, Ludwig, DS. A low-glycemic index diet in the treatment of pediatric obesity. Arch Pediatr Adolesc Med. 2000. 154:947–51. doi:10.1001/archpedi.154.9.947 10980801 | Intervention/Exposure
2243 | Spiller, GA, Miller, A, Olivera, K, Reynolds, J, Miller, B, Morse, SJ, Dewell, A, Farquhar, JW. Effects of plant-based diets high in raw or roasted almonds, or roasted almond butter on serum lipoproteins in humans. J Am Coll Nutr. 2003. 22:195–200. doi:10.1080/07315724.2003.10719293 12805245 | Intervention/Exposure
2244 | Spring, B, Moller, AC, Colangelo, LA, Siddique, J, Roehrig, M, Daviglus, ML, Polak, JF, Reis, JP, Sidney, S, Liu, K. Healthy lifestyle change and subclinical atherosclerosis in young adults: Coronary Artery Risk Development in Young Adults (CARDIA) study. Circulation. 2014. 130:10–7. doi:10.1161/circulationaha.113.005445 24982115 | Intervention/Exposure
2245 | Sta hl, M, Hulthen, L, Manousou, S, Larsson, C, Lindahl, B, Mellberg, C, Olsson, T, Ryberg, M, Sandberg, S, Filipsson Nystrom, H. A modified paleolithic diet results in iodine deficiency-a study of 24 hour urinary iodine excretion in postmenopausal overweight and obese women in Sweden. Thyroid. 2013. 23:A23–A24. doi:10.1089/thy.2013.2310.abs | Publication Status
2246 | Stang, J, Zephier, EM, Story, M, Himes, JH, Yeh, JL, Welty, T, Howard, BV. Dietary intakes of nutrients thought to modify cardiovascular risk from three groups of American Indians: The Strong Heart Dietary Study, Phase II. J Am Diet Assoc. 2005. 105:1895–903. doi:10.1016/j.jada.2005.09.003 16321595 | Study Design; Outcome
2247 | Stanhope, KL, Bremer, AA, Medici, V, Nakajima, K, Ito, Y, Nakano, T, Chen, G, Fong, TH, Lee, V, Menorca, RI, Keim, NL, Havel, PJ. Consumption of fructose and high fructose corn syrup increase postprandial triglycerides, LDL-cholesterol, and apolipoprotein-B in young men and women. J Clin Endocrinol Metab. 2011. 96:E1596–605. doi:10.1210/jc.2011-1251 21849529 | Intervention/Exposure; Study duration
2248 | Steer, CD, Lattka, E, Koletzko, B, Golding, J, Hibbeln, JR. Maternal fatty acids in pregnancy, FADS polymorphisms, and child intelligence quotient at 8 y of age. Am J Clin Nutr. 2013. 98:1575–82. doi:10.3945/ajcn.112.051524 24067669 | Study Design; AGE: Intervention/Exposure
2249 | Steffen, LM, Hootman, KC. A posteriori data-derived dietary patterns and incident coronary heart disease: Making sense of inconsistent findings. Curr Nutr Rep. 2016. 5:168–179. doi:10.1007/s13668-016-0176-4 28480131 | Study Design
2250 | Steffen, LM, Jacobs, DR, Jr, Murtaugh, MA, Moran, A, Steinberger, J, Hong, CP, Sinaiko, AR. Whole grain intake is associated with lower body mass and greater insulin sensitivity among adolescents. Am J Epidemiol. 2003. 158:243–50. doi:10.1093/aje/kwg146 12882946 | Study Design
2251 | Steffen, LM. A variety of food and drink improves CVD profile. Br J Nutr. 2009. 101:305–6. doi:10.1017/s0007114508076319 18834552 | Study Design; Publication Status
2252 | Stefler, D, Pikhart, H, Jankovic, N, Kubinova, R, Pajak, A, Malyutina, S, Simonova, G, Feskens, EJM, Peasey, A, Bobak, M. Healthy diet indicator and mortality in Eastern European populations: prospective evidence from the HAPIEE cohort. Eur J Clin Nutr. 2014. 68:1346–1352. doi:10.1038/ejcn.2014.134 25028084 | Intervention/Exposure
2253 | Steinberg, D, Kay, M, Burroughs, J, Svetkey, LP, Bennett, GG. The Effect of a Digital Behavioral Weight Loss Intervention on Adherence to the Dietary Approaches to Stop Hypertension (DASH) Dietary Pattern in Medically Vulnerable Primary Care Patients: Results from a Randomized Controlled Trial. J Acad Nutr Diet. 2019. 119:574–584. doi:10.1016/j.jand.2018.12.011 30905430 | Study Design; Intervention/Exposure
2254 | Stelmach-Mardas, M, Mardas, M, Warchol, W, Jamka, M, Walkowiak, J. Successful maintenance of body weight reduction after individualized dietary counseling in obese subjects. Sci Rep. 2014. 4:6620. doi:10.1038/srep06620 25311271 | Intervention/Exposure
2255 | Stentz, FB, Brewer, A, Wan, J, Garber, C, Daniels, B, Sands, C, Kitabchi, AE. Remission of pre-diabetes to normal glucose tolerance in obese adults with high protein versus high carbohydrate diet: randomized control trial. BMJ Open Diabetes Res Care. 2016. 4:e000258. doi:10.1136/bmjdrc-2016-000258 | Intervention/Exposure
2256 | Stentz, FB, Garber, C, Kitabchi, A. Efficacy of high protein vs. High carbohydrate diet on remission of impaired glucose tolerance (IGT) to normal glucose tolerance (NGT) and physiological parameters in obese adults. Diabetes. 2015. 64:A512. doi:10.2337/db1519292253 | Publication Status
2257 | Sterling, S, Judd, S, Bertrand, B, Carson, TL, Chandler-Laney, P, Baskin, ML. Dietary Patterns Among Overweight and Obese African-American Women Living in the Rural South. J Racial Ethn Health Disparities. 2018. 5:141–150. doi:10.1007/s40615-017-0351-3 28281179 | Study Design; Outcome
2258 | Stern, L, Iqbal, N, Seshadri, P, Chicano, KL, Daily, DA, McGrory, J, Williams, M, Gracely, EJ, Samaha, FF. The effects of low-carbohydrate versus conventional weight loss diets in severely obese adults: one-year follow-up of a randomized trial. Ann Intern Med. 2004. 140:778–85. doi:10.7326/0003-4819-140-10-200405180-00007 15148064 | Power/Size; Weight loss/Hypocaloric
2259 | Stettler, R, Ith, M, Acheson, KJ, Decombaz, J, Boesch, C, Tappy, L, Binnert, C. Interaction between dietary lipids and physical inactivity on insulin sensitivity and on intramyocellular lipids in healthy men. Diabetes Care. 2005. 28:1404–9. doi:10.2337/diacare.28.6.1404 15920059 | Study duration
2260 | Stewart, JW, Kaplan, ML, Beitz, DC. Pork with a high content of polyunsaturated fatty acids lowers LDL cholesterol in women. Am J Clin Nutr. 2001. 74:179–87. doi:10.1093/ajcn/74.2.179 11470718 | Intervention/Exposure
2261 | Stewart, KJ, Ouyang, P, Silber, HA, Zakaria, S, Desai, D, Shapiro, EP, Dobrosielski, DA. Effect of a low-carbohydrate versus a low-fat weight loss program on endothelial function. Circulation. 2012. 125:. doi:unavailable | Intervention/Exposure; Publication Status
2262 | Stewart, KJ, Ouyang, P, Vaidya, D, Dobrosielski, DA. Reductions in systematic inflammation after a low-carbohydrate diet versus a low-fat diet each combined with exercise. Circulation. 2012. 126:. doi:unavailable | Publication Status
2263 | Stinson, EJ, Piaggi, P, Ibrahim, M, Venti, C, Krakoff, J, Votruba, SB. High Fat and Sugar Consumption During Ad Libitum Intake Predicts Weight Gain. Obesity (Silver Spring). 2018. 26:689–695. doi:10.1002/oby.22124 29504262 | Study Design; Study duration
2264 | Stoa, EM, Nyhus, LK, Borresen, SC, Nygaard, C, Hovet, AM, Bratland-Sanda, S, Helgerud, J, Storen, O. Day to day variability in fat oxidation and the effect after only 1 day of change in diet composition. Appl Physiol Nutr Metab. 2016. 41:397–404. doi:10.1139/apnm-2015-0334 26960444 | Outcome; Study duration
2265 | Stocks, T, Angquist, L, Banasik, K, Harder, MN, Taylor, MA, Hager, J, Arner, P, Oppert, JM, Martinez, JA, Polak, J, Rousseau, F, Langin, D, Rossner, S, Holst, C, MacDonald, IA, Kamatani, Y, Pfeiffer, AF, Kunesova, M, Saris, WH, Hansen, T, Pedersen, O, Astrup, A, Sorensen, TI. TFAP2B influences the effect of dietary fat on weight loss under energy restriction. PLoS One. 2012. 7:e43212. doi:10.1371/journal.pone.0043212 22952648 | Study Design; Intervention/Exposure
2266 | Stocks, T, Taylor, MA, Angquist, L, Macdonald, IA, Arner, P, Holst, C, Oppert, JM, Martinez, JA, Rossner, S, Polak, J, Langin, D, Saris, WH, Astrup, A, Sorensen, TI. Change in proportional protein intake in a 10-week energy-restricted low- or high-fat diet, in relation to changes in body size and metabolic factors. Obes Facts. 2013. 6:217–27. doi:10.1159/000351726 23711745 | Intervention/Exposure
2267 | Stoernell, CK, Tangney, CC, Rockway, SW. Short-term changes in lipoprotein subclasses and C-reactive protein levels of hypertriglyceridemic adults on low-carbohydrate and low-fat diets. Nutr Res. 2008. 28:443–9. doi:10.1016/j.nutres.2008.03.013 19083444 | Study duration
2268 | Stomby, A, Simonyte, K, Mellberg, C, Ryberg, M, Stimson, RH, Larsson, C, Lindahl, B, Andrew, R, Walker, BR, Olsson, T. Diet-induced weight loss has chronic tissue-specific effects on glucocorticoid metabolism in overweight postmenopausal women. Int J Obes (Lond). 2015. 39:814–9. doi:10.1038/ijo.2014.188 25349058 | Power/Size
2269 | Stonehouse, W, Benassi-Evans, B, James-Martin, G, Abeywardena, M. Fatty acid regio-specificity of triacylglycerol molecules may affect plasma lipid responses to dietary fats-a randomised controlled cross-over trial. Eur J Clin Nutr. 2019. :. doi:10.1038/s41430-019-0452-7 | Intervention/Exposure
2270 | St-Onge, MP, Newcomer, BR, Buchthal, S, Aban, I, Allison, DB, Bosarge, A, Gower, B. Intramyocellular lipid content is lower with a low-fat diet than with high-fat diets, but that may not be relevant for health. Am J Clin Nutr. 2007. 86:1316–22. doi:10.1093/ajcn/86.5.1316 17991641 | Study duration
2271 | St-Onge, MP, Zhang, S, Darnell, B, Allison, DB. Baseline serum C-reactive protein is associated with lipid responses to low-fat and high-polyunsaturated fat diets. J Nutr. 2009. 139:680–3. doi:10.3945/jn.108.098251 19297430 | Study duration
2272 | Storniolo, CE, Casillas, R, Bullo, M, Castaner, O, Ros, E, Saez, GT, Toledo, E, Estruch, R, Ruiz-Gutierrez, V, Fito, M, Martinez-Gonzalez, MA, Salas-Salvado, J, Mitjavila, MT, Moreno, JJ. A Mediterranean diet supplemented with extra virgin olive oil or nuts improves endothelial markers involved in blood pressure control in hypertensive women. Eur J Nutr. 2017. 56:89–97. doi:10.1007/s00394-015-1060-5 26450601 | Intervention/Exposure; Outcome
2273 | Stow, R, Ives, N, Smith, C, Rick, C, Rushton, A. A cluster randomised feasibility trial evaluating nutritional interventions in the treatment of malnutrition in care home adult residents. Trials. 2015. 16:433. doi:10.1186/s13063-015-0952-2 26416253 | Intervention/Exposure
2274 | Strandberg, E, Edholm, P, Ponsot, E, Wahlin-Larsson, B, Hellmen, E, Nilsson, A, Engfeldt, P, Cederholm, T, Riserus, U, Kadi, F. Influence of combined resistance training and healthy diet on muscle mass in healthy elderly women: a randomized controlled trial. J Appl Physiol (1985). 2015. 119:918–25. doi:10.1152/japplphysiol.00066.2015 26338453 | Intervention/Exposure
2275 | Straznicky, NE, Grima, MT, Sari, CI, Lambert, EA, Phillips, SE, Eikelis, N, Kobayashi, D, Hering, D, Mariani, JA, Dixon, JB, Nestel, PJ, Karapanagiotidis, S, Schlaich, MP, Lambert, GW. Reduction in peripheral vascular resistance predicts improvement in insulin clearance following weight loss. Cardiovasc Diabetol. 2015. 14:113. doi:10.1186/s12933-015-0276-2 26297500 | Power/Size
2276 | Streppel, MT, Sluik, D, van Yperen, JF, Geelen, A, Hofman, A, Franco, OH, Witteman, JC, Feskens, EJ. Nutrient-rich foods, cardiovascular diseases and all-cause mortality: the Rotterdam study. Eur J Clin Nutr. 2014. 68:741–7. doi:10.1038/ejcn.2014.35 24642783 | Intervention/Exposure
2277 | Struijk, EA, Beulens, JWJ, May, AM, Fransen, HP, Boer, JMA, De Wit, GA, Onland-Moret, NG, Van Der Schouw, YT, Hoekstra, J, Bueno-De-Mesquita, HB, Peeters, PHM. Dietary patterns in relation to disease burden expressed in Disability-Adjusted Life Years. American Journal of Clinical Nutrition. 2014. 100:1158–1165. doi:10.3945/ajcn.113.082032 | Outcome
2278 | Stulnig, TM. The ZONE Diet and Metabolic Control in Type 2 Diabetes. J Am Coll Nutr. 2015. 34 Suppl 1:39–41. doi:10.1080/07315724.2015.1080110 26400433 | Study Design
2279 | Su, HY, Lee, HC, Cheng, WY, Huang, SY. A calorie-restriction diet supplemented with fish oil and high-protein powder is associated with reduced severity of metabolic syndrome in obese women. Eur J Clin Nutr. 2015. 69:322–8. doi:10.1038/ejcn.2014.196 25248358 | Intervention/Exposure
2280 | Su, M, Qiu, L, Wang, Q, Jiang, Z, Liu, XJ, Lin, J, Fang, DZ. Associations of Leu72Met Polymorphism of Preproghrelin with Ratios of Plasma Lipids Are Diversified by a High-Carbohydrate Diet in Healthy Chinese Adolescents. Ann Nutr Metab. 2015. 67:236–42. doi:10.1159/000440777 26536003 | Study Design
2281 | Suchanek, P, Lanska, V, Hubacek, JA. Body Composition Changes in Adult Females after Lifestyle Intervention Are Influenced by the NYD-SP18 Variant. Cent Eur J Public Health. 2015. 23 Suppl:S19–22. doi:10.21101/cejph.a4105 26849538 | Study Design; Intervention/Exposure
2282 | Suckling, RJ, Swift, PA. The health impacts of dietary sodium and a low-salt diet. Clin Med (Lond). 2015. 15:585–8. doi:10.7861/clinmedicine.15-6-585 26621954 | Study Design
2283 | Sugawara, S, Kushida, M, Iwagaki, Y, Asano, M, Yamamoto, K, Tomata, Y, Tsuji, I, Tsuduki, T. The 1975 Type Japanese Diet Improves Lipid Metabolic Parameters in Younger Adults: A Randomized Controlled Trial. J Oleo Sci. 2018. 67:599–607. doi:10.5650/jos.ess17259 29710042 | Study duration
2284 | Sugihiro, T, Yoneda, M, Ohno, H, Oki, K, Hattori, N. Associations of nutrient intakes with obesity and diabetes mellitus in the longitudinal medical surveys of Japanese Americans. J Diabetes Investig. 2019. 10:1229–1236. doi:10.1111/jdi.13010 | Intervention/Exposure
2285 | Suh, Y, Kang, H, Kim, M, Kim, S. Effect of weight reduction on Korean high protein diet in obese women. Obesity reviews. 2014. 15:229. doi:10.1111/obr.12153 | Publication Status
2286 | Suljkovicova, H, Marion-Latard, F, Hejnova, J, Majercik, M, Crampes, F, De Glisezinski, I, Berlan, M, Riviere, D, Stich, V. Effect of macronutrient composition of the diet on the regulation of lipolysis in adipose tissue at rest and during exercise: microdialysis study. Metabolism. 2002. 51:1291–7. doi:10.1053/meta.2002.35190 12370849 | Study duration
2287 | Sumithran, P, Prendergast, LA, Delbridge, E, Purcell, K, Shulkes, A, Kriketos, A, Proietto, J. Ketosis and appetite-mediating nutrients and hormones after weight loss. Eur J Clin Nutr. 2013. 67:759–64. doi:10.1038/ejcn.2013.90 23632752 | Study Design; Intervention/Exposure
2288 | Summer, SS, Brehm, BJ, Benoit, SC, D’Alessio, DA. Adiponectin changes in relation to the macronutrient composition of a weight-loss diet. Obesity (Silver Spring). 2011. 19:2198–204. doi:10.1038/oby.2011.60 21455123 | Health Status
2289 | Sun, D, Heianza, Y, Huang, T, Wang, T, Han, L, Bray, GA, Sacks, FM, Qi, L. Genetic susceptibility and changes of blood pressure in response to weight-loss diets: the pounds lost trial. Diabetes. 2017. 66:A401–A402. doi:unavailable | Publication Status
2290 | Sun, J, Buys, NJ, Hills, AP. Dietary pattern and its association with the prevalence of obesity, hypertension and other cardiovascular risk factors among Chinese older adults. Int J Environ Res Public Health. 2014. 11:3956–71. doi:10.3390/ijerph110403956 24727356 | Study Design
2291 | Sundararajan, K, Campbell, MK, Choi, YH, Sarma, S. The relationship between diet quality and adult obesity: evidence from Canada. J Am Coll Nutr. 2014. 33:1–17. doi:10.1080/07315724.2013.848157 24533603 | Study Design
2292 | Sunehag, AL, Toffolo, G, Campioni, M, Bier, DM, Haymond, MW. Effects of dietary macronutrient intake on insulin sensitivity and secretion and glucose and lipid metabolism in healthy, obese adolescents. J Clin Endocrinol Metab. 2005. 90:4496–502. doi:10.1210/jc.2005-0626 15928240 | Study duration
2293 | Sung, KC, Sung, E, Byrne, CD, Kim, YB, Ahn, CW, Chung, HK. Composition of dietary macronutrient intake is not associated with prevalence of coronary artery calcification in healthy Korean adults. Ann Nutr Metab. 2015. 66:36–43. doi:10.1159/000369563 25531976 | Study Design; Outcome
2294 | Sureda, A, Bibiloni, MDM, Julibert, A, Bouzas, C, Argelich, E, Llompart, I, Pons, A, Tur, JA. Adherence to the Mediterranean Diet and Inflammatory Markers. Nutrients. 2018. 10:. doi:10.3390/nu10010062 | Study Design
2295 | Surowska, A, Jegatheesan, P, Campos, V, Marques, AS, Egli, L, Cros, J, Rosset, R, Lecoultre, V, Kreis, R, Boesch, C, Pouymayou, B, Schneiter, P, Tappy, L. Effects of Dietary Protein and Fat Content on Intrahepatocellular and Intramyocellular Lipids during a 6-Day Hypercaloric, High Sucrose Diet: A Randomized Controlled Trial in Normal Weight Healthy Subjects. Nutrients. 2019. 11:. doi:10.3390/nu11010209 | Study duration
2296 | Suyardi, MA, Johanes, W, Harahap, IP. The effects of balanced low calorie diet on body composition and serum leptin of obese women. Medical Journal of Indonesia. 2005. 14:220–224. doi:10.13181/mji.v14i4.202 | Study duration
2297 | Suzuki, R, Tamura, Y, Takeno, K, Kakehi, S, Funayama, T, Furukawa, Y, Kaga, H, Sugimoto, D, Kadowaki, S, Someya, Y, Kanazawa, A, Kawamori, R, Watada, H. Three days of a eucaloric, low-carbohydrate/high-fat diet increases insulin clearance in healthy non-obese Japanese men. Sci Rep. 2019. 9:3857. doi:10.1038/s41598-019-40498-6 30846785 | Study duration
2298 | Svetkey, LP, Moore, TJ, Simons-Morton, DG, Appel, LJ, Bray, GA, Sacks, FM, Ard, JD, Mortensen, RM, Mitchell, SR, Conlin, PR, Kesari, M. Angiotensinogen genotype and blood pressure response in the Dietary Approaches to Stop Hypertension (DASH) study. J Hypertens. 2001. 19:1949–56. doi:10.1097/00004872-200111000-00004 11677359 | Intervention/Exposure
2299 | Swinburn, BA, Metcalf, PA, Ley, SJ. Long-term (5-year) effects of a reduced-fat diet intervention in individuals with glucose intolerance. Diabetes Care. 2001. 24:619–24. doi:10.2337/diacare.24.4.619 11315819 | Weight loss/Hypocaloric
2300 | Sylvetsky, AC, Edelstein, SL, Walford, G, Boyko, EJ, Horton, ES, Ibebuogu, UN, Knowler, WC, Montez, MG, Temprosa, M, Hoskin, M, Rother, KI, Delahanty, LM. A High-Carbohydrate, High-Fiber, Low-Fat Diet Results in Weight Loss among Adults at High Risk of Type 2 Diabetes. J Nutr. 2017. 147:2060–2066. doi:10.3945/jn.117.252395 28954840 | Intervention/Exposure
2301 | Szczuko, M, Gutowska, I, Seidler, T. Nutrition and nourishment status of Polish students in comparison with students from other countries. Rocz Panstw Zakl Hig. 2015. 66:261–8. doi:unavailable26400123 | Study Design
2302 | Tabung, FK, Fung, TT, Chavarro, JE, Smith-Warner, SA, Willett, WC, Giovannucci, EL. Associations between adherence to the World Cancer Research Fund/American Institute for Cancer Research cancer prevention recommendations and biomarkers of inflammation, hormonal, and insulin response. Int J Cancer. 2017. 140:764–776. doi:10.1002/ijc.30494 27798951 | Study Design; Outcome
2303 | Takagi, H, Kobayashi, Y, Taguchi, O, Takei, Y, Sumida, Y. Influence of dietary intake of fish oil, magnesium, and zinc on metabolic parameters among individuals tested for diabetes. Nutrition. 2015. 31:988–93. doi:10.1016/j.nut.2015.02.019 26059373 | Study Design
2304 | Talaei, M, Koh, WP, Yuan, JM, van Dam, RM. DASH Dietary Pattern, Mediation by Mineral Intakes, and the Risk of Coronary Artery Disease and Stroke Mortality. J Am Heart Assoc. 2019. 8:e011054. doi:10.1161/jaha.118.011054 30806152 | Country
2305 | Tam, CH, Wang, Y, Lee, HM, Luk, AO, Tong, PC, Chan, MH, Ozaki, R, Kong, AP, So, WY, Chan, JC, Ma, RC. Early gene-diet interaction between glucokinase regulatory protein (GCKR) polymorphism, vegetable and fish intakes in modulating triglyceride levels in healthy adolescents. Nutr Metab Cardiovasc Dis. 2015. 25:951–8. doi:10.1016/j.numecd.2015.06.011 26234566 | Study Design
2306 | Tambalis, KD, Panagiotakos, DB, Psarra, G, Sidossis, LS. Association of cardiorespiratory fitness levels with dietary habits and lifestyle factors in schoolchildren. Appl Physiol Nutr Metab. 2019. 44:539–545. doi:10.1139/apnm-2018-0407 30321490 | Study Design
2307 | Tamura, T, Yatabe, T, Kitagawa, H, Yamashita, K, Hanazaki, K, Yokoyama, M. Oral carbohydrate loading with 18% carbohydrate beverage alleviates insulin resistance. Asia Pac J Clin Nutr. 2013. 22:48–53. doi:10.6133/apjcn.2013.22.1.20 23353610 | Study duration
2308 | Tamura, Y, Watada, H, Igarashi, Y, Nomiyama, T, Onishi, T, Takahashi, K, Doi, S, Katamoto, S, Hirose, T, Tanaka, Y, Kawamori, R. Short-term effects of dietary fat on intramyocellular lipid in sprinters and endurance runners. Metabolism. 2008. 57:373–9. doi:10.1016/j.metabol.2007.10.013 18249210 | Study duration
2309 | Tang, H, Zhang, Z, Li, Z, Lin, J, Fang, DZ. High-Carbohydrate/Low-Fat Diet-Induced Gender-Specific Serum Lipid Profile Changes Are Associated with LEPR Polymorphisms in Chinese Youth. Ann Nutr Metab. 2017. 70:1–8. doi:10.1159/000455165 | Study duration
2310 | Tang, M, Armstrong, CL, Leidy, HJ, Campbell, WW. Normal vs. high-protein weight loss diets in men: effects on body composition and indices of metabolic syndrome. Obesity (Silver Spring). 2013. 21:E204–10. doi:10.1002/oby.20078 23592676 | Power/Size
2311 | Tang, M, Leidy, HJ, Campbell, WW. Regional, but not total, body composition changes in overweight and obese adults consuming a higher protein, energy-restricted diet are sex specific. Nutr Res. 2013. 33:629–35. doi:10.1016/j.nutres.2013.05.012 23890352 | Intervention/Exposure
2312 | Tang, Z, Zhou, T, Luo, Y, Xie, C, Huo, D, Tao, L, Pan, L, Sun, F, Zhu, H, Yang, X, Wang, W, Yan, A, Li, X, Guo, X. Risk factors for cerebrovascular disease mortality among the elderly in Beijing: A competing risk analysis. PLoS ONE. 2014. 9:. doi:10.1371/journal.pone.0087884 | Intervention/Exposure; Country
2313 | Tangney, C, Sarkar, D, Staffileno, BA. Comparison of three DASH scoring paradigms and prevalent hypertension among older Hispanics. J Hum Hypertens. 2016. 30:210–5. doi:10.1038/jhh.2015.50 26016593 | Study Design
2314 | Tanisawa, K, Ito, T, Sun, X, Ise, R, Oshima, S, Cao, ZB, Sakamoto, S, Tanaka, M, Higuchi, M. Strong influence of dietary intake and physical activity on body fatness in elderly Japanese men: age-associated loss of polygenic resistance against obesity. Genes Nutr. 2014. 9:416. doi:10.1007/s12263-014-0416-4 25030601 | Study Design; Intervention/Exposure
2315 | Tanskey, LA, Goldberg, JP, Chui, K, Must, A, Sacheck, JM. Accelerated Summer Weight Gain in a Low-Income, Ethnically Diverse Sample of Elementary School Children in Massachusetts. Child Obes. 2019. 15:244–253. doi:10.1089/chi.2017.0228 30888836 | Intervention/Exposure
2316 | Tapsell, L, Batterham, M, Huang, XF, Tan, SY, Teuss, G, Charlton, K, Oshea, J, Warensjo, E. Short term effects of energy restriction and dietary fat sub-type on weight loss and disease risk factors. Nutr Metab Cardiovasc Dis. 2010. 20:317–25. doi:10.1016/j.numecd.2009.04.007 19570664 | Intervention/Exposure; Comparator
2317 | Tapsell, LC, Batterham, MJ, Charlton, KE, Neale, EP, Probst, YC, O’Shea, JE, Thorne, RL, Zhang, Q, Louie, JC. Foods, nutrients or whole diets: effects of targeting fish and LCn3PUFA consumption in a 12mo weight loss trial. BMC Public Health. 2013. 13:1231. doi:10.1186/1471-2458-13-1231 24369765 | Intervention/Exposure; Comparator
2318 | Tardivo, AP, Nahas-Neto, J, Orsatti, CL, Dias, FB, Poloni, PF, Schmitt, EB, Nahas, EA. Effects of omega-3 on metabolic markers in postmenopausal women with metabolic syndrome. Climacteric. 2015. 18:290–8. doi:10.3109/13697137.2014.981521 25394692 | Intervention/Exposure
2319 | Tay, J, Brinkworth, GD, Noakes, M, Keogh, J, Clifton, PM. Metabolic effects of weight loss on a very-low-carbohydrate diet compared with an isocaloric high-carbohydrate diet in abdominally obese subjects. J Am Coll Cardiol. 2008. 51:59–67. doi:10.1016/j.jacc.2007.08.050 18174038 | Weight loss/Hypocaloric
2320 | Tayyem, RF, Al-Radaideh, AM, Hammad, SS, Al-Hajaj, S, Allehdan, SS, Agraib, LM, Al-Fayomi, KI, Malkawi, AA, Hijjawi, NS. Subcutaneous and visceral fat volumes measured by MRI and their relationships with nutrient intakes among adults. Asia Pac J Clin Nutr. 2019. 28:300–309. doi:10.6133/apjcn.201906_28(2).0012 31192559 | Study Design
2321 | Te Morenga, L, Docherty, P, Williams, S, Mann, J. The Effect of a Diet Moderately High in Protein and Fiber on Insulin Sensitivity Measured Using the Dynamic Insulin Sensitivity and Secretion Test (DISST). Nutrients. 2017. 9:. doi:10.3390/nu9121291 | Study Design; Intervention/Exposure
2322 | Te Morenga, LA, Levers, MT, Williams, SM, Brown, RC, Mann, J. Comparison of high protein and high fiber weight-loss diets in women with risk factors for the metabolic syndrome: a randomized trial. Nutr J. 2011. 10:40. doi:10.1186/1475-2891-10-40 21524314 | Study duration
2323 | Te Morenga, LA, McAuley, KA, Docherty, PD, Williams, SM, Mann, J. The effect of a high protein, high fibre diet on insulin sensitivity measured using the Dynamic Insulin Sensitivity and Secretion Test (DISST). Australasian medical journal. 2011. 4:780. doi:unavailable | Publication Status
2324 | Teff, KL, Elliott, SS, Tschop, M, Kieffer, TJ, Rader, D, Heiman, M, Townsend, RR, Keim, NL, D’Alessio, D, Havel, PJ. Dietary fructose reduces circulating insulin and leptin, attenuates postprandial suppression of ghrelin, and increases triglycerides in women. J Clin Endocrinol Metab. 2004. 89:2963–72. doi:10.1210/jc.2003-031855 15181085 | Study duration
2325 | Teixeira, JA, Castro, TG, Grant, CC, Wall, CR, Castro, Alds, Francisco, RPV, Vieira, SE, Saldiva, Srdm, Marchioni, DM. Dietary patterns are influenced by socio-demographic conditions of women in childbearing age: a cohort study of pregnant women. BMC Public Health. 2018. 18:301. doi:10.1186/s12889-018-5184-4 29490638 | Outcome; Participants
2326 | Telford, RD, Cunningham, RB, Telford, RM, Riley, M, Abhayaratna, WP. Determinants of Childhood Adiposity: Evidence from the Australian LOOK Study. PLoS ONE. 2012. 7:. doi:10.1371/journal.pone.0050014 | Intervention/Exposure
2327 | Telford, RD, Telford, RM, Martin, MK, Welvaert, M. Drivers of adolescent adiposity: Evidence from the Australian LOOK study. J Sci Med Sport. 2019. :. doi:10.1016/j.jsams.2019.07.013 | Intervention/Exposure
2328 | Teunissen-Beekman, KF, Dopheide, J, Geleijnse, JM, Bakker, SJ, Brink, EJ, de Leeuw, PW, Schalkwijk, CG, van Baak, MA. Dietary proteins improve endothelial function under fasting conditions but not in the postprandial state, with no effects on markers of low-grade inflammation. Br J Nutr. 2015. 114:1819–28. doi:10.1017/s0007114515003530 26400262 | Study Design; Study duration
2329 | Thalacker-Mercer, AE, Fleet, JC, Craig, BA, Carnell, NS, Campbell, WW. Inadequate protein intake affects skeletal muscle transcript profiles in older humans. Am J Clin Nutr. 2007. 85:1344–52. doi:10.1093/ajcn/85.5.1344 17490972 | Study duration
2330 | Tharrey, M, Mariotti, F, Mashchak, A, Barbillon, P, Delattre, M, Huneau, JF, Fraser, GE. Patterns of amino acids intake are strongly associated with cardiovascular mortality, independently of the sources of protein. Int J Epidemiol. 2019. :. doi:10.1093/ije/dyz194 | Intervention/Exposure
2331 | The Editors Of The Lancet Diabetes, Endocrinology. Expression of concern-Effect of a high-fat Mediterranean diet on bodyweight and waist circumference: a prespecified secondary outcomes analysis of the PREDIMED randomised controlled trial. Lancet Diabetes Endocrinol. 2018. 6:763. doi:10.1016/s2213-8587(18)30236-5 30097355 | Publication Status
2332 | Thomas, SJ, Booth, JN, 3rd, Dai, C, Li, X, Allen, N, Calhoun, D, Carson, AP, Gidding, S, Lewis, CE, Shikany, JM, Shimbo, D, Sidney, S, Muntner, P. Cumulative Incidence of Hypertension by 55 Years of Age in Blacks and Whites: The CARDIA Study. J Am Heart Assoc. 2018. 7:. doi:10.1161/jaha.117.007988 | Outcome
2333 | Thorning, TK, Raziani, F, Bendsen, NT, Astrup, A, Tholstrup, T, Raben, A. Diets with high-fat cheese, high-fat meat, or carbohydrate on cardiovascular risk markers in overweight postmenopausal women: a randomized crossover trial. Am J Clin Nutr. 2015. 102:573–81. doi:10.3945/ajcn.115.109116 26178720 | Study duration
2334 | Thorning, TK, Raziani, F, Bendsen, NT, Astrup, A, Tholstrup, T, Raben, A. Effect of a high cheese intake compared to high-fat meat or carbohydrate on cardiovascular risk markers in overweight postmenopausal women. Atherosclerosis. 2015. 241:e143. doi:unavailable | Publication Status
2335 | Thorpe, MG, Milte, CM, Crawford, D, McNaughton, SA. A comparison of the dietary patterns derived by principal component analysis and cluster analysis in older Australians. Int J Behav Nutr Phys Act. 2016. 13:30. doi:10.1186/s12966-016-0353-2 26928406 | Study Design
2336 | Thorpe, MP, Jacobson, EH, Layman, DK, He, X, Kris-Etherton, PM, Evans, EM. A diet high in protein, dairy, and calcium attenuates bone loss over twelve months of weight loss and maintenance relative to a conventional high-carbohydrate diet in adults. J Nutr. 2008. 138:1096–100. doi:10.1093/jn/138.6.1096 18492840 | Intervention/Exposure
2337 | Threapleton, DE, Burley, VJ, Greenwood, DC, Cade, JE. Dietary fibre intake and risk of ischaemic and haemorrhagic stroke in the UK Women’s Cohort Study. Eur J Clin Nutr. 2015. 69:467–74. doi:10.1038/ejcn.2014.260 25469464 | Intervention/Exposure
2338 | Tian, X, Huang, Y, Wang, H. Deviation of Chinese Adults’ Diet from the Chinese Food Pagoda 2016 and Its Association with Adiposity. Nutrients. 2017. 9:. doi:10.3390/nu9090995 | Country
2339 | Tielemans, MJ, Erler, NS, Leermakers, ET, van den Broek, M, Jaddoe, VW, Steegers, EA, Kiefte-de Jong, JC, Franco, OH. A Priori and a Posteriori Dietary Patterns during Pregnancy and Gestational Weight Gain: The Generation R Study. Nutrients. 2015. 7:9383–99. doi:10.3390/nu7115476 26569303 | Participants
2340 | Tielemans, SM, Kromhout, D, Altorf-van der Kuil, W, Geleijnse, JM. Associations of plant and animal protein intake with 5-year changes in blood pressure: the Zutphen Elderly Study. Nutr Metab Cardiovasc Dis. 2014. 24:1228–33. doi:10.1016/j.numecd.2014.05.013 24998077 | Outcome
2341 | Tinker, LF, Bonds, DE, Margolis, KL, Manson, JE, Howard, BV, Larson, J, Perri, MG, Beresford, SA, Robinson, JG, Rodriguez, B, Safford, MM, Wenger, NK, Stevens, VJ, Parker, LM. Low-fat dietary pattern and risk of treated diabetes mellitus in postmenopausal women: the Women’s Health Initiative randomized controlled dietary modification trial. Arch Intern Med. 2008. 168:1500–11. doi:10.1001/archinte.168.14.1500 18663162 | Publication Date Overlaps with Existing Review
2342 | Tinker, LF, Sarto, GE, Howard, BV, Huang, Y, Neuhouser, ML, Mossavar-Rahmani, Y, Beasley, JM, Margolis, KL, Eaton, CB, Phillips, LS, Prentice, RL. Biomarker-calibrated dietary energy and protein intake associations with diabetes risk among postmenopausal women from the Women’s Health Initiative. Am J Clin Nutr. 2011. 94:1600–6. doi:10.3945/ajcn.111.018648 22071707 | Intervention/Exposure
2343 | Tinsley, GM, Morales, E, Forsse, JS, Grandjean, PW. Impact of Acute Dietary Manipulations on DXA and BIA Body Composition Estimates. Med Sci Sports Exerc. 2017. 49:823–832. doi:10.1249/mss.0000000000001148 27875499 | Study duration
2344 | Tippens, KM, Erlandsen, A, Hanes, DA, Graybill, R, Jackson, C, Briley, J, Zwickey, H. Impact of a Short-Term Naturopathic Whole-Foods-Based Nutrition Education Intervention on Dietary Behavior and Diabetes Risk Markers: A Pilot Study. J Altern Complement Med. 2019. 25:234–240. doi:10.1089/acm.2018.0025 30312107 | Intervention/Exposure; Comparator
2345 | Todd, SA, Wright, C. Weight loss intervention trial comparing intermittent low carbohydrate versus continuous Mediterranean diet. Obesity facts. Conference: european obesity summit (EOS): 1st joint congress of EASO and IFSO-EC. Gothenburg sweden. Conference start: 20160601. Conference end: 20160604. Conference publication: (var.pagings). 2016. 9:252. doi:10.1159/000446744 | Publication Status
2346 | Tognon, G, Lissner, L, Saebye, D, Walker, KZ, Heitmann, BL. The Mediterranean diet in relation to mortality and CVD: a Danish cohort study. Br J Nutr. 2014. 111:151–9. doi:10.1017/s0007114513001931 23823619 | Publication Date Overlaps with Existing Review
2347 | Tognon, G, Rothenberg, E, Eiben, G, Sundh, V, Winkvist, A, Lissner, L. Does the Mediterranean diet predict longevity in the elderly? A Swedish perspective. Age (Dordr). 2011. 33:439–50. doi:10.1007/s11357-010-9193-1 21110231 | Outcome
2348 | Toledo, E, Hu, FB, Estruch, R, Salas-Salvado, J, Corella, D, Covas, MI, Aros, F, Gomez-Gracia, E, Fiol, M, Ruiz-Gutierrez, V, , . Association between adherence to the Mediterranean diet and blood pressure: 4-year follow-up in the PREDIMED trial. European journal of epidemiology. 2012. 27:S46–S47. doi:10.1007/s10654-012-9722-6 | Publication Status
2349 | Toledo, E, Wang, DD, Ruiz-Canela, M, Clish, CB, Razquin, C, Zheng, Y, Guasch-Ferre, M, Hruby, A, Corella, D, Gomez-Gracia, E, Fiol, M, Estruch, R, Ros, E, Lapetra, J, Fito, M, Aros, F, Serra-Majem, L, Liang, L, Salas-Salvado, J, Hu, FB, Martinez-Gonzalez, MA. Plasma lipidomic profiles and cardiovascular events in a randomized intervention trial with the Mediterranean diet. Am J Clin Nutr. 2017. 106:973–983. doi:10.3945/ajcn.116.151159 28814398 | Intervention/Exposure; Outcome
2350 | Tometich, DB, Mosher, CE, Winger, JG, Badr, HJ, Snyder, DC, Sloane, RJ, Demark-Wahnefried, W. Effects of diet and exercise on weight-related outcomes for breast cancer survivors and their adult daughters: an analysis of the DAMES trial. Support Care Cancer. 2017. 25:2559–2568. doi:10.1007/s00520-017-3665-0 28417203 | Intervention/Exposure; Outcome
2351 | Tomlinson, DJ, Erskine, RM, Morse, CI, Onambele, GL. Impact of Above-Average Proanabolic Nutrients Is Overridden by High Protein and Energy Intake in the Muscle-Tendon Unit Characteristics of Middle- to Older-Aged Adults. J Nutr. 2018. 148:1776–1785. doi:10.1093/jn/nxy185 30247586 | Study Design; Intervention/Exposure
2352 | Tonstad, S, Malik, N, Haddad, E. A high-fibre bean-rich diet versus a low-carbohydrate diet for obesity. J Hum Nutr Diet. 2014. 27 Suppl 2:109–16. doi:10.1111/jhn.12118 23627924 | Weight loss/Hypocaloric
2353 | Torbay, N, Hwalla Baba, N, Sawaya, S, Bajjani, R, Habbal, Z, Azar, S, Hashim, SA. High protein vs high carbohydrate hypoenergetic diet in treatment of obese normoinsulinemic and hyperinsulinemic subjects. Nutrition Research. 2002. 22:587–598. doi:10.1016/S0271-5317(02)00359-7 | Study duration
2354 | Torres, SJ, Nowson, CA. Effect of a weight-loss program on mental stress-induced cardiovascular responses and recovery. Nutrition. 2007. 23:521–8. doi:10.1016/j.nut.2007.04.016 17560080 | Intervention/Exposure
2355 | Torres, SJ, Robinson, S, Orellana, L, O’Connell, SL, Grimes, CA, Mundell, NL, Dunstan, DW, Nowson, CA, Daly, RM. Effects of progressive resistance training combined with a protein-enriched lean red meat diet on health-related quality of life in elderly women: Secondary analysis of a 4-month cluster randomised controlled trial. British Journal of Nutrition. 2017. 117:1550–1559. doi:10.1017/S0007114517001507 | Outcome
2356 | Torres-Pena, JD, Garcia-Rios, A, Delgado-Casado, N, Gomez-Luna, P, Alcala-Diaz, JF, Yubero-Serrano, EM, Gomez-Delgado, F, Leon-Acuna, A, Lopez-Moreno, J, Camargo, A, Tinahones, FJ, Delgado-Lista, J, Ordovas, JM, Perez-Martinez, P, Lopez-Miranda, J. Mediterranean diet improves endothelial function in patients with diabetes and prediabetes: A report from the CORDIOPREV study. Atherosclerosis. 2018. 269:50–56. doi:10.1016/j.atherosclerosis.2017.12.012 29274507 | Intervention/Exposure; Health Status
2357 | Tovar, A, Choumenkovitch, SF, Hennessy, E, Boulos, R, Must, A, Hughes, SO, Gute, DM, Vikre, EK, Economos, CD. Low demanding parental feeding style is associated with low consumption of whole grains among children of recent immigrants. Appetite. 2015. 95:211–8. doi:10.1016/j.appet.2015.06.006 26122753 | Study Design; Intervention/Exposure
2358 | Tovar, J, Johansson, M, Bjorck, I. A multifunctional diet improves cardiometabolic-related biomarkers independently of weight changes: an 8-week randomized controlled intervention in healthy overweight and obese subjects. Eur J Nutr. 2016. 55:2295–306. doi:10.1007/s00394-015-1039-2 26370118 | Study duration
2359 | Towner, EK, Robson, SM, Stark, LJ. Secondary impact of a behavioral intervention on dietary quality in preschoolers with obesity. Children’s Health Care. 2019. 48:75–89. doi:10.1080/02739615.2018.1463532 | Outcome
2360 | Trapp, CM, Burke, G, Gorin, AA, Wiley, JF, Hernandez, D, Crowell, RE, Grant, A, Beaulieu, A, Cloutier, MM. The relationship between dietary patterns, body mass index percentile, and household food security in young urban children. Child Obes. 2015. 11:148–55. doi:10.1089/chi.2014.0105 25719450 | Study Design
2361 | Trepanowski, JF. Improved insulin sensitivity with a healthy low fat or a healthy low carbohydrate weight loss diet: a twelve month randomized trial. Circulation. 2017. 135:. doi:unavailable | Publication Status
2362 | Trichopoulou, A, Psaltopoulou, T, Orfanos, P, Hsieh, CC, Trichopoulos, D. Low-carbohydrate-high-protein diet and long-term survival in a general population cohort. Eur J Clin Nutr. 2007. 61:575–81. doi:10.1038/sj.ejcn.1602557 17136037 | Intervention/Exposure; Outcome
2363 | Trico, D, Trifiro, S, Mengozzi, A, Morgantini, C, Baldi, S, Mari, A, Natali, A. Reducing Cholesterol and Fat Intake Improves Glucose Tolerance by Enhancing beta Cell Function in Nondiabetic Subjects. J Clin Endocrinol Metab. 2018. 103:622–631. doi:10.1210/jc.2017-02089 29095990 | Intervention/Exposure; Study duration
2364 | Tricò, D, Trifirò, S, Mengozzi, A, Morgantini, C, Baldi, S, Mari, A, Natali, A. Reducing Cholesterol and Fat Intake Improves Glucose Tolerance by Enhancing β Cell Function in Nondiabetic Subjects. Journal of clinical endocrinology and metabolism. 2018. 103:622–631. doi:10.1210/jc.2017-02089 29095990 | Study duration
2365 | Tripp, ML, Dahlberg, CJ, Eliason, S, Lamb, JJ, Ou, JJ, Gao, W, Bhandari, J, Graham, D, Dudleenamjil, E, Babish, JG. A Low-Glycemic, Mediterranean Diet and Lifestyle Modification Program with Targeted Nutraceuticals Reduces Body Weight, Improves Cardiometabolic Variables and Longevity Biomarkers in Overweight Subjects: A 13-Week Observational Trial. J Med Food. 2019. 22:479–489. doi:10.1089/jmf.2018.0063 31084538 | Study Design; Intervention/Exposure
2366 | Truby, H, Baxter, K, Ware, RS, Jensen, DE, Cardinal, JW, Warren, JM, Daniels, L, Davies, PS, Barrett, P, Blumfield, ML, Batch, JA. A Randomized Controlled Trial of Two Different Macronutrient Profiles on Weight, Body Composition and Metabolic Parameters in Obese Adolescents Seeking Weight Loss. PLoS One. 2016. 11:e0151787. doi:10.1371/journal.pone.0151787 27022913 | Weight loss/Hypocaloric
2367 | Trude, AC, Kharmats, A, Jock, B, Liu, D, Lee, K, Martins, PA, Pardilla, M, Swartz, J, Gittelsohn, J. Patterns of Food Consumption are Associated with Obesity, Self-Reported Diabetes and Cardiovascular Disease in Five American Indian Communities. Ecol Food Nutr. 2015. 54:437–54. doi:10.1080/03670244.2014.922070 26036617 | Study Design
2368 | Tsaban, G, Wolak, A, Avni, H, Gepner, Y, Shelef, I, Schwarzfuchs, D, Ceglarek, U, Stumvoll, M, Bluher, M, Thiery, J, , . Pericardial adiposity trajectory during long-term dietary intervention. European heart journal. 2016. 37:547-. doi:10.1093/eurheartj/ehw432 | Publication Status
2369 | Tsigga, M, Filis, V, Hatzopoulou, K, Kotzamanidis, C, Grammatikopoulou, MG. Healthy Eating Index during pregnancy according to pre-gravid and gravid weight status. Public Health Nutr. 2011. 14:290–6. doi:10.1017/s1368980010001989 20642871 | Study Design; Outcome
2370 | Tsilingiris, D, Dellis, D, Eleftheriadou, I, Tentolouris, A, Karanasiou, M, Meimari, A, Dellis, G, Dimosthenopoulos, C, Lazarou, S, Kokkinos, A, , . Integration of half-day carbohydrate restriction into a hypocaloric Mediterranean-type diet in overweight and obese subjects: an open label, randomised, controlled trial. Diabetologia. 2018. 61:S98-. doi:10.1007/s00125-018-4693-0 | Publication Status
2371 | Tsioufis, C. The Mediterranean and the DASH dietary patterns: Insights into their role in cardiovascular disease prevention. Hellenic J Cardiol. 2018. 59:134–135. doi:10.1016/j.hjc.2017.04.006 29704564 | Study Design; Publication Status
2372 | Tsugane, S, Sawada, N. The JPHC study: design and some findings on the typical Japanese diet. Jpn J Clin Oncol. 2014. 44:777–82. doi:10.1093/jjco/hyu096 25104790 | Study Design
2373 | Tucker, LA, LeCheminant, JD, Bailey, BW. Meat Intake and Insulin Resistance in Women without Type 2 Diabetes. J Diabetes Res. 2015. 2015:174742. doi:10.1155/2015/174742 26240831 | Intervention/Exposure
2374 | Tulk, HM, Robinson, LE. Modifying the n-6/n-3 polyunsaturated fatty acid ratio of a high-saturated fat challenge does not acutely attenuate postprandial changes in inflammatory markers in men with metabolic syndrome. Metabolism. 2009. 58:1709–16. doi:10.1016/j.metabol.2009.05.031 19625064 | Study duration
2375 | Tuomilehto, J, Lindström, J, Eriksson, JG. Changes in diet and physical activity prevented type 2 diabetes mellitus in people with impaired glucose tolerance. Evidence-Based Medicine. 2001. 6:176. doi:10.1136/ebm.6.6.176 | Study Design; Publication Status
2376 | Tura, A, Conte, B, Caparrotto, C, Spinella, P, Maestrelli, P, Valerio, A, Pacini, G, Avogaro, A. Insulin sensitivity and secretion in young, healthy subjects are not changed by Zone and Mediterranean diets. Mediterranean Journal of Nutrition and Metabolism. 2010. 3:233–237. doi:10.1007/s12349-010-0026-7 | Study duration
2377 | Turner, KM, Keogh, JB, Clifton, PM. Red meat, dairy, and insulin sensitivity: a randomized crossover intervention study. Am J Clin Nutr. 2015. 101:1173–9. doi:10.3945/ajcn.114.104976 25809854 | Intervention/Exposure; Study duration
2378 | Turner, KM, Keogh, JB, Meikle, PJ, Clifton, PM. Changes in Lipids and Inflammatory Markers after Consuming Diets High in Red Meat or Dairy for Four Weeks. Nutrients. 2017. 9:. doi:10.3390/nu9080886 | Study duration
2379 | Turner-McGrievy, GM, Barnard, ND, Scialli, AR. A two-year randomized weight loss trial comparing a vegan diet to a more moderate low-fat diet. Obesity (Silver Spring). 2007. 15:2276–81. doi:10.1038/oby.2007.270 17890496 | Intervention/Exposure
2380 | Turner-McGrievy, GM, Davidson, CR, Wilcox, S. Does the type of weight loss diet affect who participates in a behavioral weight loss intervention? A comparison of participants for a plant-based diet versus a standard diet trial. Appetite. 2014. 73:156–62. doi:10.1016/j.appet.2013.11.008 24269507 | Outcome
2381 | Turner-McGrievy, GM, Wirth, MD, Shivappa, N, Wingard, EE, Fayad, R, Wilcox, S, Frongillo, EA, Hebert, JR. Randomization to plant-based dietary approaches leads to larger short-term improvements in Dietary Inflammatory Index scores and macronutrient intake compared with diets that contain meat. Nutr Res. 2015. 35:97–106. doi:10.1016/j.nutres.2014.11.007 25532675 | Outcome
2382 | Tuttolomondo, A, Casuccio, A, Butta, C, Pecoraro, R, Di Raimondo, D, Della Corte, V, Arnao, V, Clemente, G, Maida, C, Simonetta, I, Miceli, G, Lucifora, B, Cirrincione, A, Di Bona, D, Corpora, F, Maugeri, R, Iacopino, DG, Pinto, A. Mediterranean Diet in patients with acute ischemic stroke: Relationships between Mediterranean Diet score, diagnostic subtype, and stroke severity index. Atherosclerosis. 2015. 243:260–7. doi:10.1016/j.atherosclerosis.2015.09.017 26409625 | Health Status
2383 | Tykhorskyi, O, Dzhym, V, Slavitiak, O, Galashko, N, Zhadan, A, Piven, O, Melnyk, A. Influence of hypo-caloric diet on absolute and relative strength of elite male bodybuilders’ while preparing for the competition. Research Journal of Pharmaceutical, Biological and Chemical Sciences. 2019. 10:1434–1440. doi:unavailable | Intervention/Exposure; Study duration
2384 | Tyrovolas, S, Haro, JM, Polychronopoulos, E, Mariolis, A, Piscopo, S, Valacchi, G, Makri, K, Zeimbekis, A, Tyrovola, D, Bountziouka, V, Gotsis, E, Metallinos, G, Katsoulis, Y, Tur, JA, Matalas, A, Lionis, C, Panagiotakos, D. Factors associated with components of arterial pressure among older individuals (the multinational MEDIS study): the role of the Mediterranean diet and alcohol consumption. J Clin Hypertens (Greenwich). 2014. 16:645–51. doi:10.1111/jch.12370 25056587 | Study Design
2385 | Tyrovolas, S, Psaltopoulou, T, Pounis, G, Papairakleous, N, Bountziouka, V, Zeimbekis, A, Gotsis, E, Antonopoulou, M, Metallinos, G, Polychronopoulos, E, Lionis, C, Panagiotakos, DB. Nutrient intake in relation to central and overall obesity status among elderly people living in the Mediterranean islands: the MEDIS study. Nutr Metab Cardiovasc Dis. 2011. 21:438–45. doi:10.1016/j.numecd.2009.10.012 20153615 | Study Design
2386 | Tyson, CC, Barnhart, H, Sapp, S, Poon, V, Lin, PH, Svetkey, LP. Ambulatory blood pressure in the dash diet trial: Effects of race and albuminuria. J Clin Hypertens (Greenwich). 2018. 20:308–314. doi:10.1111/jch.13170 29384243 | Intervention/Exposure
2387 | Tyson, CC, Davenport, CA, Lin, PH, Scialla, JJ, Hall, R, Diamantidis, CJ, Lunyera, J, Bhavsar, N, Rebholz, CM, Pendergast, J, Boulware, LE, Svetkey, LP. DASH Diet and Blood Pressure Among Black Americans With and Without CKD: The Jackson Heart Study. Am J Hypertens. 2019. 32:975–982. doi:10.1093/ajh/hpz090 31187128 | Intervention/Exposure; Outcome
2388 | Tyson, CC, Kuchibhatla, M, Patel, UD, Pun, PH, Chang, A, Nwankwo, C, Joseph, MA, Svetkey, LP. Impact of Kidney Function on Effects of the Dietary Approaches to Stop Hypertension (Dash) Diet. J Hypertens (Los Angel). 2014. 3:. doi:10.4172/2167-1095.1000168 | Intervention/Exposure
2389 | Uauy, R, Mize, CE, Castillo-Duran, C. Fat intake during childhood: metabolic responses and effects on growth. Am J Clin Nutr. 2000. 72:1354s–1360s. doi:10.1093/ajcn/72.5.1354s 11063477 | Intervention/Exposure
2390 | Um, YJ, Oh, SW, Lee, CM, Kwon, HT, Joh, HK, Kim, YJ, Kim, HJ, Ahn, SH. Dietary Fat Intake and the Risk of Metabolic Syndrome in Korean Adults. Korean J Fam Med. 2015. 36:245–52. doi:10.4082/kjfm.2015.36.5.245 26435816 | Intervention/Exposure; Outcome
2391 | Umemoto, S, Kawano, R, Kawamura, A, Onaka, U, Motoi, S, Mitarai, M. Effects of Japan diet-based antihypertensive diet on blood pressure and its variability in subjects with untreated normal high blood pressure and stage I hypertension: a randomized controlled trial. Circulation. 2017. 136:. doi:unavailable | Publication Status
2392 | Umpleby, AM, Shojaee-Moradie, F, Fielding, B, Li, X, Marino, A, Alsini, N, Isherwood, C, Jackson, N, Ahmad, A, Stolinski, M, Lovegrove, JA, Johnsen, S, Jeewaka, RMendisAS, Wright, J, Wilinska, ME, Hovorka, R, Bell, JD, Thomas, EL, Frost, GS, Griffin, BA. Impact of liver fat on the differential partitioning of hepatic triacylglycerol into VLDL subclasses on high and low sugar diets. Clin Sci (Lond). 2017. 131:2561–2573. doi:10.1042/cs20171208 28923880 | Intervention/Exposure
2393 | Unwin, D, Unwin, J. Low carbohydrate diet to achieve weight loss and improve HbA1c in type 2 diabetes and pre-diabetes: Experience from one general practice. Practical Diabetes. 2014. 31:76–79. doi:10.1002/pdi.1835 | Study Design; Intervention/Exposure
2394 | Unwin, DJ, Tobin, SD, Murray, SW, Delon, C, Brady, AJ. Substantial and Sustained Improvements in Blood Pressure, Weight and Lipid Profiles from a Carbohydrate Restricted Diet: An Observational Study of Insulin Resistant Patients in Primary Care. Int J Environ Res Public Health. 2019. 16:. doi:10.3390/ijerph16152680 | Intervention/Exposure; Health Status
2395 | Urbain, P, Strom, L, Morawski, L, Wehrle, A, Deibert, P, Bertz, H. Impact of a 6-week non-energy-restricted ketogenic diet on physical fitness, body composition and biochemical parameters in healthy adults. Nutr Metab (Lond). 2017. 14:17. doi:10.1186/s12986-017-0175-5 28239404 | Study Design
2396 | Utzschneider, KM, Arbuckle, MD, Tidwell, JM, Craft, S. An isocaloric low-fat diet decreases liver fat in older subjects. #journal#. 2010. :. doi:unavailable | Publication Status
2397 | Utzschneider, KM, Bayer-Carter, JL, Arbuckle, MD, Tidwell, JM, Richards, TL, Craft, S. Beneficial effect of a weight-stable, low-fat/low-saturated fat/low-glycaemic index diet to reduce liver fat in older subjects. Br J Nutr. 2013. 109:1096–104. doi:10.1017/s0007114512002966 22849970 | Study duration
2398 | Uusitupa, M. Healthy nordic diet and metabolic syndrome-the sysdiet study. Annals of nutrition and metabolism. Conference: 12th european nutrition conference, FENS 2015. Berlin germany. Conference start: 20151020. Conference end: 20151023. Conference publication: (var.pagings). 2015. 67:52. doi:10.1159/000440895 | Publication Status
2399 | Vadiveloo, M, Sacks, FM, Champagne, CM, Bray, GA, Mattei, J. Greater Healthful Dietary Variety Is Associated with Greater 2-Year Changes in Weight and Adiposity in the Preventing Overweight Using Novel Dietary Strategies (POUNDS Lost) Trial. J Nutr. 2016. 146:1552–9. doi:10.3945/jn.115.224683 27358422 | Intervention/Exposure
2400 | Vakili, R, Nematy, M. Comparison of the effect of ketogenic diet and low caloric diet on weight loss in Iranian obese and overweight children. Hormone research in paediatrics. 2011. 76:180. doi:10.1159/000334327 | Publication Status
2401 | Valente-Dos-Santos, J, Tavares, OM, Duarte, JP, Sousa, ESilvaPM, Rama, LM, Casanova, JM, Fontes-Ribeiro, CA, Marques, EA, Courteix, D, Ronque, ERV, Cyrino, ES, Conde, J, Coelho, ESilvaMJ. Total and regional bone mineral and tissue composition in female adolescent athletes: comparison between volleyball players and swimmers. BMC Pediatr. 2018. 18:212. doi:10.1186/s12887-018-1182-z 29970045 | Study Design; Intervention/Exposure
2402 | Van Baak, M, Dopheide, J, Geleijnse, J, Bakker, S, Brink, E. Blood pressure and postprandial hemodynamic changes on a high protein versus high carbohydrate diet. Annals of nutrition and metabolism. 2011. 58:188. doi:10.1159/000334393 21757892 | Publication Status
2403 | van Baak, MA, Larsen, TM, Jebb, SA, Martinez, A, Saris, WHM, Handjieva-Darlenska, T, Kafatos, A, Pfeiffer, AFH, Kunesova, M, Astrup, A. Dietary Intake of Protein from Different Sources and Weight Regain, Changes in Body Composition and Cardiometabolic Risk Factors after Weight Loss: The DIOGenes Study. Nutrients. 2017. 9:. doi:10.3390/nu9121326 | Study Design
2404 | van Bakel, MM, Kaaks, R, Feskens, EJ, Rohrmann, S, Welch, AA, Pala, V, Avloniti, K, van der Schouw, YT, van der, Dl A, Du, H, Halkjaer, J, Tormo, MJ, Cust, AE, Brighenti, F, Beulens, JW, Ferrari, P, Biessy, C, Lentjes, M, Spencer, EA, Panico, S, Masala, G, Bueno-de-Mesquita, HB, Peeters, PH, Trichopoulou, A, Psaltopoulou, T, Clavel-Chapelon, F, Touvier, M, Skeie, G, Rinaldi, S, Sonestedt, E, Johansson, I, Schulze, M, Ardanaz, E, Buckland, G, Tjonneland, A, Overvad, K, Bingham, S, Riboli, E, Slimani, N. Dietary glycaemic index and glycaemic load in the European Prospective Investigation into Cancer and Nutrition. Eur J Clin Nutr. 2009. 63 Suppl 4:S188–205. doi:10.1038/ejcn.2009.81 19888274 | Study Design; Intervention/Exposure; Outcome
2405 | van Bussel, BC, Henry, RM, Ferreira, I, van Greevenbroek, MM, van der Kallen, CJ, Twisk, JW, Feskens, EJ, Schalkwijk, CG, Stehouwer, CD. A healthy diet is associated with less endothelial dysfunction and less low-grade inflammation over a 7-year period in adults at risk of cardiovascular disease. J Nutr. 2015. 145:532–40. doi:10.3945/jn.114.201236 25733469 | Intervention/Exposure
2406 | van Dam, RM, Rimm, EB, Willett, WC, Stampfer, MJ, Hu, FB. Dietary patterns and risk for type 2 diabetes mellitus in U.S. men. Ann Intern Med. 2002. 136:201–9. doi:10.7326/0003-4819-136-3-200202050-00008 11827496 | Publication Date Overlaps with Existing Review
2407 | van Dam, RM, Willett, WC, Rimm, EB, Stampfer, MJ, Hu, FB. Dietary fat and meat intake in relation to risk of type 2 diabetes in men. Diabetes Care. 2002. 25:417–24. doi:10.2337/diacare.25.3.417 11874924 | Intervention/Exposure
2408 | van der Gaag, EJ, Wieffer, R, van der Kraats, J. Advising Consumption of Green Vegetables, Beef, and Full-Fat Dairy Products Has No Adverse Effects on the Lipid Profiles in Children. Nutrients. 2017. 9:. doi:10.3390/nu9050518 | Intervention/Exposure
2409 | Van Elten, TM, Karsten, MDA, Geelen, A, Gemke, RJBJ, Groen, H, Hoek, A, Van Poppel, MNM, Roseboom, TJ. Preconception lifestyle intervention reduces long term energy intake in women with obesity and infertility: A randomised controlled trial 11 Medical and Health Sciences 1117 Public Health and Health Services 11 Medical and Health Sciences 1111 Nutrition and Dietetics. International Journal of Behavioral Nutrition and Physical Activity. 2019. 16:. doi:10.1186/s12966-018-0761-6 | Intervention/Exposure; Comparator
2410 | van Elten, TM, Karsten, MDA, Geelen, A, Gemke, Rjbj, Groen, H, Hoek, A, van Poppel, MNM, Roseboom, TJ. Preconception lifestyle intervention reduces long term energy intake in women with obesity and infertility: a randomised controlled trial. Int J Behav Nutr Phys Act. 2019. 16:3. doi:10.1186/s12966-018-0761-6 30621789 | Intervention/Exposure; Outcome
2411 | Van Elten, TM, Van Poppel, MNM, Gemke, Rjbj, Groen, H, Hoek, A, Mol, BW, Roseboom, TJ. Cardiometabolic Health in Relation to Lifestyle and Body Weight Changes 3(-)8 Years Earlier. Nutrients. 2018. 10:. doi:10.3390/nu10121953 | Intervention/Exposure
2412 | Van Elten, TM, Van Poppel, MNM, Gemke, RJBJ, Groen, H, Hoek, A, Mol, BW, Roseboom, TJ. Cardiometabolic health in relation to lifestyle and body weight changes 3–8 years earlier. Nutrients. 2018. 10:. doi:10.3390/nu10121953 | Intervention/Exposure
2413 | van Gemert, WA, Schuit, AJ, van der Palen, J, May, AM, Iestra, JA, Wittink, H, Peeters, PH, Monninkhof, EM. Effect of weight loss, with or without exercise, on body composition and sex hormones in postmenopausal women: the SHAPE-2 trial. Breast Cancer Res. 2015. 17:120. doi:10.1186/s13058-015-0633-9 26330303 | Intervention/Exposure
2414 | van Hees, AM, Jocken, JW, Essers, Y, Roche, HM, Saris, WH, Blaak, EE. Adipose triglyceride lipase and hormone-sensitive lipase protein expression in subcutaneous adipose tissue is decreased after an isoenergetic low-fat high-complex carbohydrate diet in the metabolic syndrome. Metabolism. 2012. 61:1404–12. doi:10.1016/j.metabol.2012.03.017 22551950 | Power/Size; Intervention/Exposure
2415 | van Herpen, NA, Schrauwen-Hinderling, VB, Schaart, G, Mensink, RP, Schrauwen, P. Three weeks on a high-fat diet increases intrahepatic lipid accumulation and decreases metabolic flexibility in healthy overweight men. J Clin Endocrinol Metab. 2011. 96:E691–5. doi:10.1210/jc.2010-2243 21252252 | Study duration
2416 | Van Horn, L, Peaceman, A, Kwasny, M, Vincent, E, Fought, A, Josefson, J, Spring, B, Neff, LM, Gernhofer, N. Dietary Approaches to Stop Hypertension Diet and Activity to Limit Gestational Weight: Maternal Offspring Metabolics Family Intervention Trial, a Technology Enhanced Randomized Trial. Am J Prev Med. 2018. 55:603–614. doi:10.1016/j.amepre.2018.06.015 30262148 | Participants
2417 | van Nassau, F, Singh, AS, Cerin, E, Salmon, J, van Mechelen, W, Brug, J, Chinapaw, MJ. The Dutch Obesity Intervention in Teenagers (DOiT) cluster controlled implementation trial: intervention effects and mediators and moderators of adiposity and energy balance-related behaviours. Int J Behav Nutr Phys Act. 2014. 11:158. doi:10.1186/s12966-014-0158-0 25539582 | Intervention/Exposure
2418 | van Nielen, M, Feskens, EJ, Rietman, A, Siebelink, E, Mensink, M. Partly replacing meat protein with soy protein alters insulin resistance and blood lipids in postmenopausal women with abdominal obesity. J Nutr. 2014. 144:1423–9. doi:10.3945/jn.114.193706 25008579 | Intervention/Exposure; Outcome; Study duration
2419 | van Oostrom, AJ, Castro Cabezas, M, Ribalta, J, Masana, L, Twickler, TB, Remijnse, TA, Erkelens, DW. Diurnal triglyceride profiles in healthy normolipidemic male subjects are associated to insulin sensitivity, body composition and diet. Eur J Clin Invest. 2000. 30:964–71. doi:10.1046/j.1365-2362.2000.00732.x 11114958 | Study duration
2420 | van Vught, AJ, Dagnelie, PC, Arts, IC, Froberg, K, Andersen, LB, El-Naaman, B, Bugge, A, Nielsen, BM, Heitman, BL. Dietary arginine and linear growth: the Copenhagen School Child Intervention Study. Br J Nutr. 2013. 109:1031–9. doi:10.1017/s0007114512002942 23046689 | Intervention/Exposure
2421 | van Vught, AJ, Heitmann, BL, Nieuwenhuizen, AG, Veldhorst, MA, Brummer, RJ, Westerterp-Plantenga, MS. Association between dietary protein and change in body composition among children (EYHS). Clin Nutr. 2009. 28:684–8. doi:10.1016/j.clnu.2009.05.001 19524336 | Intervention/Exposure
2422 | Vanacore, D, Messina, G, Lama, S, Bitti, G, Ambrosio, P, Tenore, G, Messina, A, Monda, V, Zappavigna, S, Boccellino, M, Novellino, E, Monda, M, Stiuso, P. Effect of restriction vegan diet’s on muscle mass, oxidative status, and myocytes differentiation: A pilot study. J Cell Physiol. 2018. 233:9345–9353. doi:10.1002/jcp.26427 29319158 | Study Design; Outcome
2423 | Varady, KA, Bhutani, S, Klempel, MC, Phillips, SA. Improvements in vascular health by a low-fat diet, but not a high-fat diet, are mediated by changes in adipocyte biology. Nutr J. 2011. 10:8. doi:10.1186/1475-2891-10-8 21251283 | Study duration
2424 | Varady, KA, Dam, VT, Klempel, MC, Horne, M, Cruz, R, Kroeger, CM, Santosa, S. Effects of weight loss via high fat vs. low fat alternate day fasting diets on free fatty acid profiles. Sci Rep. 2015. 5:7561. doi:10.1038/srep07561 25557754 | Power/Size
2425 | Vargas, P. Dietary Intake and Obesity among Filipino Americans in New Jersey. J Environ Public Health. 2018. 2018:6719861. doi:10.1155/2018/6719861 30305824 | Study Design
2426 | Vargas, S, Romance, R, Petro, JL, Bonilla, DA, Galancho, I, Espinar, S, Kreider, RB, Benitez-Porres, J. Efficacy of ketogenic diet on body composition during resistance training in trained men: a randomized controlled trial. J Int Soc Sports Nutr. 2018. 15:31. doi:10.1186/s12970-018-0236-9 29986720 | Intervention/Exposure
2427 | Vasilaras, TH, Raben, A, Astrup, A. Twenty-four hour energy expenditure and substrate oxidation before and after 6 months’ ad libitum intake of a diet rich in simple or complex carbohydrates or a habitual diet. Int J Obes Relat Metab Disord. 2001. 25:954–65. doi:10.1038/sj.ijo.0801630 11443492 | Intervention/Exposure
2428 | Velazquez-Lopez, L, Gonzalez-Figueroa, E, Medina-Bravo, P, Pineda-Del Aguila, I, Avila-Jimenez, L, Ramos-Hernandez, R, Klunder-Klunder, M, Escobedo-de la Pena, J. Low calorie and carbohydrate diet: to improve the cardiovascular risk indicators in overweight or obese adults with prediabetes. Endocrine. 2013. 43:593–602. doi:10.1007/s12020-012-9775-z 22941424 | Study Design; Intervention/Exposure
2429 | Velazquez-Lopez, L, Santiago-Diaz, G, Nava-Hernandez, J, Munoz-Torres, AV, Medina-Bravo, P, Torres-Tamayo, M. Mediterranean-style diet reduces metabolic syndrome components in obese children and adolescents with obesity. BMC Pediatr. 2014. 14:175. doi:10.1186/1471-2431-14-175 24997634 | Power/Size
2430 | Veldhorst, MA, Westerterp, KR, van Vught, AJ, Westerterp-Plantenga, MS. Presence or absence of carbohydrates and the proportion of fat in a high-protein diet affect appetite suppression but not energy expenditure in normal-weight human subjects fed in energy balance. Br J Nutr. 2010. 104:1395–405. doi:10.1017/s0007114510002060 20565999 | Study duration
2431 | Veldhorst, MA, Westerterp-Plantenga, MS, Westerterp, KR. Gluconeogenesis and energy expenditure after a high-protein, carbohydrate-free diet. Am J Clin Nutr. 2009. 90:519–26. doi:10.3945/ajcn.2009.27834 19640952 | Study duration
2432 | Veldhorst, MAB, Verbruggen, Scat, van Harskamp, D, Vermes, A, Schierbeek, H, van Goudoever, JB, van den Akker, ELT. Effects of a high-protein intake on metabolic targets for weight loss in children with obesity: a randomized trial. Obes Sci Pract. 2018. 4:347–356. doi:10.1002/osp4.277 30151229 | Study duration
2433 | Venn, BJ, Perry, T, Green, TJ, Skeaff, CM, Aitken, W, Moore, NJ, Mann, JI, Wallace, AJ, Monro, J, Bradshaw, A, Brown, RC, Skidmore, PM, Doel, K, O’Brien, K, Frampton, C, Williams, S. The effect of increasing consumption of pulses and wholegrains in obese people: a randomized controlled trial. J Am Coll Nutr. 2010. 29:365–72. doi:10.1080/07315724.2010.10719853 21041811 | Intervention/Exposure; Publication Date Overlaps with Existing Review
2434 | Veno, SK, Schmidt, EB, Jakobsen, MU, Lundbye-Christensen, S, Bach, FW, Overvad, K. Substitution of Linoleic Acid for Other Macronutrients and the Risk of Ischemic Stroke. Stroke. 2017. 48:3190–3195. doi:10.1161/strokeaha.117.017935 29070717 | Intervention/Exposure
2435 | Ventura, E, Davis, J, Byrd-Williams, C, Alexander, K, McClain, A, Lane, CJ, Spruijt-Metz, D, Weigensberg, M, Goran, M. Reduction in risk factors for type 2 diabetes mellitus in response to a low-sugar, high-fiber dietary intervention in overweight Latino adolescents. Arch Pediatr Adolesc Med. 2009. 163:320–7. doi:10.1001/archpediatrics.2009.11 19349560 | Intervention/Exposure
2436 | Verges, B, Fumeron, F. Potential risks associated with increased plasma plant-sterol levels. Diabetes Metab. 2015. 41:76–81. doi:10.1016/j.diabet.2014.11.003 25497968 | Study Design; Intervention/Exposure
2437 | Vergnaud, AC, Norat, T, Mouw, T, Romaguera, D, May, AM, Bueno-de-Mesquita, HB, van der, AD, Agudo, A, Wareham, N, Khaw, KT, Romieu, I, Freisling, H, Slimani, N, Perquier, F, Boutron-Ruault, MC, Clavel-Chapelon, F, Palli, D, Berrino, F, Mattiello, A, Tumino, R, Ricceri, F, Rodriguez, L, Molina-Montes, E, Amiano, P, Barricarte, A, Chirlaque, MD, Crowe, FL, Orfanos, P, Naska, A, Trichopoulou, A, Teucher, B, Kaaks, R, Boeing, H, Buijsse, B, Johansson, I, Hallmans, G, Drake, I, Sonestedt, E, Jakobsen, MU, Overvad, K, Tjonneland, A, Halkjaer, J, Skeie, G, Braaten, T, Lund, E, Riboli, E, Peeters, PH. Macronutrient composition of the diet and prospective weight change in participants of the EPIC-PANACEA study. PLoS One. 2013. 8:e57300. doi:10.1371/journal.pone.0057300 23472080 | Intervention/Exposure
2438 | Verhoef, P, van Vliet, T, Olthof, MR, Katan, MB. A high-protein diet increases postprandial but not fasting plasma total homocysteine concentrations: a dietary controlled, crossover trial in healthy volunteers. Am J Clin Nutr. 2005. 82:553–8. doi:10.1093/ajcn.82.3.553 16155267 | Study duration
2439 | Vernon, MC, Kueser, B, Transue, M, Yates, HE, Yancy, WS, Westman, EC. Clinical experience of a carbohydrate-restricted diet for the metabolic syndrome. Metab Syndr Relat Disord. 2004. 2:180–6. doi:10.1089/met.2004.2.180 18370684 | Intervention/Exposure
2440 | Veronese, N, Li, Y, Manson, JE, Willett, WC, Fontana, L, Hu, FB. Combined associations of body weight and lifestyle factors with all cause and cause specific mortality in men and women: prospective cohort study. Bmj. 2016. 355:i5855. doi:10.1136/bmj.i5855 27884868 | Intervention/Exposure
2441 | Verreijen, AM, Engberink, MF, Houston, DK, Brouwer, IA, Cawthon, PM, Newman, AB, Tylavsky, FA, Harris, TB, Weijs, PJM, Visser, M. Dietary protein intake is not associated with 5-y change in mid-thigh muscle cross-sectional area by computed tomography in older adults: the Health, Aging, and Body Composition (Health ABC) Study. Am J Clin Nutr. 2019. 109:535–543. doi:10.1093/ajcn/nqy341 30850837 | Intervention/Exposure
2442 | Verreijen, AM, Engberink, MF, Memelink, RG, van der Plas, SE, Visser, M, Weijs, PJ. Effect of a high protein diet and/or resistance exercise on the preservation of fat free mass during weight loss in overweight and obese older adults: a randomized controlled trial. Nutr J. 2017. 16:10. doi:10.1186/s12937-017-0229-6 28166780 | Intervention/Exposure; Comparator
2443 | Vetter, ML, Iqbal, N, Dalton-Bakes, C, Volger, S, Wadden, TA. Long-term effects of low-carbohydrate versus low-fat diets in obese persons. Annals of Internal Medicine. 2010. 152:334–335. doi:10.7326/0003-4819-152-5-201003020-00020 20194246 | Publication Status
2444 | Veum, V, Laupsa-Borge, J, Eng, O, Rostrup, E, Solsvik, M, Larsen, T, Nordrehaug, JE, Nygaard, O, Sagen, J, Gudbrandsen, O, , . Very-high-fat and isocaloric low-fat diet interventions in overweight middle-aged men-results from a randomized trial. Obesity facts. 2014. 7:68. doi:10.1159/000363668 | Publication Status
2445 | Veum, VL, Laupsa-Borge, J, Eng, O, Rostrup, E, Larsen, TH, Nordrehaug, JE, Nygard, OK, Sagen, JV, Gudbrandsen, OA, Dankel, SN, Mellgren, G. Visceral adiposity and metabolic syndrome after very high-fat and low-fat isocaloric diets: a loss/Hypocaloric randomized controlled trial. Am J Clin Nutr. 2017. 105:85–99. doi:10.3945/ajcn.115.123463 27903520 | Weight
2446 | Vicari, RM, Bramlet, D, Olivera, B, Barber, L, Alexander, L, Parker, L, Howard, M. Atherosclerosis and teen eating study. J Clin Lipidol. 2007. 1:194–7. doi:10.1016/j.jacl.2007.04.005 21291681 | Intervention/Exposure; Publication Date Overlaps with Existing Review
2447 | Vidal-Peracho, C, Tricas-Moreno, JM, Lucha-Lopez, AC, Lucha-Lopez, MO, Camunas-Pescador, AC, Caverni-Munoz, A, Fanlo-Mazas, P. Adherence to Mediterranean Diet Pattern among Spanish Adults Attending a Medical Centre: Nondiabetic Subjects and Type 1 and 2 Diabetic Patients. J Diabetes Res. 2017. 2017:5957821. doi:10.1155/2017/5957821 29527536 | Study Design
2448 | Vidon, C, Boucher, P, Cachefo, A, Peroni, O, Diraison, F, Beylot, M. Effects of isoenergetic high-carbohydrate compared with high-fat diets on human cholesterol synthesis and expression of key regulatory genes of cholesterol metabolism. Am J Clin Nutr. 2001. 73:878–84. doi:10.1093/ajcn/73.5.878 11333840 | Study duration
2449 | Vilela, S, Oliveira, A, Severo, M, Lopes, C. Chrono-Nutrition: The Relationship between Time-of-Day Energy and Macronutrient Intake and Children’s Body Weight Status. J Biol Rhythms. 2019. 34:332–342. doi:10.1177/0748730419838908 30917726 | Intervention/Exposure
2450 | Viljakainen, HT, Valta, H, Lipsanen-Nyman, M, Saukkonen, T, Kajantie, E, Andersson, S, Makitie, O. Bone Characteristics and Their Determinants in Adolescents and Young Adults with Early-Onset Severe Obesity. Calcif Tissue Int. 2015. 97:364–75. doi:10.1007/s00223-015-0031-4 26139232 | Study Design; Outcome
2451 | Viljanen, AP, Karmi, A, Borra, R, Parkka, JP, Lepomaki, V, Parkkola, R, Lautamaki, R, Jarvisalo, M, Taittonen, M, Ronnemaa, T, Iozzo, P, Knuuti, J, Nuutila, P, Raitakari, OT. Effect of caloric restriction on myocardial fatty acid uptake, left ventricular mass, and cardiac work in obese adults. Am J Cardiol. 2009. 103:1721–6. doi:10.1016/j.amjcard.2009.02.025 19539082 | Study Design
2452 | Viner, RT, Harris, M, Berning, JR, Meyer, NL. Energy Availability and Dietary Patterns of Adult Male and Female Competitive Cyclists With Lower Than Expected Bone Mineral Density. Int J Sport Nutr Exerc Metab. 2015. 25:594–602. doi:10.1123/ijsnem.2015-0073 26131616 | Comparator; Outcome
2453 | Virtanen, HEK, Voutilainen, S, Koskinen, TT, Mursu, J, Kokko, P, Ylilauri, MPT, Tuomainen, TP, Salonen, JT, Virtanen, JK. Dietary proteins and protein sources and risk of death: the Kuopio Ischaemic Heart Disease Risk Factor Study. Am J Clin Nutr. 2019. 109:1462–1471. doi:10.1093/ajcn/nqz025 30968137 | Outcome
2454 | Virtanen, JK, Mursu, J, Tuomainen, TP, Voutilainen, S. Dietary fatty acids and risk of coronary heart disease in men: the Kuopio Ischemic Heart Disease Risk Factor Study. Arterioscler Thromb Vasc Biol. 2014. 34:2679–87. doi:10.1161/atvbaha.114.304082 25256234 | Intervention/Exposure
2455 | Viscogliosi, G, Cipriani, E, Liguori, ML, Marigliano, B, Saliola, M, Ettorre, E, Andreozzi, P. Mediterranean dietary pattern adherence: Associations with prediabetes, metabolic syndrome, and related microinflammation. Metabolic Syndrome and Related Disorders. 2013. 11:210–216. doi:10.1089/met.2012.0168 23451814 | Study Design
2456 | Vissers, LET, Waller, M, van der Schouw, YT, Hebert, JR, Shivappa, N, Schoenaker, Dajm, Mishra, GD. A pro-inflammatory diet is associated with increased risk of developing hypertension among middle-aged women. Nutr Metab Cardiovasc Dis. 2017. 27:564–570. doi:10.1016/j.numecd.2017.03.005 28446366 | Intervention/Exposure
2457 | Visuthranukul, C, Sirimongkol, P, Prachansuwan, A, Pruksananonda, C, Chomtho, S. Low-glycemic index diet may improve insulin sensitivity in obese children. Pediatr Res. 2015. 78:567–73. doi:10.1038/pr.2015.142 26270573 | Intervention/Exposure
2458 | Vogel, RA, Corretti, MC, Plotnick, GD. The postprandial effect of components of the Mediterranean diet on endothelial function. Journal of the American College of Cardiology. 2000. 36:1455–1460. doi:10.1016/S0735-1097(00)00896-2 11079642 | Study duration
2459 | Volek, J, Sharman, M, Gomez, A, Judelson, D, Rubin, M, Watson, G, Sokmen, B, Silvestre, R, French, D, Kraemer, W. Comparison of energy-restricted very low-carbohydrate and low-fat diets on weight loss and body composition in overweight men and women. Nutr Metab (Lond). 2004. 1:13. doi:10.1186/1743-7075-1-13 15533250 | Study duration
2460 | Volek, JS, Ballard, KD, Silvestre, R, Judelson, DA, Quann, EE, Forsythe, CE, Fernandez, ML, Kraemer, WJ. Effects of dietary carbohydrate restriction versus low-fat diet on flow-mediated dilation. Metabolism. 2009. 58:1769–77. doi:10.1016/j.metabol.2009.06.005 19632695 | Power/Size
2461 | Volek, JS, Phinney, SD, Forsythe, CE, Quann, EE, Wood, RJ, Puglisi, MJ, Kraemer, WJ, Bibus, DM, Fernandez, ML, Feinman, RD. Carbohydrate restriction has a more favorable impact on the metabolic syndrome than a low fat diet. Lipids. 2009. 44:297–309. doi:10.1007/s11745-008-3274-2 19082851 | Power/Size
2462 | Volek, JS, Sharman, MJ, Gomez, AL, DiPasquale, C, Roti, M, Pumerantz, A, Kraemer, WJ. Comparison of a very low-carbohydrate and low-fat diet on fasting lipids, LDL subclasses, insulin resistance, and postprandial lipemic responses in overweight women. J Am Coll Nutr. 2004. 23:177–84. doi:10.1080/07315724.2004.10719359 15047685 | Study duration
2463 | Volek, JS, Sharman, MJ, Gomez, AL, Scheett, TP, Kraemer, WJ. An isoenergetic very low carbohydrate diet improves serum HDL cholesterol and triacylglycerol concentrations, the total cholesterol to HDL cholesterol ratio and postprandial pipemic responses compared with a low fat diet in normal weight, normolipidemic women. J Nutr. 2003. 133:2756–61. doi:10.1093/jn/133.9.2756 12949361 | Study duration
2464 | Volek, JS, Sharman, MJ, Love, DM, Avery, NG, Gomez, AL, Scheett, TP, Kraemer, WJ. Body composition and hormonal responses to a carbohydrate-restricted diet. Metabolism. 2002. 51:864–70. doi:10.1053/meta.2002.32037 12077732 | Outcome; Study duration
2465 | Volger, S, Sheng, X, Tong, LM, Zhao, D, Fan, T, Zhang, F, Ge, J, Ho, WM, Hays, NP, Yao, MP. Nutrient intake and dietary patterns in children 2.5-5 years of age with picky eating behaviours and low weight-for-height. Asia Pac J Clin Nutr. 2017. 26:104–109. doi:10.6133/apjcn.102015.02 28049269 | Intervention/Exposure; Outcome
2466 | Vollmer, WM, Sacks, FM, Svetkey, LP. New insights into the effects on blood pressure of diets low in salt and high in fruits and vegetables and low-fat dairy products. Curr Control Trials Cardiovasc Med. 2001. 2:71–74. doi:10.1186/cvm-2-2-071 11806776 | Study Design
2467 | Volp, AC, Hermsdorff, HH, Bressan, J. Glycemia and insulinemia evaluation after high-sucrose and high-fat diets in lean and overweight/obese women. J Physiol Biochem. 2008. 64:103–13. doi:unavailable19043980 | Study duration
2468 | Volp, AC, Hermsdorff, HM, Bressan, J. Effect of high sucrose- and high-fat diets ingested under free-living conditions in insulin resistance in normal weight and overweight women. Nutricion hospitalaria. 2007. 22:46–60. doi:unavailable17260532 | Language
2469 | Voltas, N, Arija, V, Aparicio, E, Canals, J. Longitudinal study of psychopathological, anthropometric and sociodemographic factors related to the level of Mediterranean diet adherence in a community sample of Spanish adolescents. Public Health Nutr. 2016. 19:1812–22. doi:10.1017/s1368980015003560 26818065 | Outcome
2470 | von Frankenberg, AD, Marina, A, Song, X, Callahan, HS, Kratz, M, Utzschneider, KM. A high-fat, high-saturated fat diet decreases insulin sensitivity without changing intra-abdominal fat in weight-stable overweight and obese adults. Eur J Nutr. 2017. 56:431–443. doi:10.1007/s00394-015-1108-6 26615402 | Outcome
2471 | von Ruesten, A, Feller, S, Bergmann, MM, Boeing, H. Diet and risk of chronic diseases: results from the first 8 years of follow-up in the EPIC-Potsdam study. Eur J Clin Nutr. 2013. 67:412–9. doi:10.1038/ejcn.2013.7 23388667 | Intervention/Exposure
2472 | Voortman, T, Braun, KV, Kiefte-de Jong, JC, Jaddoe, VW, Franco, OH, van den Hooven, EH. Protein intake in early childhood and body composition at the age of 6 years: The Generation R Study. Int J Obes (Lond). 2016. 40:1018–25. doi:10.1038/ijo.2016.29 26975442 | Intervention/Exposure; AGE: Intervention/Exposure
2473 | Voortman, T, Leermakers, ET, Franco, OH, Jaddoe, VW, Moll, HA, Hofman, A, van den Hooven, EH, Kiefte-de Jong, JC. A priori and a posteriori dietary patterns at the age of 1 year and body composition at the age of 6 years: the Generation R Study. Eur J Epidemiol. 2016. 31:775–83. doi:10.1007/s10654-016-0179-x 27384175 | AGE: Intervention/Exposure
2474 | Wade, AT, Davis, CR, Dyer, KA, Hodgson, JM, Woodman, RJ, Keage, HAD, Murphy, KJ. A Mediterranean diet supplemented with dairy foods improves mood and processing speed in an Australian sample: results from the MedDairy randomized controlled trial. Nutr Neurosci. 2018. :1–13. doi:10.1080/1028415x.2018.1543148 | Outcome
2475 | Wade, AT, Davis, CR, Dyer, KA, Hodgson, JM, Woodman, RJ, Murphy, KJ. A Mediterranean diet supplemented with dairy foods improves markers of cardiovascular risk: results from the MedDairy randomized controlled trial. Am J Clin Nutr. 2018. 108:1166–1182. doi:10.1093/ajcn/nqy207 30351388 | Study duration
2476 | Wade, AT, Davis, CR, Dyer, KA, Hodgson, JM, Woodman, RJ, Murphy, KJ. Effects of Mediterranean diet supplemented with lean pork on blood pressure and markers of cardiovascular risk: findings from the MedPork trial. Br J Nutr. 2019. 122:873–883. doi:10.1017/s0007114519001168 31177999 | Study duration
2477 | Wadolowska, L, Hamulka, J, Kowalkowska, J, Ulewicz, N, Hoffmann, M, Gornicka, M, Bronkowska, M, Leszczynska, T, Glibowski, P, Korzeniowska-Ginter, R. Changes in Sedentary and Active Lifestyle, Diet Quality and Body Composition Nine Months after an Education Program in Polish Students Aged 11(-)12 Years: Report from the ABC of Healthy Eating Study. Nutrients. 2019. 11:. doi:10.3390/nu11020331 | Intervention/Exposure; Outcome
2478 | Waern, RV, Cumming, RG, Blyth, F, Naganathan, V, Allman-Farinelli, M, Le Couteur, D, Simpson, SJ, Kendig, H, Hirani, V. Adequacy of nutritional intake among older men living in Sydney, Australia: findings from the Concord Health and Ageing in Men Project (CHAMP). Br J Nutr. 2015. 114:812–21. doi:10.1017/s0007114515002421 26266529 | Outcome
2479 | Waijers, PM, Ocke, MC, van Rossum, CT, Peeters, PH, Bamia, C, Chloptsios, Y, van der Schouw, YT, Slimani, N, Bueno-de-Mesquita, HB. Dietary patterns and survival in older Dutch women. Am J Clin Nutr. 2006. 83:1170–6. doi:10.1093/ajcn/83.5.1170 16685062 | Outcome
2480 | Waldeyer, C, Brunner, FJ, Braetz, J, Ruebsamen, N, Zyriax, BC, Blaum, C, Kroeger, F, Kohsiack, R, Schrage, B, Sinning, C, Becher, PM, Karakas, M, Zeller, T, Westermann, D, Sydow, K, Blankenberg, S, Seiffert, M, Schnabel, RB. Adherence to Mediterranean diet, high-sensitive C-reactive protein, and severity of coronary artery disease: Contemporary data from the INTERCATH cohort. Atherosclerosis. 2018. 275:256–261. doi:10.1016/j.atherosclerosis.2018.06.877 29980052 | Outcome
2481 | Waldman, HS, Krings, BM, Basham, SA, Smith, JEW, Fountain, BJ, McAllister, MJ. Effects of a 15-Day Low Carbohydrate, High-Fat Diet in Resistance-Trained Men. J Strength Cond Res. 2018. 32:3103–3111. doi:10.1519/jsc.0000000000002282 29076962 | Study duration
2482 | Waldman, HS, Smith, JW, Lamberth, J, Fountain, BJ, McAllister, MJ. A 28-Day Carbohydrate-Restricted Diet Improves Markers of Cardiometabolic Health and Performance in Professional Firefighters. J Strength Cond Res. 2019. :. doi:10.1519/jsc.0000000000003354 | Study Design
2483 | Walilko, E, Napierala, MU, Bryskiewicz, ME, Majkowska, L. Influence of short-term high-protein diet and low glycemic index diet on body mass and composition in overweight and obese subjects. Diabetes. 2013. 62:A195–A196. doi:10.2337/db13-680-858 | Publication Status; Study duration
2484 | Walker, CG, Loos, RJ, Mander, AP, Jebb, SA, Frost, GS, Griffin, BA, Lovegrove, JA, Sanders, TA, Bluck, LJ. Genetic predisposition to type 2 diabetes is associated with impaired insulin secretion but does not modify insulin resistance or secretion in response to an intervention to lower dietary saturated fat. Genes Nutr. 2012. 7:529–36. doi:10.1007/s12263-012-0284-8 22350825 | Intervention/Exposure
2485 | Walker, CG, Loos, RJ, Olson, AD, Frost, GS, Griffin, BA, Lovegrove, JA, Sanders, TA, Jebb, SA. Genetic predisposition influences plasma lipids of participants on habitual diet, but not the response to reductions in dietary intake of saturated fatty acids. Atherosclerosis. 2011. 215:421–7. doi:10.1016/j.atherosclerosis.2010.12.039 21292264 | Study Design; Intervention/Exposure
2486 | Walker, CG, Solis-Trapala, I, Holzapfel, C, Ambrosini, GL, Fuller, NR, Loos, RJ, Hauner, H, Caterson, ID, Jebb, SA. Modelling the Interplay between Lifestyle Factors and Genetic Predisposition on Markers of Type 2 Diabetes Mellitus Risk. PLoS One. 2015. 10:e0131681. doi:10.1371/journal.pone.0131681 26154605 | Intervention/Exposure
2487 | Wall, CR, Gammon, CS, Bandara, DK, Grant, CC, Atatoa Carr, PE, Morton, SM. Dietary Patterns in Pregnancy in New Zealand-Influence of Maternal Socio-Demographic, Health and Lifestyle Factors. Nutrients. 2016. 8:. doi:10.3390/nu8050300 | Study Design; Outcome; Participants
2488 | Wallström, P, Sonestedt, E, Hlebowicz, J, Ericson, U, Drake, I, Persson, M, Gullberg, B, Hedblad, B, Wirfält, E. Dietary fiber and saturated fat intake associations with cardiovascular disease differ by sex in the Malmö diet and cancer cohort: A prospective study. PLoS ONE. 2012. 7:. doi:10.1371/journal.pone.0031637 | Intervention/Exposure
2489 | Walsh, EI, Jacka, FN, Butterworth, P, Anstey, KJ, Cherbuin, N. The association between Western and Prudent dietary patterns and fasting blood glucose levels in type 2 diabetes and normal glucose metabolism in older Australian adults. Heliyon. 2017. 3:e00315. doi:10.1016/j.heliyon.2017.e00315 28626807 | Study Design
2490 | Walthouwer, MJ, Oenema, A, Lechner, L, de Vries, H. Comparing a Video and Text Version of a Web-Based Computer-Tailored Intervention for Obesity Prevention: A Randomized Controlled Trial. J Med Internet Res. 2015. 17:e236. doi:10.2196/jmir.4083 26481772 | Intervention/Exposure
2491 | Wang, C, Almoosawi, S, Palla, L. Day-Time Patterns of Carbohydrate Intake in Adults by Non-Parametric Multi-Level Latent Class Analysis-Results from the UK National Diet and Nutrition Survey (2008/09-2015/16). Nutrients. 2019. 11:. doi:10.3390/nu11102476 | Study Design; Intervention/Exposure
2492 | Wang, DD, Li, Y, Chiuve, SE, Hu, FB, Willett, WC. Improvements In US Diet Helped Reduce Disease Burden And Lower Premature Deaths, 1999-2012; Overall Diet Remains Poor. Health Aff (Millwood). 2015. 34:1916–22. doi:10.1377/hlthaff.2015.0640 26526250 | Study Design; Intervention/Exposure
2493 | Wang, DD, Li, Y, Chiuve, SE, Stampfer, MJ, Manson, JE, Rimm, EB, Willett, WC, Hu, FB. Association of Specific Dietary Fats With Total and Cause-Specific Mortality. JAMA Intern Med. 2016. 176:1134–45. doi:10.1001/jamainternmed.2016.2417 27379574 | Intervention/Exposure
2494 | Wang, H, Fox, CS, Troy, LM, McKeown, NM, Jacques, PF. Longitudinal association of dairy consumption with the changes in blood pressure and the risk of incident hypertension: the Framingham Heart Study. Br J Nutr. 2015. 114:1887–99. doi:10.1017/s0007114515003578 26395861 | Intervention/Exposure
2495 | Wang, HH, Wong, MC, Mok, RY, Kwan, MW, Chan, WM, Fan, CK, Lee, CL, Griffiths, SM. Factors associated with grade 1 hypertension: implications for hypertension care based on the Dietary Approaches to Stop Hypertension (DASH) in primary care settings. BMC Fam Pract. 2015. 16:26. doi:10.1186/s12875-015-0239-4 25888434 | Study Design
2496 | Wang, J, Garcia-Bailo, B, Nielsen, DE, El-Sohemy, A. ABO genotype, ‘blood-type’ diet and cardiometabolic risk factors. PLoS One. 2014. 9:e84749. doi:10.1371/journal.pone.0084749 24454746 | Study Design
2497 | Wang, L, Bordi, PL, Fleming, JA, Hill, AM, Kris-Etherton, PM. Effect of a moderate fat diet with and without avocados on lipoprotein particle number, size and subclasses in overweight and obese adults: a randomized, controlled trial. J Am Heart Assoc. 2015. 4:e001355. doi:10.1161/jaha.114.001355 25567051 | Study duration
2498 | Wang, L, Dalton, WT, Schetzina, KE, Fulton-Robinson, H, Holt, N, Ho, AL, Tudiver, F, Wu, T. Home food environment, dietary intake, and weight among overweight and obese children in southern appalachia. Southern Medical Journal. 2013. 106:550–557. doi:10.1097/SMJ.0000000000000008 24096948 | Study Design; Intervention/Exposure
2499 | Wang, P, Holst, C, Andersen, MR, Astrup, A, Bouwman, FG, van Otterdijk, S, Wodzig, WK, van Baak, MA, Larsen, TM, Jebb, SA, Kafatos, A, Pfeiffer, AF, Martinez, JA, Handjieva-Darlenska, T, Kunesova, M, Saris, WH, Mariman, EC. Blood profile of proteins and steroid hormones predicts weight change after weight loss with interactions of dietary protein level and glycemic index. PLoS One. 2011. 6:e16773. doi:10.1371/journal.pone.0016773 21340022 | Intervention/Exposure
2500 | Wang, T, Heianza, Y, Sun, D, Rood, J, Bray, GA, Sacks, FM, Qi, L. Dietary protein intake modifies the genetic risk on insulin resistance in the pounds lost trial. Circulation. 2016. 134:. doi:unavailable | Publication Status
2501 | Wang, X, Li, X, Vaartjes, I, Neal, B, Bots, ML, Hoes, AW, Wu, Y. Does education level affect the efficacy of a community based salt reduction program? - A post-hoc analysis of the China Rural Health Initiative Sodium Reduction Study (CRHI-SRS). BMC Public Health. 2016. 16:759. doi:10.1186/s12889-016-3454-6 27515930 | Intervention/Exposure
2502 | Wang, Y, Kaneko, T, Wang, PY, Sato, A. Decreased carbohydrate intake is more important than increased fat intake in the glucose intolerance by a low-carbohydrate/high-fat diet. Diabetes Research and Clinical Practice. 2002. 55:61–63. doi:10.1016/S0168-8227(01)00291-1 11755480 | Publication Status
2503 | Wang, YF, Yancy, WS, Jr, Yu, D, Champagne, C, Appel, LJ, Lin, PH. The relationship between dietary protein intake and blood pressure: results from the PREMIER study. J Hum Hypertens. 2008. 22:745–54. doi:10.1038/jhh.2008.64 18580887 | Intervention/Exposure
2504 | Wang, Z, Adair, LS, Cai, J, Gordon-Larsen, P, Siega-Riz, AM, Zhang, B, Popkin, BM. Diet Quality Is Linked to Insulin Resistance among Adults in China. J Nutr. 2017. 147:2102–2108. doi:10.3945/jn.117.256180 28978676 | Country
2505 | Wang, Z, Siega-Riz, AM, Gordon-Larsen, P, Cai, J, Adair, LS, Zhang, B, Popkin, BM. Diet quality and its association with type 2 diabetes and major cardiometabolic risk factors among adults in China. Nutr Metab Cardiovasc Dis. 2018. 28:987–1001. doi:10.1016/j.numecd.2018.06.012 30143408 | Country
2506 | Waśkiewicz, A, Piotrowski, W, Sygnowska, E, Rywik, S, Jasiński, B. Did favourable trends in food consumption observed in the 1984-2001 period contribute to the decrease in cardiovascular mortality? - Pol-MONICA Warsaw Project. Kardiologia Polska. 2006. 64:16–23. doi:unavailable16444623 | Study Design; Intervention/Exposure
2507 | Waskiewicz, A, Piotrowski, W, Szostak-Wegierek, D, Cicha-Mikolajczyk, A. Relationship between 28-year food consumption trends and the 10-year global risk of death due to cardiovascular diseases in the adult Warsaw population. Kardiol Pol. 2015. 73:650–5. doi:10.5603/KP.a2015.0070 26310505 | Study Design
2508 | Waterplas, J, Versele, V, D’Hondt, E, Lefevre, J, Mertens, E, Charlier, R, Knaeps, S, Clarys, P. A 10-year longitudinal study on the associations between changes in plant-based diet indices, anthropometric parameters and blood lipids in a Flemish adult population. Nutr Diet. 2019. :. doi:10.1111/1747-0080.12578 | Power/Size
2509 | Weber, B, Bersch-Ferreira, AC, Torreglosa, CR, Marcadenti, A, Lara, ES, da Silva, JT, Costa, RP, . Implementation of a Brazilian Cardioprotective Nutritional (BALANCE) Program for improvement on quality of diet and secondary prevention of cardiovascular events: A randomized, multicenter trial. Am Heart J. 2019. 215:187–197. doi:10.1016/j.ahj.2019.06.010 31349110 | Study Design; Health Status
2510 | Weder, S, Hoffmann, M, Becker, K, Alexy, U, Keller, M. Energy, Macronutrient Intake, and Anthropometrics of Vegetarian, Vegan, and Omnivorous Children (1(-)3 Years) in Germany (VeChi Diet Study). Nutrients. 2019. 11:. doi:10.3390/nu11040832 | Study Design
2511 | Weech, M, Vafeiadou, K, Mihaylova, R, Hasaj, M, Yaqoob, P, Todd, S, Jackson, KG, Lovegrove, JA. Substitution of dietary saturated fatty acids with either monounsaturated or n-6 polyunsaturated fatty acids improves the plasma lipid profile in those at risk from CVD: results from the DIVAS study. Proceedings of the nutrition society. 2013. 72:E182. doi:10.1017/S0029665113002073 | Publication Status
2512 | Wei, M, Brandhorst, S, Shelehchi, M, Mirzaei, H, Cheng, CW, Budniak, J, Groshen, S, Mack, WJ, Guen, E, Di Biase, S, Cohen, P, Morgan, TE, Dorff, T, Hong, K, Michalsen, A, Laviano, A, Longo, VD. Fasting-mimicking diet and markers/risk factors for aging, diabetes, cancer, and cardiovascular disease. Science Translational Medicine. 2017. 9:. doi:10.1126/scitranslmed.aai8700 | Study duration
2513 | Weickert, MO, Roden, M, Isken, F, Hoffmann, D, Nowotny, P, Osterhoff, M, Blaut, M, Alpert, C, Gogebakan, O, Bumke-Vogt, C, Mueller, F, Machann, J, Barber, TM, Petzke, KJ, Hierholzer, J, Hornemann, S, Kruse, M, Illner, AK, Kohl, A, Loeffelholz, CV, Arafat, AM, Mohlig, M, Pfeiffer, AF. Effects of supplemented isoenergetic diets differing in cereal fiber and protein content on insulin sensitivity in overweight humans. Am J Clin Nutr. 2011. 94:459–71. doi:10.3945/ajcn.110.004374 21633074 | Power/Size
2514 | Weigle, DS, Breen, PA, Matthys, CC, Callahan, HS, Meeuws, KE, Burden, VR, Purnell, JQ. A high-protein diet induces sustained reductions in appetite, ad libitum caloric intake, and body weight despite compensatory changes in diurnal plasma leptin and ghrelin concentrations. Am J Clin Nutr. 2005. 82:41–8. doi:10.1093/ajcn.82.1.41 16002798 | Study Design; Intervention/Exposure; Study duration
2515 | Weigle, DS, Cummings, DE, Newby, PD, Breen, PA, Frayo, RS, Matthys, CC, Callahan, HS, Purnell, JQ. Roles of leptin and ghrelin in the loss of body weight caused by a low fat, high carbohydrate diet. J Clin Endocrinol Metab. 2003. 88:1577–86. doi:10.1210/jc.2002-021262 12679442 | Power/Size
2516 | Weihua Mmed, L, Yougang, W, Jing, W. Reduced or modified dietary fat for preventing cardiovascular disease. J Cardiovasc Nurs. 2013. 28:204–5. doi:10.1097/JCN.0b013e3182816005 23575159 | Study Design; Publication Status
2517 | Weijs, PJM, Wolfe, RR. Exploration of the protein requirement during weight loss in obese older adults. Clin Nutr. 2016. 35:394–398. doi:10.1016/j.clnu.2015.02.016 25788405 | Intervention/Exposure
2518 | Weise, CM, Hohenadel, MG, Krakoff, J, Votruba, SB. Body composition and energy expenditure predict ad-libitum food and macronutrient intake in humans. Int J Obes (Lond). 2014. 38:243–51. doi:10.1038/ijo.2013.85 23736368 | Outcome; Study duration
2519 | Weker, H, Baranska, M, Riahi, A, Strucinska, M, Wiech, M, Rowicka, G, Dylag, H, Klemarczyk, W, Bzikowska, A, Socha, P. Dietary patterns in toddlers with excess weight. The 2016 pitnuts study. Dev Period Med. 2017. 21:272–285. doi:unavailable29077567 | Study Design
2520 | Wekesa, AL, Doyle, LM, Fitzmaurice, D, O’Donovan, O, Phelan, JP, Ross, MD, Cross, KS, Harrison, M. Influence of a low-carbohydrate diet on endothelial microvesicles in overweight women. Appl Physiol Nutr Metab. 2016. 41:522–7. doi:10.1139/apnm-2015-0507 26963592 | Power/Size
2521 | Wellington, N, Shanmuganathan, M, de Souza, RJ, Zulyniak, MA, Azab, S, Bloomfield, J, Mell, A, Ly, R, Desai, D, Anand, SS, Britz-McKibbin, P. Metabolic Trajectories Following Contrasting Prudent and Western Diets from Food Provisions: Identifying Robust Biomarkers of Short-Term Changes in Habitual Diet. Nutrients. 2019. 11:. doi:10.3390/nu11102407 | Study Design; Study duration
2522 | Wennberg, M, Soderberg, S, Uusitalo, U, Tuomilehto, J, Shaw, JE, Zimmet, PZ, Kowlessur, S, Pauvaday, V, Magliano, DJ. High consumption of pulses is associated with lower risk of abnormal glucose metabolism in women in Mauritius. Diabet Med. 2015. 32:513–20. doi:10.1111/dme.12618 25346062 | Intervention/Exposure; Country
2523 | West, JA, de Looy, AE. Weight loss in overweight subjects following low-sucrose or sucrose-containing diets. Int J Obes Relat Metab Disord. 2001. 25:1122–8. doi:10.1038/sj.ijo.0801652 11477496 | Intervention/Exposure
2524 | West, NR, Dorling, J, Thackray, AE, Hanson, NC, Decombel, SE, Stensel, DJ, Grice, SJ. Effect of Obesity-Linked FTO rs9939609 Variant on Physical Activity and Dietary Patterns in Physically Active Men and Women. J Obes. 2018. 2018:7560707. doi:10.1155/2018/7560707 29686893 | Study Design; Intervention/Exposure
2525 | Westcott, Weight loss, Apovian, CM, Puhala, K, Corina, L, Larosa Loud, R, Whitehead, S, Blum, K, DiNubile, N. Nutrition programs enhance exercise effects on body composition and resting blood pressure. Phys Sportsmed. 2013. 41:85–91. doi:10.3810/psm.2013.09.2027 24113706 | Intervention/Exposure
2526 | Westerbacka, J, Lammi, K, Hakkinen, AM, Rissanen, A, Salminen, I, Aro, A, Yki-Jarvinen, H. Dietary fat content modifies liver fat in overweight nondiabetic subjects. J Clin Endocrinol Metab. 2005. 90:2804–9. doi:10.1210/jc.2004-1983 15741262 | Study Design; Study duration
2527 | Westergren, HU, Gan, LM, Månsson, M, Svedlund, S. Randomized clinical trial studying effects of a personalized supervised lifestyle intervention program on cardiovascular status in physically inactive healthy volunteers. Oncotarget. 2018. 9:9498–9511. doi:10.18632/oncotarget.23958 29507706 | Intervention/Exposure
2528 | Westerterp-Plantenga, MS, Lejeune, MP, Nijs, I, van Ooijen, M, Kovacs, EM. High protein intake sustains weight maintenance after body weight loss in humans. Int J Obes Relat Metab Disord. 2004. 28:57–64. doi:10.1038/sj.ijo.0802461 14710168 | Intervention/Exposure
2529 | Westerterp-Plantenga, MS, Lejeune, MP, Smeets, AJ, Luscombe-Marsh, ND. Sex differences in energy homeostatis following a diet relatively high in protein exchanged with carbohydrate, assessed in a respiration chamber in humans. Physiol Behav. 2009. 97:414–9. doi:10.1016/j.physbeh.2009.03.010 19318111 | Study duration
2530 | Westman, EC, Yancy, WS, Haub, MD, Volek, JS. Insulin resistance from a low carbohydrate, high fat diet perspective. Metab Syndr Relat Disord. 2005. 3:14–8. doi:10.1089/met.2005.3.14 18370705 | Study Design
2531 | Wheaton, N, Millar, L, Allender, S, Nichols, M. The stability of weight status through the early to middle childhood years in Australia: a longitudinal study. BMJ Open. 2015. 5:e006963. doi:10.1136/bmjopen-2014-006963 | Intervention/Exposure
2532 | Wheeler, DH, Stentz, FB, Kitabchi, AE. Effect of macronutrient diet compositions on weight change and metabolic parameters. Journal of investigative medicine. 2012. 60:352. doi:10.231/JIM.0b013e3182820c2e | Publication Status
2533 | Whelton, SP, Silverman, MG, McEvoy, JW, Budoff, MJ, Blankstein, R, Eng, J, Blumenthal, RS, Szklo, M, Nasir, K, Blaha, MJ. Predictors of Long-Term Healthy Arterial Aging: Coronary Artery Calcium Nondevelopment in the MESA Study. JACC Cardiovasc Imaging. 2015. 8:1393–1400. doi:10.1016/j.jcmg.2015.06.019 26577261 | Outcome
2534 | White, AM, Johnston, CS, Swan, PD, Tjonn, SL, Sears, B. Blood ketones are directly related to fatigue and perceived effort during exercise in overweight adults adhering to low-carbohydrate diets for weight loss: a pilot study. J Am Diet Assoc. 2007. 107:1792–6. doi:10.1016/j.jada.2007.07.009 17904939 | Study duration
2535 | White, C, Drummond, S, De Looy, A. Comparing advice to decrease both dietary fat and sucrose, or dietary fat only, on weight loss, weight maintenance and perceived quality of life. Int J Food Sci Nutr. 2010. 61:282–94. doi:10.3109/09637480903397355 20095912 | Intervention/Exposure
2536 | White, J, Jago, R, Thompson, JL. Dietary risk factors for the development of insulin resistance in adolescent girls: a 3-year prospective study. Public Health Nutr. 2014. 17:361–8. doi:10.1017/s1368980012004983 23158020 | Study Design; Intervention/Exposure
2537 | Widya, RL, Hammer, S, Boon, MR, van der Meer, RW, Smit, JW, de Roos, A, Rensen, PC, Lamb, HJ. Effects of short-term nutritional interventions on right ventricular function in healthy men. PLoS One. 2013. 8:e76406. doi:10.1371/journal.pone.0076406 24086738 | Study duration
2538 | Wien, MA, Sabate, JM, Ikle, DN, Cole, SE, Kandeel, FR. Almonds vs complex carbohydrates in a weight reduction program. Int J Obes Relat Metab Disord. 2003. 27:1365–72. doi:10.1038/sj.ijo.0802411 14574348 | Intervention/Exposure
2539 | Wikström, K, Peltonen, M, Eriksson, JG, Aunola, S, Ilanne-Parikka, P, Keinänen-Kiukaanniemi, S, Uusitupa, M, Tuomilehto, J, Lindström, J. Educational attainment and effectiveness of lifestyle intervention in the Finnish Diabetes Prevention Study. Diabetes Research and Clinical Practice. 2009. 86:e1–e5. doi:10.1016/j.diabres.2009.06.014 19592125 | Intervention/Exposure
2540 | Wilke, MS, French, MA, Goh, YK, Ryan, EA, Jones, PJ, Clandinin, MT. Synthesis of specific fatty acids contributes to VLDL-triacylglycerol composition in humans with and without type 2 diabetes. Diabetologia. 2009. 52:1628–37. doi:10.1007/s00125-009-1405-9 19536518 | Study duration
2541 | Williams, A, de Vlieger, N, Young, M, Jensen, ME, Burrows, TL, Morgan, PJ, Collins, CE. Dietary outcomes of overweight fathers and their children in the Healthy Dads, Healthy Kids community randomised controlled trial. J Hum Nutr Diet. 2018. 31:523–532. doi:10.1111/jhn.12543 29473237 | Intervention/Exposure
2542 | Williams, CL, Strobino, BA. Childhood diet, overweight, and CVD risk factors: The healthy start project. Preventive Cardiology. 2008. 11:11–20. doi:10.1111/j.1520-037X.2007.06677.x 18174786 | Intervention/Exposure
2543 | Williams, PT, Bergeron, N, Chiu, S, Krauss, RM. A randomized, controlled trial on the effects of almonds on lipoprotein response to a higher carbohydrate, lower fat diet in men and women with abdominal adiposity. Lipids Health Dis. 2019. 18:83. doi:10.1186/s12944-019-1025-4 30943980 | Study duration
2544 | Willows, ND, Barbarich, BN, Wang, LC, Olstad, DL, Clandinin, MT. Dietary inadequacy is associated with anemia and suboptimal growth among preschool-aged children in Yunnan Province, China. Nutr Res. 2011. 31:88–96. doi:10.1016/j.nutres.2011.01.003 21419312 | Study Design; Country
2545 | Wilson, G, Pritchard, PP, Papageorgiou, C, Phillips, S, Kumar, P, Langan-Evans, C, Routledge, H, Owens, DJ, Morton, JP, Close, GL. Fasted Exercise and Increased Dietary Protein Reduces Body Fat and Improves Strength in Jockeys. Int J Sports Med. 2015. 36:1008–14. doi:10.1055/s-0035-1549920 26212241 | Study Design
2546 | Wilson, HK, Armstrong, CLH, Hogan, JA, Campbell, WW. Effects of protein quantity and source (animal versus plant) on appetite and plasma amino acid responses in energy-restricted subjects. FASEB journal. 2012. 26:. doi:unavailable | Publication Status
2547 | Wilson, JM, Lowery, RP, Roberts, MD, Sharp, MH, Joy, JM, Shields, KA, Partl, J, Volek, JS, D’Agostino, D. The Effects of Ketogenic Dieting on Body Composition, Strength, Power, and Hormonal Profiles in Resistance Training Males. J Strength Cond Res. 2017. :. doi:10.1519/jsc.0000000000001935 | Study duration
2548 | Windler, E, Nitschmann, S. Effects of glycemic index on cardiovascular risk factors: the OmniCarb randomized clinical trial. Der internist. 2015. 56:949–952. doi:10.1007/s00108-015-3765-1 26169441 | Language
2549 | Witjaksono, F, Jutamulia, J, Annisa, NG, Prasetya, SI, Nurwidya, F. Comparison of low calorie high protein and low calorie standard protein diet on waist circumference of adults with visceral obesity and weight cycling. BMC Res Notes. 2018. 11:674. doi:10.1186/s13104-018-3781-z 30241565 | Intervention/Exposure; Country
2550 | Wittenbecher, C, Muhlenbruch, K, Kroger, J, Jacobs, S, Kuxhaus, O, Floegel, A, Fritsche, A, Pischon, T, Prehn, C, Adamski, J, Joost, HG, Boeing, H, Schulze, MB. Amino acids, lipid metabolites, and ferritin as potential mediators linking red meat consumption to type 2 diabetes. Am J Clin Nutr. 2015. 101:1241–50. doi:10.3945/ajcn.114.099150 25948672 | Intervention/Exposure
2551 | Wolever, TM, Gibbs, AL, Mehling, C, Chiasson, JL, Connelly, PW, Josse, RG, Leiter, LA, Maheux, P, Rabasa-Lhoret, R, Rodger, NW, Ryan, EA. The Canadian Trial of Carbohydrates in Diabetes (CCD), a 1-y controlled trial of low-glycemic-index dietary carbohydrate in type 2 diabetes: no effect on glycated hemoglobin but reduction in C-reactive protein. Am J Clin Nutr. 2008. 87:114–25. doi:10.1093/ajcn/87.1.114 18175744 | Health Status
2552 | Wolever, TM, Isaacs, RL, Ramdath, DD. Lower diet glycaemic index in African than South Asian men in Trinidad and Tobago. Int J Food Sci Nutr. 2002. 53:297–303. doi:10.1080/09637480220138142 12090025 | Study Design; Outcome
2553 | Wolever, TM, Mehling, C. Long-term effect of varying the source or amount of dietary carbohydrate on postprandial plasma glucose, insulin, triacylglycerol, and free fatty acid concentrations in subjects with impaired glucose tolerance. Am J Clin Nutr. 2003. 77:612–21. doi:10.1093/ajcn/77.3.612 12600851 | Intervention/Exposure
2554 | Wolff, E, Vergnes, MF, Portugal, H, Defoort, C, Amiot-Carlin, MJ, Lairon, D, Nicolay, A. Cholesterol-absorber status modifies the LDL cholesterol-lowering effect of a Mediterranean-type diet in adults with moderate cardiovascular risk factors. J Nutr. 2011. 141:1791–8. doi:10.3945/jn.111.141333 21865559 | Intervention/Exposure
2555 | Wolfram, G, Bechthold, A, Boeing, H, Ellinger, S, Hauner, H, Kroke, A, Leschik-Bonnet, E, Linseisen, J, Lorkowski, S, Schulze, M, Stehle, P, Dinter, J. Evidence-Based Guideline of the German Nutrition Society: Fat Intake and Prevention of Selected Nutrition-Related Diseases. Ann Nutr Metab. 2015. 67:141–204. doi:10.1159/000437243 26414007 | Study Design
2556 | Wolters, M, Joslowski, G, Plachta-Danielzik, S, Standl, M, Muller, MJ, Ahrens, W, Buyken, AE. Dietary Patterns in Primary School are of Prospective Relevance for the Development of Body Composition in Two German Pediatric Populations. Nutrients. 2018. 10:. doi:10.3390/nu10101442 | Power/Size
2557 | Woo, J, Cheung, B, Ho, S, Sham, A, Lam, TH. Influence of dietary pattern on the development of overweight in a Chinese population. Eur J Clin Nutr. 2008. 62:480–7. doi:10.1038/sj.ejcn.1602702 17327865 | Intervention/Exposure; Country
2558 | Wood, AD, Strachan, AA, Thies, F, Aucott, LS, Reid, DM, Hardcastle, AC, Mavroeidi, A, Simpson, WG, Duthie, GG, Macdonald, HM. Patterns of dietary intake and serum carotenoid and tocopherol status are associated with biomarkers of chronic low-grade systemic inflammation and cardiovascular risk. Br J Nutr. 2014. 112:1341–52. doi:10.1017/s0007114514001962 25313576 | Outcome
2559 | Wood, RJ, Volek, JS, Liu, Y, Shachter, NS, Contois, JH, Fernandez, ML. Carbohydrate restriction alters lipoprotein metabolism by modifying VLDL, LDL, and HDL subfraction distribution and size in overweight men. J Nutr. 2006. 136:384–9. doi:10.1093/jn/136.2.384 16424116 | Study Design; Intervention/Exposure
2560 | Woodhall-Melnik, J, Cooke, M, Bigelow, PL. Serving the food nation: Exploring Body Mass Index in food service workers. Work. 2015. 52:901–9. doi:10.3233/wor-152101 26409347 | Study Design; Intervention/Exposure
2561 | Woolhead, C, Walsh, MC, Gibney, MJ, Daniel, H, Drevon, CA, Lovegrove, JA, Manios, Y, Martinez, JA, Mathers, JC, Traczyk, I, , . Dietary patterns in Europe: the Food4Me proof of principle study. Proceedings of the nutrition society. 2015. 74:. doi:10.1017/S002966511500275X | Publication Status
2562 | Wosje, KS, Khoury, PR, Claytor, RP, Copeland, KA, Hornung, RW, Daniels, SR, Kalkwarf, HJ. Dietary patterns associated with fat and bone mass in young children. Am J Clin Nutr. 2010. 92:294–303. doi:10.3945/ajcn.2009.28925 20519562 | Publication Date Overlaps with Existing Review
2563 | Wright, C, Zhou, J, Sayer, R, Kim, JE, Campbell, W. Effect of a high protein, high egg diet on muscle composition, metabolic health and systemic inflammation in overweight and obese, older adults. FASEB journal. 2015. 29:. doi:unavailable | Intervention/Exposure; Publication Status
2564 | Wright, CS, Zhou, J, Sayer, RD, Kim, JE, Campbell, WW. Effects of a High-Protein Diet Including Whole Eggs on Muscle Composition and Indices of Cardiometabolic Health and Systemic Inflammation in Older Adults with Overweight or Obesity: A Randomized Controlled Trial. Nutrients. 2018. 10:. doi:10.3390/nu10070946 | Weight loss/Hypocaloric
2565 | Wright, M, Sotres-Alvarez, D, Mendez, MA, Adair, L. The association of trajectories of protein intake and age-specific protein intakes from 2 to 22 years with BMI in early adulthood. Br J Nutr. 2017. 117:750–758. doi:10.1017/s0007114517000502 28347359 | Intervention/Exposure; Country
2566 | Wroble, KA, Trott, MN, Schweitzer, GG, Rahman, RS, Kelly, PV, Weiss, EP. Low-carbohydrate, ketogenic diet impairs anaerobic exercise performance in exercise-trained women and men: a randomized-sequence crossover trial. J Sports Med Phys Fitness. 2019. 59:600–607. doi:10.23736/s0022-4707.18.08318-4 29619799 | Outcome; Study duration
2567 | Wu, H, Flint, AJ, Qi, Q, van Dam, RM, Sampson, LA, Rimm, EB, Holmes, MD, Willett, WC, Hu, FB, Sun, Q. Association between dietary whole grain intake and risk of mortality: two large prospective studies in US men and women. JAMA Intern Med. 2015. 175:373–84. doi:10.1001/jamainternmed.2014.6283 25559238 | Intervention/Exposure
2568 | Wu, S, An, S, Li, W, Lichtenstein, AH, Gao, J, Kris-Etherton, PM, Wu, Y, Jin, C, Huang, S, Hu, FB, Gao, X. Association of Trajectory of Cardiovascular Health Score and Incident Cardiovascular Disease. JAMA Netw Open. 2019. 2:e194758. doi:10.1001/jamanetworkopen.2019.4758 31150075 | Country
2569 | Wulan, SN, Bouwman, FG, Westerterp, KR, Mariman, ECM, Plasqui, G. Molecular adaptation in adipose tissue in response to overfeeding with a high-fat diet under sedentary conditions in South Asian and Caucasian men. Br J Nutr. 2019. 122:241–251. doi:10.1017/s0007114519001260 31475655 | Intervention/Exposure; Study duration
2570 | Wulan, SN, Schrauwen-Hinderling, VB, Westerterp, KR, Plasqui, G. Substrate utilization and metabolic profile in response to overfeeding with a high-fat diet in South Asian and white men: a sedentary lifestyle study. Int J Obes (Lond). 2019. :. doi:10.1038/s41366-019-0368-2 | Study duration
2571 | Wulan, SN, Westerterp, KR, Plasqui, G. Dietary and 24-h fat oxidation in Asians and whites who differ in body composition. Am J Clin Nutr. 2012. 95:1335–41. doi:10.3945/ajcn.111.031369 22552026 | Study Design; Study duration
2572 | Wulan, SN, Westerterp, KR, Plasqui, G. Metabolic profile before and after short-term overfeeding with a high-fat diet: a comparison between South Asian and White men. Br J Nutr. 2014. 111:1853–61. doi:10.1017/s0007114514000014 24506887 | Study duration
2573 | Wyatt, CJ, Triana Tejas, MA. Nutrient intake and growth of preschool children from different socioeconomic regions in the city of oaxaca, Mexico. Ann Nutr Metab. 2000. 44:14–20. doi:10.1159/000012816 10838462 | Study Design
2574 | Wycherley, T, Brinkworth, G, Clifton, P, Noakes, M. A one year high protein, low fat weight loss diet improves body composition and cardiometabolic risk factors in overweight males. FASEB journal. 2012. 26:. doi:unavailable | Publication Status
2575 | Wycherley, TP, Brinkworth, GD, Clifton, PM, Noakes, M. A one year high protein, low fat weight loss diet improves body composition and cardiometabolic risk factors in overweight males with features of the metabolic syndrome. Australasian medical journal. 2011. 4:731. doi:unavailable | Publication Status
2576 | Wycherley, TP, Brinkworth, GD, Clifton, PM, Noakes, M. Comparison of the effects of 52 weeks weight loss with either a high-protein or high-carbohydrate diet on body composition and cardiometabolic risk factors in overweight and obese males. Nutr Diabetes. 2012. 2:e40. doi:10.1038/nutd.2012.11 23448804 | Weight loss/Hypocaloric
2577 | Wycherley, TP, Brinkworth, GD, Keogh, JB, Noakes, M, Buckley, JD, Clifton, PM. Long-term effects of weight loss with a very low carbohydrate and low fat diet on vascular function in overweight and obese patients. J Intern Med. 2010. 267:452–61. doi:10.1111/j.1365-2796.2009.02174.x 20141567 | Power/Size
2578 | Wycherley, TP, Brinkworth, GD, Keogh, JB, Noakes, M, Buckley, JD, Clifton, PM. Long-term effects of weight loss with a very low carbohydrate and low fat diet on vascular function in overweight and obese patients: Original Article. Journal of Internal Medicine. 2010. 267:452–461. doi:10.1111/j.1365-2796.2009.02174.x 20141567 | Study Design; Outcome
2579 | Wycherley, TP, Buckley, JD, Noakes, M, Clifton, PM, Brinkworth, GD. Comparison of the effects of weight loss from a high-protein versus standard-protein energy-restricted diet on strength and aerobic capacity in overweight and obese men. Eur J Nutr. 2013. 52:317–25. doi:10.1007/s00394-012-0338-0 22406907 | Power/Size
2580 | Wycherley, TP, Buckley, JD, Noakes, M, Clifton, PM, Brinkworth, GD. Long-term effects of a very low-carbohydrate weight loss diet on exercise capacity and tolerance in overweight and obese adults. J Am Coll Nutr. 2014. 33:267–73. doi:10.1080/07315724.2014.911668 24988413 | Power/Size
2581 | Wyka, J, Malczyk, E, Misiarz, M, Zolotenka-Synowiec, M, Calyniuk, B, Baczynska, S. Assessment of food intakes for women adopting the high protein Dukan diet. Rocz Panstw Zakl Hig. 2015. 66:137–42. doi:unavailable26024402 | Study Design
2582 | Xiao, RS, Simas, TA, Person, SD, Goldberg, RJ, Waring, ME. Diet quality and history of gestational diabetes mellitus among childbearing women, United States, 2007-2010. Prev Chronic Dis. 2015. 12:E25. doi:10.5888/pcd12.140360 25719215 | Study Design; Outcome
2583 | Xu, J, Eilat-Adar, S, Loria, C, Goldbourt, U, Howard, BV, Fabsitz, RR, Zephier, EM, Mattil, C, Lee, ET. Dietary fat intake and risk of coronary heart disease: the Strong Heart Study. Am J Clin Nutr. 2006. 84:894–902. doi:10.1093/ajcn/84.4.894 17023718 | Intervention/Exposure
2584 | Xu, M, Ng, SS, Bray, GA, Ryan, DH, Sacks, FM, Ning, G, Qi, L. Dietary Fat Intake Modifies the Effect of a Common Variant in the LIPC Gene on Changes in Serum Lipid Concentrations during a Long-Term Weight-Loss Intervention Trial. J Nutr. 2015. 145:1289–94. doi:10.3945/jn.115.212514 25926410 | Intervention/Exposure
2585 | Xu, M, Qi, Q, Liang, J, Bray, GA, Hu, FB, Sacks, FM, Qi, L. Genetic determinant for amino acid metabolites and changes in body weight and insulin resistance in response to weight-loss diets: the Preventing Overweight Using Novel Dietary Strategies (POUNDS LOST) trial. Circulation. 2013. 127:1283–9. doi:10.1161/circulationaha.112.000586 23446828 | Intervention/Exposure
2586 | Xu, X, Hall, J, Byles, J, Shi, Z. Dietary Pattern Is Associated with Obesity in Older People in China: Data from China Health and Nutrition Survey (CHNS). Nutrients. 2015. 7:8170–88. doi:10.3390/nu7095386 26404368 | Country
2587 | Xu, X, Hall, J, Byles, J, Shi, Z. Dietary pattern, serum magnesium, ferritin, C-reactive protein and anaemia among older people. Clin Nutr. 2017. 36:444–451. doi:10.1016/j.clnu.2015.12.015 26775754 | Study Design; Country
2588 | Xu, X, Parker, D, Shi, Z, Byles, J, Hall, J, Hickman, L. Dietary Pattern, Hypertension and Cognitive Function in an Older Population: 10-Year Longitudinal Survey. Front Public Health. 2018. 6:201. doi:10.3389/fpubh.2018.00201 30079333 | Country
2589 | Yackobovitch-Gavan, M, Nagelberg, N, Demol, S, Phillip, M, Shalitin, S. Influence of weight-loss diets with different macronutrient compositions on health-related quality of life in obese youth. Appetite. 2008. 51:697–703. doi:10.1016/j.appet.2008.06.010 18652862 | Intervention/Exposure
2590 | Yahia, DA. Insulinoresistance, inflammation, lecithin: cholesterol acyltransferase and HDL composition are improved by Mediterranean diet in metabolic syndrome patients. Annals of nutrition and metabolism. Conference: 12th european nutrition conference, FENS 2015. Berlin germany. Conference start: 20151020. Conference end: 20151023. Conference publication: (var.pagings). 2015. 67:343. doi:10.1159/000440895 | Publication Status
2591 | Yamagishi, K, Iso, H, Date, C, Fukui, M, Wakai, K, Kikuchi, S, Inaba, Y, Tanabe, N, Tamakoshi, A. Fish, omega-3 polyunsaturated fatty acids, and mortality from cardiovascular diseases in a nationwide community-based cohort of Japanese men and women the JACC (Japan Collaborative Cohort Study for Evaluation of Cancer Risk) Study. J Am Coll Cardiol. 2008. 52:988–96. doi:10.1016/j.jacc.2008.06.018 18786479 | Intervention/Exposure
2592 | Yancy, WS, Jr, Mayer, SB, Coffman, CJ, Smith, VA, Kolotkin, RL, Geiselman, PJ, McVay, MA, Oddone, EZ, Voils, CI. Effect of Allowing Choice of Diet on Weight Loss: A Randomized Trial. Ann Intern Med. 2015. 162:805–14. doi:10.7326/m14-2358 26075751 | Study Design; Comparator
2593 | Yancy, WS, Jr, Olsen, MK, Guyton, JR, Bakst, RP, Westman, EC. A low-carbohydrate, ketogenic diet versus a low-fat diet to treat obesity and hyperlipidemia: a randomized, controlled trial. Ann Intern Med. 2004. 140:769–77. doi:10.7326/0003-4819-140-10-200405180-00006 15148063 | Weight loss/Hypocaloric
2594 | Yang, H, Kim, H, Kim, JM, Chung, HW, Chang, N. Associations of dietary intake and metabolic syndrome risk parameters in Vietnamese female marriage immigrants in South Korea: The KoGES follow-up study. Nutr Res Pract. 2016. 10:313–20. doi:10.4162/nrp.2016.10.3.313 27247728 | Study Design; Intervention/Exposure
2595 | Yanos, BR, Saules, KK, Schuh, LM, Sogg, S. Predictors of Lowest Weight and Long-Term Weight Regain Among Roux-en-Y Gastric Bypass Patients. Obes Surg. 2015. 25:1364–70. doi:10.1007/s11695-014-1536-z 25519772 | Health Status
2596 | Yap, RWK, Shidoji, Y, Yap, WS, Masaki, M. Association and Interaction Effect of AGTR1 and AGTR2 Gene Polymorphisms with Dietary Pattern on Metabolic Risk Factors of Cardiovascular Disease in Malaysian Adults. Nutrients. 2017. 9:. doi:10.3390/nu9080853 | Study Design
2597 | Ye, J, Lv, Y, Li, Z, Yao, Y, Jin, L. Associations of dietary patterns with hypertension among adults in Jilin Province, China: a structural equation modelling approach. Public Health Nutr. 2018. :1–8. doi:10.1017/s1368980018003129 | Study Design; Outcome
2598 | Ye, X, Gao, X, Scott, T, Tucker, KL. Habitual sugar intake and cognitive function among middle-aged and older Puerto Ricans without diabetes. Br J Nutr. 2011. 106:1423–32. doi:10.1017/s0007114511001760 21736803 | Study Design; Intervention/Exposure; Outcome
2599 | Yeo, R, Yoon, SR, Kim, OY. The Association between Food Group Consumption Patterns and Early Metabolic Syndrome Risk in Non-Diabetic Healthy People. Clin Nutr Res. 2017. 6:172–182. doi:10.7762/cnr.2017.6.3.172 28770180 | Study Design
2600 | Yeung, EH, Appel, LJ, Miller, ER, 3rd, Kao, WH. The effects of macronutrient intake on total and high-molecular weight adiponectin: results from the OMNI-Heart trial. Obesity (Silver Spring). 2010. 18:1632–7. doi:10.1038/oby.2009.402 19876001 | Outcome
2601 | Yoon, C, Jacobs, DR, Jr, Duprez, DA, Neumark-Sztainer, D, Steffen, LM, Mason, SM. Problematic eating behaviors and attitudes predict long-term incident metabolic syndrome and diabetes: The Coronary Artery Risk Development in Young Adults Study. Int J Eat Disord. 2019. 52:304–308. doi:10.1002/eat.23020 30636022 | Intervention/Exposure
2602 | Yosaee, S, Esteghamati, A, Nazari Nasab, M, Khosravi, A, Alinavaz, M, Hosseini, B, Djafarian, K. Diet quality in obese/overweight individuals with/without metabolic syndrome compared to normal weight controls. Med J Islam Repub Iran. 2016. 30:376. doi:unavailable27493920 | Study Design
2603 | Yoshimoto, Y, Muto, S, Fujikura, J, Sakuma, M, Kaneko, Y, Otto, CT, Nakamura, L. Obesity, bone status and dietary intake of Palauan elderly congregating in a Senior Citizen’s Center. Pac Health Dialog. 2005. 12:22–32. doi:unavailable18181459 | Study Design; Intervention/Exposure
2604 | Yoshizaki, T, Ishihara, J, Kotemori, A, Yamamoto, J, Kokubo, Y, Saito, I, Yatsuya, H, Yamagishi, K, Sawada, N, Iwasaki, M, Iso, H, Tsugane, S. Association of vegetable, fruit, and Okinawan vegetable consumption with incident stroke and coronary heart disease. J Epidemiol. 2019. :. doi:10.2188/jea.JE20180130 | Intervention/Exposure
2605 | Young, D, Camhi, S, Wu, T, Hagberg, J, Stefanick, M. Relationships among changes in C-reactive protein and cardiovascular disease risk factors with lifestyle interventions. Nutr Metab Cardiovasc Dis. 2013. 23:857–63. doi:10.1016/j.numecd.2012.05.003 22831953 | Study Design; Intervention/Exposure
2606 | Young, DR, Coughlin, J, Jerome, GJ, Myers, V, Chae, SE, Brantley, PJ. Effects of the PREMIER interventions on health-related quality of life. Ann Behav Med. 2010. 40:302–12. doi:10.1007/s12160-010-9220-6 20799005 | Outcome
2607 | Young, LR, Kurzer, MS, Thomas, W, Redmon, JB, Raatz, SK. Low-fat diet with omega-3 fatty acids increases plasma insulin-like growth factor concentration in healthy postmenopausal women. Nutr Res. 2013. 33:565–71. doi:10.1016/j.nutres.2013.04.011 23827131 | Intervention/Exposure; Study duration
2608 | Young, M, Morgan, P, Hollis, J, Collins, C, Teixeira, P. Sitting time at work and marital status: novel pre-treatment predictors of weight loss success in overweight and obese men. Obesity reviews. 2014. 15:149. doi:10.1111/obr.12151 | Publication Status
2609 | Yu, C, Benhammou, JN, Goyal, D, Oh, D, Wang, L, Jacobs, J, Dixit, V, Tache, Y, Pisegna, J. High protein dietary intervention improves body mass index (BMI) and reduces the NAFLD fibrosis score (NFS) in veterans with obesity. American journal of gastroenterology. 2016. 111:S349-. doi:10.1038/ajg.2016.359 | Publication Status
2610 | Yu, D, Shu, XO, Li, H, Xiang, YB, Yang, G, Gao, YT, Zheng, W, Zhang, X. Dietary carbohydrates, refined grains, glycemic load, and risk of coronary heart disease in Chinese adults. Am J Epidemiol. 2013. 178:1542–9. doi:10.1093/aje/kwt178 24008907 | Intervention/Exposure; Country
2611 | Yu, D, Shu, XO, Li, H, Yang, G, Cai, Q, Xiang, YB, Ji, BT, Franke, AA, Gao, YT, Zheng, W, Zhang, X. Dietary isoflavones, urinary isoflavonoids, and risk of ischemic stroke in women. Am J Clin Nutr. 2015. 102:680–6. doi:10.3945/ajcn.115.111591 26245809 | Intervention/Exposure
2612 | Yu, D, Zhang, X, Xiang, YB, Yang, G, Li, H, Gao, YT, Zheng, W, Shu, XO. Adherence to dietary guidelines and mortality: A report from prospective cohort studies of 134,000 Chinese adults in urban Shanghai. American Journal of Clinical Nutrition. 2014. 100:693–700. doi:10.3945/ajcn.113.079194 | Country
2613 | Yu, D, Zheng, W, Cai, H, Xiang, YB, Li, H, Gao, YT, Shu, XO. Long-term Diet Quality and Risk of Type 2 Diabetes Among Urban Chinese Adults. Diabetes Care. 2018. 41:723–730. doi:10.2337/dc17-1626 29269510 | Country
2614 | Yu, SH, Song, Y, Park, M, Kim, SH, Shin, S, Joung, H. Relationship between adhering to dietary guidelines and the risk of obesity in Korean children. Nutr Res Pract. 2014. 8:705–12. doi:10.4162/nrp.2014.8.6.705 25489411 | Study Design
2615 | Yuan, YQ, Li, F, Meng, P, You, J, Wu, M, Li, SG, Chen, B. Gender Difference on the Association between Dietary Patterns and Obesity in Chinese Middle-Aged and Elderly Populations. Nutrients. 2016. 8:. doi:10.3390/nu8080448 | Study Design
2616 | Yubero-Serrano, EM, Delgado-Lista, J, Tierney, AC, Perez-Martinez, P, Garcia-Rios, A, Alcala-Diaz, JF, Castano, JP, Tinahones, FJ, Drevon, CA, Defoort, C, Blaak, EE, Dembinska-Kiec, A, Riserus, U, Lovegrove, JA, Perez-Jimenez, F, Roche, HM, Lopez-Miranda, J. Insulin resistance determines a differential response to changes in dietary fat modification on metabolic syndrome risk factors: the LIPGENE study. Am J Clin Nutr. 2015. 102:1509–17. doi:10.3945/ajcn.115.111286 26561628 | Intervention/Exposure
2617 | Yuzbashian, E, Asghari, G, Mirmiran, P, Amouzegar-Bahambari, P, Azizi, F. Adherence to low-sodium Dietary Approaches to Stop Hypertension-style diet may decrease the risk of incident chronic kidney disease among high-risk patients: a secondary prevention in prospective cohort study. Nephrol Dial Transplant. 2018. 33:1159–1168. doi:10.1093/ndt/gfx352 29361057 | Outcome
2618 | Zajac, A, Poprzecki, S, Maszczyk, A, Czuba, M, Michalczyk, M, Zydek, G. The effects of a ketogenic diet on exercise metabolism and physical performance in off-road cyclists. Nutrients. 2014. 6:2493–508. doi:10.3390/nu6072493 24979615 | Intervention/Exposure
2619 | Zamora, D, Gordon-Larsen, P, Jacobs, DR, Jr, Popkin, BM. Diet quality and weight gain among black and white young adults: the Coronary Artery Risk Development in Young Adults (CARDIA) Study (1985-2005). Am J Clin Nutr. 2010. 92:784–93. doi:10.3945/ajcn.2010.29161 20685947 | Publication Date Overlaps with Existing Review
2620 | Zarrazquin, I, Torres-Unda, J, Ruiz, F, Irazusta, J, Kortajarena, M, Hoyos Cillero, I, Gil, J, Irazusta, A. Longitudinal study: lifestyle and cardiovascular health in health science students. Nutr Hosp. 2014. 30:1144–51. doi:10.3305/nh.2014.30.5.7833 25365020 | Intervention/Exposure
2621 | Zaslavsky, O, Zelber-Sagi, S, Hebert, JR, Steck, SE, Shivappa, N, Tabung, FK, Wirth, MD, Bu, Y, Shikany, JM, Orchard, T, Wallace, RB, Snetselaar, L, Tinker, LF. Biomarker-calibrated nutrient intake and healthy diet index associations with mortality risks among older and frail women from the Women’s Health Initiative. Am J Clin Nutr. 2017. 105:1399–1407. doi:10.3945/ajcn.116.151530 28424183 | Outcome
2622 | Zatonski, WA, Willett, W. Changes in dietary fat and declining coronary heart disease in Poland: population based study. Bmj. 2005. 331:187–8. doi:10.1136/bmj.331.7510.187 16037448 | Study Design; Publication Status
2623 | Zazpe, I, Sanchez-Tainta, A, Toledo, E, Sanchez-Villegas, A, Martinez-Gonzalez, MA. Dietary patterns and total mortality in a Mediterranean cohort: the SUN project. J Acad Nutr Diet. 2014. 114:37–47. doi:10.1016/j.jand.2013.07.024 24095621 | Outcome
2624 | Zazpe, I, Santiago, S, Gea, A, Ruiz-Canela, M, Carlos, S, Bes-Rastrollo, M, Martinez-Gonzalez, MA. Association between a dietary carbohydrate index and cardiovascular disease in the SUN (Seguimiento Universidad de Navarra) Project. Nutr Metab Cardiovasc Dis. 2016. 26:1048–1056. doi:10.1016/j.numecd.2016.07.002 27524801 | Intervention/Exposure
2625 | Zeybek, C, Celebi, A, Aktuglu-Zeybek, C, Onal, H, Yalcin, Y, Erdem, A, Akdeniz, C, Imanov, E, Altay, S, Aydin, A. The effect of low-carbohydrate diet on left ventricular diastolic function in obese children. Pediatr Int. 2010. 52:218–23. doi:10.1111/j.1442-200X.2009.02940.x 19674355 | Study Design
2626 | Zhang, F, Tapera, TM, Gou, J. Application of a new dietary pattern analysis method in nutritional epidemiology. BMC Med Res Methodol. 2018. 18:119. doi:10.1186/s12874-018-0585-8 30373530 | Study Design
2627 | Zhang, J, Wang, C, Li, L, Man, Q, Song, P, Meng, L, Du, ZY, Froyland, L. Inclusion of Atlantic salmon in the Chinese diet reduces cardiovascular disease risk markers in dyslipidemic adult men. Nutr Res. 2010. 30:447–54. doi:10.1016/j.nutres.2010.06.010 20797476 | Country
2628 | Zhang, J, Wang, H, Wang, Y, Xue, H, Wang, Z, Du, W, Su, C, Zhang, J, Jiang, H, Zhai, F, Zhang, B. Dietary patterns and their associations with childhood obesity in China. Br J Nutr. 2015. 113:1978–84. doi:10.1017/s0007114515001154 25944159 | Study Design
2629 | Zhang, JG, Wang, ZH, Wang, HJ, Du, WW, Su, C, Zhang, J, Jiang, HR, Zhai, FY, Zhang, B. Dietary patterns and their associations with general obesity and abdominal obesity among young Chinese women. Eur J Clin Nutr. 2015. 69:1009–14. doi:10.1038/ejcn.2015.8 25690865 | Study Design
2630 | Zhang, L, Pagoto, S, Olendzki, B, Persuitte, G, Churchill, L, Oleski, J, Ma, Y. A nonrestrictive, weight loss diet focused on fiber and lean protein increase. Nutrition. 2018. 54:12–18. doi:10.1016/j.nut.2018.02.006 29704862 | Study Design
2631 | Zhang, Q, Chen, X, Liu, Z, Varma, DS, Wan, R, Wan, Q, Zhao, S. Dietary Patterns in Relation to General and Central Obesity among Adults in Southwest China. Int J Environ Res Public Health. 2016. 13:. doi:10.3390/ijerph13111080 | Study Design
2632 | Zhang, S, Zhuang, X, Lin, X, Zhong, X, Zhou, H, Sun, X, Xiong, Z, Huang, Y, Fan, Y, Guo, Y, Du, Z, Liao, X. Low-Carbohydrate Diets and Risk of Incident Atrial Fibrillation: A Prospective Cohort Study. J Am Heart Assoc. 2019. 8:e011955. doi:10.1161/jaha.119.011955 31020911 | Outcome
2633 | Zhang, X, Qi, Q, Hu, FB, Sacks, FM, Qi, L. Apoa5 genotype modulates 2-year changes in lipid profile in response to weight-loss diet intervention: the pounds lost trial. Diabetes. 2012. 61:A158. doi:10.2337/db12-378-655 | Publication Status
2634 | Zhang, Z, Lanza, E, Kris-Etherton, PM, Colburn, NH, Bagshaw, D, Rovine, MJ, Ulbrecht, JS, Bobe, G, Chapkin, RS, Hartman, TJ. A high legume low glycemic index diet improves serum lipid profiles in men. Lipids. 2010. 45:765–75. doi:10.1007/s11745-010-3463-7 20734238 | Intervention/Exposure; Publication Date Overlaps with Existing Review
2635 | Zhao, G, Etherton, TD, Martin, KR, West, SG, Gillies, PJ, Kris-Etherton, PM. Dietary alpha-linolenic acid reduces inflammatory and lipid cardiovascular risk factors in hypercholesterolemic men and women. J Nutr. 2004. 134:2991–7. doi:10.1093/jn/134.11.2991 15514264 | Intervention/Exposure; Comparator
2636 | Zhen, S, Ma, Y, Zhao, Z, Yang, X, Wen, D. Dietary pattern is associated with obesity in Chinese children and adolescents: data from China Health and Nutrition Survey (CHNS). Nutr J. 2018. 17:68. doi:10.1186/s12937-018-0372-8 29996840 | Country
2637 | Zheng, Y, Huang, T, Zhang, X, Rood, J, Bray, GA, Sacks, FM, Qi, L. Dietary Fat Modifies the Effects of FTO Genotype on Changes in Insulin Sensitivity. J Nutr. 2015. 145:977–82. doi:10.3945/jn.115.210005 25761503 | Intervention/Exposure
2638 | Zhou, J, Kim, JE, Armstrong, CL, Chen, N, Campbell, WW. Higher-protein diets improve indexes of sleep in energy-restricted overweight and obese adults: results from 2 randomized controlled trials. Am J Clin Nutr. 2016. 103:766–74. doi:10.3945/ajcn.115.124669 26864362 | Outcome
2639 | Zhou, J, Sheng, J, Fan, Y, Zhu, X, Wang, S. Dietary patterns, dietary intakes and the risk of type 2 diabetes: results from the Hefei Nutrition and Health Study. Int J Food Sci Nutr. 2019. 70:412–420. doi:10.1080/09637486.2018.1515184 30286668 | Study Design
2640 | Zhu, C, Sawrey-Kubicek, L, Beals, E, Hughes, RL, Rhodes, CH, Sacchi, R, Zivkovic, AM. Short term fast food and Mediterranean diet are able to change the HDL lipidome with different patterns. FASEB journal. 2017. 31:. doi:unavailable | Publication Status
2641 | Zhu, C, Sawrey-Kubicek, L, Beals, E, Hughes, RL, Rhodes, CH, Sacchi, R, Zivkovic, AM. The HDL lipidome is widely remodeled by fast food versus Mediterranean diet in 4 days. Metabolomics. 2019. 15:. doi:10.1007/s11306-019-1579-1 | Study duration
2642 | Zhu, X, Lin, J, Song, Y, Liu, H, Zhang, R, Fan, M, Li, Y, Tian, R, Fang, D. A high-carbohydrate diet lowered blood pressure in healthy Chinese male adolescents. Biosci Trends. 2014. 8:132–7. doi:unavailable24815391 | Study Design
2643 | Zhuang, P, Zhang, Y, He, W, Chen, X, Chen, J, He, L, Mao, L, Wu, F, Jiao, J. Dietary Fats in Relation to Total and Cause-Specific Mortality in a Prospective Cohort of 521 120 Individuals With 16 Years of Follow-Up. Circ Res. 2019. 124:757–768. doi:10.1161/circresaha.118.314038 30636521 | Intervention/Exposure; Outcome
2644 | Ziegler, D, Strom, A, Nowotny, B, Zahiragic, L, Nowotny, PJ, Carstensen-Kirberg, M, Herder, C, Roden, M. Effect of Low-Energy Diets Differing in Fiber, Red Meat, and Coffee Intake on Cardiac Autonomic Function in Obese Individuals With Type 2 Diabetes. Diabetes Care. 2015. 38:1750–7. doi:10.2337/dc15-0466 26070589 | Health Status
2645 | Zinn, C, McPhee, J, Harris, N, Williden, M, Prendergast, K, Schofield, G. A 12-week low-carbohydrate, high-fat diet improves metabolic health outcomes over a control diet in a randomised controlled trial with overweight defence force personnel. Appl Physiol Nutr Metab. 2017. 42:1158–1164. doi:10.1139/apnm-2017-0260 28700832 | Intervention/Exposure
2646 | Zinn, C, Wood, M, Williden, M, Chatterton, S, Maunder, E. Ketogenic diet benefits body composition and well-being but not performance in a pilot case study of New Zealand endurance athletes. J Int Soc Sports Nutr. 2017. 14:22. doi:10.1186/s12970-017-0180-0 28706467 | Study Design
2647 | Zoltick, ES, Sahni, S, McLean, RR, Quach, L, Casey, VA, Hannan, MT. Dietary protein intake and subsequent falls in older men and women: the Framingham Study. J Nutr Health Aging. 2011. 15:147–52. doi:unavailable21365169 | Intervention/Exposure; Outcome
2648 | Zou, P, Dennis, CL, Lee, R, Parry, M. Dietary approach to stop hypertension with sodium reduction for Chinese Canadians (Dashna-CC): A pilot randomized controlled trial. Journal of Nutrition, Health and Aging. 2017. 21:1225–1232. doi:10.1007/s12603-016-0861-4 | Intervention/Exposure; Comparator
2649 | Zubair, N, Kuzawa, CW, Lee, NR, McDade, TW, Adair, LS. Clustering and determinants of cardiometabolic risk factors among Filipino young adults. Asia Pac J Clin Nutr. 2014. 23:148–58. doi:10.6133/apjcn.2014.23.1.06 24561983 | Intervention/Exposure; Outcome
2650 | Zubair, N, Kuzawa, CW, McDade, TW, Adair, LS. Cluster analysis reveals important determinants of cardiometabolic risk patterns in Filipino women. Asia Pac J Clin Nutr. 2012. 21:271–81. doi:unavailable22507615 | Intervention/Exposure; Country
2651 | Zuo, L, He, F, Tinsley, GM, Pannell, BK, Ward, E, Arciero, PJ. Comparison of high-protein, intermittent fasting low-calorie diet and heart healthy diet for vascular health of the obese. Frontiers in Physiology. 2016. 7:. doi:10.3389/fphys.2016.00350 | Intervention/Exposure

xvi Dietary Guidelines Advisory Committee. 2020. Scientific Report of the 2020 Dietary Guidelines Advisory Committee: Advisory Report to the Secretary of Agriculture and the Secretary of Health and Human Services. U.S. Department of Agriculture, Agricultural Research Service, Washington, DC.

xvii Macronutrient percent of energy outside of the AMDR are as follows:

- Carbohydrate for all age groups: <45 or >65 percent of energy;
- Protein for children, 1-3y: <5 or >20 percent of energy, Protein for children, 4-18y: <10 or >30 percent of energy, Protein for adults, age 19y and older: <10 or >35 percent of energy;
- Fat for children, 1-3y: <30 or >40 percent of energy, Fat for children, 4-18y: <25 or >35 percent of energy, Fat for adults, age 19y and older: <20 or >35 percent of energy.

Institute of Medicine. Dietary Reference Intakes for Energy, Carbohydrate, Fiber, Fat, Fatty Acids, Cholesterol, Protein, and Amino Acids. Washington (DC): The National Academies Press; 2002.

xviii The Pregnancy and Lactation Subcommittee of the 2020 Dietary Guidelines Advisory Committee will address dietary patterns during pregnancy in relation to gestational diabetes.

xix The Human Development classification was based on the Human Development Index (HDI) ranking from the year the study intervention occurred or data were collected (UN Development Program. HDI 1990-2017 HDRO calculations based on data from UNDESA (2017a), UNESCO Institute for Statistics (2018), United Nations Statistics Division (2018b), World Bank (2018b), Barro and Lee (2016) and IMF (2018). Available from: http://hdr.undp.org/en/data). If the study did not report the year in which the intervention occurred or data were collected, the HDI classification for the year of publication was applied. HDI values are available from 1980, and then from 1990 to present. If a study was conducted prior to 1990, the HDI classification from 1990 was applied. If a study was conducted in 2018 or 2019, the most current HDI classification was applied. When a country was not included in the HDI ranking, the current country classification from the World Bank was used instead ( The World Bank. World Bank country and lending groups. Available from: https://datahelpdesk.worldbank.org/knowledgebase/articles/906519-world-country-and-lending-groups ).

xx The flow chart depicts the combined raw search totals from the electronic databases that were searched from both searches that included a total of 102,073 raw results, which were comprised of 63,384 raw results from the first search strategy and 38,689 from the second search strategy as described in the Electronic databases section. That section also provides the date range searched. Search results were combined for efficiency. Results were screened together in screening software by two analysts independently. Due to topical overlap, both of the searches were designed to comprehensively identify relevant literature in this systematic review question as well as two additional systematic reviews questions to avoid screening the same results multiple times.