# WHAT IS THE RELATIONSHIP BETWEEN DIETARY PATTERNS CONSUMED AND RISK OF TYPE 2 DIABETES?

## PLAIN LANGUAGE SUMMARY

### What is the question?

- The question is: What is the relationship between dietary patterns consumed and risk of type 2 diabetes?

### What is the answer to the question?

Dietary patterns: Children

- Insufficient evidence is available to determine the relationship between dietary patterns consumed by children or adolescents and risk of type 2 diabetes.

Dietary patterns: Adults

- The 2020 Dietary Guidelines Advisory Committee reviewed newly published evidence using a systematic evidence scan and determined that the conclusion drawn by the 2015 Dietary Guidelines Advisory Committee generally reflects the current state of science: Moderate evidence indicates that healthy dietary patterns higher in vegetables, fruits, and whole grains and lower in red and processed meats, high-fat dairy products, refined grains, and sweets/sugar-sweetened beverages reduce the risk of developing type 2 diabetes.

Diets based on macronutrient distribution: Children

- No evidence is available to determine a relationship between diets based on macronutrient proportion distribution consumed during childhood and risk of type 2 diabetes.

Diets based on macronutrient distribution: Adults

- Insufficient evidence is available to determine the relationship between macronutrient distributions with proportions of energy falling outside of the AMDR for at least one macronutrient and risk of type 2 diabetes, due to methodological limitations and inconsistent results.

### Why was this question asked?

- This important public health question was identified by the U.S. Departments of Agriculture (USDA) and Health and Human Services (HHS) to be examined by the 2020 Dietary Guidelines Advisory Committee.

### How was this question answered?

- The 2020 Dietary Guidelines Advisory Committee, Dietary Patterns Subcommittee conducted a systematic review to answer this question with support from the Nutrition Evidence Systematic Review (NESR) team.
- Dietary patterns were defined as the quantities, proportions, variety, or combination of different foods, drinks, and nutrients (when available) in diets, and the frequency with which they are habitually consumed.
- Diets based on macronutrient distribution were examined when at least one macronutrient proportion was outside of the acceptable macronutrient distribution range (AMDR) for carbohydrate, fat, and/or protein, whether or not the foods/food groups consumed were provided.

### What is the population of interest?

- Children and adults, ages 2 years and older.

### What evidence was found?

- This review identified 72 articles that met inclusion criteria.
- One article examined dietary patterns consumed during adolescence (retrospectively) and risk of type 2 diabetes.
  ○ The 2020 Committee could not draw conclusions based on one article with critical limitations.
- Fifty-two articles examined dietary patterns consumed by adults and risk of type 2 diabetes.
  ○ The 2020 Committee determined these articles were generally consistent with those from an existing NESR systematic review. Therefore, the 2020 Committee carried forward the conclusion from the 2015 Committee.
- Twenty-three articles examined diets based on macronutrient distribution consumed by adults and risk of type 2 diabetes.
  ○ The 2020 Committee could not draw conclusions from the articles because they had several limitations.

### How up-to-date is this systematic review?

- This review searched for studies from January 2000 to October 2019; and updated existing systematic reviews that included evidence from January 2000 to January 2014.

## FULL REVIEW

### Systematic review question

What is the relationship between dietary patterns consumed and risk of type 2 diabetes?

### Conclusion statements and grades

#### Dietary Patterns: Children

Insufficient evidence is available to determine the relationship between dietary patterns consumed by children or adolescents and risk of type 2 diabetes. (Grade: Grade Not Assignable)

#### Dietary Patterns: Adults

The 2020 Dietary Guidelines Advisory Committee reviewed newly published evidence using a systematic evidence scan and determined that the conclusion drawn by the 2015 Dietary Guidelines Advisory Committee generally reflects the current state of science: Moderate evidence indicates that healthy dietary patterns higher in vegetables, fruits, and whole grains and lower in red and processed meats, high-fat dairy products, refined grains, and sweets/sugar-sweetened beverages reduce the risk of developing type 2 diabetes. (2015 Dietary Guidelines Advisory Committee Grade: Moderate)

#### Diets Based on Macronutrient Distribution: Children

No evidence is available to determine a relationship between diets based on macronutrient distribution consumed by children or adolescents and risk of type 2 diabetes. (Grade: Grade Not Assignable)

#### Diets Based on Macronutrient Distribution: Adults

Insufficient evidence is available to determine the relationship between macronutrient distributions with proportions of energy falling outside of the AMDR for at least one macronutrient and risk of type 2 diabetes, due to methodological limitations and inconsistent results. (Grade: Grade Not Assignable)

### Summary of the evidence

- Seventy-two articles were identified that met inclusion criteria and examined the relationship between dietary patterns and/or diets based on macronutrient distribution and risk of type 2 diabetes
  ○ Dietary patterns were defined as the quantities, proportions, variety, or combination of different foods, drinks, and nutrients (when available) in diets, and the frequency with which they are habitually consumed.
  ○ Diets based on macronutrient distribution were examined when at least one macronutrient proportion was outside of the acceptable macronutrient distribution range (AMDR^ii^) for carbohydrate, fat, and/or protein, whether or not the foods/food groups consumed were provided.
    ■ When describing and categorizing studies included in these reviews, the Committee did not label the diets examined as “low” or “high,” because no standard definition is currently available for, for example, “low-carbohydrate” or “high-fat” diets. Instead, the Committee focused on whether, and the extent to which, the proportions of the macronutrients were below or above the AMDR.
  ○ Studies examining energy-restricted diets that induce weight loss or treat overweight and obesity for the purposes of treating additional or other medical conditions were excluded.

#### Dietary patterns: Children

- One article from a prospective cohort study examined dietary patterns consumed during adolescence (retrospectively) and risk of type 2 diabetes.^1^

#### Dietary patterns: Adults

- Fifty-two articles examined dietary patterns consumed by adults and risk of type 2 diabetes.^2–53^
  ○ These articles represent new evidence published since a systematic review completed by the 2015 Dietary Guidelines Advisory Committee.
  ○ A systematic evidence scan was conducted to identify and examine these articles, and determine whether a full systematic review update was warranted.
  ○ Based on results from the systematic evidence scan, the 2020 Committee determine that the recently published evidence was generally consistent with the body of evidence from the existing review, and a full systematic review update was not needed at this time. Therefore, the conclusion statement and grade from the existing review were carried forward.

#### Diets based on macronutrient distribution: Children

- No articles were identified that met inclusion criteria and examined diets based on macronutrient distribution consumed during childhood and risk of T2D across the lifespan.

#### Diets based on macronutrient distribution: Adults

- Twenty-three articles examined diets based on macronutrient distribution consumed by adults and risk of type 2 diabetes, met inclusion criteria, and were published between January 2000 and October 2019.^50–72^
  ○ Two studies were RCTs, and 21 articles were prospective cohort studies.
  ○ Most of the articles examined distributions in which the proportion of energy from carbohydrate was below the AMDR; Fat was above the AMDR; and protein was within the AMDR in at least one of the exposure groups compared.
  ○ Across studies, aspects of diet quality i.e., the foods/food groups consumed as part of the diet, were reported with limited detail such as “animal-based” macronutrient distributions.
  ○ Among studies that provided the context of foods/food groups, diets based on macronutrient distributions with proportions outside of the AMDR tended to have higher amounts of saturated fat, trans fat, and/or animal-based sources of protein and fat, such as processed meat, red meat, butter, and cheese as well as refined grains, SSB’s, and lower-fiber cereals/breads.
  ○ Numerous limitations were identified that prevent adequate assessment across this body of evidence:
    ■ Several studies did not directly test differences in macronutrient proportions in the context of a constant dietary pattern
    ■ The gradient between macronutrient proportions compared within and across studies varied. Several studies compared distinct proportions between groups (e.g., 33.4% vs. 47.5% carbohydrate), whereas others were much closer in proximity relative to one another (e.g., 41.0% vs. 45.0% carbohydrate) or to the AMDR limit (e.g., 44.9% vs. 45% carbohydrate)

### Description of the evidence

#### Dietary patterns: Children

One article from the Nurses’ Healthy Study (NHS) retrospectively evaluated the relationship between the Alternative Health Eating Index from 2010 (AHEI-2010) during adolescence and type 2 diabetes risk later in life.^1^ Dietary intake during high school was collected with a validated, food frequency questionnaire (FFQ) at mean age 42y. Outcome data were diagnosis of type 2 diabetes, defined as self-reported incidence confirmed by validated questionnaire using 1997 American Diabetes Association (ADA) criteria (Table 1).

#### Dietary patterns: Adults

In a systematic evidence scan, fifty-two studies met inclusion criteria, were published between January 2014 and October 2019, and examined dietary patterns in adults and risk of type 2 diabetes. Among these studies, 4 studies examined both dietary patterns and diets based on macronutrient distribution.

#### Diets based on macronutrient distribution: Children

No studies were identified that met inclusion criteria and examined diets based on macronutrient distribution during childhood and risk of type 2 diabetes.

#### Diets based on macronutrient distribution: Adults

Twenty-three articles were included from studies that examined diets based on macronutrient distribution consumed by adults and risk of type 2 diabetes, described futher below and in Table 2.

##### Population/participant characteristics

The studies were conducted in populations from the following countries: Australia, China, Finland, Germany, Japan, Korea, Netherlands, Spain, Sweden, United Kingdom, and United States. Two studies were conducted in multiple European countries. Studies enrolled healthy, primarily middle-aged or older adults. The Prevención con Dieta Mediterránea (PREDIMED) randomized controlled trial (RCT) enrolled adults at high-risk for cardiovascular disease, and its primary results were reported by Salas-Salvado,^65^ with secondary analyses reported in another article.^58^ Multiple studies reported results from the same established cohorts (e.g., Nurses’ Health Study-II (NHS-II); Health Professionals Follow-up Study, Malmö Diet and Cancer cohort), and reported different macronutrient distributions or dietary patterns. Several included articles reported data from different cohorts or data in the European Prospective Investigation into Cancer and Nutrition (EPIC) study.^53,66,70,71^

##### Intervention/exposure

Dietary intake was measured once at baseline using validated methods, either validated FFQ or diet history, in the majority of studies. In some studies, diet assessment using validated methods was conducted on an annual basis, or every ~4y during follow-up.^50,56,58,62,63,65^

Two RCTs randomized participants to consume specific diets compared to control diets. One RCT examined the effects of two different “Mediterranean” style patterns with either extra virgin olive oil (EVOO) or nuts (i.e., Med+EVOO or Med+Nuts) relative to the control group, which was advised to reduce dietary fat. The second RCT randomized participants to consume a low-fat vegan diet consisting of vegetables, grains, legumes, and fruits while avoiding animal products and added fats relative to a control group with no diet changes.

Several of the observational studies examined adherence scores for a “low” carbohydrate diet score and all applied a similar approach to derive the score by assigning from 0 to 10 points for consumption and dividing participants into groups based on 11 strata.^50,56,60,63,67^ Other studies reported % energy consumed based on macronutrient distributions from dietary patterns identified using other indices/scores,^51,53^ factor/cluster analysis,^52,54^ or reduced rank regression^53^. Remaining studies examined macronutrient distributions based on % energy from total protein intake,^55,57,62,68,70–72^ total carbohydrate intake,^64,66,69^ or total fat intake.^58,59^ Most studies used the residual-method to adjust macronutrient intake for total energy, with only a few studies applying the multivariate nutrient-density methods to consider replacement or substitution of macronutrient content.

The majority of studies examined macronutrient distributions in which energy from carbohydrate was below and fat above the AMDR in at least one of the exposure groups compared. Diets based on macronutrient distributions in which energy from carbohydrate above the AMDR and fat below the AMDR in at least one of the exposure groups compared were also examined, but in fewer studies.^59,61,63,64,67^ Among all macronutrient distributions reported, the range in proportions with % energy falling outside of the AMDR were:

- Carbohydrate below the AMDR ranged between 29.6% and 44.8%
- Carbohydrate above the AMDR ranged between 65% and 80.5%
- Fat above the AMDR ranged between 35.1% and 46.3%
- Fat below the AMDR ranged between 8.1% and 19%

##### Outcome assessment

Included studies examined risk of type 2 diabetes over mean/median follow-up ranging from 16wk to 19y. Studies reported risk of type 2 diabetes as the endpoint outcome, with one study reporting the intermediate outcome of hemoglobin A1C (HbA1C). Outcome assessment methods varied but most studies collected self-reported data to assess type 2 diabetes incidence, but then confirmed diagnosis using authoritative criteria [e.g., ADA or World Health Organization (WHO)] against physician records or registry information for diabetic-medication usage in the majority of participants.

### Evidence synthesis

#### Dietary patterns: Children

##### Summary of results

One study from the NHS cohort retrospectively evaluated the relationship between high-school AHEI-2010 adherence and type 2 diabetes risk over 13 years of follow-up.^1^ The high-school AHEI-2010 consisted of the following components: fruits, vegetables, whole grains, sugar-sweetened beverages and juices, nuts and legumes, red/processed meat, trans fats, dark meat fish, PUFA, and high sodium foods. No significant association was observed between adherence to the AHEI-2010 and type 2 diabetes risk after adjustment for confounders during high school and adulthood (see Table 1).

##### Assessment of the evidence^iii^

The only study that met inclusion criteria, published between January 2014 and October 2019, examined dietary patterns in adolescence and risk of type 2 diabetes. A number of potential risks of bias or limitations make interpretation of results difficult. The included study adjusted for most but not all potential confounders, specifically race/ethnicity of participants. The population examined recalled their dietary pattern during adolescence and therefore, directness is low. Precision cannot be determined due to only one study meeting inclusion criteria. The study was conducted in women from the United States, with relatively higher socioeconomic status (SES) that the average population.

#### Dietary patterns: Adults

##### Evidence scan results

The 2020 Dietary Guidelines Advisory Committee conducted a systematic evidence scan to identify and examine new evidence published since a review done by the 2020 Dietary Guidelines Advisory Committee.^iv^ The 2020 Committee determine that the newly published evidence was consistent with the evidence previously reviewed for the 2015 Dietary Guidelines for Americans Scientific Report.

Results across the newly published body of evidence were generally consistent with the conclusion from 2015, showing that dietary patterns of higher diet quality were typically associated with protection from developing type 2 diabetes. The populations, intervention, comparators, and outcomes of interest are directly related to the systematic review question. The evidence is primarily from prospective cohort studies, and the number of RCTs within this newly published set of evidence is limited. The study participants, interventions and/or exposures, comparators, and outcomes examined in the body of evidence are applicable to the U.S. population. Studies that examine overall dietary patterns in adults often vary in how alcohol intake is assessed, the thresholds applied for amounts of alcohol consumed, and scoring procedures of alcohol as a component (e.g., a positive component, positive in moderation, or negative component). Due to this inconsistency, the inclusion and specification of alcoholic beverages within dietary patterns warrants further investigation.

The 2020 Committee determined that the conclusion drawn by the 2015 Committee still reflects the current of science on dietary patterns in adults and risk of type 2 diabetes. Therefore, a full systematic review was not conducted at this time, and the 2015 Committee’s conclusion statement and grade were carried forward. The 2015 Committee concluded that: Moderate evidence indicates that healthy dietary patterns higher in vegetables, fruits, and whole grains and lower in red and processed meats, high-fat dairy products, refined grains, and sweets/sugar-sweetened beverages reduce the risk of developing type 2 diabetes.

#### Diets based on macronutrient distribution: Children

No studies were identified that met inclusion criteria and examined diets based on macronutrient distribution consumed during childhood and risk of type 2 diabetes.

#### Diets based on macronutrient distribution: Adults

##### Summary of results

Twenty-three studies examined diets based on macronutrient distributions with proportions of energy falling outside of the AMDR for at least one macronutrient consumed by adults and risk of type 2 diabetes. The 23 articles included 2 articles from randomized controlled trials and 21 articles from prospective cohort studies (Table 2).

Results across studies supported that diets based on macronutrient distributions moderately outside (either below or above) the AMDR compared to within or near the AMDR were associated with higher type 2 diabetes risk. Most of the macronutrient distributions outside of the AMDR were comprised of higher amounts of saturated fat, trans fat, and/or animal-based sources of protein and fat, such as processed meat, red meat, butter, and cheese, and/or higher intakes of carbohydrate from refined grains, SSB’s, and lower-fiber cereals/breads. The proportions of energy associated with these results varied below the AMDR for carbohydrate between 33.4% and 44.9%, and above the AMDR for fat between 35.8% and 46.3%.

Eleven articles reported diets with proportions of carbohydrate below and fat above the AMDR compared to within or near the AMDR (e.g., 35.8% carbohydrate, 46.3% fat vs. 50.2% carbohydrate, 30% fat) were associated with higher type 2 diabetes risk.^50,56–59,62,64,67,68,70,71^ Eight articles reported diets based on macronutrient distributions with proportions within the AMDR compared to outside the AMDR (e.g., 45% carbohydrate vs. 41% carbohydrate) were significantly associated with lower risk of type 2 diabetes.^51–54,60,63,65,69^ Four articles reported no significant associations between any macronutrient distributions compared and risk of type 2 diabetes.^61,66,72^

Several studies compared distinct proportions between groups (e.g., 33.4% vs. 47.5% carbohydrate), whereas other studies compared diets with proportions that were much closer in proximity to one another (e.g., 41.0% vs. 45.0% carbohydrate) or the AMDR limit (e.g., 44.9% vs. 45% carbohydrate).

###### Sub-group and/or sensitivity analyses

Some studies further examined relationships between macronutrient distribution and type 2 diabetes risk by weight status (BMI), age, or other factors, and reported generally consistent findings with main results. Salas-Salvado et al^65^ found no significant interaction in stratification by BMI, age, sex, or fasting glucose.^65^ Chen et al^55^ reported that results did not differ by waist circumference, age, or sex, and sensitivity analyses with further adjustment (e.g., CVD history, replacement of protein with fat) yielded similar estimates as main results. de Koning et al^56^ found no significant interactions found in stratification by age, BMI, alcohol, family history, or physical activity.^56^ Guasch-Ferre et al^58^ reported consistent results after conducting sensitivity analysis excluding early cases during follow-up.^58^

Among studies that examined results further by plant-based sources of the macronutrient distributions, most reported no significant associations with type 2 diabetes risk.^50,56,58,63,68,70,71^ One study found plant-based “low-carbohydrate” scores significantly associated with lower type 2 diabetes risk, but main analyses with overall score produced null findings.^60^

Among studies that further examined by animal-based sources of the diets based on macronutrient distributions and type 2 diabetes risk, few reported no significant associations.^60,63^ Most studies that further analyzed diets based on macronutrient distributions with animal-based foods reported significantly higher risk of type 2 diabetes.^50,58,68,70,71^ Some of these studies reported null findings in their main analyses. In additional analyses accounting for annually updated dietary intake as opposed to baseline dietary intake, Guasch-Ferre reported that macronutrient distributions based on higher animal-fat and saturated fat, whether participants were consuming a “Meditteranean” or control diet, were associated with significantly higher risk of type 2 diabetes.^58^ Additionally, Chen et al^55^ reported that distributions based on protein intake were not significantly associated with type 2 diabetes after full adjustments, but additional analyses revealed that higher total-animal protein was associated with higher risk of type 2 diabetes.

##### Assessment of the evidence^v^

This systematic review included 23 articles that examined diets based on macronutrient distribution and risk of type 2 diabetes, met inclusion criteria, and were published between January 2000 and October 2019. Multiple databases were used to obtain publications from a large, comprehensive search. Although many studies were from large prospective cohorts, studies with smaller sample sizes were also included as well as studies with both significant and non-significant results. Therefore, this risk of publication bias is relatively low. Some of the included articles were secondary analyses from the PREDIMED trial, which was subject to randomization issues established after publication of the initial study. However, the republished results confirmed the initial findings, even after accounting for participants that were subject to protocol deviation.

Most of the articles examined macronutrient distributions in which the proportion of energy from carbohydrate was below the AMDR; Fat was above the AMDR; and protein was within the AMDR in at least one of the exposure groups typically reflected poorer quality diets compared to higher quality alternatives. Therefore across studies, the comparisons were primarily of different dietary patterns and food groups that resulted in differing macronutrient proportions rather than comparing a different distribution of macronutrients within the same pattern of food intake. As a function of this, the differences in macronutrient proportions between exposure groups were either limited in magnitude, of a similar direction relative to the AMDR (e.g., all below or above the AMDR), only modestly different from the AMDR, or only relevant for a limited subset of the study population. As outlined and described below, the body of evidence was assessed for the following elements that were used when grading the strength of evidence

- Risk of bias [also see Table 3]: The included studies adjusted for most potential confounders including baseline BMI and physical activity. However, most studies did not account for race/ethnicity of participants and two studies did not account for alcohol intake, and therefore at higher risk of bias due to confounding. Most of the studies examined dietary intake once only at baseline and changes in dietary patterns were not accounted for that may have occurred over follow-up. Therefore, the studies are at a higher risk of bias due to departure from the intended exposure. Most of the studies used self-reported methods that varied to obtain dietary intake, derive macronutrient intake, and/or assess diet adherence. Studies are prone to selection bias, primarily related to the exclusion of participants with prevalent type 2 diabetes, CVD, cancer, or other medical conditions at baseline. Therefore, the results are likely representative of healthier populations. Several studies did not account for missing data, primarily related to missing diet/exposure data at baseline. Most studies used self-reported data to assess type 2 diabetes incidence, but confirmed diagnosis against physician records or registry information for diabetic-medication usage.
- Consistency: Results across studies were consistent with diets based on macronutrient distributions outside the AMDR (below or above) compared to those that were either within or closer to the AMDR associating with higher type 2 diabetes risk. Most macronutrient distributions outside of the AMDR reported higher amounts of saturated fat, trans fat, and/or “animal-based” sources of protein and fat, such as processed meat, red meat, butter, and cheese and/or refined grains, SSB’s, and lower-fiber cereals/breads. However, not all studies reported detailed information about the diet quality of the distribution examined. Not all studies consistently reported dairy and/or dairy products. Of those that did, there was inconsistency with the detail provided regarding type and/or amount e.g., “full-fat dairy”, “fermented dairy”, “milk”. Proportions of energy associated with these results varied below the AMDR for carbohydrate between 33.4% and 44.9%, and above the AMDR for fat between 35.8% and 46.3%. Few studies that met inclusion criteria examined proportion of energy below the AMDR for carbohydrate less than 33.4% and of the few that did, their results were not statistically significant. The gradient between proportions compared within and across studies varied. Several studies compared sufficiently distinct proportions between groups (e.g., 33.4% vs. 47.5% carbohydrate), whereas other proportions were much closer in proximity relative to one another (e.g., 41.0% vs. 45.0% carbohydrate) or to the actual AMDR cut-off (e.g., 44.9% vs. 45% carbohydrate). Among studies that examined macronutrient distributions using adherence scores, similar methods were used to derive the categories of macronutrient distributions within limits/strata. Studies primarily used the residual-method to adjust macronutrient intake for total energy. However, the studies varied in terms of the distribution of macronutrients that were examined and the methods used to estimate nutrient intakes, derive the proportion of energy from macronutrients, and/or apply substitution modelling (e.g., multivariate-nutrient density methods). Sensitivity analyses or sub-group analyses were conducted in a few studies based on a variety of key or potential confounding factors, and consistently confirmed robustness of main results.
- Precision: In the two RCTs, wider confidence intervals were notable with relatively smaller number of cases suggesting some degree of imprecision. Most of the observational studies did not report power analyses or sample size calculations. However, the majority of had large analytic sample sizes, with a range of n=2006 and n=92,088. The duration of follow-up varied across studies, but was sufficient to examine the development of type 2 diabetes and ranged from mean/median of 4 to 20 y in studies reporting significant associations.
- Directness: Few studies directly examined the effect of diets based on macronutrient distributions outside the AMDR in the context of a constant dietary pattern. Another important limitation to highlight is that most of the studies assessed different dietary patterns as the primary comparators rather than using a common dietary pattern and adjusting macronutrient proportions within that dietary context. Due to the variety of methods used to estimate macronutrient intake and adjust intake for total energy, the confidence in the estimated proportions falling outside the AMDR is low. The gradient between proportions compared within macronutrients varied and in some cases, may not have been large enough to distinguish differences in risk of type 2 diabetes between exposure groups. Several studies reported to be examining one particular macronutrient of interest, such as “low-carbohydrate” intake, but the proportion for that nutrient was within the AMDR e.g., 44.9%, 44.8%, and 51% carbohydrate were labeled as “low-carbohydrate” by Nanri et al.^63^ Due to these issues, directness across the body of evidence could not be adequately assessed.
- Generalizability: Across the studies, the results may be less generalizable due to differences between countries in terms of national recommendations for macronutrient distributions consumed, and other factors such as BMI-differences between countries. For example, several of the macronutrient distributions compared were from populations that consume high amounts of rice with carbohydrate well above the AMDR and fat well below the AMDR, which is not typical of diets in the United States.

### Research recommendations

In order to better assess the relationship between dietary patterns and/or diets based on macronutrient distribution and risk of type 2 diabetes, future research may:

1. Determine the impact that dietary patterns may have that is independent of adiposity and/or weight-loss, to better inform studies examining the relationship between dietary patterns and risk of type 2 diabetes, cardiovascular disease, and/or obesity
2. Conduct well-designed, sufficiently powered, randomized controlled trials that examine the relationship between dietary patterns consumed by adults and risk of type 2 diabetes, while clearly accounting for the role of concurrent weight loss.
3. Conduct well-designed, sufficiently powered studies that examine the relationship between dietary patterns consumed in childhood and prevention of type 2 diabetes outcomes. Particularly lacking are randomized controlled trials and studies during adolescence that could examine intermediate type 2 diabetes outcomes while clearly accounting for the role of concurrent weight loss/management.
4. Identify dietary patterns during childhood that may confer benefit to health outcomes including favorable growth and/or cardiometabolic health factors, over the lifecourse.
5. Develop a standardized definition for what constitutes a “very-low carbohydrate”, “low-carbohydrate”,“carbohydrate-restricted”, and/or “ketogenic diet” dietary pattern based on macronutrient proportion
6. Examine the relationship between diets based on macronutrient proportions of energy from carbohydrate below 25% within the context of specific dietary patterns to determine if and what relationship may exist between macronutrient distribution and the prevention of type 2 diabetes. These types of studies need to adequately control for the quality of food intake and role of weight loss/management.
7. Explore the role that macronutrient quality may have in the relationship between “low-carbohydrate” diets and the prevention of type 2 diabetes (i.e., effect modification), within the context of a constant dietary pattern and accounting for the role of weight loss.
8. Assess information regarding diet at more than one time-point in prospective cohort studies, preferably during the course of follow-up and in different populations, to facilitate understanding the relationship between dietary patterns over time and risk of type 2 diabetes.
9. Differentiate specific foods and food groups, in particular, the types and amounts, relevant biomarkers, and using repeated measures to facilitate both preventive strategies and overall outcomes
10. Elucidate the role of alcoholic beverage intake within dietary patterns utilizing more consistent controls and research methods to measure relative to risk of type 2 diabetes in prospective cohort studies.

### Included articles

1 Dahm CC, Chomistek AK, Jakobsen MU, . Adolescent diet quality and cardiovascular disease risk factors and incident cardiovascular disease in middle-aged women. J Am Heart Assoc. 2016;5(12). doi:10.1161/jaha.116.003583.
2 Ahmad S, Moorthy MV, Demler OV, . Assessment of risk factors and biomarkers associated with risk of cardiovascular disease among women consuming a Mediterranean diet. JAMA Netw Open. 2018;1(8):e185708. doi:10.1001/jamanetworkopen.2018.5708.30646282
3 Alae-Carew C, Scheelbeek P, Carrillo-Larco RM, Bernabe-Ortiz A, Checkley W, Miranda JJ. Analysis of dietary patterns and cross-sectional and longitudinal associations with hypertension, high BMI and type 2 diabetes in Peru. Public Health Nutr. 2020;23(6):1009–1019. doi:10.1017/s1368980019002313.31456536
4 Alhazmi A, Stojanovski E, McEvoy M, Brown W, Garg ML. Diet quality score is a predictor of type 2 diabetes risk in women: the Australian Longitudinal Study on Women’s Health. Br J Nutr. 2014;112(6):945–951. doi:10.1017/s0007114514001688.25201303
5 Babio N, Toledo E, Estruch R, . Mediterranean diets and metabolic syndrome status in the PREDIMED randomized trial. CMAJ. 2014;186(17):E649–657. doi:10.1503/cmaj.140764.25316904
6 Bantle AE, Chow LS, Steffen LM, . Association of Mediterranean diet and cardiorespiratory fitness with the development of pre-diabetes and diabetes: the Coronary Artery Risk Development in Young Adults (CARDIA) study. BMJ Open Diabetes Res Care. 2016;4(1):e000229. doi:10.1136/bmjdrc-2016-000229.
7 Casas R, Sacanella E, Urpi-Sarda M, . The effects of the Mediterranean diet on biomarkers of vascular wall inflammation and plaque vulnerability in subjects with high risk for cardiovascular disease. A randomized trial. PLoS One. 2014;9(6):e100084. doi:10.1371/journal.pone.0100084.24925270
8 Casas R, Sacanella E, Urpi-Sarda M, . Long-term immunomodulatory effects of a Mediterranean diet in adults at high risk of cardiovascular disease in the PREvencion con DIeta MEDiterranea (PREDIMED) randomized controlled trial. J Nutr. 2016;146(9):1684–1693. doi:10.3945/jn.115.229476.27440261
9 Cespedes EM, Hu FB, Tinker L, . Multiple healthful dietary patterns and type 2 diabetes in the women’s health initiative. Am J Epidemiol. 2016;183(7):622–633. doi:10.1093/aje/kwv241.26940115
10 Chen GC, Koh WP, Neelakantan N, Yuan JM, Qin LQ, van Dam RM. Diet quality indices and risk of type 2 diabetes mellitus: the Singapore Chinese Health Study. Am J Epidemiol. 2018;187(12):2651–2661. doi:10.1093/aje/kwy183.30165478
11 Chen Z, Zuurmond MG, van der Schaft N, . Plant versus animal based diets and insulin resistance, prediabetes and type 2 diabetes: the Rotterdam Study. Eur J Epidemiol. 2018;33(9):883–893. doi:10.1007/s10654-018-0414-8.29948369
12 Conway BN, Han X, Munro HM, . The obesity epidemic and rising diabetes incidence in a low-income racially diverse southern US cohort. PLoS One. 2018;13(1):e0190993. doi:10.1371/journal.pone.0190993.29324894
13 Czekajlo A, Rozanska D, Zatonska K, Szuba A, Regulska-Ilow B. Association between dietary patterns and metabolic syndrome in the selected population of Polish adults-results of the PURE Poland Study. Eur J Public Health. 2019;29(2):335–340. doi:10.1093/eurpub/cky207.30285088
14 Otto MC, Padhye NS, Bertoni AG, Jacobs DR, Jr., Mozaffarian D. Everything in moderation--dietary diversity and quality, central obesity and risk of diabetes. PLoS One. 2015;10(10):e0141341. doi:10.1371/journal.pone.0141341.26517708
15 den Braver NR, Rutters F, van der Spek A, . Adherence to a food group-based dietary guideline and incidence of prediabetes and type 2 diabetes. Eur J Nutr. 2019. doi:10.1007/s00394-019-02064-8.
16 Dow C, Balkau B, Bonnet F, . Strong adherence to dietary and lifestyle recommendations is associated with decreased type 2 diabetes risk in the AusDiab cohort study. Prev Med. 2019;123:208–216. doi:10.1016/j.ypmed.2019.03.006.30851294
17 Eguaras S, Bes-Rastrollo M, Ruiz-Canela M, Carlos S, de la Rosa P, Martinez-Gonzalez MA. May the Mediterranean diet attenuate the risk of type 2 diabetes associated with obesity: the Seguimiento Universidad de Navarra (SUN) cohort. Br J Nutr. 2017;117(10):1478–1485. doi:10.1017/s0007114517001404.28625175
18 Ericson U, Hindy G, Drake I, . Dietary and genetic risk scores and incidence of type 2 diabetes. Genes Nutr. 2018;13:13. doi:10.1186/s12263-018-0599-1.29796113
19 Filippatos TD, Panagiotakos DB, Georgousopoulou EN, . Mediterranean diet and 10-year (2002-2012) incidence of diabetes and cardiovascular disease in participants with prediabetes: the ATTICA study. Rev Diabet Stud. 2016;13(4):226–235. doi:10.1900/rds.2016.13.226.28278309
20 Galbete C, Kroger J, Jannasch F, . Nordic diet, Mediterranean diet, and the risk of chronic diseases: the EPIC-Potsdam study. BMC Med. 2018;16(1):99. doi:10.1186/s12916-018-1082-y.29945632
21 Hirahatake KM, Jacobs DR, Jr., Shikany JM, Jiang L, Wong ND, Odegaard AO. Cumulative average dietary pattern scores in young adulthood and risk of incident type 2 diabetes: the CARDIA study. Diabetologia. 2019;62(12):2233–2244. doi:10.1007/s00125-019-04989-5.31478081
22 Howard BV, Aragaki AK, Tinker LF, . A low-fat dietary pattern and diabetes: a secondary analysis from the Women’s Health Initiative Dietary Modification Trial. Diabetes Care. 2018;41(4):680–687. doi:10.2337/dc17-0534.29282203
23 Jacobs S, Harmon BE, Boushey CJ, . A priori-defined diet quality indexes and risk of type 2 diabetes: the Multiethnic Cohort. Diabetologia. 2015;58(1):98–112. doi:10.1007/s00125-014-3404-8.25319012
24 Jacobs S, Kroeger J, Schulze MB, . Dietary patterns derived by reduced rank regression are inversely associated with type 2 diabetes risk across 5 ethnic groups in the multiethnic cohort. Curr Dev Nutr. 2017;1(5):e000620. doi:10.3945/cdn.117.000620.29955702
25 Jacobs S, Boushey CJ, Franke AA, . A priori-defined diet quality indices, biomarkers and risk for type 2 diabetes in five ethnic groups: the Multiethnic Cohort. Br J Nutr. 2017;118(4):312–320. doi:10.1017/s0007114517002033.28875870
26 Jannasch F, Kroger J, Agnoli C, . Generalizability of a diabetes-associated country-specific exploratory dietary pattern is feasible across european populations. J Nutr. 2019;149(6):1047–1055. doi:10.1093/jn/nxz031.31149710
27 Johns DJ, Lindroos AK, Jebb SA, Sjostrom L, Carlsson LM, Ambrosini GL. Dietary patterns, cardiometabolic risk factors, and the incidence of cardiovascular disease in severe obesity. Obesity 2015;23(5):1063–1070. doi:10.1002/oby.20920.25865622
28 Kanerva N, Rissanen H, Knekt P, Havulinna AS, Eriksson JG, Mannisto S. The healthy Nordic diet and incidence of type 2 diabetes--10-year follow-up. Diabetes Res Clin Pract. 2014;106(2):e34–37. doi:10.1016/j.diabres.2014.08.016.25245974
29 Khalili-Moghadam S, Mirmiran P, Bahadoran Z, Azizi F. The Mediterranean diet and risk of type 2 diabetes in Iranian population. Eur J Clin Nutr. 2019;73(1):72–78. doi:10.1038/s41430-018-0336-2.30315315
30 Koloverou E, Panagiotakos DB, Pitsavos C, . Adherence to Mediterranean diet and 10-year incidence (2002-2012) of diabetes: correlations with inflammatory and oxidative stress biomarkers in the ATTICA cohort study. Diabetes Metab Res Rev. 2016;32(1):73–81. doi:10.1002/dmrr.2672.26104243
31 Koloverou E, Panagiotakos DB, Georgousopoulou EN, . Dietary patterns and 10-year (2002-2012) incidence of type 2 diabetes: results from the ATTICA cohort study. Rev Diabet Stud. 2016;13(4):246–256. doi:10.1900/rds.2016.13.246.28394951
32 Konieczna J, Yanez A, Monino M, . Longitudinal changes in Mediterranean diet and transition between different obesity phenotypes. Clin Nutr. 2020;39(3):966–975. doi:10.1016/j.clnu.2019.04.002.31053509
33 Lacoppidan SA, Kyro C, Loft S, . Adherence to a healthy Nordic food index is associated with a lower risk of type-2 diabetes--The Danish Diet, Cancer and Health Cohort Study. Nutrients. 2015;7(10):8633–8644. doi:10.3390/nu7105418.26506373
34 Lee HA, Son N, Lee WK, Park H. A diabetes-related dietary pattern is associated with incident diabetes in obese men in the Korean Genome Epidemiology Study. J Nutr. 2019;149(2):323–329. doi:10.1093/jn/nxy274.30590687
35 Ley SH, Pan A, Li Y, . Changes in overall diet quality and subsequent type 2 diabetes risk: three U.S. prospective cohorts. Diabetes Care. 2016;39(11):2011–2018. doi:10.2337/dc16-0574.27634391
36 Mandalazi E, Drake I, Wirfalt E, Orho-Melander M, Sonestedt E. A high diet quality based on dietary recommendations is not associated with lower incidence of type 2 diabetes in the Malmo Diet and Cancer cohort. Int J Mol Sci. 2016;17(6). doi:10.3390/ijms17060901.
37 Papier K, Appleby PN, Fensom GK, . Vegetarian diets and risk of hospitalisation or death with diabetes in British adults: results from the EPIC-Oxford study. Nutr Diabetes. 2019;9(1):7. doi:10.1038/s41387-019-0074-0.30804320
38 Pastorino S, Richards M, Pierce M, Ambrosini GL. A high-fat, high-glycaemic index, low-fibre dietary pattern is prospectively associated with type 2 diabetes in a British birth cohort. Br J Nutr. 2016;115(9):1632–1642. doi:10.1017/s0007114516000672.27245103
39 Pinto X, Fanlo-Maresma M, Corbella E, . A Mediterranean diet rich in extra-virgin olive oil Is associated with a reduced prevalence of nonalcoholic fatty liver disease in older individuals at high cardiovascular risk. J Nutr. 2019;149(11):1920–1929. doi:10.1093/jn/nxz147.31334554
40 Poulsen SK, Due A, Jordy AB, . Health effect of the New Nordic Diet in adults with increased waist circumference: a 6-mo randomized controlled trial. Am J Clin Nutr. 2014;99(1):35–45. doi:10.3945/ajcn.113.069393.24257725
41 Qiao Y, Tinker L, Olendzki BC, . Racial/ethnic disparities in association between dietary quality and incident diabetes in postmenopausal women in the United States: the Women’s Health Initiative 1993-2005. Ethn Health. 2014;19(3):328–347. doi:10.1080/13557858.2013.797322.23697968
42 Salas-Salvado J, Bullo M, Estruch R, . Prevention of diabetes with Mediterranean diets: a subgroup analysis of a randomized trial. Ann Intern Med. 2014;160(1):1–10. doi:10.7326/m13-1725.
43 Satija A, Bhupathiraju SN, Rimm EB, . Plant-based dietary patterns and incidence of type 2 diabetes in US men and women: results from three prospective cohort studies. PLoS Med. 2016;13(6):e1002039. doi:10.1371/journal.pmed.1002039.27299701
44 Seah JYH, Ong CN, Koh WP, Yuan JM, van Dam RM. A dietary pattern derived from reduced rank regression and fatty acid biomarkers is associated with lower risk of type 2 diabetes and coronary artery disease in Chinese adults. J Nutr. 2019;149(11):2001–2010. doi:10.1093/jn/nxz164.31386157
45 Shan Z, Li Y, Zong G, . Rotating night shift work and adherence to unhealthy lifestyle in predicting risk of type 2 diabetes: results from two large US cohorts of female nurses. BMJ. 2018;363:k4641. doi:10.1136/bmj.k4641.30464025
46 Song S, Lee JE. Dietary patterns related to triglyceride and high-density lipoprotein cholesterol and the incidence of type 2 diabetes in Korean men and women. Nutrients. 2018;11(1). doi:10.3390/nu11010008.
47 Steffen LM, Van Horn L, Daviglus ML, . A modified Mediterranean diet score is associated with a lower risk of incident metabolic syndrome over 25 years among young adults: the CARDIA (Coronary Artery Risk Development in Young Adults) study. Br J Nutr. 2014;112(10):1654–1661. doi:10.1017/s0007114514002633.25234439
48 Tait CA, L’Abbe MR, Smith PM, Watson T, Kornas K, Rosella LC. Adherence to predefined dietary patterns and risk of developing type 2 diabetes in the Canadian adult population. Can J Diabetes. 2020;44(2):175–183.e172. doi:10.1016/j.jcjd.2019.06.002.31420278
49 Voortman T, Kiefte-de Jong JC, Ikram MA, . Adherence to the 2015 Dutch dietary guidelines and risk of non-communicable diseases and mortality in the Rotterdam Study. Eur J Epidemiol. 2017;32(11):993–1005. doi:10.1007/s10654-017-0295-2.28825166
50 Bao W, Li S, Chavarro JE, . Low carbohydrate-diet scores and long-term risk of type 2 diabetes among women with a history of gestational diabetes mellitus: a prospective cohort study. Diabetes Care. 2016;39(1):43–49. doi:10.2337/dc15-1642.26577416
51 Dominguez LJ, Bes-Rastrollo M, Basterra-Gortari FJ, Gea A, Barbagallo M, Martinez-Gonzalez MA. Association of a dietary score with incident type 2 diabetes: the dietary-based diabetes-risk score (DDS). PLoS One. 2015;10(11):e0141760. doi:10.1371/journal.pone.0141760.26544985
52 Ericson U, Brunkwall L, Alves Dias J, . Food patterns in relation to weight change and incidence of type 2 diabetes, coronary events and stroke in the Malmo Diet and Cancer cohort. Eur J Nutr. 2019;58(5):1801–1814. doi:10.1007/s00394-018-1727-9.29855685
53 InterAct C. Adherence to predefined dietary patterns and incident type 2 diabetes in European populations: EPIC-InterAct Study. Diabetologia. 2014;57(2):321–333. doi:10.1007/s00125-013-3092-9.24196190
54 Brunner EJ, Mosdol A, Witte DR, . Dietary patterns and 15-y risks of major coronary events, diabetes, and mortality. Am J Clin Nutr. 2008;87(5):1414–1421. doi:10.1093/ajcn/87.5.1414.18469266
55 Chen Z, Franco OH, Lamballais S, . Associations of specific dietary protein with longitudinal insulin resistance, prediabetes and type 2 diabetes: The Rotterdam Study. Clin Nutr. 2020;39(1):242–249. doi:10.1016/j.clnu.2019.01.021.30739809
56 de Koning L, Fung TT, Liao X, . Low-carbohydrate diet scores and risk of type 2 diabetes in men. Am J Clin Nutr. 2011;93(4):844–850. doi:10.3945/ajcn.110.004333.21310828
57 Ericson U, Sonestedt E, Gullberg B, . High intakes of protein and processed meat associate with increased incidence of type 2 diabetes. Br J Nutr. 2013;109(6):1143–1153. doi:10.1017/s0007114512003017.22850191
58 Guasch-Ferre M, Becerra-Tomas N, Ruiz-Canela M, . Total and subtypes of dietary fat intake and risk of type 2 diabetes mellitus in the Prevencion con Dieta Mediterranea (PREDIMED) study. Am J Clin Nutr. 2017;105(3):723–735. doi:10.3945/ajcn.116.142034.28202478
59 Ha K, Joung H, Song Y. Inadequate fat or carbohydrate intake was associated with an increased incidence of type 2 diabetes mellitus in Korean adults: a 12-year community-based prospective cohort study. Diabetes Res Clin Pract. 2019;148:254–261. doi:10.1016/j.diabres.2019.01.024.30703429
60 Halton TL, Liu S, Manson JE, Hu FB. Low-carbohydrate-diet score and risk of type 2 diabetes in women. Am J Clin Nutr. 2008;87(2):339–346. doi:10.1093/ajcn/87.2.339.18258623
61 Kahleova H, Dort S, Holubkov R, Barnard ND. A plant-based high-carbohydrate, low-fat diet in overweight individuals in a 16-week randomized clinical trial: the role of carbohydrates. Nutrients. 2018;10(9). doi:10.3390/nu10091302.
62 Malik VS, Li Y, Tobias DK, Pan A, Hu FB. Dietary protein intake and risk of type 2 diabetes in US men and women. Am J Epidemiol. 2016;183(8):715–728. doi:10.1093/aje/kwv268.27022032
63 Nanri A, Mizoue T, Kurotani K, . Low-carbohydrate diet and type 2 diabetes risk in Japanese men and women: the Japan Public Health Center-Based Prospective Study. PLoS One. 2015;10(2):e0118377. doi:10.1371/journal.pone.0118377.25695497
64 Sakurai M, Nakamura K, Miura K, . Dietary carbohydrate intake, presence of obesity and the incident risk of type 2 diabetes in Japanese men. J Diabetes Investig. 2016;7(3):343–351. doi:10.1111/jdi.12433.
65 Salas-Salvado J, Bullo M, Babio N, . Reduction in the incidence of type 2 diabetes with the Mediterranean diet: results of the PREDIMED-Reus nutrition intervention randomized trial. Diabetes Care. 2011;34(1):14–19. doi:10.2337/dc10-1288.20929998
66 Schulze MB, Schulz M, Heidemann C, Schienkiewitz A, Hoffmann K, Boeing H. Carbohydrate intake and incidence of type 2 diabetes in the European Prospective Investigation into Cancer and Nutrition (EPIC)-Potsdam Study. Br J Nutr. 2008;99(5):1107–1116. doi:10.1017/s0007114507853360.17988431
67 Shan R, Duan W, Liu L, . Low-carbohydrate, high-protein, high-fat diets rich in livestock, poultry and their products predict impending risk of type 2 diabetes in Chinese individuals that exceed their calculated caloric requirement. Nutrients. 2018;10(1). doi:10.3390/nu10010077.
68 Shang X, Scott D, Hodge AM, . Dietary protein intake and risk of type 2 diabetes: results from the Melbourne Collaborative Cohort Study and a meta-analysis of prospective studies. Am J Clin Nutr. 2016;104(5):1352–1365. doi:10.3945/ajcn.116.140954.27629053
69 Simila ME, Kontto JP, Valsta LM, Mannisto S, Albanes D, Virtamo J. Carbohydrate substitution for fat or protein and risk of type 2 diabetes in male smokers. Eur J Clin Nutr. 2012;66(6):716–721. doi:10.1038/ejcn.2012.24.22378225
70 Sluijs I, Beulens JW, van der AD, Spijkerman AM, Grobbee DE, van der Schouw YT. Dietary intake of total, animal, and vegetable protein and risk of type 2 diabetes in the European Prospective Investigation into Cancer and Nutrition (EPIC)-NL study. Diabetes Care. 2010;33(1):43–48. doi:10.2337/dc09-1321.19825820
71 van Nielen M, Feskens EJ, Mensink M, . Dietary protein intake and incidence of type 2 diabetes in Europe: the EPIC-InterAct Case-Cohort Study. Diabetes Care. 2014;37(7):1854–1862. doi:10.2337/dc13-2627.24722499
72 Virtanen HEK, Koskinen TT, Voutilainen S, . Intake of different dietary proteins and risk of type 2 diabetes in men: the Kuopio Ischaemic Heart Disease Risk Factor Study. Br J Nutr. 2017;117(6):882–893. doi:10.1017/s0007114517000745.28397639

Table 1 Description of studies that examined the relationship between dietary patterns in children or adolescents and risk of type 2 diabetes^vi^

Study and Participant Characteristics | Dietary Pattern | Summary of Results | Methodological Considerations
Dahm, 2016 ^1^; United States, Nurses’ Health Study II (NHS II); Prospective cohort study, using retrospective data; N=27,406 for T2D outcome, N=42112 for CVD outcomes; 100% female; Excluded those with history of CVD, cancer, hypercholesterolemia, hypertension, and/or T2D | [underlined: Index/score:] Alternative Healthy Eating Index (AHEI)-2010; examined as quintiles with Q1 as reference, or continuous per 10pt increment | No significant association between AHEI-2010 scores (categorical or continuous) and T2D risk at 13 y follow-up | [underlined: Did not account for:]; Race/ethnicity; N/A: Alcohol, Smoking; [underlined: Limitations:]; Diet assessed once at baseline, and was recalled retrospectively; [underlined: Funding:]; Carlsbergfondet Postdoc Travel Grant; the Danish Ministry of Science, Innovation and Higher Education International Network Programme; the Danish Council for Strategic Research; NIH

Table 2 Description of studies that examined the relationship between diets based on macronutrient distribution in adults and risk of type 2 diabetes^vii^

Study and Participant Characteristics^viii^ | Diet Intervention or Exposure^ix^ | Category | Macronutrient Distribution, % Energy Carbohydrate, Fat, Protein | | | Summary of Findings^x^ | Methodological considerations
Bao, 2016 ^50^; United States; Nurses Health Study II (NHS); Health Professionals Follow-up Study (HPFS), PCS; N=4502; 100% female; Exclusively those with history of gestational diabetes | % energy (E) based on “low-carbohydrate” diet (LCD) scores examined as a continuous, overall LCD score; animal-LCD score; and vegetable-LCD score; Foods/Food groups: Red meat, poultry, fish, eggs, dairy, fruits, vegetables, nuts, legumes, whole grains, SSBs by quintiles provided | Q1, ref | 57.3 | 27.3 | 17.0 | ↑ risk of type 2 diabetes (T2D) at 20y f/u, overall LCD score; Q4 vs. Q1; ↑ T2D, animal-LCD score; ᴓ T2D, vegetable-LCD score | Did not account for: N/A; [underlined: Funding]: Intramural Research Program of the Eunice Kennedy Shriver National Institute of Child Health and Human Development, NIH, American Diabetes Association
Bao, 2016 ^50^; United States; Nurses Health Study II (NHS); Health Professionals Follow-up Study (HPFS), PCS; N=4502; 100% female; Exclusively those with history of gestational diabetes | | Q2 | 52.3 | 29.8 | 19.0 | ↑ risk of type 2 diabetes (T2D) at 20y f/u, overall LCD score; Q4 vs. Q1; ↑ T2D, animal-LCD score; ᴓ T2D, vegetable-LCD score | Did not account for: N/A; [underlined: Funding]: Intramural Research Program of the Eunice Kennedy Shriver National Institute of Child Health and Human Development, NIH, American Diabetes Association
Bao, 2016 ^50^; United States; Nurses Health Study II (NHS); Health Professionals Follow-up Study (HPFS), PCS; N=4502; 100% female; Exclusively those with history of gestational diabetes | | Q3 | 49.6 | 31.9 | 19.3 | ↑ risk of type 2 diabetes (T2D) at 20y f/u, overall LCD score; Q4 vs. Q1; ↑ T2D, animal-LCD score; ᴓ T2D, vegetable-LCD score | Did not account for: N/A; [underlined: Funding]: Intramural Research Program of the Eunice Kennedy Shriver National Institute of Child Health and Human Development, NIH, American Diabetes Association
Bao, 2016 ^50^; United States; Nurses Health Study II (NHS); Health Professionals Follow-up Study (HPFS), PCS; N=4502; 100% female; Exclusively those with history of gestational diabetes | | Q4 | 46.0 | 34.4 | 20.2 | ↑ risk of type 2 diabetes (T2D) at 20y f/u, overall LCD score; Q4 vs. Q1; ↑ T2D, animal-LCD score; ᴓ T2D, vegetable-LCD score | Did not account for: N/A; [underlined: Funding]: Intramural Research Program of the Eunice Kennedy Shriver National Institute of Child Health and Human Development, NIH, American Diabetes Association
Bao, 2016 ^50^; United States; Nurses Health Study II (NHS); Health Professionals Follow-up Study (HPFS), PCS; N=4502; 100% female; Exclusively those with history of gestational diabetes | | Q5 | 42.0 | 36.9 | 21.6 | ↑ risk of type 2 diabetes (T2D) at 20y f/u, overall LCD score; Q4 vs. Q1; ↑ T2D, animal-LCD score; ᴓ T2D, vegetable-LCD score | Did not account for: N/A; [underlined: Funding]: Intramural Research Program of the Eunice Kennedy Shriver National Institute of Child Health and Human Development, NIH, American Diabetes Association
Brunner, 2008 ^54^; United Kingdom; Whitehall II study, PCS; N=7731 | % E in 4 patterns identified by cluster analysis; ‘Unhealthy’: Higher than average consumption of meat and sausages, white bread, fries, and full-cream milk. Average consumption of wine and beer. Very low consumption of fruit and vegetables | ‘Unhealthy’, ref. | 41.4 | 33.1 | 17.3 | ↓ T2D, Healthy vs. Unealthy; ᴓ T2D, Sweet vs. Unhealthy; Mediterranean vs. Unhealthy | Did not account for: N/A; [underlined: Funding:] UK Medical Research Council, the British Heart Foundation, the Health and Safety Executive, the Department of Health, NHLBI, National Institute on Aging, Agency for Health Care Policy Research, and the MacArthur Foundation Research Network on Socio-economic Status and Health.
Brunner, 2008 ^54^; United Kingdom; Whitehall II study, PCS; N=7731 | ‘Sweet’: Higher than average consumption of biscuits, cakes, meat, sausages and savory pies, white bread, full-cream milk, butter, and wine and beer. Average intake of fruit and vegetables. | ‘Sweet’ | 43.2 | 33.6 | 15.7 | ↓ T2D, Healthy vs. Unealthy; ᴓ T2D, Sweet vs. Unhealthy; Mediterranean vs. Unhealthy
Brunner, 2008 ^54^; United Kingdom; Whitehall II study, PCS; N=7731 | ‘Mediterranean-like’: Higher than average consumption of whole-meal bread, fruit, vegetables, pasta and rice, and wine and beer. Low intake of full-cream milk but high intake of butter. Average consumption of white bread. | ‘Mediterranean-like’ | 40.4 | 32.0 | 16.8 | ↓ T2D, Healthy vs. Unealthy; ᴓ T2D, Sweet vs. Unhealthy; Mediterranean vs. Unhealthy
Brunner, 2008 ^54^; United Kingdom; Whitehall II study, PCS; N=7731 | ‘Healthy’: Higher than average consumption of whole-meal bread, fruit and vegetables, and polyunsaturated margarine. Average to low consumption of red meat, sweet foods, and wine and beer. | ‘Healthy’ | 43.4 | 30.5 | 17.9 | ↓ T2D, Healthy vs. Unealthy; ᴓ T2D, Sweet vs. Unhealthy; Mediterranean vs. Unhealthy
Chen, 2019 ^55^; Netherlands; Rotterdam Study (RS), PCS; N=6813, ≥45 y Included only those with data for T2D (Attrition ~1%) | % E based on “Low-carbohydrate” diet (LCD) score, examined by total protein intake, per-5% increase of protein from carbohydrate, from animal-protein, or plant-protein; Foods/Food groups: Reported protein intake from meat, dairy, fish, grains, legumes and nuts, potato, vegetables and fruit | LCD score, per-5% increase of protein from carbohydrate; LCD score, animal-protein; LCD score, plant-protein | 43.7 | 32.8 | 16.3 | ᴓ T2D at ~5-10y f/u, per 5 E% total-p, animal-, or plant-protein intake at the expense of carbohydrate | Did not account for: N/A; [underlined: Funding:] Erasmus MC and Erasmus University Rotterdam…^xi^
de Koning, 2011 ^56^; United States; Health Professionals Follow-up Study (HPFS), PCS; N=40,745; 0% female | “Low-carbohydrate” diet (LCD) score with % E of total protein-fat intake; Foods/Food groups: Reported intake from red and processed meat together and separate, chicken, dairy, fish, eggs, whole grains, refined grains, legumes, nuts, vegetables, and fruit | Q1, LCD score, total protein-fat; ref. | 57.7 | 25.6 | 15.7 | ↑ T2D at 20y f/u | Did not account for: Race/ethnicity; Diet assessed every 4y, with validated FFQ, using cumulative average; Self-reported T2D using validated methods with confirmation from medical records; [underlined: Funding:]; Canadian Institutes of Health Research and the Canadian Diabetes Association; NIH
de Koning, 2011 ^56^; United States; Health Professionals Follow-up Study (HPFS), PCS; N=40,745; 0% female | | Q5, LCD score, total protein-fat | 37.3 | 38.6 | 21.5 | ↑ T2D at 20y f/u
de Koning, 2011 ^56^; United States; Health Professionals Follow-up Study (HPFS), PCS; N=40,745; 0% female | | Q1, LCD score, animal protein-fat, ref. | 57.4 | 26.5 | 15.7 | ↑ T2D at 20y f/u
de Koning, 2011 ^56^; United States; Health Professionals Follow-up Study (HPFS), PCS; N=40,745; 0% female | | Q5, LCD score, animal protein-fat | 37.4 | 37.5 | 21.6 | ↑ T2D at 20y f/u
de Koning, 2011 ^56^; United States; Health Professionals Follow-up Study (HPFS), PCS; N=40,745; 0% female | | Q1, LCD score, vegetable protein-fat, ref. | 51.2 | 28.3 | 18.2 | ᴓ T2D at 20y f/u
de Koning, 2011 ^56^; United States; Health Professionals Follow-up Study (HPFS), PCS; N=40,745; 0% female | | Q5, LCD score, vegetable protein-fat | 43.0 | 36.4 | 18.4 | ᴓ T2D at 20y f/u
Dominguez, 2015 ^51^; Spain; Seguimiento Universidad de Navarra (SUN), PCS; N=17292 | Diabetes Dietary score (DDS): Low, 11–24; Intermediate, 25–39; High, 40–60;; Positive DDS components: vegetables, fruit, fiber, whole cereals, nuts, coffee, PUFA, low-fat dairy, alcohol in moderate amounts; Negatve DDS components: red meat, processed meat, and SSB; Foods/Food groups: Reported intake from meat/meat products, whole dairy products, low-fat dairy products, fish and other seafood, cereals, whole bread, potatoes, eggs, legumes, nuts, vegetables, fruit | Low Diabetes Dietary score (DDS), ref | 41.0 | 40.0 | 17.8 | ↓ T2D, Intermediate DDS vs. ref at 9y f/u; ↓ T2D, High DDS vs. ref at 9y f/u; Sensivitiy analyses per-5-point increase in DDS was associated with ↓ T2D risk; yeilding generally inverse associations between DDS and T2D by sex, age, BMI, or excluding early cases | Did not account for: Race/ethnicity; Measured diet once at baseline using validated FFQ; Residual method used to adjust nutrient intake for energy; Self-reported T2D using validated methods with confirmation from medical records; [underlined: Funding:]; Spanish Ministry of Health and European Regional Development Fund; the Navarra Regional Government
Dominguez, 2015 ^51^; Spain; Seguimiento Universidad de Navarra (SUN), PCS; N=17292 | | Intermediate DDS | 43.0 | 37.0 | 18.2
Dominguez, 2015 ^51^; Spain; Seguimiento Universidad de Navarra (SUN), PCS; N=17292 | | High DDS | 45.0 | 34.0 | 18.1
Ericson, 2013 ^57^; Sweden; Malmö Diet and Cancer cohort, PCS; N=27140 | % E of total protein intake in women; Foods/Food groups: NR by quintile of protein intake; alcohol and fiber intake varied by quintiles at baseline | Q1, ref | 47.5 | 39.7 | 12.8 | ᴓ T2D at 12y f/u; ↑ T2D per-5% substitution of carbohydrate with protein | Did not account for: Race/ethnicity; Measured diet once at baseline using validated diet history methods; Self-reported T2D diangosis, medication, or registered information; [underlined: Funding:] Swedish Research Council, Region Skåne, Skåne University Hospital, Novo Nordic Foundation, Albert Påhlsson Research Foundation
Ericson, 2013 ^57^; Sweden; Malmö Diet and Cancer cohort, PCS; N=27140 | % E of total protein intake in women; Foods/Food groups: NR by quintile of protein intake; alcohol and fiber intake varied by quintiles at baseline | Q2 | 46.9 | 38.4 | 14.7 | ᴓ T2D at 12y f/u; ↑ T2D per-5% substitution of carbohydrate with protein
Ericson, 2013 ^57^; Sweden; Malmö Diet and Cancer cohort, PCS; N=27140 | % E of total protein intake in women; Foods/Food groups: NR by quintile of protein intake; alcohol and fiber intake varied by quintiles at baseline | Q3 | 46.2 | 37.8 | 16.0 | ᴓ T2D at 12y f/u; ↑ T2D per-5% substitution of carbohydrate with protein
Ericson, 2013 ^57^; Sweden; Malmö Diet and Cancer cohort, PCS; N=27140 | % E of total protein intake in women; Foods/Food groups: NR by quintile of protein intake; alcohol and fiber intake varied by quintiles at baseline | Q4 | 45.6 | 37.1 | 17.4 | ᴓ T2D at 12y f/u; ↑ T2D per-5% substitution of carbohydrate with protein
Ericson, 2013 ^57^; Sweden; Malmö Diet and Cancer cohort, PCS; N=27140 | % E of total protein intake in women; Foods/Food groups: NR by quintile of protein intake; alcohol and fiber intake varied by quintiles at baseline | Q5 | 44.2 | 35.8 | 20.0 | ᴓ T2D at 12y f/u; ↑ T2D per-5% substitution of carbohydrate with protein
Ericson, 2013 ^57^; Sweden; Malmö Diet and Cancer cohort, PCS; N=27140 | % E of total protein intake in men; Foods/Food groups: NR; alcohol and fiber intake varied by quintiles at baseline | Q1, ref | 46.5 | 41.0 | 12.5 | ᴓ T2D at 12y f/u; ↑ T2D per-5% substitution of carbohydrate with protein
Ericson, 2013 ^57^; Sweden; Malmö Diet and Cancer cohort, PCS; N=27140 | % E of total protein intake in men; Foods/Food groups: NR; alcohol and fiber intake varied by quintiles at baseline | Q2 | 45.9 | 39.7 | 14.3 | ᴓ T2D at 12y f/u; ↑ T2D per-5% substitution of carbohydrate with protein
Ericson, 2013 ^57^; Sweden; Malmö Diet and Cancer cohort, PCS; N=27140 | % E of total protein intake in men; Foods/Food groups: NR; alcohol and fiber intake varied by quintiles at baseline | Q3 | 45.7 | 38.8 | 15.6 | ᴓ T2D at 12y f/u; ↑ T2D per-5% substitution of carbohydrate with protein
Ericson, 2013 ^57^; Sweden; Malmö Diet and Cancer cohort, PCS; N=27140 | % E of total protein intake in men; Foods/Food groups: NR; alcohol and fiber intake varied by quintiles at baseline | Q4 | 44.9 | 38.3 | 16.9 | ᴓ T2D at 12y f/u; ↑ T2D per-5% substitution of carbohydrate with protein
Ericson, 2013 ^57^; Sweden; Malmö Diet and Cancer cohort, PCS; N=27140 | % E of total protein intake in men; Foods/Food groups: NR; alcohol and fiber intake varied by quintiles at baseline | Q5 | 43.4 | 37.1 | 19.5 | ᴓ T2D at 12y f/u; ↑ T2D per-5% substitution of carbohydrate with protein
Ericson, 2019 ^52^; Sweden; Malmö Diet and Cancer cohort, PCS; N=20487 | % E in 6 patterns identified by PCA in women and men; Health-conscious cluster in women; Foods/Food groups: characterized by high intakes of cottage cheese, fibre-rich bread, fruits, vegetables, breakfast cereals, fish and low-fat yoghurt, and by low intake of low-fibre bread, red and processed meat and SSB | Q1, ref | 44.9 | 40.2 | 14.9 | ↓ T2D after ~15y f/u, across quintiles and continuous | Did not account for: Race/ethnicity; [underlined: Funding:] Swedish Research Council, Region Skåne, Skåne University Hospital, Novo Nordic Foundation Albert Påhlsson Research Foundation
Ericson, 2019 ^52^; Sweden; Malmö Diet and Cancer cohort, PCS; N=20487 | | Q2 | 45.6 | 39.2 | 15.2 | ↓ T2D after ~15y f/u, across quintiles and continuous | Did not account for: Race/ethnicity; [underlined: Funding:] Swedish Research Council, Region Skåne, Skåne University Hospital, Novo Nordic Foundation Albert Påhlsson Research Foundation
Ericson, 2019 ^52^; Sweden; Malmö Diet and Cancer cohort, PCS; N=20487 | | Q3 | 45.8 | 38.8 | 14.4 | ↓ T2D after ~15y f/u, across quintiles and continuous | Did not account for: Race/ethnicity; [underlined: Funding:] Swedish Research Council, Region Skåne, Skåne University Hospital, Novo Nordic Foundation Albert Påhlsson Research Foundation
Ericson, 2019 ^52^; Sweden; Malmö Diet and Cancer cohort, PCS; N=20487 | | Q4 | 46.6 | 37.7 | 15.6 | ↓ T2D after ~15y f/u, across quintiles and continuous | Did not account for: Race/ethnicity; [underlined: Funding:] Swedish Research Council, Region Skåne, Skåne University Hospital, Novo Nordic Foundation Albert Påhlsson Research Foundation
Ericson, 2019 ^52^; Sweden; Malmö Diet and Cancer cohort, PCS; N=20487 | | Q5 | 47.7 | 36.1 | 16.2 | ↓ T2D after ~15y f/u, across quintiles and continuous | Did not account for: Race/ethnicity; [underlined: Funding:] Swedish Research Council, Region Skåne, Skåne University Hospital, Novo Nordic Foundation Albert Påhlsson Research Foundation
Ericson, 2019 ^52^; Sweden; Malmö Diet and Cancer cohort, PCS; N=20487 | Low-fat products cluster in women; Foods/Food groups: characterized by high intakes of low-fat margarines, low-fat milk and low-fat yoghurt, but by low intake of butter | Q1, ref | 43.3 | 42.3 | 14.4 | ᴓ T2D after ~15y f/u, across quintiles or continuous | Did not account for: Race/ethnicity; [underlined: Funding:] Swedish Research Council, Region Skåne, Skåne University Hospital, Novo Nordic Foundation Albert Påhlsson Research Foundation
Ericson, 2019 ^52^; Sweden; Malmö Diet and Cancer cohort, PCS; N=20487 | Low-fat products cluster in women; Foods/Food groups: characterized by high intakes of low-fat margarines, low-fat milk and low-fat yoghurt, but by low intake of butter | Q2 | 45.3 | 39.4 | 15.3 | ᴓ T2D after ~15y f/u, across quintiles or continuous | Did not account for: Race/ethnicity; [underlined: Funding:] Swedish Research Council, Region Skåne, Skåne University Hospital, Novo Nordic Foundation Albert Påhlsson Research Foundation
Ericson, 2019 ^52^; Sweden; Malmö Diet and Cancer cohort, PCS; N=20487 | Low-fat products cluster in women; Foods/Food groups: characterized by high intakes of low-fat margarines, low-fat milk and low-fat yoghurt, but by low intake of butter | Q3 | 46.6 | 37.8 | 15.6 | ᴓ T2D after ~15y f/u, across quintiles or continuous | Did not account for: Race/ethnicity; [underlined: Funding:] Swedish Research Council, Region Skåne, Skåne University Hospital, Novo Nordic Foundation Albert Påhlsson Research Foundation
Ericson, 2019 ^52^; Sweden; Malmö Diet and Cancer cohort, PCS; N=20487 | Low-fat products cluster in women; Foods/Food groups: characterized by high intakes of low-fat margarines, low-fat milk and low-fat yoghurt, but by low intake of butter | Q4 | 47.1 | 37.1 | 15.8 | ᴓ T2D after ~15y f/u, across quintiles or continuous | Did not account for: Race/ethnicity; [underlined: Funding:] Swedish Research Council, Region Skåne, Skåne University Hospital, Novo Nordic Foundation Albert Påhlsson Research Foundation
Ericson, 2019 ^52^; Sweden; Malmö Diet and Cancer cohort, PCS; N=20487 | Low-fat products cluster in women; Foods/Food groups: characterized by high intakes of low-fat margarines, low-fat milk and low-fat yoghurt, but by low intake of butter | Q5 | 48.3 | 35.4 | 16.2 | ᴓ T2D after ~15y f/u, across quintiles or continuous | Did not account for: Race/ethnicity; [underlined: Funding:] Swedish Research Council, Region Skåne, Skåne University Hospital, Novo Nordic Foundation Albert Påhlsson Research Foundation
Ericson, 2019 ^52^; Sweden; Malmö Diet and Cancer cohort, PCS; N=20487 | Dressing/vegetables cluster in women; Foods/Food groups: characterized by high intake of dressing/oils, vegetables, poultry, salty snacks, rice/pasta, fried potatoes and cheese, but by low intake of boiled potatoes and jam/sugar | Q1, ref | 47.4 | 37.4 | 15.2 | ᴓ T2D after ~15y f/u, across quintiles or continuous | Did not account for: Race/ethnicity; [underlined: Funding:] Swedish Research Council, Region Skåne, Skåne University Hospital, Novo Nordic Foundation Albert Påhlsson Research Foundation
Ericson, 2019 ^52^; Sweden; Malmö Diet and Cancer cohort, PCS; N=20487 | | Q2 | 46.8 | 37.9 | 15.2 | ᴓ T2D after ~15y f/u, across quintiles or continuous | Did not account for: Race/ethnicity; [underlined: Funding:] Swedish Research Council, Region Skåne, Skåne University Hospital, Novo Nordic Foundation Albert Påhlsson Research Foundation
Ericson, 2019 ^52^; Sweden; Malmö Diet and Cancer cohort, PCS; N=20487 | | Q3 | 46.1 | 38.5 | 15.4 | ᴓ T2D after ~15y f/u, across quintiles or continuous | Did not account for: Race/ethnicity; [underlined: Funding:] Swedish Research Council, Region Skåne, Skåne University Hospital, Novo Nordic Foundation Albert Påhlsson Research Foundation
Ericson, 2019 ^52^; Sweden; Malmö Diet and Cancer cohort, PCS; N=20487 | | Q4 | 45.3 | 39.1 | 15.6 | ᴓ T2D after ~15y f/u, across quintiles or continuous | Did not account for: Race/ethnicity; [underlined: Funding:] Swedish Research Council, Region Skåne, Skåne University Hospital, Novo Nordic Foundation Albert Påhlsson Research Foundation
Ericson, 2019 ^52^; Sweden; Malmö Diet and Cancer cohort, PCS; N=20487 | | Q5 | 44.9 | 39.1 | 16.0 | ᴓ T2D after ~15y f/u, across quintiles or continuous | Did not account for: Race/ethnicity; [underlined: Funding:] Swedish Research Council, Region Skåne, Skåne University Hospital, Novo Nordic Foundation Albert Påhlsson Research Foundation
Ericson, 2019 ^52^; Sweden; Malmö Diet and Cancer cohort, PCS; N=20487 | Health-conscious cluster of in men; Foods/Food groups: characterized by high intakes of cream, fibre-rich bread, fruits, vegetables, breakfast cereals, fish and low-fat yoghurt, and by low intake of low-fibre bread, red and processed meat and SSB | Q1, ref | 44.9 | 40.5 | 14.6 | ↓ T2D after ~15y f/u | Did not account for: Race/ethnicity; [underlined: Funding:] Swedish Research Council, Region Skåne, Skåne University Hospital, Novo Nordic Foundation Albert Påhlsson Research Foundation
Ericson, 2019 ^52^; Sweden; Malmö Diet and Cancer cohort, PCS; N=20487 | | Q2 | 44.5 | 40.7 | 14.8 | ↓ T2D after ~15y f/u | Did not account for: Race/ethnicity; [underlined: Funding:] Swedish Research Council, Region Skåne, Skåne University Hospital, Novo Nordic Foundation Albert Påhlsson Research Foundation
Ericson, 2019 ^52^; Sweden; Malmö Diet and Cancer cohort, PCS; N=20487 | | Q3 | 45.0 | 40.1 | 14.9 | ↓ T2D after ~15y f/u | Did not account for: Race/ethnicity; [underlined: Funding:] Swedish Research Council, Region Skåne, Skåne University Hospital, Novo Nordic Foundation Albert Påhlsson Research Foundation
Ericson, 2019 ^52^; Sweden; Malmö Diet and Cancer cohort, PCS; N=20487 | | Q4 | 45.4 | 39.4 | 15.2 | ↓ T2D after ~15y f/u | Did not account for: Race/ethnicity; [underlined: Funding:] Swedish Research Council, Region Skåne, Skåne University Hospital, Novo Nordic Foundation Albert Påhlsson Research Foundation
Ericson, 2019 ^52^; Sweden; Malmö Diet and Cancer cohort, PCS; N=20487 | | Q5 | 46.2 | 38.0 | 15.7 | ↓ T2D after ~15y f/u | Did not account for: Race/ethnicity; [underlined: Funding:] Swedish Research Council, Region Skåne, Skåne University Hospital, Novo Nordic Foundation Albert Påhlsson Research Foundation
Ericson, 2019 ^52^; Sweden; Malmö Diet and Cancer cohort, PCS; N=20487 | Low-fat products cluster in men; Foods/Food groups: characterized by high intakes of low-fat margarines, low-fat milk and low-fat yoghurt, but by low intake of butter | Q1, ref | 42.2 | 43.8 | 14.0 | ᴓ T2D after ~15y f/u, across quintiles or | Did not account for: Race/ethnicity; [underlined: Funding:] Swedish Research Council, Region Skåne, Skåne University Hospital, Novo Nordic Foundation Albert Påhlsson Research Foundation
Ericson, 2019 ^52^; Sweden; Malmö Diet and Cancer cohort, PCS; N=20487 | Low-fat products cluster in men; Foods/Food groups: characterized by high intakes of low-fat margarines, low-fat milk and low-fat yoghurt, but by low intake of butter | Q2 | 44.2 | 41.0 | 14.8 | ᴓ T2D after ~15y f/u, across quintiles or | Did not account for: Race/ethnicity; [underlined: Funding:] Swedish Research Council, Region Skåne, Skåne University Hospital, Novo Nordic Foundation Albert Påhlsson Research Foundation
Ericson, 2019 ^52^; Sweden; Malmö Diet and Cancer cohort, PCS; N=20487 | Low-fat products cluster in men; Foods/Food groups: characterized by high intakes of low-fat margarines, low-fat milk and low-fat yoghurt, but by low intake of butter | Q3 | 45.7 | 39.1 | 15.2 | ᴓ T2D after ~15y f/u, across quintiles or | Did not account for: Race/ethnicity; [underlined: Funding:] Swedish Research Council, Region Skåne, Skåne University Hospital, Novo Nordic Foundation Albert Påhlsson Research Foundation
Ericson, 2019 ^52^; Sweden; Malmö Diet and Cancer cohort, PCS; N=20487 | Low-fat products cluster in men; Foods/Food groups: characterized by high intakes of low-fat margarines, low-fat milk and low-fat yoghurt, but by low intake of butter | Q4 | 46.3 | 38.3 | 15.3 | ᴓ T2D after ~15y f/u, across quintiles or | Did not account for: Race/ethnicity; [underlined: Funding:] Swedish Research Council, Region Skåne, Skåne University Hospital, Novo Nordic Foundation Albert Påhlsson Research Foundation
Ericson, 2019 ^52^; Sweden; Malmö Diet and Cancer cohort, PCS; N=20487 | Low-fat products cluster in men; Foods/Food groups: characterized by high intakes of low-fat margarines, low-fat milk and low-fat yoghurt, but by low intake of butter | Q5 | 47.6 | 36.6 | 15.8 | ᴓ T2D after ~15y f/u, across quintiles or | Did not account for: Race/ethnicity; [underlined: Funding:] Swedish Research Council, Region Skåne, Skåne University Hospital, Novo Nordic Foundation Albert Påhlsson Research Foundation
Ericson, 2019 ^52^; Sweden; Malmö Diet and Cancer cohort, PCS; N=20487 | Dressing/vegetables cluster in men; Foods/Food groups: characterized by high intake of dressing/oils, vegetables, poultry, salty snacks, rice/pasta, fried potatoes and cheese, but by low intake of boiled potatoes and jam/sugar | Q1, ref | 46.6 | 38.9 | 14.5 | ᴓ T2D after ~15y f/u, across quinitles or continuous | Did not account for: Race/ethnicity; [underlined: Funding:] Swedish Research Council, Region Skåne, Skåne University Hospital, Novo Nordic Foundation Albert Påhlsson Research Foundation
Ericson, 2019 ^52^; Sweden; Malmö Diet and Cancer cohort, PCS; N=20487 | | Q2 | 45.7 | 39.5 | 14.8 | ᴓ T2D after ~15y f/u, across quinitles or continuous | Did not account for: Race/ethnicity; [underlined: Funding:] Swedish Research Council, Region Skåne, Skåne University Hospital, Novo Nordic Foundation Albert Påhlsson Research Foundation
Ericson, 2019 ^52^; Sweden; Malmö Diet and Cancer cohort, PCS; N=20487 | | Q3 | 45.0 | 39.9 | 15.1 | ᴓ T2D after ~15y f/u, across quinitles or continuous | Did not account for: Race/ethnicity; [underlined: Funding:] Swedish Research Council, Region Skåne, Skåne University Hospital, Novo Nordic Foundation Albert Påhlsson Research Foundation
Ericson, 2019 ^52^; Sweden; Malmö Diet and Cancer cohort, PCS; N=20487 | | Q4 | 44.6 | 40.2 | 15.2 | ᴓ T2D after ~15y f/u, across quinitles or continuous | Did not account for: Race/ethnicity; [underlined: Funding:] Swedish Research Council, Region Skåne, Skåne University Hospital, Novo Nordic Foundation Albert Påhlsson Research Foundation
Ericson, 2019 ^52^; Sweden; Malmö Diet and Cancer cohort, PCS; N=20487 | | Q5 | 44.1 | 40.3 | 15.6 | ᴓ T2D after ~15y f/u, across quinitles or continuous | Did not account for: Race/ethnicity; [underlined: Funding:] Swedish Research Council, Region Skåne, Skåne University Hospital, Novo Nordic Foundation Albert Påhlsson Research Foundation
Guasch-Ferre, 2017 ^58^; Spain; PREDIMED, PCS; N=3349; Exclusively high-CVD-risk sample | % E of total fat intake, additional analyses by animal-fat and vegetable-fat; Foods/Food groups: NR by quartiles of total dietary fat | Q1, ref | 50.2 | 30.0 | 16.6 | ↑ T2D after ~4y f/u; ᴓ T2D based on annually updated total fat; ᴓ T2D after ~4y f/u for animal fat; ↑ risk of T2D after ~4y f/u for vegetable fat | Did not account for: Race/ethnicity (all Spanish); [underlined: Funding:] Carlos III Health Institute; National Center of CVD Research^xii^
Guasch-Ferre, 2017 ^58^; Spain; PREDIMED, PCS; N=3349; Exclusively high-CVD-risk sample | % E of total fat intake, additional analyses by animal-fat and vegetable-fat; Foods/Food groups: NR by quartiles of total dietary fat | Q4 | 35.8 | 46.3 | 16.0 | ↑ T2D after ~4y f/u; ᴓ T2D based on annually updated total fat; ᴓ T2D after ~4y f/u for animal fat; ↑ risk of T2D after ~4y f/u for vegetable fat | Did not account for: Race/ethnicity (all Spanish); [underlined: Funding:] Carlos III Health Institute; National Center of CVD Research^xii^
Ha, 2019 ^59^; Korea; Korean Genome and Epidemiology Study, PCS; N=5595 | % E of total fat in women; Foods/Food groups: Intakes of vitamins and minerals varied by quartiles | Q1 | 80.5 | 8.1 | 11.4 | ↑ T2D after ~12y f/u | Did not account for: NA; [underlined: Funding:] National Research Foundation of Korea; Korean Government
Ha, 2019 ^59^; Korea; Korean Genome and Epidemiology Study, PCS; N=5595 | % E of total fat in women; Foods/Food groups: Intakes of vitamins and minerals varied by quartiles | Q4, ref. | 65.9 | 19.0 | 15.1 | ↑ T2D after ~12y f/u | Did not account for: NA; [underlined: Funding:] National Research Foundation of Korea; Korean Government
Ha, 2019 ^59^; Korea; Korean Genome and Epidemiology Study, PCS; N=5595 | % E of total fat in men; Foods/Food groups: Intakes of vitamins and minerals varied by quartiles | Q1 | 78.3 | 9.9 | 11.8 | ↑ T2D after ~12y f/u | Did not account for: NA; [underlined: Funding:] National Research Foundation of Korea; Korean Government
Ha, 2019 ^59^; Korea; Korean Genome and Epidemiology Study, PCS; N=5595 | % E of total fat in men; Foods/Food groups: Intakes of vitamins and minerals varied by quartiles | Q4, ref. | 64.2 | 20.6 | 15.2 | ↑ T2D after ~12y f/u | Did not account for: NA; [underlined: Funding:] National Research Foundation of Korea; Korean Government
Halton, 2008 ^60^; United States; Nurses’ Health Study, PCS; N=85059; 100% female; Excluded those with history of diabetes, cancer, CVD, missing diet data, implausible energy intake | % E by adherence to the “low-carbohydrate” diet (LCD) score; Foods/Food groups: Higher LCD scores related to lower cereal fiber, refined grain, and fruit and vegetable intakes; and higher red meat, animal fat, and saturated fat intakes | Decile 1, ref | 54.7 | 28.3 | 14.7 | ᴓ T2D after 20y f/u | Did not account for: Race/ethnicity; [underlined: Funding:] NIH
Halton, 2008 ^60^; United States; Nurses’ Health Study, PCS; N=85059; 100% female; Excluded those with history of diabetes, cancer, CVD, missing diet data, implausible energy intake | | Decile 5 | 43.4 | 35.2 | 17.8 | ᴓ T2D after 20y f/u | Did not account for: Race/ethnicity; [underlined: Funding:] NIH
Halton, 2008 ^60^; United States; Nurses’ Health Study, PCS; N=85059; 100% female; Excluded those with history of diabetes, cancer, CVD, missing diet data, implausible energy intake | | Decile 10 | 29.6 | 46.1 | 21.9 | ᴓ T2D after 20y f/u | Did not account for: Race/ethnicity; [underlined: Funding:] NIH
Halton, 2008 ^60^; United States; Nurses’ Health Study, PCS; N=85059; 100% female; Excluded those with history of diabetes, cancer, CVD, missing diet data, implausible energy intake | Animal LCD score | Decile 1, ref | 55.3 | 28.9 | 14.2 | ᴓ T2D after 20y f/u | Did not account for: Race/ethnicity; [underlined: Funding:] NIH
Halton, 2008 ^60^; United States; Nurses’ Health Study, PCS; N=85059; 100% female; Excluded those with history of diabetes, cancer, CVD, missing diet data, implausible energy intake | Animal LCD score | Decile 5 | 44.8 | 34.6 | 17.3 | ᴓ T2D after 20y f/u | Did not account for: Race/ethnicity; [underlined: Funding:] NIH
Halton, 2008 ^60^; United States; Nurses’ Health Study, PCS; N=85059; 100% female; Excluded those with history of diabetes, cancer, CVD, missing diet data, implausible energy intake | Animal LCD score | Decile 10 | 30.2 | 44.9 | 21.9 | ᴓ T2D after 20y f/u | Did not account for: Race/ethnicity; [underlined: Funding:] NIH
Halton, 2008 ^60^; United States; Nurses’ Health Study, PCS; N=85059; 100% female; Excluded those with history of diabetes, cancer, CVD, missing diet data, implausible energy intake | Vegetable LCD score | Decile 1, ref | 46.5 | 32.9 | 18.4 | ↓ T2D after 20y f/u | Did not account for: Race/ethnicity; [underlined: Funding:] NIH
Halton, 2008 ^60^; United States; Nurses’ Health Study, PCS; N=85059; 100% female; Excluded those with history of diabetes, cancer, CVD, missing diet data, implausible energy intake | Vegetable LCD score | Decile 5 | 37.7 | 39.9 | 19.2 | ↓ T2D after 20y f/u | Did not account for: Race/ethnicity; [underlined: Funding:] NIH
Halton, 2008 ^60^; United States; Nurses’ Health Study, PCS; N=85059; 100% female; Excluded those with history of diabetes, cancer, CVD, missing diet data, implausible energy intake | Vegetable LCD score | Decile 10 | 36.5 | 42.4 | 18.4 | ↓ T2D after 20y f/u | Did not account for: Race/ethnicity; [underlined: Funding:] NIH
Inter Act Consortium, 2014 ^53^; Europe - Multi-country; EPIC-InterAct, PCS; N=12595; Excluded those with prevalent diabetes and uncertain diabetes status. Only the subcohort included | aHEI score, examined between extreme quintiles; Foods/Food groups: Vegetables, fruits, nuts, ratio of white meat to red meat, cereal fiber, ratio of PUFA to SFA, alcohol | Q1, ref | 40.1 | 35.6 | 16.2 | ᴓ T2D | Did not account for: Race/ethnicity (but is adjusted for study centre which are varying countries), alcohol; [underlined: Funding:]; European Union FP6 programme
Inter Act Consortium, 2014 ^53^; Europe - Multi-country; EPIC-InterAct, PCS; N=12595; Excluded those with prevalent diabetes and uncertain diabetes status. Only the subcohort included | aHEI score, examined between extreme quintiles; Foods/Food groups: Vegetables, fruits, nuts, ratio of white meat to red meat, cereal fiber, ratio of PUFA to SFA, alcohol | Q5 | 45.0 | 34.0 | 17.8 | ᴓ T2D | Did not account for: Race/ethnicity (but is adjusted for study centre which are varying countries), alcohol; [underlined: Funding:]; European Union FP6 programme
Inter Act Consortium, 2014 ^53^; Europe - Multi-country; EPIC-InterAct, PCS; N=12595; Excluded those with prevalent diabetes and uncertain diabetes status. Only the subcohort included | DASH score, examined between extreme quintiles; Foods/Food groups: Grains (total grains, fiber content of grains), vegetables, fruits, dairy (total and fat content), meat/poultry/fish, nuts/seeds/legumes, fats and oils, sweets | Q1, ref | 41.7 | 37.7 | 15.3 | ᴓ T2D | Did not account for: Race/ethnicity (but is adjusted for study centre which are varying countries), alcohol; [underlined: Funding:]; European Union FP6 programme
Inter Act Consortium, 2014 ^53^; Europe - Multi-country; EPIC-InterAct, PCS; N=12595; Excluded those with prevalent diabetes and uncertain diabetes status. Only the subcohort included | | Q5 | 45.5 | 32.3 | 17.9 | ᴓ T2D | Did not account for: Race/ethnicity (but is adjusted for study centre which are varying countries), alcohol; [underlined: Funding:]; European Union FP6 programme
Inter Act Consortium, 2014 ^53^; Europe - Multi-country; EPIC-InterAct, PCS; N=12595; Excluded those with prevalent diabetes and uncertain diabetes status. Only the subcohort included | RRR 1 score, examined continuous per-SD and between extreme quintiles; Foods/Food groups: Positive scoring for wine, coffee, cabbages, and root vegetables; negative scoring for sugar-sweetened beverages, refined grains, processed meat, and diet soft drinks | Q1, ref | 43.3 | 36.1 | 17.9 | ↓ T2D, continuous or Q5 vs. Q1, ref. | Did not account for: Race/ethnicity (but is adjusted for study centre which are varying countries), alcohol; [underlined: Funding:]; European Union FP6 programme
Inter Act Consortium, 2014 ^53^; Europe - Multi-country; EPIC-InterAct, PCS; N=12595; Excluded those with prevalent diabetes and uncertain diabetes status. Only the subcohort included | | Q5 | 43.4 | 33.2 | 17.0 | ↓ T2D, continuous or Q5 vs. Q1, ref. | Did not account for: Race/ethnicity (but is adjusted for study centre which are varying countries), alcohol; [underlined: Funding:]; European Union FP6 programme
Inter Act Consortium, 2014 ^53^; Europe - Multi-country; EPIC-InterAct, PCS; N=12595; Excluded those with prevalent diabetes and uncertain diabetes status. Only the subcohort included | RRR 2 score, examined continuous per-SD and between extreme quintiles; Foods/Food groups: Positive scoring for fruits; negative scoring for red meat, beer, poultry, legumes, sugar-sweetened soft drinks, processed meat, and white bread | Q1, ref. | 39.5 | 35.3 | 17.9 | ᴓ T2D, continuous;; ↓ T2D Q5 vs. Q1, ref. | Did not account for: Race/ethnicity (but is adjusted for study centre which are varying countries), alcohol; [underlined: Funding:]; European Union FP6 programme
Inter Act Consortium, 2014 ^53^; Europe - Multi-country; EPIC-InterAct, PCS; N=12595; Excluded those with prevalent diabetes and uncertain diabetes status. Only the subcohort included | | Q5 | 47.5 | 33.3 | 16.0 | ᴓ T2D, continuous;; ↓ T2D Q5 vs. Q1, ref. | Did not account for: Race/ethnicity (but is adjusted for study centre which are varying countries), alcohol; [underlined: Funding:]; European Union FP6 programme
Inter Act Consortium, 2014 ^53^; Europe - Multi-country; EPIC-InterAct, PCS; N=12595; Excluded those with prevalent diabetes and uncertain diabetes status. Only the subcohort included | RRR 3 score, examined continuous per-SD and between extreme quintiles; Foods/Food groups: Positive scoring for breakfast cereals, honey, jam, sugar, dressings, and non-white bread; negative scoring for diet soft drinks, sugar-sweetened soft drinks, processed meat, salty biscuits and crackers and white bread | Q1, ref. | 41.6 | 35.8 | 17.7 | ↓ T2D, continuous or Q5 vs. Q1, ref. | Did not account for: Race/ethnicity (but is adjusted for study centre which are varying countries), alcohol; [underlined: Funding:]; European Union FP6 programme
Inter Act Consortium, 2014 ^53^; Europe - Multi-country; EPIC-InterAct, PCS; N=12595; Excluded those with prevalent diabetes and uncertain diabetes status. Only the subcohort included | | Q5 | 46.1 | 33.5 | 16.3 | ↓ T2D, continuous or Q5 vs. Q1, ref. | Did not account for: Race/ethnicity (but is adjusted for study centre which are varying countries), alcohol; [underlined: Funding:]; European Union FP6 programme
Kahleova, 2018 ^61^; United States; RCT; N=75 (4% attrition), all overweight or obese; Excluded those with history of diabetes, smoking, alcohol/ drug abuse, pregnancy/ lactation, or current use of vegan diet | Intervention: low-fat vegan diet for 16wk consisting of vegetables, grains, legumes, and fruits, and avoid animal products and added fats; plus vitamin B12 supplements provided (500g/day); Control: No diet changes | Intervention | 69.6 | 17.5 | 12.3 | ᴓ HbA1c between groups after 16wk | Adherence not fully described; [underlined: Funding:]; Physicians Committee for Responsible Medicine
| | Control | 46.6 | 35.0 | 17.0 | ᴓ HbA1c between groups after 16wk | Adherence not fully described; [underlined: Funding:]; Physicians Committee for Responsible Medicine
Malik, 2016 ^62^; United States; Nurses Health Study I and II (NHS); Health Professionals Follow-up Study (HPFS), PCS; N=72992 (NHS I); N=92088 (NHS II); N=40722 (HPFS); Excluded those with diabetes, CVD or cancer at baseline | % E of total protein intake, NHS I distribution, women; Foods/Food groups: Whole grains, fruit, vegetables, red meat, processed meat, fish, chicken, eggs, dairy foods, legumes, nuts, peanuts, peanut butter, potatoes, coffee, SSB | Q1, ref | 51.3 | 33.0 | 14.8 | ᴓ T2D risk for total protein, animal protein, or plant protein | Did not account for: N/A; [underlined: Funding:]; NIH
| | Q3 | 46.4 | 35.1 | 18.0 | ᴓ T2D risk for total protein, animal protein, or plant protein | Did not account for: N/A; [underlined: Funding:]; NIH
| | Q5 | 41.8 | 35.1 | 21.6 | ᴓ T2D risk for total protein, animal protein, or plant protein | Did not account for: N/A; [underlined: Funding:]; NIH
| % E of total protein intake, NHS II distribution, women; Foods/Food groups: Same as above | Q1, ref | 55.8 | 30.4 | 15.3 | ᴓ T2D risk for total protein, animal protein, or plant protien | Did not account for: N/A; [underlined: Funding:]; NIH
| % E of total protein intake, NHS II distribution, women; Foods/Food groups: Same as above | Q3 | 49.4 | 32.1 | 18.8 | ᴓ T2D risk for total protein, animal protein, or plant protien | Did not account for: N/A; [underlined: Funding:]; NIH
| % E of total protein intake, NHS II distribution, women; Foods/Food groups: Same as above | Q5 | 44.6 | 31.5 | 22.6 | ᴓ T2D risk for total protein, animal protein, or plant protien | Did not account for: N/A; [underlined: Funding:]; NIH
| % E of total protein intake, HPFS distribution, men; Foods/Food groups: Same as above | Q1, ref | 50.9 | 30.7 | 14.7 | ↑ T2D for total protein; ↑ T2D for animal protein; ᴓ T2D for plant protien | Did not account for: N/A; [underlined: Funding:]; NIH
| % E of total protein intake, HPFS distribution, men; Foods/Food groups: Same as above | Q3 | 46.9 | 32.5 | 18.0 | ↑ T2D for total protein; ↑ T2D for animal protein; ᴓ T2D for plant protien | Did not account for: N/A; [underlined: Funding:]; NIH
| % E of total protein intake, HPFS distribution, men; Foods/Food groups: Same as above | Q5 | 42.7 | 32.4 | 21.9 | ↑ T2D for total protein; ↑ T2D for animal protein; ᴓ T2D for plant protien | Did not account for: N/A; [underlined: Funding:]; NIH
Nanri, 2015 ^63^; Japan; Japan Public Health Center (JPHC) study, PCS; N=64674; Excluded those with a hx of T2D, or severe disease | % E by quintile of “low-carbohydrate” diet scores; “Low-carbohydrate, high-protein and fat” score, men; Foods/Food groups: NR by quintile | Q1, ref | 64.7 | 15.8 | 11.3 | ᴓ T2D over 5y f/u | Did not account for: Race/ethnicity; [underlined: Funding:]; National Cancer Center Research and Development Fund; Ministry of Health, Labour and Welfare of Japan
Nanri, 2015 ^63^; Japan; Japan Public Health Center (JPHC) study, PCS; N=64674; Excluded those with a hx of T2D, or severe disease | % E by quintile of “low-carbohydrate” diet scores; “Low-carbohydrate, high-protein and fat” score, men; Foods/Food groups: NR by quintile | Q3 | 51.6 | 22.6 | 13.2 | ᴓ T2D over 5y f/u | Did not account for: Race/ethnicity; [underlined: Funding:]; National Cancer Center Research and Development Fund; Ministry of Health, Labour and Welfare of Japan
Nanri, 2015 ^63^; Japan; Japan Public Health Center (JPHC) study, PCS; N=64674; Excluded those with a hx of T2D, or severe disease | % E by quintile of “low-carbohydrate” diet scores; “Low-carbohydrate, high-protein and fat” score, men; Foods/Food groups: NR by quintile | Q5 | 43.7 | 32.5 | 16.6 | ᴓ T2D over 5y f/u | Did not account for: Race/ethnicity; [underlined: Funding:]; National Cancer Center Research and Development Fund; Ministry of Health, Labour and Welfare of Japan
Nanri, 2015 ^63^; Japan; Japan Public Health Center (JPHC) study, PCS; N=64674; Excluded those with a hx of T2D, or severe disease | “Low-carbohydrate, high animal-protein and fat” score, men | Q1, ref | 65.0 | 16.1 | 11.5 | ᴓ T2D over 5y f/u | Did not account for: Race/ethnicity; [underlined: Funding:]; National Cancer Center Research and Development Fund; Ministry of Health, Labour and Welfare of Japan
Nanri, 2015 ^63^; Japan; Japan Public Health Center (JPHC) study, PCS; N=64674; Excluded those with a hx of T2D, or severe disease | “Low-carbohydrate, high animal-protein and fat” score, men | Q3 | 52.1 | 22.3 | 13.2 | ᴓ T2D over 5y f/u | Did not account for: Race/ethnicity; [underlined: Funding:]; National Cancer Center Research and Development Fund; Ministry of Health, Labour and Welfare of Japan
Nanri, 2015 ^63^; Japan; Japan Public Health Center (JPHC) study, PCS; N=64674; Excluded those with a hx of T2D, or severe disease | “Low-carbohydrate, high animal-protein and fat” score, men | Q5 | 42.7 | 32.2 | 16.3 | ᴓ T2D over 5y f/u | Did not account for: Race/ethnicity; [underlined: Funding:]; National Cancer Center Research and Development Fund; Ministry of Health, Labour and Welfare of Japan
Nanri, 2015 ^63^; Japan; Japan Public Health Center (JPHC) study, PCS; N=64674; Excluded those with a hx of T2D, or severe disease | “Low-carbohydrate, high plant-protein and fat” score, men | Q1, ref | 59.7 | 18 | 11.9 | ᴓ T2D over 5y f/u | Did not account for: Race/ethnicity; [underlined: Funding:]; National Cancer Center Research and Development Fund; Ministry of Health, Labour and Welfare of Japan
Nanri, 2015 ^63^; Japan; Japan Public Health Center (JPHC) study, PCS; N=64674; Excluded those with a hx of T2D, or severe disease | “Low-carbohydrate, high plant-protein and fat” score, men | Q3 | 51.7 | 23.3 | 13.7 | ᴓ T2D over 5y f/u | Did not account for: Race/ethnicity; [underlined: Funding:]; National Cancer Center Research and Development Fund; Ministry of Health, Labour and Welfare of Japan
Nanri, 2015 ^63^; Japan; Japan Public Health Center (JPHC) study, PCS; N=64674; Excluded those with a hx of T2D, or severe disease | “Low-carbohydrate, high plant-protein and fat” score, men | Q5 | 49.4 | 28.6 | 15.2 | ᴓ T2D over 5y f/u | Did not account for: Race/ethnicity; [underlined: Funding:]; National Cancer Center Research and Development Fund; Ministry of Health, Labour and Welfare of Japan
Nanri, 2015 ^63^; Japan; Japan Public Health Center (JPHC) study, PCS; N=64674; Excluded those with a hx of T2D, or severe disease | “Low-carbohydrate, high-protein and fat” score, women | Q1, ref | 67.2 | 18.7 | 12.4 | ↓ T2D over 5y f/u | Did not account for: Race/ethnicity; [underlined: Funding:]; National Cancer Center Research and Development Fund; Ministry of Health, Labour and Welfare of Japan
Nanri, 2015 ^63^; Japan; Japan Public Health Center (JPHC) study, PCS; N=64674; Excluded those with a hx of T2D, or severe disease | “Low-carbohydrate, high-protein and fat” score, women | Q3 | 55.7 | 27.7 | 15.1 | ↓ T2D over 5y f/u | Did not account for: Race/ethnicity; [underlined: Funding:]; National Cancer Center Research and Development Fund; Ministry of Health, Labour and Welfare of Japan
Nanri, 2015 ^63^; Japan; Japan Public Health Center (JPHC) study, PCS; N=64674; Excluded those with a hx of T2D, or severe disease | “Low-carbohydrate, high-protein and fat” score, women | Q5 | 44.9 | 35.9 | 17.7 | ↓ T2D over 5y f/u | Did not account for: Race/ethnicity; [underlined: Funding:]; National Cancer Center Research and Development Fund; Ministry of Health, Labour and Welfare of Japan
Nanri, 2015 ^63^; Japan; Japan Public Health Center (JPHC) study, PCS; N=64674; Excluded those with a hx of T2D, or severe disease | “Low-carbohydrate, high animal-protein and fat” score, women | Q1, ref | 67.1 | 19.0 | 12.5 | ↓ T2D over 5y f/u | Did not account for: Race/ethnicity; [underlined: Funding:]; National Cancer Center Research and Development Fund; Ministry of Health, Labour and Welfare of Japan
Nanri, 2015 ^63^; Japan; Japan Public Health Center (JPHC) study, PCS; N=64674; Excluded those with a hx of T2D, or severe disease | “Low-carbohydrate, high animal-protein and fat” score, women | Q3 | 55.9 | 27.4 | 15.0 | ↓ T2D over 5y f/u | Did not account for: Race/ethnicity; [underlined: Funding:]; National Cancer Center Research and Development Fund; Ministry of Health, Labour and Welfare of Japan
Nanri, 2015 ^63^; Japan; Japan Public Health Center (JPHC) study, PCS; N=64674; Excluded those with a hx of T2D, or severe disease | “Low-carbohydrate, high animal-protein and fat” score, women | Q5 | 44.8 | 35.9 | 17.4 | ↓ T2D over 5y f/u | Did not account for: Race/ethnicity; [underlined: Funding:]; National Cancer Center Research and Development Fund; Ministry of Health, Labour and Welfare of Japan
Nanri, 2015 ^63^; Japan; Japan Public Health Center (JPHC) study, PCS; N=64674; Excluded those with a hx of T2D, or severe disease | “Low-carbohydrate, high plant-protein and fat” score, women | Q1, ref | 61.6 | 22.3 | 13.6 | ᴓ T2D over 5y f/u | Did not account for: Race/ethnicity; [underlined: Funding:]; National Cancer Center Research and Development Fund; Ministry of Health, Labour and Welfare of Japan
Nanri, 2015 ^63^; Japan; Japan Public Health Center (JPHC) study, PCS; N=64674; Excluded those with a hx of T2D, or severe disease | “Low-carbohydrate, high plant-protein and fat” score, women | Q3 | 55.7 | 27.7 | 15.0 | ᴓ T2D over 5y f/u | Did not account for: Race/ethnicity; [underlined: Funding:]; National Cancer Center Research and Development Fund; Ministry of Health, Labour and Welfare of Japan
Nanri, 2015 ^63^; Japan; Japan Public Health Center (JPHC) study, PCS; N=64674; Excluded those with a hx of T2D, or severe disease | “Low-carbohydrate, high plant-protein and fat” score, women | Q5 | 51.0 | 31.7 | 16.4 | ᴓ T2D over 5y f/u | Did not account for: Race/ethnicity; [underlined: Funding:]; National Cancer Center Research and Development Fund; Ministry of Health, Labour and Welfare of Japan
Sakurai, 2016 ^64^; Japan, PCS; N=2006; 0% female (all men) | % E of carbohydrate categories in men; Foods/Food groups: NR | Q1 | <50.0 | 27.0 | 12.7 | ᴓ T2D after 10y; Sub-group analyses by BMI revealed ↑ T2D risk at 10y f/u in Q4 vs. Q2 (>65% carbohydrate vs. 50-57.4% carbohydrate) in obese participants | Did not account for: Race/ethnicity (all Japanese); [underlined: Funding:]; Ministry of Health, Labor and Welfare; Health and Labor Sciences, Japan; Ministry of Education, Culture, Sports, Science and Technology of Japan for Scientific Research and for Young Scientists; Kanazawa Medical University; Japan Arteriosclerosis Prevention Fund
Sakurai, 2016 ^64^; Japan, PCS; N=2006; 0% female (all men) | % E of carbohydrate categories in men; Foods/Food groups: NR | Q2, ref. | 50.0-57.4 | 24.3 | 12.4 | ᴓ T2D after 10y; Sub-group analyses by BMI revealed ↑ T2D risk at 10y f/u in Q4 vs. Q2 (>65% carbohydrate vs. 50-57.4% carbohydrate) in obese participants
Sakurai, 2016 ^64^; Japan, PCS; N=2006; 0% female (all men) | % E of carbohydrate categories in men; Foods/Food groups: NR | Q3 | 57.5-65.0 | 21.3 | 11.6 | ᴓ T2D after 10y; Sub-group analyses by BMI revealed ↑ T2D risk at 10y f/u in Q4 vs. Q2 (>65% carbohydrate vs. 50-57.4% carbohydrate) in obese participants
Sakurai, 2016 ^64^; Japan, PCS; N=2006; 0% female (all men) | % E of carbohydrate categories in men; Foods/Food groups: NR | Q4 | >65.0 | 15.7 | 10.2 | ᴓ T2D after 10y; Sub-group analyses by BMI revealed ↑ T2D risk at 10y f/u in Q4 vs. Q2 (>65% carbohydrate vs. 50-57.4% carbohydrate) in obese participants
Salas-Salvado, 2011 ^65^; Spain; PREDIMED, RCT; N=418; Population exclusively at high-risk for CVD; excluded those with severe chronic illness, alcohol or drug abuse, or BMI ≥40 | % E based diet groups: Mediterranean+EVOO (Med+EVOO), Med+Nuts, or Control; Med + EVOO: abundant olive oil, vegetables, fresh fruit and juices, legumes, fish or seafood, nuts and seeds, select white meat instead of red or processed meats, cook regularly with tomato, garlic and onion; wine preferred (if consuming alcohol); ad libitum nuts, eggs, fish, seafood, low-fat cheese, chocolate, whole-grain cereals + 15L EVOO | Med+EVOO | 41.0 | 41.0 | 16.0 | Med+EVOO vs. Control: ↓ T2D at 4y f/u; ↓ T2D in those >67 y, and those with fasting glucse >6.1 mmol/L; NSA when stratifying by sex, by BMI, in those 67 y or under and those with 6.1 mmol/L fasting glucose or less; Med+Nuts vs. Control: ↓ T2D at 4y f/u; ↓ T2D in females, and in those >67 y; NSA in males, 67 y or under, stratified by BMI or by fasting glucose | Did not account for: Race/ethnicity; [underlined: Funding:]; Spanish Ministry of Health (Instituto de Salud Carlos III); Fondo Europeo de Desarrollo Regional, and the Public Health Division of the Department of Health of the Autonomous Government of Catalonia
Salas-Salvado, 2011 ^65^; Spain; PREDIMED, RCT; N=418; Population exclusively at high-risk for CVD; excluded those with severe chronic illness, alcohol or drug abuse, or BMI ≥40 | Med + Nuts: abundant olive oil, vegetables, fresh fruit and juices, legumes, fish or seafood, nuts and seeds, select white meat instead of red or processed meats, cook regularly with tomato, garlic and onion; wine preferred (if consuming alcohol); ad libitum nuts, eggs, fish, seafood, low-fat cheese, chocolate, whole-grain cereals +15g/d walnuts, 7.5g/d almonds, and 7.5g/d hazelnuts | Med+Nuts | 40.0 | 41.0 | 16.0
Salas-Salvado, 2011 ^65^; Spain; PREDIMED, RCT; N=418; Population exclusively at high-risk for CVD; excluded those with severe chronic illness, alcohol or drug abuse, or BMI ≥40 | Control: advice to reduce dietary fat | Control diet | 41.0 | 40.0 | 16.0
Schulze, 2008 ^66^; Germany; EPIC-Potsdam, PCS; N=25067; Excluded those with diabetes | % E by quintiles of carbohydrate intake, in men; Foods/Food groups: NR | Q1, ref. | 30.2 | 45.8 | 14.6 | ᴓ T2D at ~10y f/u; ↓ T2D when carbohydrate increased 5% at the expense of protein; ᴓ T2D for exchanging carbohydrate for total fat, SFA, MUFA, or PUFA | Did not account for: Did not account for: Race/ethnicity; [underlined: Funding:]; Federal Ministry of Science, Germany; and the European Union; German Cancer Aid; and the European Community
Schulze, 2008 ^66^; Germany; EPIC-Potsdam, PCS; N=25067; Excluded those with diabetes | % E by quintiles of carbohydrate intake, in men; Foods/Food groups: NR | Q2 | 35.2 | 43.1 | 14.1 | ᴓ T2D at ~10y f/u; ↓ T2D when carbohydrate increased 5% at the expense of protein; ᴓ T2D for exchanging carbohydrate for total fat, SFA, MUFA, or PUFA | Did not account for: Did not account for: Race/ethnicity; [underlined: Funding:]; Federal Ministry of Science, Germany; and the European Union; German Cancer Aid; and the European Community
Schulze, 2008 ^66^; Germany; EPIC-Potsdam, PCS; N=25067; Excluded those with diabetes | % E by quintiles of carbohydrate intake, in men; Foods/Food groups: NR | Q3 | 38.4 | 41.6 | 13.8 | ᴓ T2D at ~10y f/u; ↓ T2D when carbohydrate increased 5% at the expense of protein; ᴓ T2D for exchanging carbohydrate for total fat, SFA, MUFA, or PUFA | Did not account for: Did not account for: Race/ethnicity; [underlined: Funding:]; Federal Ministry of Science, Germany; and the European Union; German Cancer Aid; and the European Community
Schulze, 2008 ^66^; Germany; EPIC-Potsdam, PCS; N=25067; Excluded those with diabetes | % E by quintiles of carbohydrate intake, in men; Foods/Food groups: NR | Q4 | 41.6 | 39.7 | 13.4 | ᴓ T2D at ~10y f/u; ↓ T2D when carbohydrate increased 5% at the expense of protein; ᴓ T2D for exchanging carbohydrate for total fat, SFA, MUFA, or PUFA | Did not account for: Did not account for: Race/ethnicity; [underlined: Funding:]; Federal Ministry of Science, Germany; and the European Union; German Cancer Aid; and the European Community
Schulze, 2008 ^66^; Germany; EPIC-Potsdam, PCS; N=25067; Excluded those with diabetes | % E by quintiles of carbohydrate intake, in men; Foods/Food groups: NR | Q5 | 47.3 | 35.4 | 13.2 | ᴓ T2D at ~10y f/u; ↓ T2D when carbohydrate increased 5% at the expense of protein; ᴓ T2D for exchanging carbohydrate for total fat, SFA, MUFA, or PUFA | Did not account for: Did not account for: Race/ethnicity; [underlined: Funding:]; Federal Ministry of Science, Germany; and the European Union; German Cancer Aid; and the European Community
Schulze, 2008 ^66^; Germany; EPIC-Potsdam, PCS; N=25067; Excluded those with diabetes | % E by quintiles of carbohydrate intake, in women; Foods/Food groups: NR | Q1, ref. | 36.0 | 42.9 | 14.8 | ᴓ T2D at ~10y f/u; ᴓ T2D for exchanging carbohydrate for protein, total fat, SFA, MUFA, or PUFA | Did not account for: Did not account for: Race/ethnicity; [underlined: Funding:]; Federal Ministry of Science, Germany; and the European Union; German Cancer Aid; and the European Community
Schulze, 2008 ^66^; Germany; EPIC-Potsdam, PCS; N=25067; Excluded those with diabetes | % E by quintiles of carbohydrate intake, in women; Foods/Food groups: NR | Q2 | 41.1 | 40.6 | 14.4 | ᴓ T2D at ~10y f/u; ᴓ T2D for exchanging carbohydrate for protein, total fat, SFA, MUFA, or PUFA | Did not account for: Did not account for: Race/ethnicity; [underlined: Funding:]; Federal Ministry of Science, Germany; and the European Union; German Cancer Aid; and the European Community
Schulze, 2008 ^66^; Germany; EPIC-Potsdam, PCS; N=25067; Excluded those with diabetes | % E by quintiles of carbohydrate intake, in women; Foods/Food groups: NR | Q3 | 44.1 | 38.7 | 14.0 | ᴓ T2D at ~10y f/u; ᴓ T2D for exchanging carbohydrate for protein, total fat, SFA, MUFA, or PUFA | Did not account for: Did not account for: Race/ethnicity; [underlined: Funding:]; Federal Ministry of Science, Germany; and the European Union; German Cancer Aid; and the European Community
Schulze, 2008 ^66^; Germany; EPIC-Potsdam, PCS; N=25067; Excluded those with diabetes | % E by quintiles of carbohydrate intake, in women; Foods/Food groups: NR | Q4 | 47.1 | 36.7 | 13.7 | ᴓ T2D at ~10y f/u; ᴓ T2D for exchanging carbohydrate for protein, total fat, SFA, MUFA, or PUFA | Did not account for: Did not account for: Race/ethnicity; [underlined: Funding:]; Federal Ministry of Science, Germany; and the European Union; German Cancer Aid; and the European Community
Schulze, 2008 ^66^; Germany; EPIC-Potsdam, PCS; N=25067; Excluded those with diabetes | % E by quintiles of carbohydrate intake, in women; Foods/Food groups: NR | Q5 | 52.3 | 32.6 | 13.1 | ᴓ T2D at ~10y f/u; ᴓ T2D for exchanging carbohydrate for protein, total fat, SFA, MUFA, or PUFA | Did not account for: Did not account for: Race/ethnicity; [underlined: Funding:]; Federal Ministry of Science, Germany; and the European Union; German Cancer Aid; and the European Community
Shan, 2018 ^67^; China; Harbin Cohort Study on Diet, Nutrition and Non-Communicable Diseases (Cohort 2), PCS; N=7111; Excluded those with T2D at baseline | % E of total population across tertiles (“Hi-carbohydrate”, Hi-C, “Mod-carbohydrate”, Mod-C, “Lo-carbohydrate”, Lo-C) of low-carbohydrate, high-fat, high-protein diet scores; Foods/Food groups: Rice, wheat, potato, bean, snack, beverage, ice cream, livestock, poultry, fish, dairy, egg, vegetable, fruit | Hi-C | 69.0 | 21.0 | 10.0 | ᴓ T2D at 5y f/u | Did not account for: Race/ethnicity; [underlined: Funding:]; National Natural Science Foundation of China
Shan, 2018 ^67^; China; Harbin Cohort Study on Diet, Nutrition and Non-Communicable Diseases (Cohort 2), PCS; N=7111; Excluded those with T2D at baseline | | Mod-C | 61.0 | 27.0 | 12.0 | ᴓ T2D at 5y f/u | Did not account for: Race/ethnicity; [underlined: Funding:]; National Natural Science Foundation of China
Shan, 2018 ^67^; China; Harbin Cohort Study on Diet, Nutrition and Non-Communicable Diseases (Cohort 2), PCS; N=7111; Excluded those with T2D at baseline | | Lo-C | 52.0 | 34.0 | 14.0 | ᴓ T2D at 5y f/u | Did not account for: Race/ethnicity; [underlined: Funding:]; National Natural Science Foundation of China
Shan, 2018 ^67^; China; Harbin Cohort Study on Diet, Nutrition and Non-Communicable Diseases (Cohort 2), PCS; N=7111; Excluded those with T2D at baseline | % E of population consuming extra calories across tertiles; Foods/Food groups: Same as above | Hi-C | 70.0 | 20.0 | 10.0 | ↑ T2D at 5y f/u | Did not account for: Race/ethnicity; [underlined: Funding:]; National Natural Science Foundation of China
Shan, 2018 ^67^; China; Harbin Cohort Study on Diet, Nutrition and Non-Communicable Diseases (Cohort 2), PCS; N=7111; Excluded those with T2D at baseline | % E of population consuming extra calories across tertiles; Foods/Food groups: Same as above | Mod-C | 63.0 | 25.0 | 12.0 | ↑ T2D at 5y f/u | Did not account for: Race/ethnicity; [underlined: Funding:]; National Natural Science Foundation of China
Shan, 2018 ^67^; China; Harbin Cohort Study on Diet, Nutrition and Non-Communicable Diseases (Cohort 2), PCS; N=7111; Excluded those with T2D at baseline | % E of population consuming extra calories across tertiles; Foods/Food groups: Same as above | Lo-C | 53.0 | 33.0 | 14.0 | ↑ T2D at 5y f/u | Did not account for: Race/ethnicity; [underlined: Funding:]; National Natural Science Foundation of China
Shan, 2018 ^67^; China; Harbin Cohort Study on Diet, Nutrition and Non-Communicable Diseases (Cohort 2), PCS; N=7111; Excluded those with T2D at baseline | % E of population with normal caloric intake across tertiles; Foods/Food groups: Same as above | Hi-C | 66.0 | 24.0 | 10.0 | ᴓ T2D at 4-5y f/u | Did not account for: Race/ethnicity; [underlined: Funding:]; National Natural Science Foundation of China
Shan, 2018 ^67^; China; Harbin Cohort Study on Diet, Nutrition and Non-Communicable Diseases (Cohort 2), PCS; N=7111; Excluded those with T2D at baseline | % E of population with normal caloric intake across tertiles; Foods/Food groups: Same as above | Mod-C | 59.0 | 30.0 | 11.0 | ᴓ T2D at 4-5y f/u | Did not account for: Race/ethnicity; [underlined: Funding:]; National Natural Science Foundation of China
Shan, 2018 ^67^; China; Harbin Cohort Study on Diet, Nutrition and Non-Communicable Diseases (Cohort 2), PCS; N=7111; Excluded those with T2D at baseline | % E of population with normal caloric intake across tertiles; Foods/Food groups: Same as above | Lo-C | 50.0 | 37.0 | 13.0 | ᴓ T2D at 4-5y f/u | Did not account for: Race/ethnicity; [underlined: Funding:]; National Natural Science Foundation of China
Shang, 2016 ^68^; Australia; Melbourne Collaborative Cohort Study, PCS; N=21523; Excluded those with CVD, cancer, kidney stones, or diabetes or high fasting glucose | % E of total protein, across three quintiles; Foods/Food groups: Grains, Vegetables, Fruit, Legumes and nuts, Dairy, Eggs, Unprocessed red meat, Processed red meat, Chicken, Fish | Q1, ref | 47.4 | 30.0 | 14.5 | ↑ T2D at 11y f/u | Did not account for: N/A; [underlined: Funding:]; VicHealth and Cancer Council Victoria and the Australian National Health and Medical Research Council
Shang, 2016 ^68^; Australia; Melbourne Collaborative Cohort Study, PCS; N=21523; Excluded those with CVD, cancer, kidney stones, or diabetes or high fasting glucose | % E of total protein, across three quintiles; Foods/Food groups: Grains, Vegetables, Fruit, Legumes and nuts, Dairy, Eggs, Unprocessed red meat, Processed red meat, Chicken, Fish | Q3 | 45.7 | 30.5 | 17.7 | ↑ T2D at 11y f/u | Did not account for: N/A; [underlined: Funding:]; VicHealth and Cancer Council Victoria and the Australian National Health and Medical Research Council
Shang, 2016 ^68^; Australia; Melbourne Collaborative Cohort Study, PCS; N=21523; Excluded those with CVD, cancer, kidney stones, or diabetes or high fasting glucose | % E of total protein, across three quintiles; Foods/Food groups: Grains, Vegetables, Fruit, Legumes and nuts, Dairy, Eggs, Unprocessed red meat, Processed red meat, Chicken, Fish | Q5 | 41.1 | 31.6 | 21.9 | ↑ T2D at 11y f/u | Did not account for: N/A; [underlined: Funding:]; VicHealth and Cancer Council Victoria and the Australian National Health and Medical Research Council
Shang, 2016 ^68^; Australia; Melbourne Collaborative Cohort Study, PCS; N=21523; Excluded those with CVD, cancer, kidney stones, or diabetes or high fasting glucose | % E of animal-protein, across three quintiles; Foods/Food groups: Same as above | Q1, ref | 49.1 | 28.8 | 15.2 | ↑ T2D at 11y f/u | Did not account for: N/A; [underlined: Funding:]; VicHealth and Cancer Council Victoria and the Australian National Health and Medical Research Council
Shang, 2016 ^68^; Australia; Melbourne Collaborative Cohort Study, PCS; N=21523; Excluded those with CVD, cancer, kidney stones, or diabetes or high fasting glucose | % E of animal-protein, across three quintiles; Foods/Food groups: Same as above | Q3 | 45.4 | 30.4 | 17.7 | ↑ T2D at 11y f/u | Did not account for: N/A; [underlined: Funding:]; VicHealth and Cancer Council Victoria and the Australian National Health and Medical Research Council
Shang, 2016 ^68^; Australia; Melbourne Collaborative Cohort Study, PCS; N=21523; Excluded those with CVD, cancer, kidney stones, or diabetes or high fasting glucose | % E of animal-protein, across three quintiles; Foods/Food groups: Same as above | Q5 | 40.1 | 32.6 | 21.4 | ↑ T2D at 11y f/u | Did not account for: N/A; [underlined: Funding:]; VicHealth and Cancer Council Victoria and the Australian National Health and Medical Research Council
Shang, 2016 ^68^; Australia; Melbourne Collaborative Cohort Study, PCS; N=21523; Excluded those with CVD, cancer, kidney stones, or diabetes or high fasting glucose | % E of plant-protein, across three quintiles; Foods/Food groups: Same as above | Q1, ref | 42.9 | 31.7 | 17.6 | ↑ T2D at 11y f/u4 | Did not account for: N/A; [underlined: Funding:]; VicHealth and Cancer Council Victoria and the Australian National Health and Medical Research Council
Shang, 2016 ^68^; Australia; Melbourne Collaborative Cohort Study, PCS; N=21523; Excluded those with CVD, cancer, kidney stones, or diabetes or high fasting glucose | % E of plant-protein, across three quintiles; Foods/Food groups: Same as above | Q3 | 44.4 | 31.3 | 17.9 | ↑ T2D at 11y f/u4 | Did not account for: N/A; [underlined: Funding:]; VicHealth and Cancer Council Victoria and the Australian National Health and Medical Research Council
Shang, 2016 ^68^; Australia; Melbourne Collaborative Cohort Study, PCS; N=21523; Excluded those with CVD, cancer, kidney stones, or diabetes or high fasting glucose | % E of plant-protein, across three quintiles; Foods/Food groups: Same as above | Q5 | 48.9 | 27.6 | 18.4 | ↑ T2D at 11y f/u4 | Did not account for: N/A; [underlined: Funding:]; VicHealth and Cancer Council Victoria and the Australian National Health and Medical Research Council
Simila, 2012 ^69^; Finland; Alpha-Tocopherol, Beta-Carotene Cancer Prevention (ATBC) Study, PCS; N=25943; 0% female (100% male smokers); Excluded those with diabetes | % E by quintile of carbohydrate in men; Foods/Food groups: Cereals, potatoes, milk, soft drinks, fruits and berries, vegetables and legumes | Q1, ref. | 33.4 | 44.8 | 14.4 | ↓ T2D at 12y f/u; ↓ T2D for 2 E% substitution replacing total fat with total carbohydrate; ↓ T2D risk for 2 E% substitution replacing total protein with total carbohydrate | Did not account for: Alcohol, Race/ethnicity; [underlined: Funding:]; National Cancer Institute; Academy of Finland; Doctoral Programs in Public Health, the Finnish Cultural Foundation, the Kyllikki and Uolevi Lehikoinen Foundation, and the Juho Vainio Foundation.
Simila, 2012 ^69^; Finland; Alpha-Tocopherol, Beta-Carotene Cancer Prevention (ATBC) Study, PCS; N=25943; 0% female (100% male smokers); Excluded those with diabetes | % E by quintile of carbohydrate in men; Foods/Food groups: Cereals, potatoes, milk, soft drinks, fruits and berries, vegetables and legumes | Q2 | 37.5 | 43.2 | 14.4 | ↓ T2D at 12y f/u; ↓ T2D for 2 E% substitution replacing total fat with total carbohydrate; ↓ T2D risk for 2 E% substitution replacing total protein with total carbohydrate
Simila, 2012 ^69^; Finland; Alpha-Tocopherol, Beta-Carotene Cancer Prevention (ATBC) Study, PCS; N=25943; 0% female (100% male smokers); Excluded those with diabetes | % E by quintile of carbohydrate in men; Foods/Food groups: Cereals, potatoes, milk, soft drinks, fruits and berries, vegetables and legumes | Q3 | 40.4 | 41.5 | 14.4 | ↓ T2D at 12y f/u; ↓ T2D for 2 E% substitution replacing total fat with total carbohydrate; ↓ T2D risk for 2 E% substitution replacing total protein with total carbohydrate
Simila, 2012 ^69^; Finland; Alpha-Tocopherol, Beta-Carotene Cancer Prevention (ATBC) Study, PCS; N=25943; 0% female (100% male smokers); Excluded those with diabetes | % E by quintile of carbohydrate in men; Foods/Food groups: Cereals, potatoes, milk, soft drinks, fruits and berries, vegetables and legumes | Q4 | 43.3 | 39.6 | 14.3 | ↓ T2D at 12y f/u; ↓ T2D for 2 E% substitution replacing total fat with total carbohydrate; ↓ T2D risk for 2 E% substitution replacing total protein with total carbohydrate
Simila, 2012 ^69^; Finland; Alpha-Tocopherol, Beta-Carotene Cancer Prevention (ATBC) Study, PCS; N=25943; 0% female (100% male smokers); Excluded those with diabetes | % E by quintile of carbohydrate in men; Foods/Food groups: Cereals, potatoes, milk, soft drinks, fruits and berries, vegetables and legumes | Q5 | 47.4 | 36.1 | 14.1 | ↓ T2D at 12y f/u; ↓ T2D for 2 E% substitution replacing total fat with total carbohydrate; ↓ T2D risk for 2 E% substitution replacing total protein with total carbohydrate
Sluijs, 2010 ^70^; Netherlands; European Prospective Investigation into Cancer and Nutrition(EPIC)-NL, PCS; N=38094 | % E of total protein intake, animal-protein, or vegetable-protein across quartiles, per-10g, and per 5% E substitution; Foods/food groups: NR | Q1, ref. | 45.5 | 33.5 | 12.2 | ↑ T2D at 10y f/u per-10g total protein, HR: 1.16, 95% CI: 1.06, 1.26, p<0.05; ᴓ across quartiles; ↑ T2D risk per-10g animal-protein, HR: 1.13, 95% CI: 1.04, 1.22, p<0.05; ᴓ across quartiles; ᴓ vegetable-protein, NS; ↑ T2D risk per-5% E substitution of protein for fat, HR: 1.31, 95% CI: 1.06, 1.61, p<0.05; ↑ T2D risk per-5% E substitution of protein for carbohydrate, HR: 1.28, 95% CI: 1.01, 1.61, p<0.05; ᴓ T2D risk per-5% E substitution of animal or veg protein for fat or carbohydrate | Did not account for: Race/ethnicity; [underlined: Funding:]; None reported
Sluijs, 2010 ^70^; Netherlands; European Prospective Investigation into Cancer and Nutrition(EPIC)-NL, PCS; N=38094 | % E of total protein intake, animal-protein, or vegetable-protein across quartiles, per-10g, and per 5% E substitution; Foods/food groups: NR | Q2 | 44.0 | 33.1 | 13.7 | | Did not account for: Race/ethnicity; [underlined: Funding:]; None reported
Sluijs, 2010 ^70^; Netherlands; European Prospective Investigation into Cancer and Nutrition(EPIC)-NL, PCS; N=38094 | % E of total protein intake, animal-protein, or vegetable-protein across quartiles, per-10g, and per 5% E substitution; Foods/food groups: NR | Q3 | 44.6 | 33.6 | 15.2 | | Did not account for: Race/ethnicity; [underlined: Funding:]; None reported
Sluijs, 2010 ^70^; Netherlands; European Prospective Investigation into Cancer and Nutrition(EPIC)-NL, PCS; N=38094 | % E of total protein intake, animal-protein, or vegetable-protein across quartiles, per-10g, and per 5% E substitution; Foods/food groups: NR | Q4 | 46.3 | 34.6 | 18.0 | | Did not account for: Race/ethnicity; [underlined: Funding:]; None reported
van Nielen, 2014 ^71^; 8 European countries; EPIC-InterAct, PCS; N=16154 | % E of total protein, animal-protein, and plant-protein intake across three quintiles, in women; Foods/Food groups: Animal protein from red meat, processed meat, poultry, milk and dairy, cheese, fish, eggs; plant protein from bread, potatoes, pasta and rice, legumes | Q1, ref. | 48.0 | 35.1 | 13.2 | ↑ T2D after 12y f/u for total proteinand per 10 g of total protein (men and women combined); ↑ T2D after 12y f/u for animal-proteinand per 10 g of animal-protein (men and women combined); ᴓ T2D after 12y f/u for vegetable-protein and or per 10 g vegetable-protein (men and women combined) | Did not account for: Race/ethnicity; [underlined: Funding:]; European Union FP6 programme
van Nielen, 2014 ^71^; 8 European countries; EPIC-InterAct, PCS; N=16154 | | Q3 | 45.1 | 34.9 | 17.2 | | Did not account for: Race/ethnicity; [underlined: Funding:]; European Union FP6 programme
van Nielen, 2014 ^71^; 8 European countries; EPIC-InterAct, PCS; N=16154 | | Q5 | 40.9 | 35.5 | 21.6 | | Did not account for: Race/ethnicity; [underlined: Funding:]; European Union FP6 programme
van Nielen, 2014 ^71^; 8 European countries; EPIC-InterAct, PCS; N=16154 | % E of total protein, animal-protein, and plant-protein across three quintiles, in men | Q1, ref. | 46.0 | 34.4 | 12.8 | | Did not account for: Race/ethnicity; [underlined: Funding:]; European Union FP6 programme
van Nielen, 2014 ^71^; 8 European countries; EPIC-InterAct, PCS; N=16154 | % E of total protein, animal-protein, and plant-protein across three quintiles, in men | Q3 | 43.1 | 34.1 | 16.5 | | Did not account for: Race/ethnicity; [underlined: Funding:]; European Union FP6 programme
van Nielen, 2014 ^71^; 8 European countries; EPIC-InterAct, PCS; N=16154 | % E of total protein, animal-protein, and plant-protein across three quintiles, in men | Q5 | 38.7 | 35.4 | 20.7 | | Did not account for: Race/ethnicity; [underlined: Funding:]; European Union FP6 programme
Virtanen, 2017 ^72^; Finland; Kuopio Ischaemic Heart Disease Risk Factor Study, PCS; N=2332; 0% female | % E of total protein intake, examined across quartiles; per-5g-increase; per-1% substitution of carbohydrate with protein; Foods/Food groups: Reported intake in g/d of Fruits, berries, and vegetables, Potatoes, Whole grain products, Unprocessed red meat, Processed red meat, Fish, Non fermented dairy, Fermented dairy, Coffee, mL/d | Q1, ref | 43.9 | 39.9 | 12.8 | ᴓ T2D after 19y f/u, across quintiles, per-5g increase, or per 1% substitution of carbohydrate with protein | Did not account for: Race/ethnicity (all Finnish); [underlined: Funding:]; Finnish Cultural Foundation North Savo Regional; Päivikki and Sakari Sohlberg Foundation; University of Eastern Finland; Finnish Foundation for Cardiovascular Research and the Otto A. Malm Foundation
Virtanen, 2017 ^72^; Finland; Kuopio Ischaemic Heart Disease Risk Factor Study, PCS; N=2332; 0% female | | Q4 | 41.5 | 37.3 | 18.6 | ᴓ T2D after 19y f/u, across quintiles, per-5g increase, or per 1% substitution of carbohydrate with protein
Virtanen, 2017 ^72^; Finland; Kuopio Ischaemic Heart Disease Risk Factor Study, PCS; N=2332; 0% female | % E of animal-protein, examined across quartiles; per-5g-increase; Foods/Food groups: Protein from red meat, Unprocessed red meat, Processed red meat, Fish, Eggs, Dairy products, Non fermented dairy, Fermented dairy, Milk, Cheese | Q1, ref | 46.4 | 37.9 | 13.1 | ᴓ T2D after 19y f/u, across quintiles or per-5g increase
Virtanen, 2017 ^72^; Finland; Kuopio Ischaemic Heart Disease Risk Factor Study, PCS; N=2332; 0% female | | Q4 | 39.8 | 38.8 | 18.4 | ᴓ T2D after 19y f/u, across quintiles or per-5g increase
Virtanen, 2017 ^72^; Finland; Kuopio Ischaemic Heart Disease Risk Factor Study, PCS; N=2332; 0% female | % E of plant-protein, examined across quartiles; per-5g-increase; Foods/Food groups: protein from grain products, and non-grain plant protein sources (e.g., vegetables, potatoes) | Q1, ref | 37.7 | 41.9 | 15.6 | ᴓ T2D after 19y f/u, across quintiles or per-5g increase
Virtanen, 2017 ^72^; Finland; Kuopio Ischaemic Heart Disease Risk Factor Study, PCS; N=2332; 0% female | % E of plant-protein, examined across quartiles; per-5g-increase; Foods/Food groups: protein from grain products, and non-grain plant protein sources (e.g., vegetables, potatoes) | Q4 | 48.0 | 35.2 | 15.6 | ᴓ T2D after 19y f/u, across quintiles or per-5g increase

Table 3 Risk of bias for randomized controlled trials examining diets based on macronutrient distribution consumed by adults and risk of type 2 diabetes^xiii,xiv^

Article | Randomization | Deviations from intended interventions - effect assignment | Deviations from intended interventions - per protocol | Missing outcome data | Outcome measurement | Selection of the reported result
Kahleova, 2018 ^61^ | Low | Low | Low | Low | Low | Low
Salas-Salvado, 2011 ^65^ | Some concerns | Low | Low | Low | Low | Some concerns

Table 4 Risk of bias for observational studies examining diets based on macronutrient distribution consumed by adults and risk of type 2 diabetes^xv^

Article | Confounding | Selection of participants | Classification of exposures | Deviations from intended exposures | Missing data | Outcome measurement | Selection of the reported result
Bao, 2016 ^50^ | Serious | Serious | Low | Serious | Serious | Low | Moderate
Brunner 2008 ^54^ | Serious | Serious | Low | Serious | Moderate | Low | Moderate
Chen, 2020 ^55^ | Moderate | Moderate | Low | Serious | Moderate | Low | Moderate
de Koning, 2011 ^56^ | Serious | Serious | Low | Moderate | Serious | Low | Moderate
Dominguez, 2015 ^51^ | Serious | Serious | Low | Serious | Serious | Moderate | Moderate
Ericson, 2013 ^57^ | Serious | Serious | Low | Serious | Serious | Moderate | Moderate
Ericson, 2019 ^52^ | Serious | Serious | Low | Serious | Serious | Moderate | Serious
Guasch-Ferre, 2017 ^58^ | Serious | Serious | Low | Moderate | Moderate | Low | Moderate
Ha, 2019 ^59^ | Moderate | Moderate | Low | Serious | Moderate | Low | Moderate
Halton, 2008 ^60^ | Serious | Moderate | Moderate | Moderate | Moderate | Low | Moderate
Kroger, 2014 ^53^ | Serious | Moderate | Low | Serious | Serious | Moderate | Moderate
Malik, 2016 ^62^ | Moderate | Serious | Low | Moderate | Serious | Low | Moderate
Nanri, 2015 ^63^ | Serious | Serious | Low | Moderate | Moderate | Low | Moderate
Sakurai, 2016 ^64^ | Moderate | Serious | Moderate | Serious | Moderate | Low | Moderate
Schulze, 2008 ^66^ | Serious | Serious | Low | Serious | Serious | Low | Moderate
Shan, 2018 ^67^ | Serious | Serious | Low | Serious | Moderate | Low | Moderate
Shang, 2016 ^68^ | Moderate | Serious | Low | Serious | Moderate | Moderate | Moderate
Simila, 2012 ^69^ | Serious | Serious | Low | Serious | Moderate | Low | Moderate
Sluijs, 2010 ^70^ | Serious | Serious | Low | Serious | Moderate | Moderate | Moderate
van Nielen, 2014 | Serious | Moderate | Moderate | Serious | Moderate | Low | Moderate
Virtanen, 2017 ^71^ | Serious | Moderate | Moderate | Serious | Moderate | Moderate | Moderate
Voortman, 2017 ^72^ | Moderate | Serious | Serious | Serious | Moderate | Low | Moderate

ii Briefly, the AMDR in adults are as follows: Carbohydrate: 45 to 65% of energy; Fat: 25 to 35% of energy; Protein: 10 to 35% of energy. The AMDR for children are as follows: Carbohydrate: 45 to 65% of energy; Protein, ages 1-3y: 5 to 20% of energy, ages 4-18y: 10 to 30% of energy; Fat, ages 1-3y: 30 to 40% of energy, ages 4-18y: 25 to 35% of energy. Source: Institute of Medicine. Dietary Reference Intakes for Energy, Carbohydrate, Fiber, Fat, Fatty Acids, Cholesterol, Protein, and Amino Acids. Washington (DC): The National Academies Press; 2002 . For more details on AMDR, see the Intervention/Exposure Inclusion and Exclusion criteria

iii A detailed description of the methodology used for grading the strength of the evidence is available on the NESR website: https://nesr.usda.gov/2020-dietary-guidelines-advisory-committee-systematic-reviews and in Part C of the following reference: Dietary Guidelines Advisory Committee. 2020. Scientific Report of the 2020 Dietary Guidelines Advisory Committee: Advisory Report to the Secretary of Agriculture and the Secretary of Health and Human Services. U.S. Department of Agriculture, Agricultural Research Service, Washington, DC.

iv Dietary Guidelines Advisory Committee. 2015. Scientific Report of the 2015 Dietary Guidelines Advisory Committee: Advisory Report to the Secretary of Health and Human Services and the Secretary of Agriculture. U.S. Department of Agriculture, Agricultural Research Service, Washington, DC.

v A detailed description of the methodology used for grading the strength of the evidence is available on the NESR website: https://nesr.usda.gov/2020-dietary-guidelines-advisory-committee-systematic-reviews and in Part C of the following reference: Dietary Guidelines Advisory Committee. 2020. Scientific Report of the 2020 Dietary Guidelines Advisory Committee: Advisory Report to the Secretary of Agriculture and the Secretary of Health and Human Services. U.S. Department of Agriculture, Agricultural Research Service, Washington, DC.

vi Abbreviations: CVD, cardiovascular disease; N/A, Not applicable; NIH, National Institutes of Health; T2D, Type 2 diabetes; y, year(s)

vii Abbreviations: % E, Percent energy; EPIC, European Prospective Investigation into Cancer and Nutrition; E, energy; EVOO, extra virgin olive oil; f/u, follow-up; Med, Mediterranean; N/A, Not applicable; NHLBI, National Heart Lung and Blood Institute; NIH, National Institutes of Health; NR, Not reported; mo, month(s); PCS, Prospective cohort study; RCT, randomized controlled trial; T2D, Type 2 diabetes; wk, week(s); y, year(s)

viii Includes last name of first author, publication year, country, analytic sample size, and select participant characteristics.

ix Unless otherwise noted, the first category listed was used as the referent group.

x Relevant results for the systematic review question are summarized using the following symbols:

- ↑ Significant (positive) association between higher adherence to diet and higher risk of T2D;
- ᴓ Association or difference between diet groups and risk of T2D was not statistically significant;
- ↓ Significant (inverse) association between higher adherence to diet and lower risk of T2D

xi Additional funding sources reported by Chen, 2019 were: the Netherlands Organisation for Scientific Research; the Netherlands Organisation for Health Research and Development; the Research Institute for Diseases in the Elderly; the Netherlands Genomics Initiative; the Netherlands Ministry of Education, Culture and Science; the Netherlands Ministry of Health, Welfare and Sports; the European Commission; and the Municipality of Rotterdam

xii Additional funding sources reported by Guasch-Ferre, 2017 were: European Regional Development Fund; Ministry of Science and Innovation; Mapre Foundation, Regional Government of Andalusia Ministry of Health; Autonomous Government of Catalonia Department of Health; Regional Government of Navarra

xiii A detailed description of the methodology used for assessing risk of bias is available on the NESR website: https://nesr.usda.gov/2020-dietary-guidelines-advisory-committee-systematic-reviews and in Part C of the following reference: Dietary Guidelines Advisory Committee. 2020. Scientific Report of the 2020 Dietary Guidelines Advisory Committee: Advisory Report to the Secretary of Agriculture and the Secretary of Health and Human Services. U.S. Department of Agriculture, Agricultural Research Service, Washington, DC.

xiv Possible ratings of low, some concerns, or high determined using the “Cochrane Risk-of-bias 2.0” (RoB 2.0) (August 2016 version)” ( Higgins JPT, Sterne JAC, Savović J, Page MJ, Hróbjartsson A, Boutron I, Reeves B, Eldridge S. A revised tool for assessing risk of bias in randomized trials In: Chandler J, McKenzie J, Boutron I, Welch V (editors). Cochrane Methods. Cochrane Database of Systematic Reviews 2016, Issue 10 (Suppl 1). 10.1002/14651858.CD201601. )

xv Possible ratings of low, moderate, serious, critical, or no information determined using the “Risk of Bias for Nutrition Observational Studies” tool (RoB-NObs) ( Dietary Guidelines Advisory Committee. 2020. Scientific Report of the 2020 Dietary Guidelines Advisory Committee: Advisory Report to the Secretary of Agriculture and the Secretary of Health and Human Services. U.S. Department of Agriculture, Agricultural Research Service, Washington, DC. )