# List of abbreviations

Abbreviation: Full name
AHEI: Alternate Health Eating Index
AMDR: Acceptable Macronutrient Distribution Range
BMI: Body mass index
BP: Blood pressure
CHD: Coronary heart disease
CVD: Cardiovascular disease
DBP: Diastolic blood pressure
f/u: Follow-up
FFQ: Food frequency questionnaire
HDL: High-density lipoprotein cholesterol
HF: Heart failure
HHS: United States Department of Health and Human Services
HPFS: Health Professionals Follow-Up Study
HTN: Hypertension
LDL: Low-density lipoprotein cholesterol
MI: Myocardial infarction
mo: Month(s)
N/A: Not applicable
NESR: Nutrition Evidence Systematic Review
NHS: Nurses’ Health Study
NHS: National Health Service (UK)
NIH: National Institutes of Health
PCS: Prospective cohort study
PREDIMED: Prevención con Dieta Mediterránea
RCT: Randomized controlled trial
SBP: Systolic Blood Pressure
TAG: Triacylglycerol
TC: Total Cholesterol
TG: Triglyceride(s)
USDA: United States Department of Agriculture
wk: Week(s)
y: Year(s)