# WHAT IS THE RELATIONSHIP BETWEEN DIETARY PATTERNS CONSUMED AND RISK OF CARDIOVASCULAR DISEASE?

## PLAIN LANGUAGE SUMMARY

### What is the question?

- The question is: What is the relationship between dietary patterns consumed and risk of cardiovascular disease?

### What is the answer to the question?

Dietary Patterns: Children

- Limited evidence suggests that dietary patterns consumed by children and adolescents reflecting higher intakes of vegetables, fruits, whole grains, fish, low-fat dairy, legumes, and lower intake of sugar-sweetened beverages, other sweets, and processed meat, are associated with lower blood pressure and blood lipid levels, including low-density lipoprotein cholesterol, high-density lipoprotein cholesterol, and triglycerides later in life.

Dietary Patterns: Adults

- The 2020 Dietary Guidelines Advisory Committee conducted a systematic evidence scan and confirmed that the conclusion drawn by the 2015 Dietary Guidelines Advisory Committee generally reflects the current state of science: Strong and consistent evidence demonstrates that dietary patterns associated with decreased risk of cardiovascular disease are characterized by higher consumption of vegetables, fruits, whole grains, low-fat dairy, and seafood, and lower consumption of red and processed meat, and lower intakes of refined grains, and sugar-sweetened foods and beverages relative to less healthy patterns. Regular consumption of nuts and legumes and moderate consumption of alcohol also are shown to be components of a beneficial dietary pattern in most studies. Randomized dietary intervention studies have demonstrated that healthy dietary patterns exert clinically meaningful impact on cardiovascular risk factors, including blood lipids and blood pressure. Additionally, research that includes specific nutrients in their description of dietary patterns indicate that patterns that are lower in saturated fat, cholesterol, and sodium and richer in fiber, potassium, and unsaturated fats are beneficial for reducing cardiovascular disease risk.

Diets Based on Macronutrient Distribution: Children

- No evidence was available to determine the relationship between diets based on macronutrient distribution consumed by children or adolescents and concurrent or future development of cardiovascular disease.

Diets Based on Macronutrient Distribution: Adults

- Limited evidence suggests non-energy restricted diets based solely on macronutrient distribution with either carbohydrate, fat, and/or protein proportions outside of the Acceptable Macronutrient Distribution Range, are neither beneficial nor detrimental regarding risk of cardiovascular disease in adults, primarily among those at high-risk, such as those with overweight, obesity or features of metabolic syndrome.

### Why was this question asked?

- This important public health question was identified by the U.S. Departments of Agriculture (USDA) and Health and Human Services (HHS) to be examined by the 2020 Dietary Guidelines Advisory Committee.

### How was this question answered?

- The 2020 Dietary Guidelines Advisory Committee, Dietary Patterns Subcommittee conducted a systematic review and a systematic evidence scan to answer this question with support from the Nutrition Evidence Systematic Review (NESR) team.
- Dietary patterns were defined as the quantities, proportions, variety, or combination of different foods, drinks, and nutrients (when available) in diets, and the frequency with which they are habitually consumed.
- Diets based on macronutrient distribution were examined when at least one macronutrient proportion outside of the acceptable macronutrient distribution range (AMDR ) for carbohydrate, fat, and/or protein, whether or not the foods/food groups consumed were provided.

### What is the population of interest?

- Children and adults, ages 2 years and older

### What evidence was found?

- This review identified 190 articles that met inclusion criteria.
- Four articles examined dietary patterns consumed by children and risk of cardiovascular disease.
  ○ Dietary patterns that were higher in vegetables, fruits, whole grains, fish, low-fat dairy, legumes, and lower in sugar-sweetened beverages, other sweets, and processed meat, are associated with lower blood pressure and blood lipid levels later in life.
  ○ The 2020 Committee determined the strength of this evidence was limited.
- One-hundred forty-nine articles examined dietary patterns consumed by adults and risk of cardiovascular disease.
  ○ The 2020 Committee determined these articles were generally consistent with those from an existing NESR systematic review. Therefore, the 2020 Committee carried forward the conclusion from the 2015 Committee.
- No studies were included that examined diets based on macronutrient distribution consumed by children or adolescents and risk of cardiovascular disease.
  ○ The 2020 Committee could not draw a conclusion due to a lack of evidence.
- Forty-nine articles examined diets based on macronutrient distribution consumed by adults and risk of cardiovascular disease, primarily in those who were overweight or obese, or had features of metabolic syndrome.
  ○ Most studies found no significant effects of macronutrient distributions outside the AMDR on risk of cardiovascular disease.
  ○ Several limitations in the study design and conduct of included articles were identified.
  ○ The 2020 Committee determined the strength of this evidence was limited.

### How up-to-date is this systematic review?

- This review searched for studies from January, 2000 to October, 2019; and updated existing systematic reviews that included evidence from January 2000 to January 2014.

## FULL REVIEW

### Systematic review question

What is the relationship between dietary patterns consumed and risk of cardiovascular disease?

### Conclusion statements and grades

#### Dietary Patterns: Children

Limited evidence suggests that dietary patterns consumed by children and adolescents reflecting higher intakes of vegetables, fruits, whole grains, fish, low-fat dairy, legumes, and lower intake of sugar-sweetened beverages, other sweets, and processed meat, are associated with lower blood pressure and blood lipid levels, including low-density lipoprotein cholesterol, high-density lipoprotein cholesterol, and triglycerides later in life. (Grade: Limited)

#### Dietary Patterns: Adults

The 2020 Dietary Guidelines Advisory Committee conducted a systematic evidence scan and confirmed that the conclusion drawn by the 2015 Dietary Guidelines Advisory Committee generally reflects the current state of science: Strong and consistent evidence demonstrates that dietary patterns associated with decreased risk of cardiovascular disease are characterized by higher consumption of vegetables, fruits, whole grains, low-fat dairy, and seafood, and lower consumption of red and processed meat, and lower intakes of refined grains, and sugar-sweetened foods and beverages relative to less healthy patterns. Regular consumption of nuts and legumes and moderate consumption of alcohol also are shown to be components of a beneficial dietary pattern in most studies. Randomized dietary intervention studies have demonstrated that healthy dietary patterns exert clinically meaningful impact on cardiovascular risk factors, including blood lipids and blood pressure. Additionally, research that includes specific nutrients in their description of dietary patterns indicate that patterns that are lower in saturated fat, cholesterol, and sodium and richer in fiber, potassium, and unsaturated fats are beneficial for reducing cardiovascular disease risk. (2015 Dietary Guidelines Advisory Committee Grade: Strong)

#### Diets Based on Macronutrient Distribution: Children

No evidence was available to determine the relationship between diets based on macronutrient distribution consumed by children or adolescents and concurrent or future development of cardiovascular disease. (Grade: Grade Not Assignable)

#### Diets Based on Macronutrient Distribution: Adults

Limited evidence suggests non-energy restricted diets based solely on macronutrient distribution with either carbohydrate, fat, and/or protein proportions outside of the Acceptable Macronutrient Distribution Range, are neither beneficial nor detrimental regarding risk of cardiovascular disease in adults, primarily among those at high-risk, such as those with overweight, obesity or features of metabolic syndrome. (Grade: Limited)

### Summary of the evidence

- One-hundred ninety articles were identified that met inclusion criteria and examined the relationship between dietary patterns and/or diets based on macronutrient proportion and risk of cardiovascular disease (CVD).^1–190^
  ○ Dietary patterns were defined as the quantities, proportions, variety, or combination of different foods, drinks, and nutrients (when available) in diets, and the frequency with which they are habitually consumed.
  ○ Diets based on macronutrient distribution were considered as those with at least one macronutrient proportion that was outside of the acceptable macronutrient distribution range (AMDR^ii^) for carbohydrate, fat, and/or protein, whether or not the foods/food groups consumed were provided.
    ▪ When describing and categorizing studies included in these reviews, the Committee did not label the diets examined as “low” or “high,” because no standard definition is currently available for, for example, “low-carbohydrate” or “high-fat” diets. Instead, the Committee focused on whether, and the extent to which, the proportions of the macronutrients were below or above the AMDR.
  ○ Studies examining energy-restricted diets that induce weight loss or treat overweight and obesity for the purposes of treating additional or other medical conditions were excluded.

#### Dietary patterns: Children

- Four included articles, all from prospective cohort studies (PCSs) published between January 2014 and October 2019, examined the relationship between dietary patterns consumed by children and CVD.^25,30,36,139^
  ○ Two of the articles used index or score analyses to examine dietary patterns.
  ○ Two of the articles examined the dietary patterns identified with factor and cluster analyses.
  ○ Most of the studies examined intermediate CVD outcomes in childhood, although one study reported on incidence of CVD in adulthood.
  ○ This body of evidence updates an existing systematic review from the 2015 Dietary Guidelines Advisory Committee, which found insufficient evidence in pediatric populations published between 1980 and 2013 that met inclusion criteria on dietary patterns and CVD and therefore, was unable to form a conclusion statement at the time.

#### Dietary patterns: Adults

- One-hundred forty-nine articles examined dietary patterns consumed by adults and CVD.^1–7,9–13,15–17,19–22,26–29,32–35,40,41,44,46,48–53,55,57,58,60,62–64,67,68,70,71,74–79,81,82,84–92,94–97,102–105,107–109,111–118,121–125,127–129,131–138,140,143,144,146,147,151–153,155–158,160–168,170–175,177,178,181,182,185–190,31,38,39,47,83,106,120,145,149,154,159,180^
  ○ These articles represent new evidence published since an existing systematic review that included articles published between January 1980 and August 2013, which was reviewed by the 2015 Committee.
  ○ A systematic evidence scan was conducted to identify and examine newly published evidence, and determine whether a full systematic review update was warranted.
  ○ Based on results from the systematic evidence scan, the 2020 Committee determined that the newly published evidence was generally consistent with the body of evidence from the existing review, and a full systematic review update was not needed at this time. Therefore, the conclusion statement and grade from the existing review were carried forward.

#### Diets based on macronutrient distribution: Children

- No articles were identified that met inclusion criteria and examined diets based on macronutrient distribution consumed by children or adolescents and risk of CVD across the lifespan.

#### Diets based on macronutrient distribution: Adults

- Forty-nine included articles examined diets based on macronutrient distribution consumed by adults and CVD outcomes, met inclusion criteria, and were published between January 2000 and October 2019.^8,14,18,23,24,31,37–39,42,43,45,47,54,56,59,61,65,66,69,72,73,80,83,93,98–101,106,110,119,120,126,130,141,142,145,148–150,154,159,169,176,179,180,183,184^
  ○ Nineteen articles came from randomized controlled trials (RCTs) and 30 articles came from PCSs.
  ○ Most studies enrolled participants who were overweight or obese, or exhibited features of metabolic syndrome.
  ○ The majority of RCTs (n=11) reported no significant effects of macronutrient distributions on intermediate CVD outcomes, such as LDL cholesterol.
    ▪ Although results from several RCTs (n=8) reported significantly improved intermediate CVD outcomes, diets compared between studies were heterogeneous with macronutrient distributions inconsistently above or below the AMDR and dependent upon the comparison of interest (e.g., fat within vs. above the AMDR).
  ○ Many PCSs reported no significant associations across specified macronutrient distributions and CVD mortality endpoint outcomes.
    ▪ Among the PCSs (n=9 of 30) that also reported dietary patterns, the majority reported that diets with energy derived from total fat intakes above the AMDR were associated with increased CVD risk, and generally reflected lower diet quality.
  ○ Numerous limitations were identified across the body of evidence:
    ▪ Vastly different study designs and diet assessment approaches were used to examine macronutrient distributions. Few studies evaluated macronutrient distribution in the context of dietary patterns in relation to CVD.
    ▪ Foods and food groups consumed as part of the diet pattern, were inconsistently assessed and reported, thereby limiting meaningful conclusions regarding nutrient density and overall nutritional quality.
    ▪ The gradient between proportions compared within and across studies varied widely.
    ▪ Although many studies compared proportions that were distinctly different, some compared only slight differences in macronutrient content (e.g., 42.0% vs 43.7% fat), thereby reducing the specificity of the impact.
    ▪ Due to the variability in methodology used to estimate macronutrient intake and/or adjust for total energy, confidence in the accuracy of reported proportions of energy falling outside the AMDR is low.
    ▪ Several studies focused on a particular macronutrient of interest, such as “high-protein” or “low-carbohydrate” intake, but the proportion for that macronutrient was within the AMDR.

### Description of the evidence

#### Dietary patterns: Children

##### Population/participant characteristics

The four articles examining the relationship between dietary patterns consumed by children and cardiovascular disease (CVD) were conducted in 4 different countries:

- United Kingdom^25^
- Australia^30^
- United States^36^
- Portugal^139^

Across these studies conducted in children, the analytic sample size ranged from 1,419^30^ to 42,112^36^ and all had a follow up time period of at least 10 years.

Data from these studies represented 4 established cohorts (Avon Longitudinal Study of Parents and Children, Western Australian Pregnancy Cohort, Nurses’ Health Study-II (NHS II), and Generation XXI Birth Cohort). Three of these were birth cohorts following participants from birth onward, and one was a study of adults but inquired retrospectively about dietary habits in adolescence.^36^

Studies included participants who were under the age of 18 years at the time of diet exposure that were healthy and/or at risk of chronic disease. One study excluded participants that reported a diagnosis of cardiovascular disease or cancer prior to returning dietary questionnaire.^36^ The birth cohort studies included both girls and boys^25,30,139^ and the one study that evaluated intake retrospectively included middle-aged women.^36^ The 3 birth cohort studies did not report information regarding race/ethnicity of participants, and the fourth study was conducted among predominantly White female participants.^36^

##### Intervention/exposure

Dietary patterns consumed during childhood were assessed by two different methods. Two articles used only index or score analysis^30,36^ and two used only factor and cluster analysis.^25,139^ Dietary intake was primarily assessed using food frequency questionnaires (FFQ), with one study that utilized dietary histories. The diet assessment methods used are as follows:

- One article reported diet collection with validated FFQ at more than one time point over the course of the study [at age 14 y (baseline) and age 17y (follow-up)]^30^
- Two articles reported diet collection with validated FFQ at one time point at baseline^36,139^
- One article reported diet collection with multiple food diaries (at ages 7, 10, and 13 y^25^

##### Outcome assessment

All included studies examined risk of intermediate CVD disease outcomes and one evaluated CVD incidence. Included studies examined risk of CVD or intermediate outcomes, with follow-up ranging from 10 y to 17 y. For the birth cohort studies, the length of follow-up was equivalent to the age of participant. Studies examined the following CVD intermediate outcomes: systolic blood pressure (SBP), diastolic blood pressure (DBP), low-density lipoprotein cholesterol (LDL), high-density lipoprotein cholesterol (HDL), and/or triglycerides (TG)^25,30,36,139^ with two of these studies additionally evaluating total cholesterol (TC).^25,30^ One study also examined risk of CVD.^36^

#### Dietary patterns: Adults

##### Evidence scan results

One hundred forty-nine articles that met inclusion criteria, were published between January 2014 and October 2019, and examined dietary patterns consumed by adults and risk of CVD.^1–7,9–13,15–17,19–22,26–29,32–35,40,41,44,46,48–53,55,57,58,60,62–64,67,68,70,71,74–79,81,82,84–92,94–97,102–105,107–109,111–118,121–125,127–129,131–138,140,143,144,146,147,151–153,155–158,160–168,170–175,177,178,181,182,185–189^ Among these 149, 137 articles examined dietary patterns consumed by adults^1–7,9–13,15–17,19–22,26–29,32–35,40,41,44,46,48–53,55,57,58,60,62–64,67,68,70,71,74–79,81,82,84–94,96,97,102–105,107–109,111–118,121–125,127–129,131–138,140,143,144,146,147,151–153,155–158,160–168,170–175,177,178,181,182,185–189^ and 12 examined both dietary patterns and diets based on macronutrient distribution.^31,38,39,47,83,106,120,145,149,154,159,180^

#### Diets based on macronutrient distribution: Children

No studies that were identified met inclusion criteria that examined diets based on macronutrient distributions with proportions of energy falling outside of the AMDR for at least one macronutrient in children and intermediate or endpoint CVD outcomes across the lifespan.

#### Diets based on macronutrient distribution: Adults

Forty-nine articles that met inclusion criteria, were published between January 2000 and October 2019, and examined diets based on macronutrient distribution consumed by adults and risk of cardiovascular disease. The 49 articles were comprised of 19 RCTs,^8,14,18,37–39,42,45,56,73,80,130,145,148,150,169,176,179,184^ and 30 prospective cohort studies (PCSs).^23,24,31,43,47,54,59,61,65,66,69,72,83,93,98–101,106,110,119,120,126,141,142,149,154,159,180,183^

##### Population/participant characteristics

The studies examining dietary patterns or diets based on macronutrient distribution consumed by adults that are included in this systematic review were conducted in the following countries:

- Australia^38,39,42,180^
- China^184^
- France^130,179^
- Japan^119,120^
- New Zealand^37^
- Spain^24,59,69,149^
- Sweden^47,93,98–100^
- United Kingdom^23,106,145,148^
- United States^8,14,18,31,43,45,54,56,61,65,66,72,73,80,83,101,110,141,142,154,159^
- Three studies were conducted in multiple European countries^150,169,176^

Studies enrolled healthy adults as well as those that were obese or overweight, with high CVD risk, or those with features of metabolic syndrome. Participants were primarily middle-aged and older adults. No studies that were identified evaluated diets based on macronutrient proportions in children. Of the prospective cohort studies, many were conducted in the same cohorts of participants, including the Malmo Diet and Cancer Cohort,^47,98–100^ Atherosclerosis Risk in Communities cohort,^65,66,83^ Prevención con Dieta Mediterránea (PREDIMED),^59,69^ the Nurses’ Health Study (NHS),^54,61,159^ and the Health Professionals Follow-up Study (HPFS).^101,141,142^ Although multiple articles from the same cohorts were included, each of the included articles represent unique data by examining different sub-samples, time-points or duration of follow-up, different CVD outcomes, or different macronutrient distributions and/or dietary patterns.

##### Intervention/exposure

Among the 30 prospective cohort studies^23,24,31,43,47,54,59,61,65,66,69,72,83,93,98–101,106,110,119,120,126,141,142,149,154,159,180,183^ that examined diets based on macronutrient distribution, most used validated methods to assess macronutrient intake at baseline, although methods varied across studies. Dietary intake was measured by FFQ once at baseline in 13 articles,^23,24,31,43,72,93,110,119,126,149,154,180,183^ or using two or more FFQs at regular intervals during the study in 11 articles.^54,59,61,65,66,69,83,101,141,142,159^ Several studies utilized multiple methods of measuring dietary intake, including FFQs and multiple day dietary records.^47,98–100^ The remaining studies used multi-day dietary records^106,120^ or a 24-hour dietary recall.^110^ For the studies that evaluated both diets based on macronutrient distribution and dietary patterns, various methods were used to determine or derive dietary patterns, including factor and cluster analyses, index scores, and reduced rank regression.

Among the 19 RCTs,^8,14,18,37–39,42,45,56,73,80,130,145,148,150,169,176,179,184^ participants were randomized to consume specific diets either based on an underlying dietary pattern or based on specific macronutrient levels. One RCT compared diets of different protein levels,^8^ one compared a “high-carbohydrate” diet to a “high-protein” diet,^42^ four compared “low-fat” and control diets,^18,45,73,80^ and five examined macronutrient distributions based on dietary patterns compared either to each other or to a control group.^38,39,145,176,179^ The remaining 8 RCTs compared low carbohydrate and low fat diets,^14,56,184^ high fat and high carbohydrate diets,^37,148^ or varying fat level diets with a change in the quality of carbohydrates compared to a control.^130,150,169^ The label of the level of macronutrients were determined by the authors of each paper (i.e., ‘low fat’ may have different definitions by each article).

Among the macronutrient distributions reported, the proportions of energy falling outside of the AMDR were as follows:

- Carbohydrate below the AMDR ranged between 25.3% and 44.9%
- Carbohydrate above the AMDR ranged between 66% and 72.7%
- Fat above the AMDR ranged between 35.2% and 46.1%
- Fat below the AMDR ranged between 10.8% and 18.9%
- Protein was above the AMDR in one study at 43.5%

Most of the studies (38 of 49) examined macronutrient distributions in which the proportion of energy from carbohydrate was below the AMDR in at least one of the exposure groups compared.^8,14,23,24,37–39,42,43,45,47,54,56,59,61,65,66,69,83,93,98–101,110,126,130,141,142,145,148,149,154,159,169,176,179,180^ In most cases, the corresponding proportion of energy from total fat was above the AMDR. In one of study, the proportion of energy from protein was above the AMDR.^8^ Six studies examined macronutrient distributions in which the proportion of energy from carbohydrate was above the AMDR.^80,110,119,120,183,184^ In most but not all six of these studies, the corresponding proportion of energy from total fat was below the AMDR. Two studies examined macronutrient distributions in which the proportion of energy from total fat was above the AMDR in at least one of the exposure groups compared, with other macronutrients (carbohydrate, protein) within the AMDR.^31,73^

##### Outcome assessment

Studies that examined the relationship between diets based on macronutrient proportion and CVD outcomes examined both endpoint and intermediate outcomes over follow-up ranging from 16 wk to 6 y (RCTs) and 4 y to 32 y (PCSs). The following CVD outcomes were reported in these studies:

- Endpoint outcomes: CVD-mortality, and/or incidence of CVD or coronary-heart disease (CHD), CVD-events, coronary-events, fatal or non-fatal myocardial infarction (MI), angina, stroke, and ischemic heart-disease
- Intermediate outcomes: TC, HDL, LDL, HDL:LDL ratio, triacylglycerol (TAG)/TG, blood pressure [BP, including systolic (SBP), and diastolic (DBP)]

### Evidence synthesis

#### Dietary patterns: Children

##### Summary of results

Results reported in the studies included in this systematic review were mixed (Table 1). Bull and Northstone^25^ identified 4 dietary patterns using cluster analysis in a cohort of children (and their parents) in the United Kingdom assessed at ages 7, 10 and 13 y. Results showed that higher adherence to a “processed” compared to a “healthy” dietary pattern at ages 7 and 10 y was associated with significantly lower odds of high LDL and lower odds of high TG. Adherence to the “packed lunch” compared to the “healthy” dietary pattern at age 7 y was associated with significantly higher HDL. Higher adherence to the “traditional” compared to “healthy” dietary pattern at age 10 y was associated with significantly lower elevated DBP, high TG, and high TC. Additionally, there was no significant association between any of the patterns at any age and elevated SBP. Pubertal stage was not reported and the validation of the assessment methods and accuracy of the data tables are unclear. It should be noted that the accuracy/validity of these data are unclear and that study authors acknowledged a lack of robustness in results for these outcomes.

Pinto et al^139^ also utilized factor/cluster analysis to identify 4 dietary patterns, as well as including 3 patterns identified in a previous paper for a total of 7 dietary patterns examined at age 7 y in a Portugal birth cohort. Higher adherence to the Partial Least Squares – Factor 1 (PLS-1) pattern emphasizing processed meats, cakes, and soft drinks was significantly associated with higher DBP, and higher adherence to the “Principal Component Analysis – Factor 1” (PCA-1) pattern emphasizing sugary drinks, sweets, and salty snacks was significantly associated with higher SBP. Both of these patterns were classified as “less healthy” than their comparator. There were no significant associations between PLS-2 or PCA-2 at age 7 y despite the emphasis on fish in the PLS-2 pattern and the emphasis on fruits, vegetables, and low fat dairy in the PCA-2 pattern with any of the evaluated intermediate cardiovascular outcomes (SBP, DBP, TG, HDL, LDL). Of the 3 patterns identified in a previous paper there were no significant associations between the “Snacking” or “Energy-dense foods” patterns when compared to the “Healthier” pattern and intermediate cardiovascular outcomes.

Chan She Ping-Delfos et al^30^ examined the relationship between the Australian Dietary Guideline Index for Children and Adolescents (DGI-CA) and intermediate cardiovascular outcomes from age 14 to age 17 y. Higher vs. lower adherence to the DGI-CA score was significantly associated with decreased TG and SBP, but was not significantly associated with any change in TC, HDL, LDL, or DBP.

Finally, Dahm et al^36^ retrospectively evaluated the relationship between the Alternative Health Eating Index from 2010 (AHEI-2010) and hypertension and CVD risk in women from the NHS. Higher vs. lower adherence to the AHEI-2010 score was significantly associated with a lower hypertension risk but not significantly associated with CVD risk.

##### Assessment of the evidence^iii^

This systematic review update in children included 4 studies that met inclusion criteria. There was limited evidence that suggests dietary patterns consumed by children and adolescents reflecting higher intakes of vegetables, fruits, whole grains, fish, seafood, low-fat dairy, legumes, and lower intake of sugar sweetened beverages, other sweets, and processed meat, are associated with lower BP and blood lipid levels, including LDL, HDL and TG later in life. This new, but limited, evidence in pediatric populations highlights similar dietary pattern components as those identified in adult populations that are associated with improved CVD outcomes. Included studies had relatively large sample sizes with both significant and non-significant results. Therefore, this risk of publication bias is relatively low. As outlined and described below, this body of evidence was assessed for the following elements used when grading the strength of evidence

- Risk of bias: There were a number of potential risks of bias, or limitations, across the body of evidence (see Table 4) that make interpretation of results difficult. Most studies adjusted for confounders, but a key confounder not considered in any of the four studies was race/ethnicity. Alcohol and smoking were not considered key confounders in this group due to the age of participants being under 18 y. Diet was assessed only once at baseline in all of the included studies. While three of the studies assessed diet once prospectively at baseline, one study retrospectively evaluated diet from a prospective cohort analysis which may have led to possible recall bias; the validity and reliability of those data are unclear.
- Consistency: All four articles came from observational studies that used two approaches to assess dietary patterns, including two that examined adherence to different indices/scores and two that derived dietary patterns by factor/cluster analysis. Despite variability in the methods used to examine dietary patterns, consistent elements included relatively higher intake of vegetables, fruits, whole grains, low-fat dairy, legumes, and lower intake of sugar sweetened beverages, processed meat, and sweets. Across the body of evidence, the direction of findings was relatively consistent, but varied based on age at exposure.
- Directness: The populations, intervention, comparators, and outcomes of interest in the included studies are directly related to the systematic review question.
- Precision: Sample sizes were relatively large (1400+) in the four studies. Effect sizes were relatively small across the small body of evidence, pointing to imprecision.
- Generalizability: The study participants, interventions and/or exposures, comparators, and outcomes examined in the body of evidence may not be applicable to the United States population since three of the four included studies were conducted outside of the U.S. and had varying demographics.

The 2020 Dietary Guidelines Advisory Committee updated an existing systematic review on dietary patterns and risk of CVD, which was used to inform the 2015 Dietary Guidelines Advisory Committee. The 2015 Committee found insufficient available evidence to assess in pediatric populations and was therefore, unable to draw a conclusion regarding dietary patterns during childhood and risk of CVD. Therefore, the current systematic review identifies a newly published body of evidence that evaluates dietary patterns consumed by children or adolescents and CVD risk, met inclusion criteria, and were published between January 2014 and October 2019, but is overall limited with four included studies.

#### Dietary patterns: Adults

##### Evidence scan results

The 2020 Dietary Guidelines Advisory Committee conducted a systematic evidence scan to identify and examine new evidence published since a review done by the 2015 Dietary Guidelines Advisory Committee^iv^ The 2020 Committee determine that the newly published evidence was consistent with the evidence previously reviewed for the 2015 Dietary Guidelines for Americans Scientific Report.

Results across the newly published body of evidence were generally consistent with the conclusion from 2015, showing that dietary patterns of higher diet quality were typically associated with protection from developing cardiovascular disease. The populations, intervention, comparators, and outcomes of interest are directly related to the systematic review question. Study participants, interventions and/or exposures, comparators, and outcomes examined in the newly published body of evidence are applicable to the U.S. population.

The 2015 Dietary Guidelines Advisory Committee noted in the existing review that most studies showing beneficial effects on cardiovascular outcomes considered regular consumption of nuts and legumes in the overall dietary pattern, but these were not necessarily components of all dietary patterns. Additionally, the existing conclusion statement from 2015 also noted that many studies reported beneficial effects between an overall dietary pattern that may include alcoholic beverage intake and cardiovascular outcomes in adults. For the newly published evidence, inclusion of moderate alcohol intake within an overall dietary pattern may still be acceptable but not necessarily recommended, particularly with regards to prevention of co-morbid conditions that may be exacerbated with alcoholic beverage intake, e.g., hypertension, cancer, etc. Studies that examine overall dietary patterns consumed by adults often vary in how alcohol intake is assessed, the thresholds applied for amounts of alcohol consumed, and scoring procedures of alcohol as a component (e.g., a positive component, positive in moderation, or negative component). Due to this inconsistency, the inclusion and specification of alcoholic beverages within dietary patterns warrants further investigation.

The 2020 Dietary Guidelines Advisory Committee determined that the conclusion drawn by the 2015 Dietary Guidelines Advisory Committee still generally reflects the current of science on dietary patterns consumed by adults and risk of CVD. Therefore, a full systematic review was not conducted at this time, and the 2015 Committee’s conclusion statement and grade were carried forward. The 2015 Committee concluded that: Strong and consistent evidence demonstrates that dietary patterns associated with decreased risk of CVD are characterized by higher consumption of vegetables, fruits, whole grains, low-fat dairy, and seafood, and lower consumption of red and processed meat, and lower intakes of refined grains, and sugar-sweetened foods and beverages relative to less healthy patterns. Regular consumption of nuts and legumes and moderate consumption of alcohol also are shown to be components of a beneficial dietary pattern in most studies. Randomized dietary intervention studies have demonstrated that healthy dietary patterns exert clinically meaningful impact on cardiovascular risk factors, including blood lipids and BP. Additionally, research that includes specific nutrients in their description of dietary patterns indicate that patterns that are lower in saturated fat, cholesterol, and sodium, and richer in fiber, potassium, and unsaturated fats are beneficial for reducing cardiovascular disease risk.

#### Diets based on macronutrient distributions: Children

No studies identified met inclusion criteria that examined diets based on macronutrient distributions with proportions of energy falling outside of the AMDR for at least one macronutrient in children and CVD outcomes across the lifespan.

#### Diets based on macronutrient distributions: Adults

##### Summary of results

Forty-nine studies^8,14,18,23,24,31,37–39,42,43,45,47,54,56,59,61,65,66,69,72,73,80,83,93,98–101,106,110,119,120,126,130,141,142,145,148–150,154,159,169,176,179,180,183,184^ examined diets based on macronutrient distributions with proportions of energy falling outside of the AMDR for at least one macronutrient and CVD outcomes. The 49 articles included 19 RCTs (summarized in Table 2)^8,14,18,37–39,42,45,56,73,80,130,145,148,150,169,176,179,184^ and 30 articles from PCSs (summarized in Table 3).^23,24,31,43,47,54,59,61,65,66,69,72,83,93,98–101,106,110,119,120,126,141,142,149,154,159,180,183^

Results reported across studies varied by study design, macronutrient distributions compared, dietary patterns examined, or reported outcomes. Significant and/or mixed associations were reported in 27 of the included articles,^14,23,24,31,37,39,43,47,54,56,59,61,69,73,80,83,93,98,100,106,110,120,126,145,154,159,184^ with the majority of studies reporting that certain diets based on macronutrient distribution were associated with decreased risk of CVD outcomes (e.g., lower BP, reduced incidence of stroke, MI, CHD, or lower risk of CVD-mortality). Significant results were reported in eight RCTs.^14,37,39,56,73,80,145,184^ Observational studies primarily examined endpoint outcomes with some reporting significant results for multiple types of endpoint outcomes, e.g., reduced CVD-mortality as well as reduced CVD-risk,^83^ or increased CVD-mortality and increased CVD-risk.^69^ No significant associations between diets based on macronutrient distribution and any/all CVD outcomes were reported in 22 of the included articles, including both RCTs and observational studies described further below.

###### Randomized controlled trials

Eight RCTs reported significant relationships between macronutrient based diet exposures and intermediate CVD outcomes,^14,37,39,56,73,80,145,184^ whereas the remaining (11 of 19) RCTs reported no significant relationship between macronutrient distributions compared and intermediate CVD outcomes.

Among the studies with any significant effects reported, different macronutrient distributions were compared. Five studies compared diets based on macronutrient proportions of carbohydrate below the AMDR compared to either carbohydrate within the AMDR^14,37,56,145^ or carbohydrate below the AMDR with fat above the AMDR.^39^ Results from these studies were inconsistent. Improved HDL levels after 12 mo were observed in two studies that tested participants exclusively with overweight or obesity, who were following “low-carbohydrate” diets, at 27.5% or 29.8% carbohydrate, compared to “low-fat” diets within the AMDR at 27.9% or 28.7% fat.^14,56^ Neither study reported any significant improvements in BP but both studies reported outcomes after 12 mo follow-up duration. It should be noted that Bazzano et al^14^ also reported significantly improved TG and TC:HDL ratio, but no changes in LDL and Gardner et al^56^ reported no changes in TG. It is likely that methodological differences between studies account for inconsistency in findings, such as the race/ethnicity was 51% African-American in Bazzano et al,^14^ but ~3-4% in Gardner et al.^56^

Some studies showed improved HDL, TC, and LDL levels when comparing diets based on macronutrient distributions within the AMDR compared to outside with diets that emphasized plant-based elements labeled as “low-fat Vegan” or “dietary guidelines” diet.^80,145^

Among studies testing varied levels of total fat intake, lower levels of fat intake within the AMDR were typically associated with improved CVD outcomes over shorter-term follow-up, but this was inconsistent. Howard et al^73^ tested diets at varied levels of reduced fat intake within the AMDR compared to control diets with fat intake above the AMDR from the Women’s Health Initiative Diet Modification Trial that targeted total fat reduction to 20% kcal with primary outcome being breast cancer. Qualitative changes in fat composition aimed at cardiovascular disease risk reduction was not considered. Lower BMI, waist circumference and body weight were reported after 1 y, but ultimately no significant differences between groups at the end of 6 y follow-up. Wan et al^184^ assessed “low”, “moderate”, and “high” levels of fat and carbohydrate intake, with the proportion of fat above the AMDR at 40% in the “high-fat” distribution, and proportion of carbohydrate slightly above the AMDR at 66% of energy in the “high-carbohydrate”. All other proportions, including “low-fat” were within the AMDR. Lowerfat levels within the AMDR and either “high-carbohydrate” at 66% or “moderate-carbohydrate” at 56% were significantly associated with lower TC, HDL, and LDL after 6 mo of follow-up.

Most of these trials had sufficient contrast between comparisons of the macronutrient distributions. However, one study compared intervention and control groups with macronutrient proportions similarly outside of the AMDR in the same direction (e.g., 37.8% carbohydrate, 38.8% fat, 19.4% protein vs. 40.3% carbohydrate, 35.6% fat, 19.2% protein).^39^

###### Observational studies

Significant results were reported in 19 of the observational studies and varied depending on the macronutrient distribution compared or dietary patterns examined. Eleven studies reported macronutrient distributions that were significantly associated with reduced CVD outcomes, including lower risk of CVD-mortality,^23,31,83,98,100^ decreased risk of (incident) CVD/CHD,^24,43,47,61,83,93^ or reduced cerebral infarction.^93^ Among those studies, the macronutrient distributions included fat above the AMDR compared to either fat within the AMDR,^43,61,83^ or above the AMDR,^47^ and carbohydrate below the AMDR.^93^

Six studies reported macronutrient distributions with carbohydrate below the AMDR and fat above the AMDR that were significantly associated with higher CVD-mortality and CVD-risk, including CHD and CVD-events.^54,59,69,110,126,154^ One study reported higher CVD-mortality risk when comparing macronutrient distributions within the AMDR compared to carbohydrate above and fat below the AMDR.^120^

Two studies reported similar findings that were dependent on whether the underlying dietary pattern was animal- or plant-based.^54,159^ Both studies reported that plant- or vegetable-based diets with macronutrient distributions of carbohydrate below the AMDR and fat above the AMDR compared to distributions with all proportions within the AMDR were significantly associated with lower risk of CVD-mortality, and the opposite for animal-based patterns, i.e., significantly associated with higher risk of CVD-mortality.

##### Assessment of the evidence^v^

This systematic review included 49 articles that examined diets based on macronutrient distribution and risk of CVD, met inclusion criteria, and were published between January 2000 and October 2019. Multiple databases were used to obtain publications from a large, comprehensive search. Although several studies were from large prospective cohorts, studies with smaller sample sizes were also included and reported both significant and non-significant results. Therefore, this risk of publication bias is low. As outlined and described below, the body of evidence was assessed for the following elements used when grading the strength of evidence.

- Risk of bias: There were a number of potential risks of bias, or limitations, across the body of evidence that make interpretation of results difficult (Table 5 and Table 6). While studies adjusted for most potential confounders, they did not adjust for all key confounders, such as race/ethnicity. Many studies evaluated dietary data only once at baseline, though generally validated methods were utilized. Several studies did not assess the impact of missing data, either due to loss to follow-up or criteria used when selecting participants into the analyses. Studies enrolled healthy adults as well as those who were obese or overweight, with high cardiovascular disease risk, or those with features of metabolic syndrome, so CVD risk at baseline varied across the body of evidence.
- Consistency: Of the 49 articles, there was variability in study design with 19 included from RCTs and 30 articles from PCSs. Results across the evidence, both in trials and observational studies were inconsistent in both directions and within outcomes. Most studies examined macronutrient distributions in which the proportion of energy from carbohydrate was below the AMDR in at least one of the exposure groups compared and the corresponding proportion of energy from fat was above the AMDR. However, the direction of findings was relatively spilt in terms of reduced vs. increased risk of CVD. Statistically significant relationships were observed but the gradient between the macronutrient distributions was narrow across studies (e.g., 43.6% vs. 45.2%). Studies varied in terms of the distribution of macronutrients that were examined and the methods used to estimate nutrient intakes, derive the proportion of energy from macronutrients (either from dietary record or FFQ data), and/or apply substitution modelling.
- Directness: The populations, intervention, comparators, and outcomes of interest in the included studies may be less directly related to the systematic review question. Several studies did not examine the impact of replacing energy from one macronutrient relative to another.
- Precision: All of the RCTs demonstrated adequate power with a wide range of sample sizes, although some studies had a very small sample size (n=16). The assessment of variance within these studies was relatively narrow, but several indicated wider variance in results. Most of the observational studies did not report power analyses or sample size calculations. However, the majority had large analytic sample sizes, with a range between n=2,006 and n=92,088
- Generalizability: The study participants, interventions and/or exposures, comparators, and outcomes examined in the body of evidence are applicable to the U.S. population. However, there is some concern with regards to variability in race/ethnicity of the study participants as a result of study design and a lack of accounting for race/ethnicity in many studies.

### Research recommendations

1. Determine the impact that dietary patterns may have that is independent of adiposity and/or weight-loss, to better inform studies examining the relationship between dietary patterns and risk of type 2 diabetes, cardiovascular disease, and/or obesity.
2. Conduct well-designed, sufficiently powered, studies that examine the relationship between well-defined and quantified dietary patterns consumed by children/adolescents and the prevention of cardiovascular disease in adulthood; particularly lacking are RCTs. Assessment of pubertal status in adolescents is important due to hormonal influences on CVD risk factors.
3. Develop a standardized definition and validated assessment methods for what constitutes a “very-low carbohydrate”, “ketogenic diet”, “low-carbohydrate” and/or “carbohydrate-restricted” dietary pattern based on macronutrient proportion.
4. Examine the relationship between diets based on macronutrient proportions of energy from carbohydrate below 25%, that include adequate information about diet quality to determine if and what relationship may exist between macronutrient-based dietary patterns, e.g., “low-carbohydrate”, and the prevention of cardiovascular disease. These types of studies need to adequately control for the quality of food intake and meeting Dietary Reference Intakes (DRIs).
5. Explore the role that macronutrient quality may have in the relationship between “low-carbohydrate” diets and the prevention of cardiovascular disease (i.e., effect modification).
6. Examine additional body fat distribution outcomes and in particular, ectopic fat.
7. Assess habitual diet intake at more than one time-point, over the course of follow-up, to facilitate potential causal relationships between dietary patterns and CVD risk factors over time.
8. Differentiate specific foods and food groups, in particular, the types and amounts, relevant biomarkers, and repeated measures to facilitate development of both preventive strategies and evaluate impact on the overall outcomes

### Included articles

1 Agha G, Loucks EB, Tinker LF, . Healthy lifestyle and decreasing risk of heart failure in women: the Women’s Health Initiative observational study. J Am Coll Cardiol. 2014;64(17):1777–1785. doi:10.1016/j.jacc.2014.07.981.25443698
2 Ahmad S, Moorthy MV, Demler OV, . Assessment of Risk Factors and Biomarkers Associated With Risk of Cardiovascular Disease Among Women Consuming a Mediterranean Diet. JAMA Netw Open. 2018;1(8):e185708. doi:10.1001/jamanetworkopen.2018.5708.30646282
3 Aigner A, Becher H, Jacobs S, . Low diet quality and the risk of stroke mortality: the multiethnic cohort study. Eur J Clin Nutr. 2018;72(7):1035–1045. doi:10.1038/s41430-018-0103-4.29426930
4 Akesson A, Larsson SC, Discacciati A, Wolk A. Low-risk diet and lifestyle habits in the primary prevention of myocardial infarction in men: a population-based prospective cohort study. J Am Coll Cardiol. 2014;64(13):1299–1306. doi:10.1016/j.jacc.2014.06.1190.25257629
5 Alvarez-Alvarez I, de Rojas JP, Fernandez-Montero A, . Strong inverse associations of Mediterranean diet, physical activity and their combination with cardiovascular disease: The Seguimiento Universidad de Navarra (SUN) cohort. Eur J Prev Cardiol. 2018;25(11):1186–1197. doi:10.1177/2047487318783263.29944010
6 Alvarez-Alvarez I, Zazpe I, Perez de Rojas J, . Mediterranean diet, physical activity and their combined effect on all-cause mortality: The Seguimiento Universidad de Navarra (SUN) cohort. Prev Med. 2018;106:45–52. doi:10.1016/j.ypmed.2017.09.021.28964855
7 Amor AJ, Serra-Mir M, Martinez-Gonzalez MA, . Prediction of Cardiovascular Disease by the Framingham-REGICOR Equation in the High-Risk PREDIMED Cohort: Impact of the Mediterranean Diet Across Different Risk Strata. J Am Heart Assoc. 2017;6(3). doi:10.1161/jaha.116.004803.
8 Arciero PJ, Gentile CL, Pressman R, . Moderate protein intake improves total and regional body composition and insulin sensitivity in overweight adults. Metabolism. 2008;57(6):757–765. doi:10.1016/j.metabol.2008.01.015.18502257
9 Asadi Z, Shafiee M, Sadabadi F, . Association of dietary patterns and risk of cardiovascular disease events in the MASHAD cohort study. J Hum Nutr Diet. 2019;32(6):789–801. doi:10.1111/jhn.12669.31332855
10 Atkins JL, Whincup PH, Morris RW, Lennon LT, Papacosta O, Wannamethee SG. High diet quality is associated with a lower risk of cardiovascular disease and all-cause mortality in older men. J Nutr. 2014;144(5):673–680. doi:10.3945/jn.113.186486.24572037
11 Atkins JL, Whincup PH, Morris RW, Lennon LT, Papacosta O, Wannamethee SG. Dietary patterns and the risk of CVD and all-cause mortality in older British men. Br J Nutr. 2016;116(7):1246–1255. doi:10.1017/s0007114516003147.27620002
12 Babio N, Toledo E, Estruch R, . Mediterranean diets and metabolic syndrome status in the PREDIMED randomized trial. Cmaj. 2014;186(17):E649–657. doi:10.1503/cmaj.140764.25316904
13 Baden MY, Liu G, Satija A, . Changes in Plant-Based Diet Quality and Total and Cause-Specific Mortality. Circulation. 2019;140(12):979–991. doi:10.1161/circulationaha.119.041014.31401846
14 Bazzano LA, Hu T, Reynolds K, . Effects of low-carbohydrate and low-fat diets: a randomized trial. Ann Intern Med. 2014;161(5):309–318. doi:10.7326/m14-0180.25178568
15 Bertoia ML, Triche EW, Michaud DS, . Mediterranean and Dietary Approaches to Stop Hypertension dietary patterns and risk of sudden cardiac death in postmenopausal women. Am J Clin Nutr. 2014;99(2):344–351. doi:10.3945/ajcn.112.056135.24351877
16 Biesbroek S, Kneepkens MC, van den Berg SW, . Dietary patterns within educational groups and their association with CHD and stroke in the European Prospective Investigation into Cancer and Nutrition-Netherlands cohort. Br J Nutr. 2018;119(8):949–956. doi:10.1017/s0007114518000569.29644959
17 Biesbroek S, van der AD, Brosens MC, . Identifying cardiovascular risk factor-related dietary patterns with reduced rank regression and random forest in the EPIC-NL cohort. Am J Clin Nutr. 2015;102(1):146–154. doi:10.3945/ajcn.114.092288.25971717
18 Bladbjerg EM, Larsen TM, Due A, Jespersen J, Stender S, Astrup A. Long-term effects on haemostatic variables of three ad libitum diets differing in type and amount of fat and carbohydrate: a 6-month randomised study in obese individuals. Br J Nutr. 2010;104(12):1824–1830. doi:10.1017/s0007114510002837.20670466
19 Bo S, Ponzo V, Goitre I, . Predictive role of the Mediterranean diet on mortality in individuals at low cardiovascular risk: a 12-year follow-up population-based cohort study. J Transl Med. 2016;14:91. doi:10.1186/s12967-016-0851-7.27071746
20 Bonaccio M, Di Castelnuovo A, Costanzo S, . Mediterranean diet and mortality in the elderly: a prospective cohort study and a meta-analysis. Br J Nutr. 2018;120(8):841–854. doi:10.1017/s0007114518002179.30157978
21 Bonaccio M, Di Castelnuovo A, Pounis G, . High adherence to the Mediterranean diet is associated with cardiovascular protection in higher but not in lower socioeconomic groups: prospective findings from the Moli-sani study. Int J Epidemiol. 2017;46(5):1478–1487. doi:10.1093/ije/dyx145.29040542
22 Booth JN, 3rd, Colantonio LD, Howard G, . Healthy lifestyle factors and incident heart disease and mortality in candidates for primary prevention with statin therapy. Int J Cardiol. 2016;207:196–202. doi:10.1016/j.ijcard.2016.01.001.26803243
23 Brunner EJ, Mosdol A, Witte DR, . Dietary patterns and 15-y risks of major coronary events, diabetes, and mortality. Am J Clin Nutr. 2008;87(5):1414–1421. doi:10.1093/ajcn/87.5.1414.18469266
24 Buckland G, Gonzalez CA, Agudo A, . Adherence to the Mediterranean diet and risk of coronary heart disease in the Spanish EPIC Cohort Study. Am J Epidemiol. 2009;170(12):1518–1529. doi:10.1093/aje/kwp282.19903723
25 Bull CJ, Northstone K. Childhood dietary patterns and cardiovascular risk factors in adolescence: results from the Avon Longitudinal Study of Parents and Children (ALSPAC) cohort. Public Health Nutr. 2016;19(18):3369–3377. doi:10.1017/s1368980016001592.27339189
26 Campos CL, Wood A, Burke GL, Bahrami H, Bertoni AG. Dietary Approaches to Stop Hypertension Diet Concordance and Incident Heart Failure: The Multi-Ethnic Study of Atherosclerosis. Am J Prev Med. 2019;56(6):819–826. doi:10.1016/j.amepre.2018.11.022.31003810
27 Casas R, Sacanella E, Urpi-Sarda M, . The effects of the mediterranean diet on biomarkers of vascular wall inflammation and plaque vulnerability in subjects with high risk for cardiovascular disease. A randomized trial. PLoS One. 2014;9(6):e100084. doi:10.1371/journal.pone.0100084.24925270
28 Casas R, Sacanella E, Urpi-Sarda M, . Long-Term Immunomodulatory Effects of a Mediterranean Diet in Adults at High Risk of Cardiovascular Disease in the PREvencion con DIeta MEDiterranea (PREDIMED) Randomized Controlled Trial. J Nutr. 2016;146(9):1684–1693. doi:10.3945/jn.115.229476.27440261
29 Chan RSM, Yu BWM, Leung J, . How Dietary Patterns are Related to Inflammaging and Mortality in Community-Dwelling Older Chinese Adults in Hong Kong - A Prospective Analysis. J Nutr Health Aging. 2019;23(2):181–194. doi:10.1007/s12603-018-1143-0.30697629
30 Chan She Ping-Delfos WL, Beilin LJ, Oddy WH, Burrows S, Mori TA. Use of the Dietary Guideline Index to assess cardiometabolic risk in adolescents. Br J Nutr. 2015;113(11):1741–1752. doi:10.1017/s0007114515001026.25873301
31 Cheng E, Um CY, Prizment A, Lazovich D, Bostick RM. Associations of evolutionary-concordance diet, Mediterranean diet and evolutionary-concordance lifestyle pattern scores with all-cause and cause-specific mortality. Br J Nutr. 2018:1–10. doi:10.1017/s0007114518003483.
32 Chiuve SE, Cook NR, Shay CM, . Lifestyle-based prediction model for the prevention of CVD: the Healthy Heart Score. J Am Heart Assoc. 2014;3(6):e000954. doi:10.1161/jaha.114.000954.25398889
33 Chomistek AK, Chiuve SE, Eliassen AH, Mukamal KJ, Willett WC, Rimm EB. Healthy lifestyle in the primordial prevention of cardiovascular disease among young women. J Am Coll Cardiol. 2015;65(1):43–51. doi:10.1016/j.jacc.2014.10.024.25572509
34 Cuenca-Garcia M, Artero EG, Sui X, Lee DC, Hebert JR, Blair SN. Dietary indices, cardiovascular risk factors and mortality in middle-aged adults: findings from the Aerobics Center Longitudinal Study. Ann Epidemiol. 2014;24(4):297–303.e292. doi:10.1016/j.annepidem.2014.01.007.24529647
35 Czekajlo A, Rozanska D, Zatonska K, Szuba A, Regulska-Ilow B. Association between dietary patterns and metabolic syndrome in the selected population of Polish adults-results of the PURE Poland Study. Eur J Public Health. 2019;29(2):335–340. doi:10.1093/eurpub/cky207.30285088
36 Dahm CC, Chomistek AK, Jakobsen MU, . Adolescent Diet Quality and Cardiovascular Disease Risk Factors and Incident Cardiovascular Disease in Middle-Aged Women. J Am Heart Assoc. 2016;5(12). doi:10.1161/jaha.116.003583.
37 Dale KS, McAuley KA, Taylor RW, . Determining optimal approaches for weight maintenance: a randomized controlled trial. Cmaj. 2009;180(10):E39–46. doi:10.1503/cmaj.080974.19433812
38 Daly RM, O’Connell SL, Mundell NL, Grimes CA, Dunstan DW, Nowson CA. Protein-enriched diet, with the use of lean red meat, combined with progressive resistance training enhances lean tissue mass and muscle strength and reduces circulating IL-6 concentrations in elderly women: a cluster randomized controlled trial. Am J Clin Nutr. 2014;99(4):899–910. doi:10.3945/ajcn.113.064154.24477043
39 Davis CR, Bryan J, Hodgson JM, Woodman R, Murphy KJ. A Mediterranean Diet Reduces F2-Isoprostanes and Triglycerides among Older Australian Men and Women after 6 Months. J Nutr. 2017;147(7):1348–1355. doi:10.3945/jn.117.248419.28566524
40 Davis CR, Hodgson JM, Woodman R, Bryan J, Wilson C, Murphy KJ. A Mediterranean diet lowers blood pressure and improves endothelial function: results from the MedLey randomized intervention trial. Am J Clin Nutr. 2017;105(6):1305–1313. doi:10.3945/ajcn.116.146803.28424187
41 Del Gobbo LC, Kalantarian S, Imamura F, . Contribution of Major Lifestyle Risk Factors for Incident Heart Failure in Older Adults: The Cardiovascular Health Study. JACC Heart Fail. 2015;3(7):520–528. doi:10.1016/j.jchf.2015.02.009.26160366
42 Delbridge EA, Prendergast LA, Pritchard JE, Proietto J. One-year weight maintenance after significant weight loss in healthy overweight and obese subjects: does diet composition matter? Am J Clin Nutr. 2009;90(5):1203–1214. doi:10.3945/ajcn.2008.27209.19793858
43 Diehr P, Beresford SA. The relation of dietary patterns to future survival, health, and cardiovascular events in older adults. J Clin Epidemiol. 2003;56(12):1224–1235. doi:10.1016/s0895-4356(03)00202-6.14680674
44 Djousse L, Ho YL, Nguyen XT, . DASH Score and Subsequent Risk of Coronary Artery Disease: The Findings From Million Veteran Program. J Am Heart Assoc. 2018;7(9). doi:10.1161/jaha.117.008089.
45 Due A, Larsen TM, Mu H, Hermansen K, Stender S, Astrup A. Comparison of 3 ad libitum diets for weight-loss maintenance, risk of cardiovascular disease, and diabetes: a 6-mo randomized, controlled trial. Am J Clin Nutr. 2008;88(5):1232–1241. doi:10.3945/ajcn.2007.25695.18996857
46 Eguaras S, Toledo E, Hernandez-Hernandez A, Cervantes S, Martinez-Gonzalez MA. Better Adherence to the Mediterranean Diet Could Mitigate the Adverse Consequences of Obesity on Cardiovascular Disease: The SUN Prospective Cohort. Nutrients. 2015;7(11):9154–9162. doi:10.3390/nu7115457.26556370
47 Ericson U, Brunkwall L, Alves Dias J, . Food patterns in relation to weight change and incidence of type 2 diabetes, coronary events and stroke in the Malmo Diet and Cancer cohort. Eur J Nutr. 2019;58(5):1801–1814. doi:10.1007/s00394-018-1727-9.29855685
48 Estruch R, Ros E, Salas-Salvado J, . Primary Prevention of Cardiovascular Disease with a Mediterranean Diet Supplemented with Extra-Virgin Olive Oil or Nuts. N Engl J Med. 2018;378(25):e34. doi:10.1056/NEJMoa1800389.29897866
49 Fanelli Kuczmarski M, Brewer BC, Rawal R, Pohlig RT, Zonderman AB, Evans MK. Aspects of Dietary Diversity Differ in Their Association with Atherosclerotic Cardiovascular Risk in a Racially Diverse US Adult Population. Nutrients. 2019;11(5). doi:10.3390/nu11051034.
50 Fazel-Tabar Malekshah A, Zaroudi M, Etemadi A, . The Combined Effects of Healthy Lifestyle Behaviors on All-Cause Mortality: The Golestan Cohort Study. Arch Iran Med. 2016;19(11):752–761. .27845543
51 Filippatos TD, Panagiotakos DB, Georgousopoulou EN, . Mediterranean Diet and 10-year (2002-2012) Incidence of Diabetes and Cardiovascular Disease in Participants with Prediabetes: The ATTICA study. Rev Diabet Stud. 2016;13(4):226–235. doi:10.1900/rds.2016.13.226.28278309
52 Fransen HP, May AM, Stricker MD, . A posteriori dietary patterns: how many patterns to retain? J Nutr. 2014;144(8):1274–1282. doi:10.3945/jn.113.188680.24872222
53 Fung TT, Pan A, Hou T, . Food quality score and the risk of coronary artery disease: a prospective analysis in 3 cohorts. Am J Clin Nutr. 2016;104(1):65–72. doi:10.3945/ajcn.116.130393.27281310
54 Fung TT, van Dam RM, Hankinson SE, Stampfer M, Willett WC, Hu FB. Low-carbohydrate diets and all-cause and cause-specific mortality: two cohort studies. Ann Intern Med. 2010;153(5):289–298. doi:10.7326/0003-4819-153-5-201009070-00003.20820038
55 Galbete C, Kroger J, Jannasch F, . Nordic diet, Mediterranean diet, and the risk of chronic diseases: the EPIC-Potsdam study. BMC Med. 2018;16(1):99. doi:10.1186/s12916-018-1082-y.29945632
56 Gardner CD, Trepanowski JF, Del Gobbo LC, . Effect of Low-Fat vs Low-Carbohydrate Diet on 12-Month Weight Loss in Overweight Adults and the Association With Genotype Pattern or Insulin Secretion: The DIETFITS Randomized Clinical Trial. Jama. 2018;319(7):667–679. doi:10.1001/jama.2018.0245.29466592
57 George SM, Ballard-Barbash R, Manson JE, . Comparing indices of diet quality with chronic disease mortality risk in postmenopausal women in the Women’s Health Initiative Observational Study: evidence to inform national dietary guidance. Am J Epidemiol. 2014;180(6):616–625. doi:10.1093/aje/kwu173.25035143
58 Georgousopoulou EN, Panagiotakos DB, Pitsavos C, Stefanadis C. Assessment of diet quality improves the classification ability of cardiovascular risk score in predicting future events: The 10-year follow-up of the ATTICA study (2002-2012). Eur J Prev Cardiol. 2015;22(11):1488–1498. doi:10.1177/2047487314555095.25316412
59 Guasch-Ferre M, Babio N, Martinez-Gonzalez MA, . Dietary fat intake and risk of cardiovascular disease and all-cause mortality in a population at high risk of cardiovascular disease. Am J Clin Nutr. 2015;102(6):1563–1573. doi:10.3945/ajcn.115.116046.26561617
60 Gunge VB, Andersen I, Kyro C, . Adherence to a healthy Nordic food index and risk of myocardial infarction in middle-aged Danes: the diet, cancer and health cohort study. Eur J Clin Nutr. 2017;71(5):652–658. doi:10.1038/ejcn.2017.1.28247857
61 Halton TL, Willett WC, Liu S, . Low-carbohydrate-diet score and the risk of coronary heart disease in women. N Engl J Med. 2006;355(19):1991–2002. doi:10.1056/NEJMoa055317.17093250
62 Hansen CP, Overvad K, Kyro C, . Adherence to a Healthy Nordic Diet and Risk of Stroke: A Danish Cohort Study. Stroke. 2017;48(2):259–264. doi:10.1161/strokeaha.116.015019.28049735
63 Hansen CP, Overvad K, Tetens I, . Adherence to the Danish food-based dietary guidelines and risk of myocardial infarction: a cohort study. Public Health Nutr. 2018;21(7):1286–1296. doi:10.1017/s1368980017003822.29331164
64 Hansen SH, Overvad K, Hansen CP, Dahm CC. Adherence to national food-based dietary guidelines and incidence of stroke: A cohort study of Danish men and women. PLoS One. 2018;13(10):e0206242. doi:10.1371/journal.pone.0206242.30356304
65 Haring B, Gronroos N, Nettleton JA, von Ballmoos MC, Selvin E, Alonso A. Dietary protein intake and coronary heart disease in a large community based cohort: results from the Atherosclerosis Risk in Communities (ARIC) study [corrected]. PLoS One. 2014;9(10):e109552. doi:10.1371/journal.pone.0109552.25303709
66 Haring B, Misialek JR, Rebholz CM, . Association of Dietary Protein Consumption With Incident Silent Cerebral Infarcts and Stroke: The Atherosclerosis Risk in Communities (ARIC) Study. Stroke. 2015;46(12):3443–3450. doi:10.1161/strokeaha.115.010693.26514185
67 Harmon BE, Boushey CJ, Shvetsov YB, . Associations of key diet-quality indexes with mortality in the Multiethnic Cohort: the Dietary Patterns Methods Project. Am J Clin Nutr. 2015;101(3):587–597. doi:10.3945/ajcn.114.090688.25733644
68 Hellstrand S, Ericson U, Schulz CA, . Genetic susceptibility to dyslipidemia and incidence of cardiovascular disease depending on a diet quality index in the Malmo Diet and Cancer cohort. Genes Nutr. 2016;11:20. doi:10.1186/s12263-016-0536-0.27551321
69 Hernandez-Alonso P, Salas-Salvado J, Ruiz-Canela M, . High dietary protein intake is associated with an increased body weight and total death risk. Clin Nutr. 2016;35(2):496–506. doi:10.1016/j.clnu.2015.03.016.25886710
70 Hodge AM, Bassett JK, Dugue PA, . Dietary inflammatory index or Mediterranean diet score as risk factors for total and cardiovascular mortality. Nutr Metab Cardiovasc Dis. 2018;28(5):461–469. doi:10.1016/j.numecd.2018.01.010.29576250
71 Hoevenaar-Blom MP, Spijkerman AM, Boshuizen HC, Boer JM, Kromhout D, Verschuren WM. Effect of using repeated measurements of a Mediterranean style diet on the strength of the association with cardiovascular disease during 12 years: the Doetinchem Cohort Study. Eur J Nutr. 2014;53(5):1209–1215. doi:10.1007/s00394-013-0621-8.24276223
72 Houston DK, Ding J, Lee JS, . Dietary fat and cholesterol and risk of cardiovascular disease in older adults: the Health ABC Study. Nutr Metab Cardiovasc Dis. 2011;21(6):430–437. doi:10.1016/j.numecd.2009.11.007.20338738
73 Howard BV, Curb JD, Eaton CB, . Low-fat dietary pattern and lipoprotein risk factors: the Women’s Health Initiative Dietary Modification Trial. Am J Clin Nutr. 2010;91(4):860–874. doi:10.3945/ajcn.2009.28034.20164311
74 Hu EA, Steffen LM, Coresh J, Appel LJ, Rebholz CM. Adherence to the Healthy Eating Index-2015 and Other Dietary Patterns May Reduce Risk of Cardiovascular Disease, Cardiovascular Mortality, and All-Cause Mortality. J Nutr. 2020;150(2):312–321. doi:10.1093/jn/nxz218.31529069
75 Hulsegge G, Looman M, Smit HA, Daviglus ML, van der Schouw YT, Verschuren WM. Lifestyle Changes in Young Adulthood and Middle Age and Risk of Cardiovascular Disease and All-Cause Mortality: The Doetinchem Cohort Study. J Am Heart Assoc. 2016;5(1). doi:10.1161/jaha.115.002432.
76 Jackson JK, MacDonald-Wicks LK, McEvoy MA, . Better diet quality scores are associated with a lower risk of hypertension and non-fatal CVD in middle-aged Australian women over 15 years of follow-up. Public Health Nutr. 2020;23(5):882–893. doi:10.1017/s1368980019002842.31607277
77 Jenkins DJA, Boucher BA, Ashbury FD, . Effect of Current Dietary Recommendations on Weight Loss and Cardiovascular Risk Factors. J Am Coll Cardiol. 2017;69(9):1103–1112. doi:10.1016/j.jacc.2016.10.089.28254171
78 Johns DJ, Lindroos AK, Jebb SA, Sjostrom L, Carlsson LM, Ambrosini GL. Dietary patterns, cardiometabolic risk factors, and the incidence of cardiovascular disease in severe obesity. Obesity (Silver Spring). 2015;23(5):1063–1070. doi:10.1002/oby.20920.25865622
79 Jones NRV, Forouhi NG, Khaw KT, Wareham NJ, Monsivais P. Accordance to the Dietary Approaches to Stop Hypertension diet pattern and cardiovascular disease in a British, population-based cohort. Eur J Epidemiol. 2018;33(2):235–244. doi:10.1007/s10654-017-0354-8.29318403
80 Kahleova H, Dort S, Holubkov R, Barnard ND. A Plant-Based High-Carbohydrate, Low-Fat Diet in Overweight Individuals in a 16-Week Randomized Clinical Trial: The Role of Carbohydrates. Nutrients. 2018;10(9). doi:10.3390/nu10091302.
81 Kaluza J, Hakansson N, Harris HR, Orsini N, Michaelsson K, Wolk A. Influence of anti-inflammatory diet and smoking on mortality and survival in men and women: two prospective cohort studies. J Intern Med. 2019;285(1):75–91. doi:10.1111/joim.12823.30209831
82 Kastorini CM, Panagiotakos DB, Chrysohoou C, . Metabolic syndrome, adherence to the Mediterranean diet and 10-year cardiovascular disease incidence: The ATTICA study. Atherosclerosis. 2016;246:87–93. doi:10.1016/j.atherosclerosis.2015.12.025.26761772
83 Kim H, Caulfield LE, Garcia-Larsen V, Steffen LM, Coresh J, Rebholz CM. Plant-Based Diets Are Associated With a Lower Risk of Incident Cardiovascular Disease, Cardiovascular Disease Mortality, and All-Cause Mortality in a General Population of Middle-Aged Adults. J Am Heart Assoc. 2019;8(16):e012865. doi:10.1161/jaha.119.012865.31387433
84 Konieczna J, Yanez A, Monino M, . Longitudinal changes in Mediterranean diet and transition between different obesity phenotypes. Clin Nutr. 2020;39(3):966–975. doi:10.1016/j.clnu.2019.04.002.31053509
85 Kouvari M, Panagiotakos DB, Chrysohoou C, . Gender-specific, Lifestyle-related Factors and 10-year Cardiovascular Disease Risk; the ATTICA and GREECS Cohort Studies. Curr Vasc Pharmacol. 2019;17(4):401–410. doi:10.2174/1570161116666180608121720.29886832
86 Krieger JP, Cabaset S, Pestoni G, Rohrmann S, Faeh D. Dietary Patterns Are Associated with Cardiovascular and Cancer Mortality among Swiss Adults in a Census-Linked Cohort. Nutrients. 2018;10(3). doi:10.3390/nu10030313.
87 Kulezic A, Bergwall S, Fatemi S, . Healthy diet and fiber intake are associated with decreased risk of incident symptomatic peripheral artery disease - A prospective cohort study. Vasc Med. 2019;24(6):511–518. doi:10.1177/1358863x19867393.31431146
88 Kurotani K, Akter S, Kashino I, . Quality of diet and mortality among Japanese men and women: Japan Public Health Center based prospective study. Bmj. 2016;352:i1209. doi:10.1136/bmj.i1209.27005903
89 Lankinen M, Schwab U, Kolehmainen M, . A Healthy Nordic Diet Alters the Plasma Lipidomic Profile in Adults with Features of Metabolic Syndrome in a Multicenter Randomized Dietary Intervention. J Nutr. 2015;146(4):662–672. doi:10.3945/jn.115.220459.26962194
90 Lara KM, Levitan EB, Gutierrez OM, . Dietary Patterns and Incident Heart Failure in U.S. Adults Without Known Coronary Disease. J Am Coll Cardiol. 2019;73(16):2036–2045. doi:10.1016/j.jacc.2019.01.067.31023426
91 Larsson SC, Akesson A, Wolk A. Healthy diet and lifestyle and risk of stroke in a prospective cohort of women. Neurology. 2014;83(19):1699–1704. doi:10.1212/wnl.0000000000000954.25298305
92 Larsson SC, Akesson A, Wolk A. Overall diet quality and risk of stroke: a prospective cohort study in women. Atherosclerosis. 2014;233(1):27–29. doi:10.1016/j.atherosclerosis.2013.11.072.24529117
93 Larsson SC, Virtamo J, Wolk A. Dietary protein intake and risk of stroke in women. Atherosclerosis. 2012;224(1):247–251. doi:10.1016/j.atherosclerosis.2012.07.009.22854187
94 Larsson SC, Wallin A, Wolk A. Dietary Approaches to Stop Hypertension Diet and Incidence of Stroke: Results From 2 Prospective Cohorts. Stroke. 2016;47(4):986–990. doi:10.1161/strokeaha.116.012675.26869384
95 Larsson SC, Wolk A, Back M. Dietary patterns, food groups, and incidence of aortic valve stenosis: A prospective cohort study. Int J Cardiol. 2019;283:184–188. doi:10.1016/j.ijcard.2018.11.007.30416029
96 Lassale C, Gunter MJ, Romaguera D, . Diet Quality Scores and Prediction of All-Cause, Cardiovascular and Cancer Mortality in a Pan-European Cohort Study. PLoS One. 2016;11(7):e0159025. doi:10.1371/journal.pone.0159025.27409582
97 Lee HA, An H, Park H. Identification of Dietary Patterns Related to Metabolic Diseases and Their Association with Cardiovascular Disease: From the Korean Genome and Epidemiology Study. Nutrients. 2019;11(10). doi:10.3390/nu11102434.
98 Leosdottir M, Nilsson P, Nilsson JA, Mansson H, Berglund G. The association between total energy intake and early mortality: data from the Malmo Diet and Cancer Study. J Intern Med. 2004;256(6):499–509. doi:10.1111/j.1365-2796.2004.01407.x.15554951
99 Leosdottir M, Nilsson PM, Nilsson JA, Berglund G. Cardiovascular event risk in relation to dietary fat intake in middle-aged individuals: data from The Malmo Diet and Cancer Study. Eur J Cardiovasc Prev Rehabil. 2007;14(5):701–706. doi:10.1097/HJR.0b013e3282a56c45.17925631
100 Leosdottir M, Nilsson PM, Nilsson JA, Mansson H, Berglund G. Dietary fat intake and early mortality patterns-data from The Malmo Diet and Cancer Study. J Intern Med. 2005;258(2):153–165. doi:10.1111/j.1365-2796.2005.01520.x.16018792
101 Li Y, Hruby A, Bernstein AM, . Saturated Fats Compared With Unsaturated Fats and Sources of Carbohydrates in Relation to Risk of Coronary Heart Disease: A Prospective Cohort Study. J Am Coll Cardiol. 2015;66(14):1538–1548. doi:10.1016/j.jacc.2015.07.055.26429077
102 Li Y, Pan A, Wang DD, . Impact of Healthy Lifestyle Factors on Life Expectancies in the US Population. Circulation. 2018;138(4):345–355. doi:10.1161/circulationaha.117.032047.29712712
103 Li Y, Sato Y, Yamaguchi N. Lifestyle factors as predictors of general cardiovascular disease: use for early self-screening. Asia Pac J Public Health. 2014;26(4):414–424. doi:10.1177/1010539511423067.22156564
104 Lima ST, da Silva Nalin de Souza B, Franca AK, Salgado Filho N, Sichieri R. Dietary approach to hypertension based on low glycaemic index and principles of DASH (Dietary Approaches to Stop Hypertension): a randomised trial in a primary care service. Br J Nutr. 2013;110(8):1472–1479. doi:10.1017/s0007114513000718.23632203
105 Lopez-Laguna N, Martinez-Gonzalez MA, Toledo E, . Risk of peripheral artery disease according to a healthy lifestyle score: The PREDIMED study. Atherosclerosis. 2018;275:133–140. doi:10.1016/j.atherosclerosis.2018.05.049.29902701
106 Maddock J, Ambrosini GL, Griffin JL, . A dietary pattern derived using B-vitamins and its relationship with vascular markers over the life course. Clin Nutr. 2019;38(3):1464–1473. doi:10.1016/j.clnu.2018.06.969.30005901
107 Maddock J, Ziauddeen N, Ambrosini GL, Wong A, Hardy R, Ray S. Adherence to a Dietary Approaches to Stop Hypertension (DASH)-type diet over the life course and associated vascular function: a study based on the MRC 1946 British birth cohort. Br J Nutr. 2018;119(5):581–589. doi:10.1017/s0007114517003877.29508688
108 Martinez-Gonzalez MA, Sanchez-Tainta A, Corella D, . A provegetarian food pattern and reduction in total mortality in the Prevencion con Dieta Mediterranea (PREDIMED) study. Am J Clin Nutr. 2014;100 Suppl 1:320s–328s. doi:10.3945/ajcn.113.071431.24871477
109 Martinez-Gonzalez MA, Zazpe I, Razquin C, . Empirically-derived food patterns and the risk of total mortality and cardiovascular events in the PREDIMED study. Clin Nutr. 2015;34(5):859–867. doi:10.1016/j.clnu.2014.09.006.25304294
110 Mazidi M, Katsiki N, Mikhailidis DP, Sattar N, Banach M. Lower carbohydrate diets and all-cause and cause-specific mortality: a population-based cohort study and pooling of prospective studies. Eur Heart J. 2019;40(34):2870–2879. doi:10.1093/eurheartj/ehz174.31004146
111 Menotti A, Puddu PE. Comparison Of Four Dietary Scores As Determinants Of Coronary Heart Disease Mortality. Sci Rep. 2018;8(1):15001. doi:10.1038/s41598-018-33339-5.30301921
112 Menotti A, Puddu PE, Maiani G, Catasta G. Lifestyle behaviour and lifetime incidence of heart diseases. Int J Cardiol. 2015;201:293–299. doi:10.1016/j.ijcard.2015.08.050.26301663
113 Menotti A, Puddu PE, Maiani G, Catasta G. Cardiovascular and other causes of death as a function of lifestyle habits in a quasi extinct middle-aged male population. A 50-year follow-up study. Int J Cardiol. 2016;210:173–178. doi:10.1016/j.ijcard.2016.02.115.26962972
114 Mertens E, Markey O, Geleijnse JM, Givens DI, Lovegrove JA. Dietary Patterns in Relation to Cardiovascular Disease Incidence and Risk Markers in a Middle-Aged British Male Population: Data from the Caerphilly Prospective Study. Nutrients. 2017;9(1). doi:10.3390/nu9010075.
115 Mertens E, Markey O, Geleijnse JM, Lovegrove JA, Givens DI. Adherence to a healthy diet in relation to cardiovascular incidence and risk markers: evidence from the Caerphilly Prospective Study. Eur J Nutr. 2018;57(3):1245–1258. doi:10.1007/s00394-017-1408-0.28293738
116 Miller V, Mente A, Dehghan M, . Fruit, vegetable, and legume intake, and cardiovascular disease and deaths in 18 countries (PURE): a prospective cohort study. Lancet. 2017;390(10107):2037–2049. doi:10.1016/s0140-6736(17)32253-5.28864331
117 Mirmiran P, Bahadoran Z, Vakili AZ, Azizi F. Western dietary pattern increases risk of cardiovascular disease in Iranian adults: a prospective population-based study. Appl Physiol Nutr Metab. 2017;42(3):326–332. doi:10.1139/apnm-2016-0508.28177742
118 Mirmiran P, Moslehi N, Mahmoudof H, Sadeghi M, Azizi F. A Longitudinal Study of Adherence to the Mediterranean Dietary Pattern and Metabolic Syndrome in a Non-Mediterranean Population. Int J Endocrinol Metab. 2015;13(3):e26128. doi:10.5812/ijem.26128v2.26425127
119 Nagata C, Nakamura K, Wada K, . Total fat intake is associated with decreased mortality in Japanese men but not in women. J Nutr. 2012;142(9):1713–1719. doi:10.3945/jn.112.161661.22810986
120 Nakamura Y, Okuda N, Okamura T, . Low-carbohydrate diets and cardiovascular and total mortality in Japanese: a 29-year follow-up of NIPPON DATA80. Br J Nutr. 2014;112(6):916–924. doi:10.1017/s0007114514001627.25201302
121 Nanri A, Mizoue T, Shimazu T, . Dietary patterns and all-cause, cancer, and cardiovascular disease mortality in Japanese men and women: The Japan public health center-based prospective study. PLoS One. 2017;12(4):e0174848. doi:10.1371/journal.pone.0174848.28445513
122 Nazari SSH, Mokhayeri Y, Mansournia MA, Khodakarim S, Soori H. Associations between dietary risk factors and ischemic stroke: a comparison of regression methods using data from the Multi-Ethnic Study of Atherosclerosis. Epidemiol Health. 2018;40:e2018021. doi:10.4178/epih.e2018021.29807407
123 Neelakantan N, Koh WP, Yuan JM, van Dam RM. Diet-Quality Indexes Are Associated with a Lower Risk of Cardiovascular, Respiratory, and All-Cause Mortality among Chinese Adults. J Nutr. 2018;148(8):1323–1332. doi:10.1093/jn/nxy094.29982724
124 Neelakantan N, Naidoo N, Koh WP, Yuan JM, van Dam RM. The Alternative Healthy Eating Index Is Associated with a Lower Risk of Fatal and Nonfatal Acute Myocardial Infarction in a Chinese Adult Population. J Nutr. 2016;146(7):1379–1386. doi:10.3945/jn.116.231605.27306893
125 Nobbs HM, Yaxley A, Thomas J, . Do dietary patterns in older age influence the development of cancer and cardiovascular disease: A longitudinal study of ageing. Clin Nutr. 2016;35(2):528–535. doi:10.1016/j.clnu.2015.04.003.25912186
126 O’Neil A, Shivappa N, Jacka FN, . Pro-inflammatory dietary intake as a risk factor for CVD in men: a 5-year longitudinal study. Br J Nutr. 2015;114(12):2074–2082. doi:10.1017/S0007114515003815.26450630
127 Odegaard AO, Koh WP, Yuan JM, Gross MD, Pereira MA. Dietary patterns and mortality in a Chinese population. Am J Clin Nutr. 2014;100(3):877–883. doi:10.3945/ajcn.114.086124.25057151
128 Ogilvie RP, Lutsey PL, Heiss G, Folsom AR, Steffen LM. Dietary intake and peripheral arterial disease incidence in middle-aged adults: the Atherosclerosis Risk in Communities (ARIC) Study. Am J Clin Nutr. 2017;105(3):651–659. doi:10.3945/ajcn.116.137497.28077376
129 Okada E, Nakamura K, Ukawa S, . The Japanese food score and risk of all-cause, CVD and cancer mortality: the Japan Collaborative Cohort Study. Br J Nutr. 2018;120(4):464–471. doi:10.1017/s000711451800154x.29923480
130 Paineau DL, Beaufils F, Boulier A, . Family dietary coaching to improve nutritional intakes and body weight control: a randomized controlled trial. Arch Pediatr Adolesc Med. 2008;162(1):34–43. doi:10.1001/archpediatrics.2007.2.18180410
131 Panagiotakos DB, Georgousopoulou EN, Georgiopoulos GA, . Adherence to Mediterranean Diet Offers an Additive Protection Over the Use of Statin Therapy: Results from the ATTICA Study (2002-2012). Curr Vasc Pharmacol. 2015;13(6):778–787. doi:10.2174/1570161113666150416124957.25877292
132 Panagiotakos DB, Georgousopoulou EN, Pitsavos C, . Exploring the path of Mediterranean diet on 10-year incidence of cardiovascular disease: the ATTICA study (2002-2012). Nutr Metab Cardiovasc Dis. 2015;25(3):327–335. doi:10.1016/j.numecd.2014.09.006.25445882
133 Panaretos D, Koloverou E, Dimopoulos AC, . A comparison of statistical and machine-learning techniques in evaluating the association between dietary patterns and 10-year cardiometabolic risk (2002-2012): the ATTICA study. Br J Nutr. 2018;120(3):326–334. doi:10.1017/s0007114518001150.29789037
134 Panizza CE, Shvetsov YB, Harmon BE, . Testing the Predictive Validity of the Healthy Eating Index-2015 in the Multiethnic Cohort: Is the Score Associated with a Reduced Risk of All-Cause and Cause-Specific Mortality? Nutrients. 2018;10(4). doi:10.3390/nu10040452.
135 Papadaki A, Martinez-Gonzalez MA, Alonso-Gomez A, . Mediterranean diet and risk of heart failure: results from the PREDIMED randomized controlled trial. Eur J Heart Fail. 2017;19(9):1179–1185. doi:10.1002/ejhf.750.28133855
136 Park YM, Fung TT, Steck SE, . Diet Quality and Mortality Risk in Metabolically Obese Normal-Weight Adults. Mayo Clin Proc. 2016;91(10):1372–1383. doi:10.1016/j.mayocp.2016.06.022.27712636
137 Park YM, Steck SE, Fung TT, . Mediterranean diet and mortality risk in metabolically healthy obese and metabolically unhealthy obese phenotypes. Int J Obes (Lond). 2016;40(10):1541–1549. doi:10.1038/ijo.2016.114.27339604
138 Paterson KE, Myint PK, Jennings A, . Mediterranean Diet Reduces Risk of Incident Stroke in a Population With Varying Cardiovascular Disease Risk Profiles. Stroke. 2018:2415–2420. doi:10.1161/strokeaha.117.020258.30580733
139 Pinto A, Santos AC, Lopes C, Oliveira A. Dietary patterns at 7 year-old and their association with cardiometabolic health at 10 year-old. Clin Nutr. 2020;39(4):1195–1202. doi:10.1016/j.clnu.2019.05.007.31133488
140 Poulsen SK, Due A, Jordy AB, . Health effect of the New Nordic Diet in adults with increased waist circumference: a 6-mo randomized controlled trial. Am J Clin Nutr. 2014;99(1):35–45. doi:10.3945/ajcn.113.069393.24257725
141 Preis SR, Stampfer MJ, Spiegelman D, Willett WC, Rimm EB. Dietary protein and risk of ischemic heart disease in middle-aged men. Am J Clin Nutr. 2010;92(5):1265–1272. doi:10.3945/ajcn.2010.29626.20881068
142 Preis SR, Stampfer MJ, Spiegelman D, Willett WC, Rimm EB. Lack of association between dietary protein intake and risk of stroke among middle-aged men. Am J Clin Nutr. 2010;91(1):39–45. doi:10.3945/ajcn.2009.28060.19889826
143 Reedy J, Krebs-Smith SM, Miller PE, . Higher diet quality is associated with decreased risk of all-cause, cardiovascular disease, and cancer mortality among older adults. J Nutr. 2014;144(6):881–889. doi:10.3945/jn.113.189407.24572039
144 Reedy J, Lerman JL, Krebs-Smith SM, . Evaluation of the Healthy Eating Index-2015. J Acad Nutr Diet. 2018;118(9):1622–1633. doi:10.1016/j.jand.2018.05.019.30146073
145 Reidlinger DP, Darzi J, Hall WL, Seed PT, Chowienczyk PJ, Sanders TA. How effective are current dietary guidelines for cardiovascular disease prevention in healthy middle-aged and older men and women? A randomized controlled trial. Am J Clin Nutr. 2015;101(5):922–930. doi:10.3945/ajcn.114.097352.25787998
146 Roswall N, Sandin S, Lof M, . Adherence to the healthy Nordic food index and total and cause-specific mortality among Swedish women. Eur J Epidemiol. 2015;30(6):509–517. doi:10.1007/s10654-015-0021-x.25784368
147 Roswall N, Sandin S, Scragg R, . No association between adherence to the healthy Nordic food index and cardiovascular disease amongst Swedish women: a cohort study. J Intern Med. 2015;278(5):531–541. doi:10.1111/joim.12378.25991078
148 Sanders TA, Lewis FJ, Goff LM, Chowienczyk PJ. SFAs do not impair endothelial function and arterial stiffness. Am J Clin Nutr. 2013;98(3):677–683. doi:10.3945/ajcn.113.063644.23964054
149 Santiago S, Zazpe I, Gea A, . Fat Quality Index and Risk of Cardiovascular Disease in the Sun Project. J Nutr Health Aging. 2018;22(4):526–533. doi:10.1007/s12603-018-1003-y.29582893
150 Saris WH, Astrup A, Prentice AM, . Randomized controlled trial of changes in dietary carbohydrate/fat ratio and simple vs complex carbohydrates on body weight and blood lipids: the CARMEN study. The Carbohydrate Ratio Management in European National diets. Int J Obes Relat Metab Disord. 2000;24(10):1310–1318. doi:10.1038/sj.ijo.0801451.11093293
151 Satija A, Bhupathiraju SN, Spiegelman D, . Healthful and Unhealthful Plant-Based Diets and the Risk of Coronary Heart Disease in U.S. Adults. J Am Coll Cardiol. 2017;70(4):411–422. doi:10.1016/j.jacc.2017.05.047.28728684
152 Seah JYH, Ong CN, Koh WP, Yuan JM, van Dam RM. A Dietary Pattern Derived from Reduced Rank Regression and Fatty Acid Biomarkers Is Associated with Lower Risk of Type 2 Diabetes and Coronary Artery Disease in Chinese Adults. J Nutr. 2019;149(11):2001–2010. doi:10.1093/jn/nxz164.31386157
153 Shah NS, Leonard D, Finley CE, . Dietary Patterns and Long-Term Survival: A Retrospective Study of Healthy Primary Care Patients. Am J Med. 2018;131(1):48–55. doi:10.1016/j.amjmed.2017.08.010.28860032
154 Shikany JM, Safford MM, Newby PK, Durant RW, Brown TM, Judd SE. Southern Dietary Pattern is Associated With Hazard of Acute Coronary Heart Disease in the Reasons for Geographic and Racial Differences in Stroke (REGARDS) Study. Circulation. 2015;132(9):804–814. doi:10.1161/circulationaha.114.014421.26260732
155 Shivappa N, Hebert JR, Kivimaki M, Akbaraly T. Alternative Healthy Eating Index 2010, Dietary Inflammatory Index and risk of mortality: results from the Whitehall II cohort study and meta-analysis of previous Dietary Inflammatory Index and mortality studies. Br J Nutr. 2017;118(3):210–221. doi:10.1017/S0007114517001908.28831955
156 Shvetsov YB, Harmon BE, Ettienne R, . The influence of energy standardisation on the alternate Mediterranean diet score and its association with mortality in the Multiethnic Cohort. Br J Nutr. 2016;116(9):1592–1601. doi:10.1017/s0007114516003482.27766989
157 Sidahmed E, Cornellier ML, Ren J, . Development of exchange lists for Mediterranean and Healthy Eating diets: implementation in an intervention trial. J Hum Nutr Diet. 2014;27(5):413–425. doi:10.1111/jhn.12158.24112099
158 Sonestedt E, Hellstrand S, Drake I, . Diet Quality and Change in Blood Lipids during 16 Years of Follow-up and Their Interaction with Genetic Risk for Dyslipidemia. Nutrients. 2016;8(5). doi:10.3390/nu8050274.
159 Song M, Fung TT, Hu FB, . Association of Animal and Plant Protein Intake With All-Cause and Cause-Specific Mortality. JAMA Intern Med. 2016;176(10):1453–1463. doi:10.1001/jamainternmed.2016.4182.27479196
160 Sotos-Prieto M, Bhupathiraju SN, Mattei J, . Changes in Diet Quality Scores and Risk of Cardiovascular Disease Among US Men and Women. Circulation. 2015;132(23):2212–2219. doi:10.1161/circulationaha.115.017158.26644246
161 Sotos-Prieto M, Bhupathiraju SN, Mattei J, . Association of Changes in Diet Quality with Total and Cause-Specific Mortality. N Engl J Med. 2017;377(2):143–153. doi:10.1056/NEJMoa1613502.28700845
162 Srour B, Fezeu LK, Kesse-Guyot E, . Ultra-processed food intake and risk of cardiovascular disease: prospective cohort study (NutriNet-Sante). Bmj. 2019;365:l1451. doi:10.1136/bmj.l1451.31142457
163 Steffen LM, Van Horn L, Daviglus ML, . A modified Mediterranean diet score is associated with a lower risk of incident metabolic syndrome over 25 years among young adults: the CARDIA (Coronary Artery Risk Development in Young Adults) study. Br J Nutr. 2014;112(10):1654–1661. doi:10.1017/s0007114514002633.25234439
164 Stefler D, Malyutina S, Kubinova R, . Mediterranean diet score and total and cardiovascular mortality in Eastern Europe: the HAPIEE study. Eur J Nutr. 2017;56(1):421–429. doi:10.1007/s00394-015-1092-x.26578528
165 Struijk EA, May AM, Wezenbeek NL, . Adherence to dietary guidelines and cardiovascular disease risk in the EPIC-NL cohort. Int J Cardiol. 2014;176(2):354–359. doi:10.1016/j.ijcard.2014.07.017.25107447
166 Tektonidis TG, Akesson A, Gigante B, Wolk A, Larsson SC. A Mediterranean diet and risk of myocardial infarction, heart failure and stroke: A population-based cohort study. Atherosclerosis. 2015;243(1):93–98. doi:10.1016/j.atherosclerosis.2015.08.039.26363438
167 Tektonidis TG, Akesson A, Gigante B, Wolk A, Larsson SC. Adherence to a Mediterranean diet is associated with reduced risk of heart failure in men. Eur J Heart Fail. 2016;18(3):253–259. doi:10.1002/ejhf.481.26781788
168 Tharrey M, Mariotti F, Mashchak A, Barbillon P, Delattre M, Fraser GE. Patterns of plant and animal protein intake are strongly associated with cardiovascular mortality: the Adventist Health Study-2 cohort. Int J Epidemiol. 2018;47(5):1603–1612. doi:10.1093/ije/dyy030.29618018
169 Tierney AC, McMonagle J, Shaw DI, . Effects of dietary fat modification on insulin sensitivity and on other risk factors of the metabolic syndrome-LIPGENE: a European randomized dietary intervention study. Int J Obes (Lond). 2011;35(6):800–809. doi:10.1038/ijo.2010.209.20938439
170 Tikk K, Sookthai D, Monni S, . Primary preventive potential for stroke by avoidance of major lifestyle risk factors: the European Prospective Investigation into Cancer and Nutrition-Heidelberg cohort. Stroke. 2014;45(7):2041–2046. doi:10.1161/strokeaha.114.005025.24876086
171 Toledo E, Hu FB, Estruch R, . Effect of the Mediterranean diet on blood pressure in the PREDIMED trial: results from a randomized controlled trial. BMC Med. 2013;11:207. doi:10.1186/1741-7015-11-207.24050803
172 Tong TY, Wareham NJ, Khaw KT, Imamura F, Forouhi NG. Prospective association of the Mediterranean diet with cardiovascular disease incidence and mortality and its population impact in a non-Mediterranean population: the EPIC-Norfolk study. BMC Med. 2016;14(1):135. doi:10.1186/s12916-016-0677-4.27679997
173 Tong TYN, Appleby PN, Bradbury KE, . Risks of ischaemic heart disease and stroke in meat eaters, fish eaters, and vegetarians over 18 years of follow-up: results from the prospective EPIC-Oxford study. Bmj. 2019;366:l4897. doi:10.1136/bmj.l4897.31484644
174 Trebuchet A, Julia C, Fezeu L, . Prospective association between several dietary scores and risk of cardiovascular diseases: Is the Mediterranean diet equally associated to cardiovascular diseases compared to National Nutritional Scores? Am Heart J. 2019;217:1–12. doi:10.1016/j.ahj.2019.07.009.31450161
175 Tsivgoulis G, Psaltopoulou T, Wadley VG, . Adherence to a Mediterranean diet and prediction of incident stroke. Stroke. 2015;46(3):780–785. doi:10.1161/strokeaha.114.007894.25628306
176 Uusitupa M, Hermansen K, Savolainen MJ, . Effects of an isocaloric healthy Nordic diet on insulin sensitivity, lipid profile and inflammation markers in metabolic syndrome - a randomized study (SYSDIET). J Intern Med. 2013;274(1):52–66. doi:10.1111/joim.12044.23398528
177 van Lee L, Geelen A, Kiefte-de Jong JC, . Adherence to the Dutch dietary guidelines is inversely associated with 20-year mortality in a large prospective cohort study. Eur J Clin Nutr. 2016;70(2):262–268. doi:10.1038/ejcn.2015.163.26486300
178 Veglia F, Baldassarre D, de Faire U, . A priori-defined Mediterranean-like dietary pattern predicts cardiovascular events better in north Europe than in Mediterranean countries. Int J Cardiol. 2019;282:88–92. doi:10.1016/j.ijcard.2018.11.124.30545617
179 Vincent-Baudry S, Defoort C, Gerber M, . The Medi-RIVAGE study: reduction of cardiovascular disease risk factors after a 3-mo intervention with a Mediterranean-type diet or a low-fat diet. Am J Clin Nutr. 2005;82(5):964–971. doi:10.1093/ajcn/82.5.964.16280426
180 Vissers LE, Waller MA, van der Schouw YT, . The relationship between the dietary inflammatory index and risk of total cardiovascular disease, ischemic heart disease and cerebrovascular disease: Findings from an Australian population-based prospective cohort study of women. Atherosclerosis. 2016;253:164–170. doi:10.1016/j.atherosclerosis.2016.07.929.27498398
181 Voortman T, Kiefte-de Jong JC, Ikram MA, . Adherence to the 2015 Dutch dietary guidelines and risk of non-communicable diseases and mortality in the Rotterdam Study. Eur J Epidemiol. 2017;32(11):993–1005. doi:10.1007/s10654-017-0295-2.28825166
182 Vormund K, Braun J, Rohrmann S, Bopp M, Ballmer P, Faeh D. Mediterranean diet and mortality in Switzerland: an alpine paradox? Eur J Nutr. 2015;54(1):139–148. doi:10.1007/s00394-014-0695-y.24710740
183 Wakai K, Naito M, Date C, Iso H, Tamakoshi A, Group JS. Dietary intakes of fat and total mortality among Japanese populations with a low fat intake: the Japan Collaborative Cohort (JACC) Study. Nutr Metab (Lond). 2014;11(1):12. doi:10.1186/1743-7075-11-12.24597664
184 Wan Y, Wang F, Yuan J, . Effects of Macronutrient Distribution on Weight and Related Cardiometabolic Profile in Healthy Non-Obese Chinese: A 6-month, Randomized Controlled-Feeding Trial. EBioMedicine. 2017;22:200–207. doi:10.1016/j.ebiom.2017.06.017.28655596
185 Wang H, Qu M, Yang P, Yang B, Deng F. Dietary patterns and cardio-cerebrovascular disease in a Chinese population. Nutr Res Pract. 2015;9(3):313–318. doi:10.4162/nrp.2015.9.3.313.26060544
186 Warensjo Lemming E, Byberg L, Wolk A, Michaelsson K. A comparison between two healthy diet scores, the modified Mediterranean diet score and the Healthy Nordic Food Index, in relation to all-cause and cause-specific mortality. Br J Nutr. 2018;119(7):836–846. doi:10.1017/s0007114518000387.29569544
187 Whalen KA, Judd S, McCullough ML, Flanders WD, Hartman TJ, Bostick RM. Paleolithic and Mediterranean Diet Pattern Scores Are Inversely Associated with All-Cause and Cause-Specific Mortality in Adults. J Nutr. 2017;147(4):612–620. doi:10.3945/jn.116.241919.28179490
188 Wirth J, di Giuseppe R, Boeing H, Weikert C. A Mediterranean-style diet, its components and the risk of heart failure: a prospective population-based study in a non-Mediterranean country. Eur J Clin Nutr. 2016;70(9):1015–1021. doi:10.1038/ejcn.2016.140.27507073
189 Yu D, Sonderman J, Buchowski MS, . Healthy Eating and Risks of Total and Cause-Specific Death among Low-Income Populations of African-Americans and Other Adults in the Southeastern United States: A Prospective Cohort Study. PLoS Med. 2015;12(5):e1001830; discussion e1001830. doi:10.1371/journal.pmed.1001830.26011727
190 Mokhtari Z, Sharafkhah M, Poustchi H, . Adherence to the Dietary Approaches to Stop Hypertension (DASH) diet and risk of total and cause-specific mortality: results from the Golestan Cohort Study. Int J Epidemiol. 2019;48(6):1824–1838. doi:10.1093/ije/dyz079.31056682

Table 1 Studies that examined dietary patterns consumed during childhood and risk of cardiovascular disease^vi^

Study and Participant Characteristics^vii^ | Dietary Pattern | Results^viii^ | Methodological Considerations
Bull, 2016 ^25^; United Kingdom, Avon Longitudinal Study of Parents and Children (ALSPAC) cohort; Prospective Cohort Study; N=2311; 56% female; Excluded those with missing data on CVD measures, dietary patterns info at all time points, and covariable data | [underlined: Factor/cluster analysis:]; Four dietary patterns at ages 7, 10, and 13y; - Healthy, ref.: Non-white bread, reduced-fat milk, cheese, yoghurt and fromage frais, butter, breakfast cereal, rice, pasta, eggs, fish, vegetable and vegetarian dishes, soup, salad, legumes, fruit, crackers and crispbreads, high-energy-density sauces (e.g. mayonnaise), fruit juice, water; - Processed: Processed meat, pies and pasties, coated and fried chicken and white fish, pizza, chips, baked beans and tinned pasta, chocolate, sweets, sugar, diet and regular fizzy drinks; - Traditional: Red meat, poultry, potatoes, vegetables, starch-based products, low-energy-density sauces, puddings, tea, coffee; - Packed Lunch: White bread, margarine, ham and bacon, sweet spreads, salty flavourings, crisps, biscuits, diet squash, tea, coffee | [underlined: Dietary patterns at age 7y:]; ᴓ SBP, DBP at 17 y f/u [all patterns]; ↓ high LDL at 17 y f/u [Processed vs. Healthy; ᴓ other patterns]; ↑ low HDL at 17 y f/u [Packed-lunch vs. Healthy; ᴓ other patterns]; ↓ high TG at 17 y f/u [Processed vs. Healthy; ᴓ other patterns]; [underlined: Dietary patterns at age 10y:]; ᴓ SBP, DBP at 17 y f/u [all patterns]; ↓ LDL at 17 y f/u [Processed vs. Healthy; ᴓ other patterns]; ↓ high TG at 17 y f/u [Processed vs. Healthy and Traditional vs. Healthy; ᴓ Packed-lunch]; ↓ high TC at 17 y f/u [Traditional vs. Healthy and Packed-lunch vs. Healthy; ᴓ Processed]; [underlined: Dietary patterns at age 13y:]; ᴓ SBP, DBP, LDL, HDL, TG, or TC at 17 y f/u [all patterns] | [underlined: Did not account for:]; Race/ethnicity, Physical activity, Anthropometry; N/A: Alcohol, Smoking; [underlined: Limitations:]; Diet assessed once each age time point; Unclear if diet assessment methods were valid/reliable; [underlined: Funding:]; The UK Medical Research Council and the Wellcome Trust and the University of Bristol
Chan She Ping-Delfos, 2015 ^30^; Australia, Western Australian Pregnancy Cohort; Prospective Cohort Study; N=1419; 53% female; Excluded those with missing data, implausible energy intake | [underlined: Index/score:] Dietary Guideline Index for Children and Adolescents (DGI-CA) score (continuous) at 14y; Components: Fruit/100% fruit juice, vegetables and legumes, breads and cereals, whole grain bread relative to total, meat and alternatives (excluding processed meat); dairy products: reduced- or low-fat dairy, water as a beverage, healthy fats: total fats, <3/d ‘extra foods’ | ᴓ TC, HDL, LDL, DBP at 17 y f/u (NS); ↓TAG at 17 y f/u; ↓SBP at 17 y f/u | Did not account for: Race/ethnicity; N/A: Alcohol, Smoking; [underlined: Limitations:]; Diet assessed once at baseline; Diet assessment record validated in adults only; [underlined: Funding:]; University of Western Australia; the Faculty of Medicine, Dentistry and Health Sciences at the University of Western Australia; the Telethon Kids Institute; the Women and Infants Research Foundation; Curtin University; and the Raine Medical Research Foundation; National Health and Medical Research Council; Telstra Research Fund; National Health and Medical Research Council
Dahm, 2016 ^36^; United States, Nurses’ Health Study II (NHS II); Prospective Cohort Study, with retrospectively analzyed data.; N=27406 for T2D outcome, N=42112 for CVD outcomes; 100% female; Excluded those with hx of CVD, cancer, hypercholesterolemia, HTN, T2DM | [underlined: Index/score:] Alternative Healthy Eating Index (AHEI)-2010, examined as quintiles w/ Q1, ref and continuous per 10pt increment | ᴓ CVD risk at 13 y f/u (categorical and continuous); ↓ HTN risk at 13 y f/u (categorical and continuous) | [underlined: Did not account for:]; Race/ethnicity; [underlined: Limitations:]; Diet assessed once at baseline, and was recalled retrospectively; [underlined: Funding:]; Carlsbergfondet Postdoc Travel Grant; the Danish Ministry of Science, Innovation and Higher Education International Network Programme; the Danish Council for Strategic Research; NIH
Pinto, 2019 Clin Nutr^139^; Portugal, Generation XXI Birth Cohort; Prospective Cohort Study; N=3350; 48% female; Excluded those with missing data, twins | [underlined: Factor/cluster analysis:]; Seven dietary patterns at age 7y; - PCA-1: Higher loadings for sugary drinks, sweets, salty snacks, lower loadings for fish, vegetable, soup, fruits; - PCA-2: Skim milk, yogurt. cheese, eggs, ham, fish, vegetables, fruits, fruit, rice, potatoes, pasta, 100% fruit juice; - PLS-1: Higher loadings for processed meats, cakes, soft drinks, lower loadings for vegetable soup; - PLS-2: Lower loadings for energy-dense foods, sugary drinks, higher loadings for fish; - EDF: Sweets, soft drinks, salty pastry, processed meat; - Snacking: Snack foods, lower in fish, meat, eggs, rice, pasta, potatoes, vegetables; - Healthier: Higher in vegetables, fish, and lower in energy dense foods | PLS-1: ↑ DBP at 10 y f/u, ᴓ SBP, TG, HDL, LDL; PCA-1: ↑ SBP at 10 y f/u, ᴓ DBP, TG, HDL, LDL; PCA-2, PLS-2: ᴓ SBP, DBP, TG, HDL, LDL at 10 y f/u; EDF vs. Healthier: ᴓ SBP, DBP, TG, HDL, LDL at 10 y f/u; Snacking vs. Healthier: ᴓ SBP, DBP, TG, HDL, LDL at 10 y f/u | [underlined: Did not account for:]; Race/ethnicity; N/A: Alcohol, Smoking; [underlined: Limitations:]; Diet assessed once at baseline; [underlined: Funding:]; Instituto de Salud Carlos III

Table 2 Description of randomized controlled trials that examined the relationship between diets based on macronutrient proportion and risk of cardiovascular disease^ix^

Study and Participant Characteristics^x^ | Diet Intervention Groups^xi^ | Macronutrient Distribution, % Energy | | | Summary of Findings^xii^ | Methodological considerations
Study and Participant Characteristics^x^ | Diet Intervention Groups^xi^ | Carbohydrate | Fat | Protein | Summary of Findings^xii^ | Methodological considerations
Arciero, 2008 ^8^; United States, N=16; All overweight or obese | % E in “high-protein” (HP) diet | 25.3 | 31.3 | 43.5 | ᴓ TC, HDL, TC/HDL ratio, or TG at 3mo f/u | NA; [underlined: Funding:]; Abbott Laboratories
Arciero, 2008 ^8^; United States, N=16; All overweight or obese | % E in “moderate-protein” (MP) diet | 41.9 | 28.8 | 26.9 | ᴓ TC, HDL, TC/HDL ratio, or TG at 3mo f/u | NA; [underlined: Funding:]; Abbott Laboratories
Bazzano, 2014 ^14^; United States; N=148; 89% female; All obese (BMI 30-45 kg/m2) | %E in “low-carbohydrate” (LC) diet at baseline | 46.0 | 34.7 | 17.6 | N/A (baseline) | NA; [underlined: Funding:]; National Center for Research Resources of the NIH
Bazzano, 2014 ^14^; United States; N=148; 89% female; All obese (BMI 30-45 kg/m2) | % E in “low-fat” (LF) diet at baseline | 48.1 | 32.5 | 17.3 | N/A (baseline) | NA; [underlined: Funding:]; National Center for Research Resources of the NIH
Bazzano, 2014 ^14^; United States; N=148; 89% female; All obese (BMI 30-45 kg/m2) | LC diet at 3mo | 52.9 | 27.5 | 19 | ᴓ TC, LDL, HDL, SBP, DBP at 3mo; ↓ TG and TC:HDL ratio | NA; [underlined: Funding:]; National Center for Research Resources of the NIH
Bazzano, 2014 ^14^; United States; N=148; 89% female; All obese (BMI 30-45 kg/m2) | LF diet at 3mo | 28.9 | 42.7 | 25.6 | ᴓ TC, LDL, HDL, SBP, DBP at 3mo; ↓ TG and TC:HDL ratio | NA; [underlined: Funding:]; National Center for Research Resources of the NIH
Bazzano, 2014 ^14^; United States; N=148; 89% female; All obese (BMI 30-45 kg/m2) | LC diet at 6mo | 52.4 | 27.9 | 18.3 | ᴓ TC, LDL, SBP, DBP at 3mo; ↑ HDL at 6mo;; ↓ TG, and TC:HDL ratio at 6mo;; ᴓ TC, LDL, SBP, DBP at 12mo; ↑ HDL at 12mo;; ↓ TG, and TC:HDL ratio at 12mo; | NA; [underlined: Funding:]; National Center for Research Resources of the NIH
Bazzano, 2014 ^14^; United States; N=148; 89% female; All obese (BMI 30-45 kg/m2) | LF diet at 6mo | 27.5 | 43.4 | 26.3 | ᴓ TC, LDL, SBP, DBP at 3mo; ↑ HDL at 6mo;; ↓ TG, and TC:HDL ratio at 6mo;; ᴓ TC, LDL, SBP, DBP at 12mo; ↑ HDL at 12mo;; ↓ TG, and TC:HDL ratio at 12mo; | NA; [underlined: Funding:]; National Center for Research Resources of the NIH
Bazzano, 2014 ^14^; United States; N=148; 89% female; All obese (BMI 30-45 kg/m2) | LC diet at 12mo | 54 | 29.8 | 18.6 | ᴓ TC, LDL, SBP, DBP at 3mo; ↑ HDL at 6mo;; ↓ TG, and TC:HDL ratio at 6mo;; ᴓ TC, LDL, SBP, DBP at 12mo; ↑ HDL at 12mo;; ↓ TG, and TC:HDL ratio at 12mo; | NA; [underlined: Funding:]; National Center for Research Resources of the NIH
Bazzano, 2014 ^14^; United States; N=148; 89% female; All obese (BMI 30-45 kg/m2) | LF diet at 12mo | 34 | 40.7 | 23.6 | ᴓ TC, LDL, SBP, DBP at 3mo; ↑ HDL at 6mo;; ↓ TG, and TC:HDL ratio at 6mo;; ᴓ TC, LDL, SBP, DBP at 12mo; ↑ HDL at 12mo;; ↓ TG, and TC:HDL ratio at 12mo; | NA; [underlined: Funding:]; National Center for Research Resources of the NIH
Bladbjerg, 2010 ^18^; United States, Mono Unsaturated Fatty acids in Obesity (MUFObes); N=131; All obese, otherwise healthy post-weight-loss phase | % E in monounsatured fat (MUFA) diet or low-fat (LF) diet vs. control for 6mo; MUFA diet: high content of vegetable oils, whole-grain food, nuts and legumes. | 43.3 | 38.4 | 15.3 | ᴓ TAG or TC over 6mo f/u | NA; Groups differed at baseline in BMI and effect persisted over 6mo; [underlined: Funding:]; HA Foundation, The Danish Heart Association, The Danish Diabetes Association, Centre for Advanced Food Research, The state Research Councils, and The Danish Pork Council foundations, associations, and research councils
Bladbjerg, 2010 ^18^; United States, Mono Unsaturated Fatty acids in Obesity (MUFObes); N=131; All obese, otherwise healthy post-weight-loss phase | LF: data NR (Due, 2008) | 57.6 | 23.6 | 15.8 | ᴓ TAG or TC over 6mo f/u
Bladbjerg, 2010 ^18^; United States, Mono Unsaturated Fatty acids in Obesity (MUFObes); N=131; All obese, otherwise healthy post-weight-loss phase | Control diet: average Danish diet | 49.2 | 32.1 | 15.9 | ᴓ TAG or TC over 6mo f/u
Dale, 2009 ^37^; New Zealand, N=174; All women, without chronic disease | High MUFA diet, year 1 | 43 | 30 | 23 | ᴓ SBP, DBP, HDL, TG at 1y, 2y; ↓ TC, LD at 1y, 2y | [underlined: Funding:]; Health Research Council of New Zealand.
Dale, 2009 ^37^; New Zealand, N=174; All women, without chronic disease | High MUFA, year 2 | 43 | 30 | 23 | ᴓ SBP, DBP, HDL, TG at 1y, 2y; ↓ TC, LD at 1y, 2y | [underlined: Funding:]; Health Research Council of New Zealand.
Dale, 2009 ^37^; New Zealand, N=174; All women, without chronic disease | “High-Carbohydrate”, year 1 | 43 | 31 | 22 | ᴓ SBP, DBP, HDL, TG at 1y, 2y; ↓ TC, LD at 1y, 2y | [underlined: Funding:]; Health Research Council of New Zealand.
Dale, 2009 ^37^; New Zealand, N=174; All women, without chronic disease | “High-Carbohydrate”, year 2 | 47 | 27 | 22 | ᴓ SBP, DBP, HDL, TG at 1y, 2y; ↓ TC, LD at 1y, 2y | [underlined: Funding:]; Health Research Council of New Zealand.
Daly, 2014 ^38^; Australia, N=91; All women, 60-90y, without acute or terminal illness, hx of fracture, type 1 diabetes, kidney disease | “Lean meat” group | 41.3 | 29.6 | 23.9 | ᴓ SBP, DBP, TC, HDL, LDL, TG at 16wk | Ran 2 sessions of the intervention within each village, 1 y apart; [underlined: Funding:]; Meat and Livestock Australia Ltd, a National Health and Medical Research Council Career Development Award; an Australian Research Council Future Fellowship
Daly, 2014 ^38^; Australia, N=91; All women, 60-90y, without acute or terminal illness, hx of fracture, type 1 diabetes, kidney disease | “Rice/pasta” group | 42.1 | 33.2 | 17.9 | ᴓ SBP, DBP, TC, HDL, LDL, TG at 16wk
Davis, 2017 ^39^; Australia, N=166; All non-smoker, without chronic disease and major psychological illnesses | “Traditional” Diet | 37.8 | 38.8 | 19.4 | ᴓ TC, LDL, HDL, at 3mo, 6mo; ↓ TG at 3mo, 6mo | NA; [underlined: Funding:]; National Health and Medical Research Council (Australian government)
Davis, 2017 ^39^; Australia, N=166; All non-smoker, without chronic disease and major psychological illnesses | “Habitual” Diet | 40.3 | 35.6 | 19.2 | ᴓ TC, LDL, HDL, at 3mo, 6mo; ↓ TG at 3mo, 6mo | NA; [underlined: Funding:]; National Health and Medical Research Council (Australian government)
Delbridge, 2009 ^42^; Australia, N=141; All overweight or obese | “High Carbohydrate” diet | 55 | 30 | 15 | ᴓ TC, HDL, LDL, TG, SBP, DBP at 12mo | NA; [underlined: Funding:]; Meat and Livestock Australia
Delbridge, 2009 ^42^; Australia, N=141; All overweight or obese | “High Protein” diet | 40 | 30 | 30 | ᴓ TC, HDL, LDL, TG, SBP, DBP at 12mo | NA; [underlined: Funding:]; Meat and Livestock Australia
Due, 2008 ^45^; United States, N=125; All lost >8% Wt after pre-intervention phase | “MUFA” diet Guidance to consume vegetables, fruit, whole-meal cereals, vegetable oils, nuts, pulses, fish, poultry, eggs; restrictred meat, butter, dairy, white rice, plain pasta, white bread, potatoes, sweets, soft drinks | 43.3 | 38.4 | 15.3 | ᴓ TC, LDL, HDL, TG at 6mo | NA; [underlined: Funding:]; H.A. Foundation, The Danish Heart Association, The Danish Diabetes Association, the Centre for Advanced Food Research, the State Research Councils, and The Danish Pork Council foundations, associations, and research councils
Due, 2008 ^45^; United States, N=125; All lost >8% Wt after pre-intervention phase | “Low-Fat” diet Guidance to consume vegetables, fruit, whole-meal cereals, vegetable oils, nuts, pulses, fish, poultry, eggs; restrictred meat, butter, dairy, white rice, plain pasta, white bread, potatoes, sweets, soft drinks | 57.6 | 23.6 | 15.8 | ᴓ TC, LDL, HDL, TG at 6mo
Due, 2008 ^45^; United States, N=125; All lost >8% Wt after pre-intervention phase | Control; Guidance to consume dairy, cheese, red meat; less fish, poultry, eggs, rice/pasta, bread, sweets, soft drinks, fruit, vegetables, pulses, nuts, oils | 49.8 | 32.1 | 15.9 | ᴓ TC, LDL, HDL, TG at 6mo
Gardner, 2018 ^56^; United States, DIETFITS; N=609; All overweight or obese | “Healthy Low Fat” diet Guidance to consume oils, fatty meats, whole-fat dairy, nuts | 48.4 | 28.7 | 20.6 | ᴓ BP at 12mo; ↑ HDL, LDL at 12mo, LC vs. LF; ↓ TG at 12mo, LC vs. LF | NA; [underlined: Funding:]; National Institute of Diabetes and Digestive and Kidney Diseases; Nutrition Science Initiative; National Heart, Lung, and Blood Institute, and the Stanford Clinical and Translational Science Award.
Gardner, 2018 ^56^; United States, DIETFITS; N=609; All overweight or obese | “Healthy Low Carbohydrate” diet Guidance to consume cereals, grains, rice, starchy vegetables, legumes | 29.8 | 44.6 | 22.9 | ᴓ BP at 12mo; ↑ HDL, LDL at 12mo, LC vs. LF; ↓ TG at 12mo, LC vs. LF
Howard, 2010 ^73^; United States, Women’s Health Initiative Dietary Modification Trial; N=2730; All postmenopausal women, w/o hx of cancer, >32%E fat intake | “Low Fat Diet“, year 1 | 58 | 25.3 | 17.5 | ↓ SBP in control vs. low fat diet at 1y, 3y, ᴓ at 6y; ↓ TC in control vs. intervention at 3y, ᴓ at 1y, 6y; ↓ LDL in control vs. intervention at 3y, ᴓ at 1y, 6y; ↓ HDL in control vs. intervention at1y, ᴓ at 3y, 6y; ᴓ TG at 1y, 3y, 6y | NA; Some missing outcome data not accounted for; [underlined: Funding:]; National Heart, Lung, and Blood Institute, NIH, HHS
Howard, 2010 ^73^; United States, Women’s Health Initiative Dietary Modification Trial; N=2730; All postmenopausal women, w/o hx of cancer, >32%E fat intake | “Low Fat Diet“, year 3 | 56.4 | 26.5 | 17.6 | | NA; Some missing outcome data not accounted for; [underlined: Funding:]; National Heart, Lung, and Blood Institute, NIH, HHS
Howard, 2010 ^73^; United States, Women’s Health Initiative Dietary Modification Trial; N=2730; All postmenopausal women, w/o hx of cancer, >32%E fat intake | “Low Fat Diet“, year 6; Guidance to reduce fat from ~35%E to 20%E of energy, 5 servings/d fruits and vegetables, 6 serving/d grains | 53.9 | 29.3 | 17.7 | | NA; Some missing outcome data not accounted for; [underlined: Funding:]; National Heart, Lung, and Blood Institute, NIH, HHS
Howard, 2010 ^73^; United States, Women’s Health Initiative Dietary Modification Trial; N=2730; All postmenopausal women, w/o hx of cancer, >32%E fat intake | Control Diet, year 1 | 47.9 | 35.7 | 16.5 | | NA; Some missing outcome data not accounted for; [underlined: Funding:]; National Heart, Lung, and Blood Institute, NIH, HHS
Howard, 2010 ^73^; United States, Women’s Health Initiative Dietary Modification Trial; N=2730; All postmenopausal women, w/o hx of cancer, >32%E fat intake | Control Diet, year 3 | 47 | 36 | 17 | | NA; Some missing outcome data not accounted for; [underlined: Funding:]; National Heart, Lung, and Blood Institute, NIH, HHS
Howard, 2010 ^73^; United States, Women’s Health Initiative Dietary Modification Trial; N=2730; All postmenopausal women, w/o hx of cancer, >32%E fat intake | Control Diet, year 6; Received written health-related materials only | 46.3 | 37 | 17 | | NA; Some missing outcome data not accounted for; [underlined: Funding:]; National Heart, Lung, and Blood Institute, NIH, HHS
Kahleova, 2018 ^80^; United States; N=75; All overweight or obese, without Hx of diabetes, smoking, alcohol/ drug abuse, pregnancy/lactation, or current use of vegan diet | “Low Fat, Vegan” Diet: Guidance to consume vegetables, grains, legumes, and fruits, and avoid animal products and added fats; Control Diet | 69.6 | 17.5 | 12.3 | ↓ TC, HDL, LDL at 16wk; ᴓ TG at 16wk | NA; Adherence not fully described; No information about foods and beverages consumed; [underlined: Funding:]; Physicians Committee for Responsible Medicine.
Kahleova, 2018 ^80^; United States; N=75; All overweight or obese, without Hx of diabetes, smoking, alcohol/ drug abuse, pregnancy/lactation, or current use of vegan diet | “Low Fat, Vegan” Diet: Guidance to consume vegetables, grains, legumes, and fruits, and avoid animal products and added fats; Control Diet | 46.6 | 35 | 17 | ↓ TC, HDL, LDL at 16wk; ᴓ TG at 16wk | NA; Adherence not fully described; No information about foods and beverages consumed; [underlined: Funding:]; Physicians Committee for Responsible Medicine.
Paineau, 2008 ^130^; France, N=1013; All parents with children (family intervention) | Reduce Fat, Increase Complex Carbohydrate diet (Group A) | 46.4 | 32.4 | 18.8 | ᴓ TG, LDL, HDL, TC at 8mo | NA; [underlined: Funding:]; French Ministry of Research; ELPAS study’s private partners
Paineau, 2008 ^130^; France, N=1013; All parents with children (family intervention) | Reduce Fat, Sugar, Increase Complex Carbohydrate diet (Group B) | 45.3 | 33 | 19.3 | ᴓ TG, LDL, HDL, TC at 8mo | NA; [underlined: Funding:]; French Ministry of Research; ELPAS study’s private partners
Paineau, 2008 ^130^; France, N=1013; All parents with children (family intervention) | Control | 43.8 | 35.6 | 18 | ᴓ TG, LDL, HDL, TC at 8mo | NA; [underlined: Funding:]; French Ministry of Research; ELPAS study’s private partners
Reidlinger, 2015 ^145^; United Kingdom, CRESSIDA; N=162; All w/CVD or <20% 10y CVD risk | “Dietary Guidelines” diet | 45.2 | 33.1 | 17.7 | ↓ SBP, DBP, TC, LDL, LDL, TG at 12wk | NA; [underlined: Funding:]; United Kingdom Food Standards Agency and Department of Health and by the National Institute for Health Research (NIHR) Clinical Research Facility at Guy’s and St Thomas’ NHS Foundation Trust and NIHR Biomedical Research Centre based at Guy’s and St Thomas’ NHS Foundation Trust and King’s College London.
Reidlinger, 2015 ^145^; United Kingdom, CRESSIDA; N=162; All w/CVD or <20% 10y CVD risk | Control diet | 43.1 | 37.8 | 15.7 | ↓ SBP, DBP, TC, LDL, LDL, TG at 12wk
Sanders, 2013 ^148^; United Kingdom, RISCK; N=108; All at risk for metabolic syndrome | “High Saturated Fat” diet Guidance to use full-fat milk and cheese | 42.8 | 35.7 | 17.8 | ᴓ SBP, DBP at 24wk | NA; [underlined: Funding:]; Biological Biotechnology Scientific Research Council and Food Standards Agency and supported by the National Institute for Health Research (NIHR) Clinical Research Facility at Guy’s and St Thomas’ National Health Service (NHS) Foundation Trust and NIHR Biomedical Research Centre based at Guy’s and St Thomas’ NHS FoundationTrust and King’s College London
Sanders, 2013 ^148^; United Kingdom, RISCK; N=108; All at risk for metabolic syndrome | “High MUFA” diet Guidance to replace full-fat milk with skimmed and full-fat cheese with half-fat cheese; snack foods provided (nuts and potato crisps) | 47.2 | 34.4 | 16.2 | ᴓ SBP, DBP at 24wk
Sanders, 2013 ^148^; United Kingdom, RISCK; N=108; All at risk for metabolic syndrome | “High Carbohydrate” diet Guidance to replace full-fat milk with skimmed and full-fat cheese with half-fat cheese; advised to consume additional portions of bread, potatoes, and rice | 53.1 | 26.1 | 17.8 | ᴓ SBP, DBP at 24wk
Saris, 2000 ^150^; European countries, CARMEN (trial); N=316; All “moderately obese” with BMI between 26 and 30 kg/m2; Excluded those with endocrine, liver, kidney or blood disease, and BMI <26 or >35 kg/m2 | “Low-fat, high-simple-carbohydrate” group (LFHSC) | 55.5 | 25.5 | 15.8 | ᴓ TC, HDL, LDL, HDL:LDL, TAG, LFHSC vs. Control; LFHSC vs. LFHCC; or LFHCC vs. Control at 6mo | NA; All foods provided via laboratory shop system Note:Fat % E “remained constant” in control group during; [underlined: Funding:]; EU-FAIR program; European Sugar industries
| “Low-fat, high-complex-carbohydrate” group (LFHCC) | 51.8 | 27.8 | 17.9 | ᴓ TC, HDL, LDL, HDL:LDL, TAG, LFHSC vs. Control; LFHSC vs. LFHCC; or LFHCC vs. Control at 6mo | NA; All foods provided via laboratory shop system Note:Fat % E “remained constant” in control group during; [underlined: Funding:]; EU-FAIR program; European Sugar industries
| Control diet group, ref. | 45.5 | 36.5 | 15.2 | ᴓ TC, HDL, LDL, HDL:LDL, TAG, LFHSC vs. Control; LFHSC vs. LFHCC; or LFHCC vs. Control at 6mo | NA; All foods provided via laboratory shop system Note:Fat % E “remained constant” in control group during; [underlined: Funding:]; EU-FAIR program; European Sugar industries
Tierney, 2011 ^169^; Europe - Multiple Countries, LIPGENE; N=417; All w/ metabolic syndrome | “High-Fat, High-Saturated Fat” diet | 41.2 | 39.8 | 17.4 | ᴓ HDL, LDL, SBP, DBP, TG at 12wk | NA; [underlined: Funding:]; EU 6 Framework Food Safety & Quality Programme; Norwegian Foundation for Health and Rehabilitation, South Eastern Norway Regional Health Authority, the Johan Throne Holst Foundation for Nutrition Research and the Freia Medical Research Foundation.
Tierney, 2011 ^169^; Europe - Multiple Countries, LIPGENE; N=417; All w/ metabolic syndrome | “High-Fat, High-MUFA” diet | 42.1 | 38.9 | 16.9 | ᴓ HDL, LDL, SBP, DBP, TG at 12wk
Tierney, 2011 ^169^; Europe - Multiple Countries, LIPGENE; N=417; All w/ metabolic syndrome | “Low-Fat, High-Complex-carbohydrate” diet, +sunflower oil supplement | 49.4 | 29.6 | 19.2 | ᴓ HDL, LDL, SBP, DBP, TG at 12wk
Tierney, 2011 ^169^; Europe - Multiple Countries, LIPGENE; N=417; All w/ metabolic syndrome | “Low-Fat, High-Complex-carbohydrate diet, +n-3 PUFA supplement) | 50.2 | 29.1 | 18.3 | ᴓ HDL, LDL, SBP, DBP, TG at 12wk
Uusitupa, 2013 ^176^; Finland, Sweden, Denmark, Iceland, SYSDIET; N=166; All with features of metabolic syndrome | “Healthy Nordic” diet Guidance to consume whole-grain products, berries, fruit, vegetables, rapeseed oil, three fish meals/wk, low-fat dairy products and avoid sugar-sweetened products | 46.1 | 32.9 | 16.9 | ᴓ TC, LDL, HDL, TG, SBP, DBP at 18/24wk (note: LDL, HDL P<0.1) | NA; [underlined: Funding:]; NordForsk; Academy of Finland, Finnish Diabetes Research Foundation, Finnish Foundation for Cardiovascular Research, The Sigfrid Juselius Foundation, Kuopio University Hospital (Finland); the Druvan Foundation, ESPEN, Skane County Council Research and Development Foundation, The Heart-Lung Foundation, Diabetesfonden and Foundation Cerealia (Sweden); The Danish Obesity Research Centre (DanORC), The Danish Council for Strategic Research (Dairy-Health, BioFunCarb) (Denmark), The Agricultural Productivity Fund, The Research Fund of the University of Iceland (Iceland)
Uusitupa, 2013 ^176^; Finland, Sweden, Denmark, Iceland, SYSDIET; N=166; All with features of metabolic syndrome | Control diet | 44.6 | 35.2 | 16.2 | ᴓ TC, LDL, HDL, TG, SBP, DBP at 18/24wk (note: LDL, HDL P<0.1)
Vincent-Baudry, 2005 ^179^; France, Medi-RIVAge; N=212; All at high CVD risk | “Mediterranean” diet Guidance to consume nuts, whole-meal bread, cereals, fruit, vegetables, legumes, olive oil; fish 4/wk, red meat 1/wk; sheep, poultry; oat-brain enriched pasta, tomato sauce, olive oil provided | 45.9 | 34.6 | 19.6 | ᴓ SBP, DBP, TC, HDL, LDL, TG at 3mo | NA; [underlined: Funding:]; French Research Ministry; INSERM (IDS grant), the Provence-Alpes-Côte d’Azur Regional Council, the Bouches du Rhône General Council, the CRITT-PACA; Rivoire & Carret Lustucru, Jean Martin, Le Cabanon, Boulangerie Coagulation Surgelés, Distplack Mariani, and Minoterie Giraud.
Vincent-Baudry, 2005 ^179^; France, Medi-RIVAge; N=212; All at high CVD risk | “Low-Fat” diet Guidance to consume more poultry than mammal meat, avoid offal and SF-rich animal products, fish 2-3 times/wk; fruit, vegetables, low-fat dairy products, vegetable oils | 44.8 | 33.9 | 21.3 | ᴓ SBP, DBP, TC, HDL, LDL, TG at 3mo
Wan, 2017 ^184^; China, N=307; All BMI <28 kg/m2 | “Low-Fat, High-Carbohydrate” (LF-HC) diet | 66.0 | 20.0 | 14.0 | ↓ TC, HDL, LDL in LF-HC vs. MF-MC, HF-LC at 6mo; ᴓ TC, HDL, LDL in HF-LC vs. MF-MC at 6mo | NA; [underlined: Funding:]; National Basic Research Program of China
Wan, 2017 ^184^; China, N=307; All BMI <28 kg/m2 | “Moderate-Fat, Moderate Carbohydrate” (MF-MC) diet | 56.0 | 30.0 | 14.0 | ↓ TC, HDL, LDL in LF-HC vs. MF-MC, HF-LC at 6mo; ᴓ TC, HDL, LDL in HF-LC vs. MF-MC at 6mo | NA; [underlined: Funding:]; National Basic Research Program of China
Wan, 2017 ^184^; China, N=307; All BMI <28 kg/m2 | “High-Fat, Low-Carbohydrate” (HF-LC) diet | 46.0 | 40.0 | 14.0 | ↓ TC, HDL, LDL in LF-HC vs. MF-MC, HF-LC at 6mo; ᴓ TC, HDL, LDL in HF-LC vs. MF-MC at 6mo | NA; [underlined: Funding:]; National Basic Research Program of China

Table 3 Description of prospective cohort studies that examined the relationship between diets based on macronutrient proportion and risk of cardiovascular disease^xiii^

Study and Partcipant Characteristcs^xiiv^ | Diet Exposure Groups | Category | Macronutrient Distribution, % En | | | Summary of Findings^xv^ | Methodological considerations
Study and Partcipant Characteristcs^xiiv^ | Diet Exposure Groups | Category | Carbohydrate | Fat | Protein | Summary of Findings^xv^ | Methodological considerations
Brunner, 2008 ^23^; United Kingdom, Whitehall II study; N=7731 | % E in four dietary patterns identified by cluster analysis; ‘Unhealthy’: Higher than average consumption of meat and sausages, white bread, fries, and full-cream milk. Average consumption of wine and beer; very low consumption of fruit and vegetables | ‘Unhealthy’, ref. | 41.4 | 33.1 | 17.3 | ↓’fatal CHD + non-fatal MI in ‘Healthy’ vs. ‘Unhealthy’ at f/u; ᴓ fatal CHD + non-fatal MI in ‘Sweet’vs. ‘Unhealthy’; or ‘Mediterranean-type’ vs. ‘Unhealthy’ at f/u | Confounders accounted for: Sex, Age, Race/ethnicity, Alcohol: Part of dietary pattern, Physical activity, EI/EE (BMI within), Smoking; Other: SES, Total Energy Intake (EI/EE); Did not account for the following key confounders: N/A; Diet assessed once at baseline using validated FFQ; Missing data on exposures; [underlined: Funding:]; United K Medical Research Council (MRC), the British Heart Foundation, the Health and Safety Executive, the Department of Health, the National Heart Lung and Blood Institute, the National Institute on Aging, the Agency for Health Care Policy Research, and the MacArthur Foundation Research Network on Socio-economic Status and Health.
Brunner, 2008 ^23^; United Kingdom, Whitehall II study; N=7731 | ‘Sweet’: Higher than average consumption of biscuits, cakes, meat, sausages and savory pies, white bread, full-cream milk, butter, and wine and beer. Average intake of fruit and vegetables. | ‘Sweet’ | 43.2 | 33.6 | 15.7 | ↓’fatal CHD + non-fatal MI in ‘Healthy’ vs. ‘Unhealthy’ at f/u; ᴓ fatal CHD + non-fatal MI in ‘Sweet’vs. ‘Unhealthy’; or ‘Mediterranean-type’ vs. ‘Unhealthy’ at f/u
Brunner, 2008 ^23^; United Kingdom, Whitehall II study; N=7731 | ‘Mediterranean-like’: Higher than average consumption of whole-meal bread, fruit, vegetables, pasta and rice, and wine and beer. Low intake of full-cream milk but high intake of butter. Average consumption of white bread | ‘Mediterranean-like’ | 40.4 | 32 | 16.8 | ↓’fatal CHD + non-fatal MI in ‘Healthy’ vs. ‘Unhealthy’ at f/u; ᴓ fatal CHD + non-fatal MI in ‘Sweet’vs. ‘Unhealthy’; or ‘Mediterranean-type’ vs. ‘Unhealthy’ at f/u
Brunner, 2008 ^23^; United Kingdom, Whitehall II study; N=7731 | ‘Healthy’: Higher than average consumption of whole-meal bread, fruit and vegetables, and polyunsaturated margarine. Average to low consumption of | ‘Healthy’ | 43.4 | 30.5 | 17.9 | ↓’fatal CHD + non-fatal MI in ‘Healthy’ vs. ‘Unhealthy’ at f/u; ᴓ fatal CHD + non-fatal MI in ‘Sweet’vs. ‘Unhealthy’; or ‘Mediterranean-type’ vs. ‘Unhealthy’ at f/u
Buckland, 2009 ^24^; Spain,; N=41078; All healthy participants, those with CVD excluded, as well as those with missing data on smoking, diabetes, HTN, or hyperlipidemia status | Tertiles of adhrence to a relative Mediterranean diet (rMED).; Positive Components: Fruit, Vegetables, Legumes, Alcohol (moderate intake, otherwise alcohol was neutral), Cereals, Fresh Fish and Olive Oil.; Negative Components: Total meat and dairy products | T1 | 39.8 | 38.3 | 18.0 | ↓’CHD at10 y f/u; Sensitivity Analyses: The relationship remains unchanged when excluding those with diabetes at baseline, when censoring CHD cases and at-risk participants in the first 2 years of follow-up, and when censoring CHD cases classified as unstable anginas. With energy adjusted tertiles of rMED score or sex-specific medians, the relationship also remains unchanged. | Confounders accounted for: Sex, Age, Race/ethnicity: all Spanish participants, Physical activity, SES: Education, Anthropometry: BMI, smoking, Alcohol: part of dietary pattern, Other: Study center, diabetes, HTN, and hyperlipidemia status at follow up and total caloric intake.; Did not account for the following key confounders: N/A; Diet assessed once at baseline using validated FFQ; [underlined: Funding:]; Health Research Institute Carlos III, Spain (RETIC) from the Spanish Ministry of Health
Buckland, 2009 ^24^; Spain,; N=41078; All healthy participants, those with CVD excluded, as well as those with missing data on smoking, diabetes, HTN, or hyperlipidemia status | | T2 | 41.7 | 37.1 | 17.9
Buckland, 2009 ^24^; Spain,; N=41078; All healthy participants, those with CVD excluded, as well as those with missing data on smoking, diabetes, HTN, or hyperlipidemia status | | T3 | 42.7 | 35.8 | 17.5
Cheng, 2018 ^31^; United States, Iowa Women’s Health Study; N=35221; Attrition: 16% | % E in quintiles of adherence [categorical, continuous] to the modified alternate Med Diet Score (mMDS) (modified Fung,2005); Positive: Vegetables (not potatoes), Fruits, Whole grains, Legumes, Fish, Nuts, MUFA:SFA; Negative: Red and processed meats,; Other: Alcohol | Q1, ref. | 45.4 | 36.9 | 17.9 | ↓CVD-mortality, continuous, at ~26y f/u; ↓CVD-mortality, Q2 vs. Q1; Q5vs. Q1, at ~26y f/u; ᴓ CVD-mortality, Q3 or Q4 at ~26y f/u | Confounders accounted for: Sex, Age, Race/ethnicity: 99% White, Physical activity, Anthropometry: BMI, Smoking, Alcohol, Other: SES: Education; Marital status, Total energy intake, family history of chronic disease, HRT use; Did not account for the following key confounders: N/A; [underlined: Funding:]; National Cancer Institute of the NIH
Cheng, 2018 ^31^; United States, Iowa Women’s Health Study; N=35221; Attrition: 16% | | Q5 | 51.2 | 31.9 | 18.2 | ↓CVD-mortality, continuous, at ~26y f/u; ↓CVD-mortality, Q2 vs. Q1; Q5vs. Q1, at ~26y f/u; ᴓ CVD-mortality, Q3 or Q4 at ~26y f/u
Cheng, 2018 ^31^; United States, Iowa Women’s Health Study; N=35221; Attrition: 16% | % E in quintiles of adherence [categorical, continuous] to the evolutionary-concordance diet score (Whalen, 2014, 2016,2017); Positive: Vegetables, Fruits, Lean meats, Fish, Nuts, Fruit and vegetable diversity, Calcium; Negative: Red and processed meats, Sodium, Dairy foods, Grains and starches, Baked goods, SSB, Alcohol | Q1, ref. | 46.5 | 36.8 | 16.8 | ᴓ CVD-mortality overall LCD at ~26y f/u
Cheng, 2018 ^31^; United States, Iowa Women’s Health Study; N=35221; Attrition: 16% | | Q5 | 51.1 | 30.7 | 19.8 | ᴓ CVD-mortality overall LCD at ~26y f/u
| % E in 5 clusters based on absolute intake | Unhealthy’ | 37.7 | 41.1 | 20 | | Confounders accounted for: Sex; Age;
Diehr, 2003 ^43^; United States, Cardiovascular Health Study (CHS); N=4610; Attrition: 22% | ‘Unhealthy’: expected calories, low in carbohydrate (1SD below mean); high in fat and protein (1SD above mean) | | | | | ↓angina-event 10y past baseline, ‘Low 4’ vs. ‘Healthy’; ↓Mi-event 10y past baseline, ‘Low 4’ vs. ‘Healthy’; ᴓ Stroke-event, HF-event 10y past baseline, all other clusters vs. ‘Healthy’ | Race/ethnicity; Alcohol; Physical activity; Anthropometry: BMI; Smoking; Other: SES: Education; Marital status; Did not account for the following key confounders N/A; Intake reflective of absolute vs. relative nutrients; [underlined: Funding:]; National Heart, Lung, and Blood Institute
Diehr, 2003 ^43^; United States, Cardiovascular Health Study (CHS); N=4610; Attrition: 22% | ‘Hi Cal’: high in calories, expected levels of carbohydrate, fat, protein, and fiber | Hi Cal’ | 44.8 | 36.3 | 17.8 | ↓angina-event 10y past baseline, ‘Low 4’ vs. ‘Healthy’; ↓Mi-event 10y past baseline, ‘Low 4’ vs. ‘Healthy’; ᴓ Stroke-event, HF-event 10y past baseline, all other clusters vs. ‘Healthy’
Diehr, 2003 ^43^; United States, Cardiovascular Health Study (CHS); N=4610; Attrition: 22% | Foods NR; ‘Low Cal’: low in calories; lower levels of carbohydrate, fat, protein, and fiber | Low Cal’ | 51 | 30.7 | 18.1 | ↓angina-event 10y past baseline, ‘Low 4’ vs. ‘Healthy’; ↓Mi-event 10y past baseline, ‘Low 4’ vs. ‘Healthy’; ᴓ Stroke-event, HF-event 10y past baseline, all other clusters vs. ‘Healthy’
Diehr, 2003 ^43^; United States, Cardiovascular Health Study (CHS); N=4610; Attrition: 22% | ‘Low 4’: low in calories; higher levels of carbohydrate, fat, protein, and fiber | Low 4’ | 42.3 | 38.8 | 15.1 | ↓angina-event 10y past baseline, ‘Low 4’ vs. ‘Healthy’; ↓Mi-event 10y past baseline, ‘Low 4’ vs. ‘Healthy’; ᴓ Stroke-event, HF-event 10y past baseline, all other clusters vs. ‘Healthy’
Diehr, 2003 ^43^; United States, Cardiovascular Health Study (CHS); N=4610; Attrition: 22% | ‘Healthy’: expected calories, high in carbohydrate, low in fat, high in fiber | Healthy’ | 56 | 26.83 | 17.3 | ↓angina-event 10y past baseline, ‘Low 4’ vs. ‘Healthy’; ↓Mi-event 10y past baseline, ‘Low 4’ vs. ‘Healthy’; ᴓ Stroke-event, HF-event 10y past baseline, all other clusters vs. ‘Healthy’
Ericson, 2019 ^47^; Sweden, Malmo¨ Diet and Cancer cohort; PCS N=20,487 | %E in women for Health-Conscious Dietary Pattern; Higher loadings for cottage cheese, fibre-rich bread, fruits, vegetables, breakfast cereals, fish and low-fat yoghurt; lower loadings for low-fibre bread, red and processed meat, sugar-sweetened beverages | Q1, ref. | 44.9 | 40.2 | 14.9 | ↓Coronary events after 15y, continuous; ᴓ categorical; ᴓ Stroke after 15y | Confounders accounted for: Sex, Age, Alcohol, Physical activity, Anthropometry: BMI, Smoking; Other: Total energy, Education, Method version, Season; Did not account for the following key confounders: Race/ethnicity Measured diet once at baseline using validated diet history methods; Note: Macronutrient distributions were NR for three additional patterns, “traditional meal”, “tea-breakfast”, and “sugar-rich”, which showed NS results; [underlined: Funding:]; The Swedish Research Council, the Region Skane, the Skane University Hospital, the Novo Nordic Foundation, the Albert Pahlsson Research Foundation.
Ericson, 2019 ^47^; Sweden, Malmo¨ Diet and Cancer cohort; PCS N=20,487 | | Q2 | 45.6 | 39.2 | 15.2 | ↓Coronary events after 15y, continuous; ᴓ categorical; ᴓ Stroke after 15y
Ericson, 2019 ^47^; Sweden, Malmo¨ Diet and Cancer cohort; PCS N=20,487 | | Q3 | 45.8 | 38.8 | 14.4 | ↓Coronary events after 15y, continuous; ᴓ categorical; ᴓ Stroke after 15y
Ericson, 2019 ^47^; Sweden, Malmo¨ Diet and Cancer cohort; PCS N=20,487 | | Q4 | 46.6 | 37.7 | 15.6 | ↓Coronary events after 15y, continuous; ᴓ categorical; ᴓ Stroke after 15y
Ericson, 2019 ^47^; Sweden, Malmo¨ Diet and Cancer cohort; PCS N=20,487 | | Q5 | 47.7 | 36.1 | 16.2 | ↓Coronary events after 15y, continuous; ᴓ categorical; ᴓ Stroke after 15y
Ericson, 2019 ^47^; Sweden, Malmo¨ Diet and Cancer cohort; PCS N=20,487 | %E in women for Low-Fat Products Dietary Pattern; Higher loadings for low-fat margarines, low-fat milk, low-fat yoghurt; lower loadings for butter | Q1, ref. | 43.3 | 42.3 | 14.4 | ᴓ Coronary events, Stroke after 15y
Ericson, 2019 ^47^; Sweden, Malmo¨ Diet and Cancer cohort; PCS N=20,487 | %E in women for Low-Fat Products Dietary Pattern; Higher loadings for low-fat margarines, low-fat milk, low-fat yoghurt; lower loadings for butter | Q2 | 45.3 | 39.4 | 15.3 | ᴓ Coronary events, Stroke after 15y
Ericson, 2019 ^47^; Sweden, Malmo¨ Diet and Cancer cohort; PCS N=20,487 | %E in women for Low-Fat Products Dietary Pattern; Higher loadings for low-fat margarines, low-fat milk, low-fat yoghurt; lower loadings for butter | Q3 | 46.6 | 37.8 | 15.6 | ᴓ Coronary events, Stroke after 15y
Ericson, 2019 ^47^; Sweden, Malmo¨ Diet and Cancer cohort; PCS N=20,487 | %E in women for Low-Fat Products Dietary Pattern; Higher loadings for low-fat margarines, low-fat milk, low-fat yoghurt; lower loadings for butter | Q4 | 47.1 | 37.1 | 15.8 | ᴓ Coronary events, Stroke after 15y
Ericson, 2019 ^47^; Sweden, Malmo¨ Diet and Cancer cohort; PCS N=20,487 | %E in women for Low-Fat Products Dietary Pattern; Higher loadings for low-fat margarines, low-fat milk, low-fat yoghurt; lower loadings for butter | Q5 | 48.3 | 35.4 | 16.2 | ᴓ Coronary events, Stroke after 15y
Ericson, 2019 ^47^; Sweden, Malmo¨ Diet and Cancer cohort; PCS N=20,487 | %E in women for Dressing-Vegetables Dietary Pattern; Higher loadings for dressing/oils, vegetables, poultry, salty snacks, rice/pasta, fried potatoes, cheese; lower loadings for boiled potatoes, jam/sugar | Q1, ref. | 47.4 | 37.4 | 15.2 | ᴓ Coronary events, Stroke after 15y
Ericson, 2019 ^47^; Sweden, Malmo¨ Diet and Cancer cohort; PCS N=20,487 | | Q2 | 46.8 | 37.9 | 15.2 | ᴓ Coronary events, Stroke after 15y
Ericson, 2019 ^47^; Sweden, Malmo¨ Diet and Cancer cohort; PCS N=20,487 | | Q3 | 46.1 | 38.5 | 15.4 | ᴓ Coronary events, Stroke after 15y
Ericson, 2019 ^47^; Sweden, Malmo¨ Diet and Cancer cohort; PCS N=20,487 | | Q4 | 45.3 | 39.1 | 15.6 | ᴓ Coronary events, Stroke after 15y
Ericson, 2019 ^47^; Sweden, Malmo¨ Diet and Cancer cohort; PCS N=20,487 | | Q5 | 44.9 | 39.1 | 16.0 | ᴓ Coronary events, Stroke after 15y
Ericson, 2019 ^47^; Sweden, Malmo¨ Diet and Cancer cohort; PCS N=20,487 | %E in men for Health-Conscious Dietary Pattern; Higher loadings for cream, fibre-rich bread, fruits, vegetables, breakfast cereals, fish, low-fat yoghurt; lower loadings for low-fibre bread, red and processed meat, sugar-sweetened beverages | Q1, ref. | 44.9 | 40.5 | 14.6 | ↓Coronary events after 15y, continuous; ᴓ categorical; ↓Stroke after 15y
Ericson, 2019 ^47^; Sweden, Malmo¨ Diet and Cancer cohort; PCS N=20,487 | | Q2 | 44.5 | 40.7 | 14.8 | ↓Coronary events after 15y, continuous; ᴓ categorical; ↓Stroke after 15y
Ericson, 2019 ^47^; Sweden, Malmo¨ Diet and Cancer cohort; PCS N=20,487 | | Q3 | 45.0 | 40.1 | 14.9 | ↓Coronary events after 15y, continuous; ᴓ categorical; ↓Stroke after 15y
Ericson, 2019 ^47^; Sweden, Malmo¨ Diet and Cancer cohort; PCS N=20,487 | | Q4 | 45.4 | 39.4 | 15.2 | ↓Coronary events after 15y, continuous; ᴓ categorical; ↓Stroke after 15y
Ericson, 2019 ^47^; Sweden, Malmo¨ Diet and Cancer cohort; PCS N=20,487 | | Q5 | 46.2 | 38.0 | 15.7 | ↓Coronary events after 15y, continuous; ᴓ categorical; ↓Stroke after 15y
Ericson, 2019 ^47^; Sweden, Malmo¨ Diet and Cancer cohort; PCS N=20,487 | %E in men for Low-Fat Products Dietary Pattern; Higher loadings for low-fat margarines, low-fat milk, low-fat yoghurt; lower loadings for butter | Q1, ref. | 42.2 | 43.8 | 14.0 | ᴓCoronary events, Stroke after 15y
Ericson, 2019 ^47^; Sweden, Malmo¨ Diet and Cancer cohort; PCS N=20,487 | %E in men for Low-Fat Products Dietary Pattern; Higher loadings for low-fat margarines, low-fat milk, low-fat yoghurt; lower loadings for butter | Q2 | 44.2 | 41.0 | 14.8 | ᴓCoronary events, Stroke after 15y
Ericson, 2019 ^47^; Sweden, Malmo¨ Diet and Cancer cohort; PCS N=20,487 | %E in men for Low-Fat Products Dietary Pattern; Higher loadings for low-fat margarines, low-fat milk, low-fat yoghurt; lower loadings for butter | Q3 | 45.7 | 39.1 | 15.2 | ᴓCoronary events, Stroke after 15y
Ericson, 2019 ^47^; Sweden, Malmo¨ Diet and Cancer cohort; PCS N=20,487 | %E in men for Low-Fat Products Dietary Pattern; Higher loadings for low-fat margarines, low-fat milk, low-fat yoghurt; lower loadings for butter | Q4 | 46.3 | 38.3 | 15.3 | ᴓCoronary events, Stroke after 15y
Ericson, 2019 ^47^; Sweden, Malmo¨ Diet and Cancer cohort; PCS N=20,487 | %E in men for Low-Fat Products Dietary Pattern; Higher loadings for low-fat margarines, low-fat milk, low-fat yoghurt; lower loadings for butter | Q5 | 47.6 | 36.6 | 15.8 | ᴓCoronary events, Stroke after 15y
Ericson, 2019 ^47^; Sweden, Malmo¨ Diet and Cancer cohort; PCS N=20,487 | %E in men for Dressing-Vegetables Dietary Pattern; Higher loadings for dressing/oils, vegetables, poultry, salty snacks, rice/pasta, fried potatoes,cheese; lower loadings for boiled potatoes, jam/sugar | Q1, ref. | 46.6 | 38.9 | 14.5 | ↓Coronary events after 15y; ᴓ Stroke after 15y
Ericson, 2019 ^47^; Sweden, Malmo¨ Diet and Cancer cohort; PCS N=20,487 | | Q2 | 45.7 | 39.5 | 14.8 | ↓Coronary events after 15y; ᴓ Stroke after 15y
Ericson, 2019 ^47^; Sweden, Malmo¨ Diet and Cancer cohort; PCS N=20,487 | | Q3 | 45 | 39.9 | 15.1 | ↓Coronary events after 15y; ᴓ Stroke after 15y
Ericson, 2019 ^47^; Sweden, Malmo¨ Diet and Cancer cohort; PCS N=20,487 | | Q4 | 44.6 | 40.2 | 15.2 | ↓Coronary events after 15y; ᴓ Stroke after 15y
Ericson, 2019 ^47^; Sweden, Malmo¨ Diet and Cancer cohort; PCS N=20,487 | | Q5 | 44.1 | 40.3 | 15.6 | ↓Coronary events after 15y; ᴓ Stroke after 15y
Fung, 2010^54^; United States, Nurses’ Health Study (NHS); Health Professionals Follow-up Study (HPFS); N=129716; Attrition: 25% | % E by decile adherence to ‘low-carbohydrate’ diet (LCD) score (fat and protein estimated from vegetable and animal sources) | Pooled | | | | ᴓCVD-mortality, overall LCD at ~23y f/u | Confounders accounted for: Sex: Design, Age, Alcohol, Physical activity, Anthropometry: BMI, Smoking; Did not account for the following key confounders: Race/ethnicity; Diet assessed every 4y using validated FFQ; [underlined: Funding:]; NIH
Fung, 2010^54^; United States, Nurses’ Health Study (NHS); Health Professionals Follow-up Study (HPFS); N=129716; Attrition: 25% | Women,; Categorical, continuous analyses for overall LCD, animal-based, and vegetable-based scores | D1, ref. | 60.5 | 25.8 | 15 | ᴓCVD-mortality overall LCD at ~26y f/u; ↑ CVD-mortality, animal-based LCD at ~26y f/u; ↓CVD-mortality, vegetable-based LCD at ~26y f/u
Fung, 2010^54^; United States, Nurses’ Health Study (NHS); Health Professionals Follow-up Study (HPFS); N=129716; Attrition: 25% | Women,; Categorical, continuous analyses for overall LCD, animal-based, and vegetable-based scores | D5 | 50.9 | 30.4 | 17.9 | ᴓCVD-mortality overall LCD at ~26y f/u; ↑ CVD-mortality, animal-based LCD at ~26y f/u; ↓CVD-mortality, vegetable-based LCD at ~26y f/u
Fung, 2010^54^; United States, Nurses’ Health Study (NHS); Health Professionals Follow-up Study (HPFS); N=129716; Attrition: 25% | Women,; Categorical, continuous analyses for overall LCD, animal-based, and vegetable-based scores | D10 | 37.2 | 39.9 | 22.3 | ᴓCVD-mortality overall LCD at ~26y f/u; ↑ CVD-mortality, animal-based LCD at ~26y f/u; ↓CVD-mortality, vegetable-based LCD at ~26y f/u
Fung, 2010^54^; United States, Nurses’ Health Study (NHS); Health Professionals Follow-up Study (HPFS); N=129716; Attrition: 25% | Men,; Categorical, continuous analyses for overall LCD, animal-based, and vegetable-based scores | D1, ref. | 60.5 | 24.1 | 14.9 | ↑ CVD-mortality, overall LCD at ~20y f/u; ↑ CVD-mortality, animal-based LCD at ~20y f/u; ↓ CVD-mortality, vegetable-based LCD at ~20y f/u
Fung, 2010^54^; United States, Nurses’ Health Study (NHS); Health Professionals Follow-up Study (HPFS); N=129716; Attrition: 25% | Men,; Categorical, continuous analyses for overall LCD, animal-based, and vegetable-based scores | D5 | 50.9 | 31.1 | 18.1 | ↑ CVD-mortality, overall LCD at ~20y f/u; ↑ CVD-mortality, animal-based LCD at ~20y f/u; ↓ CVD-mortality, vegetable-based LCD at ~20y f/u
Fung, 2010^54^; United States, Nurses’ Health Study (NHS); Health Professionals Follow-up Study (HPFS); N=129716; Attrition: 25% | Men,; Categorical, continuous analyses for overall LCD, animal-based, and vegetable-based scores | D10 | 37.2 | 40 | 22.5 | ↑ CVD-mortality, overall LCD at ~20y f/u; ↑ CVD-mortality, animal-based LCD at ~20y f/u; ↓ CVD-mortality, vegetable-based LCD at ~20y f/u
Guasch-Ferre, 2015 ^59^; Spain, PREDIMED; N=7038; Included those with type 2 diabetes or 3 CVD risk factors | %E in quintles of total fat intake | Q1, ref | 50.2 | 16.9 | 29.7 | ↑ CVD mortality after 6y | Confounders accounted for: Sex, Age, Race/ethnicity, Alcohol, Physical activity, Anthropometry, Smoking; Other: Intervention group, energy intake, fiber, protein, dietary cholesterol, education, diabetes, hypertension, hypercholesterolemia, family fx of CVD, medication; Did not account for the following key confounders: Race/ethnicity; [underlined: Funding:]; Spanish Ministry of Health [Instituto de Salud Carlos III (ISCIII)]; FEDER (FondoEuropeo de Desarrollo Regional), and the Centre Catala de laNutricio de I’lnstitut d’Estudis Catalans; Instituto de Salud Carlos III (ISCIII)
Guasch-Ferre, 2015 ^59^; Spain, PREDIMED; N=7038; Included those with type 2 diabetes or 3 CVD risk factors | %E in quintles of total fat intake | Q5 | 33.7 | 16 | 48.7 | ↑ CVD mortality after 6y
Halton, 2006 ^61^; United States, Nurses’ Health Study; N=82802; 100% female; Excluded those with hx if diabetes, CVD, cancer | %E by deciles of total protein by adherence to the Low-Carbohydrate-Diet-Score (LCDS) | D1, ref. | 58.8 | 26.9 | 15.9 | ↓CHD after 20y, LCDS-vegetable protein; ᴓ CHD after 20y, LCDS-total, LCDS-animal protein | Confounders accounted for: Sex, Age, Alcohol, Physical activity, Anthropometry, Smoking; Other: Postmenopausal hormone use, aspirin use, vit E supplement, hx of HTN, hypercholesterolemia, parent hx of MI; Did not account for the following key confounders: Race/ethnicity, Food group intake between groups reported, but group differences not described; Only reported macro and food group intake for 3 deciles; [underlined: Funding:]; NIH
Halton, 2006 ^61^; United States, Nurses’ Health Study; N=82802; 100% female; Excluded those with hx if diabetes, CVD, cancer | %E by deciles of total protein by adherence to the Low-Carbohydrate-Diet-Score (LCDS) | D5 | 49.9 | 31.4 | 19 | ↓CHD after 20y, LCDS-vegetable protein; ᴓ CHD after 20y, LCDS-total, LCDS-animal protein
Halton, 2006 ^61^; United States, Nurses’ Health Study; N=82802; 100% female; Excluded those with hx if diabetes, CVD, cancer | %E by deciles of total protein by adherence to the Low-Carbohydrate-Diet-Score (LCDS) | D10 | 36.8 | 39.8 | 22.8 | ↓CHD after 20y, LCDS-vegetable protein; ᴓ CHD after 20y, LCDS-total, LCDS-animal protein
Halton, 2006 ^61^; United States, Nurses’ Health Study; N=82802; 100% female; Excluded those with hx if diabetes, CVD, cancer | %E by deciles, LCDS-animal protein | D1, ref. | 57.9 | 28.1 | 16 | ↓CHD after 20y, LCDS-vegetable protein; ᴓ CHD after 20y, LCDS-total, LCDS-animal protein
Halton, 2006 ^61^; United States, Nurses’ Health Study; N=82802; 100% female; Excluded those with hx if diabetes, CVD, cancer | %E by deciles, LCDS-animal protein | D5 | 49.7 | 31.5 | 19 | ↓CHD after 20y, LCDS-vegetable protein; ᴓ CHD after 20y, LCDS-total, LCDS-animal protein
Halton, 2006 ^61^; United States, Nurses’ Health Study; N=82802; 100% female; Excluded those with hx if diabetes, CVD, cancer | %E by deciles, LCDS-animal protein | D10 | 34.7 | 39.6 | 24.2 | ↓CHD after 20y, LCDS-vegetable protein; ᴓ CHD after 20y, LCDS-total, LCDS-animal protein
Halton, 2006 ^61^; United States, Nurses’ Health Study; N=82802; 100% female; Excluded those with hx if diabetes, CVD, cancer | %E by deciles, LCDS-vegetable protein; Decile 1 vs 10 had higher cereal fiber, fruits and vegetables, and lower red meat | D1, ref. | 55.6 | 27.1 | 18.2 | ↓CHD after 20y, LCDS-vegetable protein; ᴓ CHD after 20y, LCDS-total, LCDS-animal protein
Halton, 2006 ^61^; United States, Nurses’ Health Study; N=82802; 100% female; Excluded those with hx if diabetes, CVD, cancer | %E by deciles, LCDS-vegetable protein; Decile 1 vs 10 had higher cereal fiber, fruits and vegetables, and lower red meat | D5 | 50.9 | 30.4 | 19.1 | ↓CHD after 20y, LCDS-vegetable protein; ᴓ CHD after 20y, LCDS-total, LCDS-animal protein
Halton, 2006 ^61^; United States, Nurses’ Health Study; N=82802; 100% female; Excluded those with hx if diabetes, CVD, cancer | %E by deciles, LCDS-vegetable protein; Decile 1 vs 10 had higher cereal fiber, fruits and vegetables, and lower red meat | D10 | 45.4 | 35.8 | 18.7 | ↓CHD after 20y, LCDS-vegetable protein; ᴓ CHD after 20y, LCDS-total, LCDS-animal protein
Haring, 2014 ^65^; United States, ARIC; N=12066; Excluded those with hx of diabetes or CVD | %E by quintile of total protein intake | Q1, ref. | 56.2 | 30 | 12.4 | ᴓ CHD after 22y | Confounders accounted for: Sex, Age, Race/ethnicity, Alcohol, Physical activity, Anthropometry, Smoking; Other: Study center, energy intake, education, SBP, HTN meds, HDL, TC, lipid-lowering meds, BMI, waist-to-hip ratio, and carbohydrate, fiber, and Mg intake; Did not account for the following key confounders: N/A; Diet assessed twice (baseline, 6y f/u); Food group intake not reported; did not report %E macros for vegetable, animal protein; [underlined: Funding:]; National Heart, Lung, and Blood Institute
Haring, 2014 ^65^; United States, ARIC; N=12066; Excluded those with hx of diabetes or CVD | %E by quintile of total protein intake | Q2 | 51.3 | 32.5 | 15.7 | ᴓ CHD after 22y
Haring, 2014 ^65^; United States, ARIC; N=12066; Excluded those with hx of diabetes or CVD | %E by quintile of total protein intake | Q3 | 48.3 | 33.4 | 17.8 | ᴓ CHD after 22y
Haring, 2014 ^65^; United States, ARIC; N=12066; Excluded those with hx of diabetes or CVD | %E by quintile of total protein intake | Q4 | 45.8 | 34.2 | 19.8 | ᴓ CHD after 22y
Haring, 2014 ^65^; United States, ARIC; N=12066; Excluded those with hx of diabetes or CVD | %E by quintile of total protein intake | Q5 | 42.8 | 34.5 | 22.8 | ᴓ CHD after 22y
Haring, 2015 ^66^; United States, ARIC; N=11601; Excluded those with hx of diabetes or CVD | %E by quintile of total protein intake | Q1, ref. | 56.1 | 30 | 12.4 | ᴓ Stroke after 22y | Confounders accounted for: Sex, Age, Race/ethnicity, Alcohol, Physical activity, Anthropometry, Smoking; Other: Study center, energy intake, education, SBP, HTN meds, HDL, TC, lipid-lowering meds, BMI, waist-to-hip ratio, and carbohydrate, fiber, and Mg intake; Did not account for the following key confounders: N/A; Diet assessed twice (baseline, 6y f/u) Food group intake not reported; did not report %E macros for vegetable, animal protein; [underlined: Funding:]; National Heart, Lung, and Blood Institute
Haring, 2015 ^66^; United States, ARIC; N=11601; Excluded those with hx of diabetes or CVD | %E by quintile of total protein intake | Q2 | 51.3 | 32.4 | 15.7 | ᴓ Stroke after 22y
Haring, 2015 ^66^; United States, ARIC; N=11601; Excluded those with hx of diabetes or CVD | %E by quintile of total protein intake | Q3 | 48.3 | 33.4 | 17.8 | ᴓ Stroke after 22y
Haring, 2015 ^66^; United States, ARIC; N=11601; Excluded those with hx of diabetes or CVD | %E by quintile of total protein intake | Q4 | 45.8 | 34.1 | 19.8 | ᴓ Stroke after 22y
Haring, 2015 ^66^; United States, ARIC; N=11601; Excluded those with hx of diabetes or CVD | %E by quintile of total protein intake | Q5 | 42.9 | 34.5 | 22.7 | ᴓ Stroke after 22y
Hernandez-Alonso, 2016 ^69^; Spain, PREDIMED; N=7216; Excluded −3% due to attrition/LFU | % E by quintile of overall protein intake, animal-based, vegetable-based, and animal-vegetable ratio | Q1 | 42.7 | 39.2 | 13.6 | ᴓ CVD-mortality at 4y f/u, across overall quintiles; ↑ CVD-mortality, animal-protein, Q5 vs. Q3 ref, p=0.03; ᴓ CVD-mortality, vegetable-protein; ᴓ CVD-mortality risk, animal-vegetable-protein ratio; ᴓ CVD-event at 4y f/u, across overall quintiles; ↑ CVD-event, animal-protein, Q5 vs. Q3 ref, p=0.03; ᴓ CVD-event, vegetable-protein; ᴓ CVD-event, animal-vegetable-protein ratio | Confounders accounted for: Sex, Age, Race/ethnicity (all Spanish), Alcohol; Physical activity, Anthropometry, Smoking; Did not account for the following key confounders: N/A; Diet assessed at baseline and annually using validated methods; [underlined: Funding:]; ISCIII, Spain; Centra Nacional de Investigaciones Cardiovascu lares; Fondo de Investigacion Sanitaria; Ministerio de Ciencia e Innovacion; Ministerio de Sanidad-Plan Nacional de drogas; and Fundaci on Mapfre 2010, the Government of the Basque Country; the University of the Basque Country; Consejeria de Salud de la Junta de Andalucia; the Catalan government
Hernandez-Alonso, 2016 ^69^; Spain, PREDIMED; N=7216; Excluded −3% due to attrition/LFU | % E by quintile of overall protein intake, animal-based, vegetable-based, and animal-vegetable ratio | Q2 | 42 | 40 | 15.4
Hernandez-Alonso, 2016 ^69^; Spain, PREDIMED; N=7216; Excluded −3% due to attrition/LFU | % E by quintile of overall protein intake, animal-based, vegetable-based, and animal-vegetable ratio | Q3, ref. | 41.7 | 39.6 | 16.6
Hernandez-Alonso, 2016 ^69^; Spain, PREDIMED; N=7216; Excluded −3% due to attrition/LFU | % E by quintile of overall protein intake, animal-based, vegetable-based, and animal-vegetable ratio | Q4 | 41.5 | 39.2 | 17.7
Hernandez-Alonso, 2016 ^69^; Spain, PREDIMED; N=7216; Excluded −3% due to attrition/LFU | % E by quintile of overall protein intake, animal-based, vegetable-based, and animal-vegetable ratio | Q5 | 41 | 38.1 | 19.8
Houston, 2011 ^72^; United States, Health, Aging and Body Composition (Health ABC); N=1941 | % E by tertiles of total fat intake | T1, ref. | 60.6 | 25.4 | 15 | ᴓ CVD at 9y f/u, across overall tertiles | Confounders accounted for: Sex, Age, Race/ethnicity, Alcohol, Physical activity, Anthropometry: BMI, Smoking; Other: education, field center, energy intake, percent of energy from protein and other dietary fats, dietary cholesterol, fiber intake, statin and oral estrogen (females; Did not account for the following key confounders: N/A; Diet assessed at baseline using validated methods; [underlined: Funding:]; Intramural Research Program of the NIH, National Institute on Aging; Wake Forest University Claude D. Pepper Older Americans Independence Center; the American Egg Board/Egg Nutrition Center
Houston, 2011 ^72^; United States, Health, Aging and Body Composition (Health ABC); N=1941 | % E by tertiles of total fat intake | T2 | 53 | 33.4 | 14.4 | ᴓ CVD at 9y f/u, across overall tertiles
Houston, 2011 ^72^; United States, Health, Aging and Body Composition (Health ABC); N=1941 | % E by tertiles of total fat intake | T3 | 45.6 | 41.6 | 14 | ᴓ CVD at 9y f/u, across overall tertiles
Kim, 2019 ^83^; United States, Atherosclerosis Risk in Communities (ARIC); N=12168; Attrition: 23% | % E by quintile of adherence to PDI, hPDI, and uPDI scores based on:; - Healthy Plant Foods: Whole Grains, Fruits, Vegetables, Nuts, Legumes, Coffee, Tea;; - Less Healthy Plant Foods: Fruit Juices, refined grain, potatoes, sugar sweetened and artificially sweetened beverages,sweets and desserts;; - Animal Foods: Animal fat, dairy, eggs, fish or seafood, meat, miscellaneous animal foods. | PDI, Q1, ref. | 43.7 | 35.4 | 18.7 | ↓CVD-mortality, Q5, Q4, Q3, Q2 vs. Q1, over ~25y f/u; ↓CVD, Q5, Q4 vs. Q1, over ~25y f/u | Confounders accounted for: Sex, Age, Race/ethnicity, Alcohol, Physical activity, Anthropometry: BMI, Smoking; Other: SES: Education, margarine consumption; Did not account for the following key confounders: N/A Data inaccuracy concerns (BMI incorrectly reported); [underlined: Funding:]; National Heart, Lung, and Blood Institute, NIH, Department of Health and Human Services
Kim, 2019 ^83^; United States, Atherosclerosis Risk in Communities (ARIC); N=12168; Attrition: 23% | | PDI, Q2 | 47.4 | 33.3 | 18.5 | ↓CVD-mortality, Q5, Q4, Q3, Q2 vs. Q1, over ~25y f/u; ↓CVD, Q5, Q4 vs. Q1, over ~25y f/u
Kim, 2019 ^83^; United States, Atherosclerosis Risk in Communities (ARIC); N=12168; Attrition: 23% | | PDI, Q3 | 50 | 32 | 18.3 | ↓CVD-mortality, Q5, Q4, Q3, Q2 vs. Q1, over ~25y f/u; ↓CVD, Q5, Q4 vs. Q1, over ~25y f/u
Kim, 2019 ^83^; United States, Atherosclerosis Risk in Communities (ARIC); N=12168; Attrition: 23% | | PDI, Q4 | 52.1 | 30.7 | 17.9 | ↓CVD-mortality, Q5, Q4, Q3, Q2 vs. Q1, over ~25y f/u; ↓CVD, Q5, Q4 vs. Q1, over ~25y f/u
Kim, 2019 ^83^; United States, Atherosclerosis Risk in Communities (ARIC); N=12168; Attrition: 23% | | PDI, Q5 | 54.6 | 29.8 | 17 | ↓CVD-mortality, Q5, Q4, Q3, Q2 vs. Q1, over ~25y f/u; ↓CVD, Q5, Q4 vs. Q1, over ~25y f/u
Kim, 2019 ^83^; United States, Atherosclerosis Risk in Communities (ARIC); N=12168; Attrition: 23% | | hPDI, Q1, ref. | 46.5 | 35.2 | 17.7 | ↓CVD-mortality, Q5, Q4 vs. Q1, over ~25y f/u; ↓CVD, Q5, Q4 vs. Q1, over ~25y f/u
Kim, 2019 ^83^; United States, Atherosclerosis Risk in Communities (ARIC); N=12168; Attrition: 23% | | hPDI, Q2 | 47.9 | 33.5 | 18.1 | ↓CVD-mortality, Q5, Q4 vs. Q1, over ~25y f/u; ↓CVD, Q5, Q4 vs. Q1, over ~25y f/u
Kim, 2019 ^83^; United States, Atherosclerosis Risk in Communities (ARIC); N=12168; Attrition: 23% | | hPDI, Q3 | 49.2 | 32.3 | 18.2 | ↓CVD-mortality, Q5, Q4 vs. Q1, over ~25y f/u; ↓CVD, Q5, Q4 vs. Q1, over ~25y f/u
Kim, 2019 ^83^; United States, Atherosclerosis Risk in Communities (ARIC); N=12168; Attrition: 23% | | hPDI, Q4 | 50.7 | 30.9 | 18.3 | ↓CVD-mortality, Q5, Q4 vs. Q1, over ~25y f/u; ↓CVD, Q5, Q4 vs. Q1, over ~25y f/u
Kim, 2019 ^83^; United States, Atherosclerosis Risk in Communities (ARIC); N=12168; Attrition: 23% | | hPDI, Q5 | 52.4 | 29.4 | 18.6 | ↓CVD-mortality, Q5, Q4 vs. Q1, over ~25y f/u; ↓CVD, Q5, Q4 vs. Q1, over ~25y f/u
Kim, 2019 ^83^; United States, Atherosclerosis Risk in Communities (ARIC); N=12168; Attrition: 23% | | uPDI, Q1, ref. | 46.9 | 32.6 | 20.6 | ᴓ CVD-mortality across quintiles over ~25y f/u; ↓ CVD, Q4 vs. Q1only; ᴓ CVD-mortality across other quintiles over ~25y f/u
Kim, 2019 ^83^; United States, Atherosclerosis Risk in Communities (ARIC); N=12168; Attrition: 23% | | uPDI, Q2 | 48.2 | 32.5 | 19.3 | ᴓ CVD-mortality across quintiles over ~25y f/u; ↓ CVD, Q4 vs. Q1only; ᴓ CVD-mortality across other quintiles over ~25y f/u
Kim, 2019 ^83^; United States, Atherosclerosis Risk in Communities (ARIC); N=12168; Attrition: 23% | | uPDI, Q3 | 49.1 | 32.5 | 18.2 | ᴓ CVD-mortality across quintiles over ~25y f/u; ↓ CVD, Q4 vs. Q1only; ᴓ CVD-mortality across other quintiles over ~25y f/u
Kim, 2019 ^83^; United States, Atherosclerosis Risk in Communities (ARIC); N=12168; Attrition: 23% | | uPDI, Q4 | 49.8 | 32.5 | 17.1 | ᴓ CVD-mortality across quintiles over ~25y f/u; ↓ CVD, Q4 vs. Q1only; ᴓ CVD-mortality across other quintiles over ~25y f/u
Kim, 2019 ^83^; United States, Atherosclerosis Risk in Communities (ARIC); N=12168; Attrition: 23% | | uPDI, Q5 | 52.5 | 31.9 | 15 | ᴓ CVD-mortality across quintiles over ~25y f/u; ↓ CVD, Q4 vs. Q1only; ᴓ CVD-mortality across other quintiles over ~25y f/u
Kim, 2019 ^83^; United States, Atherosclerosis Risk in Communities (ARIC); N=12168; Attrition: 23% | % E by quintile of Pro-vegetarian index score adherence; Provegetarian diet index: Plant foods: grains, fruits, vegetables, nuts, legumes, and potatoes; Animal foods: animal fat, dairy, eggs, fish or seafood, meatarian index | Q1, ref. | 44.3 | 35.2 | 18.7 | ↓CVD-mortality, Q5, Q4, Q3vs. Q1, over ~25y f/u [ᴓ Q2 vs. Q1]; ↑ CVD, Q5, Q4, Q3 vs. Q1, over ~25y f/u[ᴓQ2vs. Q1]
Kim, 2019 ^83^; United States, Atherosclerosis Risk in Communities (ARIC); N=12168; Attrition: 23% | | Q2 | 47.7 | 33.3 | 18.4 | ↓CVD-mortality, Q5, Q4, Q3vs. Q1, over ~25y f/u [ᴓ Q2 vs. Q1]; ↑ CVD, Q5, Q4, Q3 vs. Q1, over ~25y f/u[ᴓQ2vs. Q1]
Kim, 2019 ^83^; United States, Atherosclerosis Risk in Communities (ARIC); N=12168; Attrition: 23% | | Q3 | 49.7 | 32.2 | 18.2 | ↓CVD-mortality, Q5, Q4, Q3vs. Q1, over ~25y f/u [ᴓ Q2 vs. Q1]; ↑ CVD, Q5, Q4, Q3 vs. Q1, over ~25y f/u[ᴓQ2vs. Q1]
Kim, 2019 ^83^; United States, Atherosclerosis Risk in Communities (ARIC); N=12168; Attrition: 23% | | Q4 | 51.6 | 31 | 17.8 | ↓CVD-mortality, Q5, Q4, Q3vs. Q1, over ~25y f/u [ᴓ Q2 vs. Q1]; ↑ CVD, Q5, Q4, Q3 vs. Q1, over ~25y f/u[ᴓQ2vs. Q1]
Kim, 2019 ^83^; United States, Atherosclerosis Risk in Communities (ARIC); N=12168; Attrition: 23% | | Q5 | 54.4 | 29.5 | 17.4 | ↓CVD-mortality, Q5, Q4, Q3vs. Q1, over ~25y f/u [ᴓ Q2 vs. Q1]; ↑ CVD, Q5, Q4, Q3 vs. Q1, over ~25y f/u[ᴓQ2vs. Q1]
Larsson, 2012 ^93^; Sweden, Swedish; Mammography Cohort; N=34670; 100% women Attrition-12% | % E by categories of total-protein intake, animal-protein and vegetable-protein; Reported only vegetable and fruit intake in servings/d and alcohol intake, g/d. | <61.8g/d | 51.6 | 29.4 | 13.0 | ↓total stroke across total protein categories, after 10yf/u;; ↓total stroke with substitution of fat for 5% protein; effects were stronger in stratified analyses by those with Hx of HTN ; results remained after exclusion by early cases or Hx ofT2D.; ↓total stroke across animal-protein categories, after 10y f/u; ᴓ total stroke across vegetable protein categories, after 10y f/u; ↓cerebral infarction across total protein and animal-protein categories, after 10yf/u; ᴓ cerebral infarction across vegetable protein categories, after 10yf/u | Confounders accounted for: Sex, Age, Alcohol, Physical activity, Anthropometry, Smoking,; Other: Education, Hx of HTN, Hx of T2D, aspirin use, Family Hx of MI, and intakes of total energy, alcohol, calcium cholsterol, total fat, fruits and vegetables. Did not account for the following key confounders: Race/ethnicity (all Swedish); Diet assessed once at baseline using validated FFQ; [underlined: Funding:]; Swedish Council for Working Life and Social Research (FAS), the Swedish Research Council/Committee for Infrastructure
Larsson, 2012 ^93^; Sweden, Swedish; Mammography Cohort; N=34670; 100% women Attrition-12% | % E by categories of total-protein intake, animal-protein and vegetable-protein; Reported only vegetable and fruit intake in servings/d and alcohol intake, g/d. | 61.8 to 67.2 g/d | 49.7 | 30.7 | 14.8
Larsson, 2012 ^93^; Sweden, Swedish; Mammography Cohort; N=34670; 100% women Attrition-12% | % E by categories of total-protein intake, animal-protein and vegetable-protein; Reported only vegetable and fruit intake in servings/d and alcohol intake, g/d. | 67.3 to 72.1 g/d | 49.1 | 31.6 | 16.2
Larsson, 2012 ^93^; Sweden, Swedish; Mammography Cohort; N=34670; 100% women Attrition-12% | % E by categories of total-protein intake, animal-protein and vegetable-protein; Reported only vegetable and fruit intake in servings/d and alcohol intake, g/d. | 72.2 to 78.6 g/d | 48.3 | 32.3 | 17.7
Larsson, 2012 ^93^; Sweden, Swedish; Mammography Cohort; N=34670; 100% women Attrition-12% | % E by categories of total-protein intake, animal-protein and vegetable-protein; Reported only vegetable and fruit intake in servings/d and alcohol intake, g/d. | ≥78.7 g/d | 43.4 | 30.8 | 19.1
Leosdottir, 2004 ^98^; Sweden, Malmo” Diet and Cancer cohort; N=27,959; >45y | % E in women by quartile of total energy intake | Q1, ref. | 46.2 | 36.4 | 17.1 | ↓CVD-mortality, Q3 vs. Q1 over 6.6y f/u | Confounders accounted for: Sex: Design; Age; Alcohol; Physical activity; Anthropometry: BMI; Smoking; Other: SES and marital status; Did not account for the following key confounders: Race/ethnicity (all Swedish); Diet assessed once at baseline using validated methods (meu-diary and FFQ); Potential for dietary measurement error; [underlined: Funding:]; Anna Jonssons Memorial Fund
Leosdottir, 2004 ^98^; Sweden, Malmo” Diet and Cancer cohort; N=27,959; >45y | % E in women by quartile of total energy intake | Q2 | 45.7 | 37.9 | 16.2 | ↓CVD-mortality, Q3 vs. Q1 over 6.6y f/u
Leosdottir, 2004 ^98^; Sweden, Malmo” Diet and Cancer cohort; N=27,959; >45y | % E in women by quartile of total energy intake | Q3 | 45.2 | 38.9 | 15.7 | ↓CVD-mortality, Q3 vs. Q1 over 6.6y f/u
Leosdottir, 2004 ^98^; Sweden, Malmo” Diet and Cancer cohort; N=27,959; >45y | % E in women by quartile of total energy intake | Q4 | 44.6 | 40.4 | 14.8 | ↓CVD-mortality, Q3 vs. Q1 over 6.6y f/u
Leosdottir, 2004 ^98^; Sweden, Malmo” Diet and Cancer cohort; N=27,959; >45y | % E in men by quartile of total energy intake; Reported only vegetable and fruit intake (g/d) and Alcohol intake (g pure ethanol/d) | Q1, ref. | 45.2 | 38 | 16.6 | ↓CVD-mortality, Q4 vs. Q1 over 6.6y f/u
Leosdottir, 2004 ^98^; Sweden, Malmo” Diet and Cancer cohort; N=27,959; >45y | % E in men by quartile of total energy intake; Reported only vegetable and fruit intake (g/d) and Alcohol intake (g pure ethanol/d) | Q2 | 45.2 | 39.1 | 15.6 | ↓CVD-mortality, Q4 vs. Q1 over 6.6y f/u
Leosdottir, 2004 ^98^; Sweden, Malmo” Diet and Cancer cohort; N=27,959; >45y | % E in men by quartile of total energy intake; Reported only vegetable and fruit intake (g/d) and Alcohol intake (g pure ethanol/d) | Q3 | 44.5 | 40.1 | 15.3 | ↓CVD-mortality, Q4 vs. Q1 over 6.6y f/u
Leosdottir, 2004 ^98^; Sweden, Malmo” Diet and Cancer cohort; N=27,959; >45y | % E in men by quartile of total energy intake; Reported only vegetable and fruit intake (g/d) and Alcohol intake (g pure ethanol/d) | Q4 | 43.6 | 41.8 | 14.6 | ↓CVD-mortality, Q4 vs. Q1 over 6.6y f/u
Leosdottir, 2005 ^100^; Sweden, Malmo” Diet and Cancer cohort; N=27,959; ≥45 | % E in women by quartile of total fat intake | Q1, ref. | 52.2 | 30.8 | 16.6 | ᴓ CVD-mortality across quartiles over 6.6y f/u | Confounders accounted for: Sex: Design; Age; Alcohol; Physical activity; Anthropometry: BMI; Smoking; Other: SES and marital status; Did not account for the following key confounders: Race/ethnicity (all Swedish); Diet assessed once at baseline using validated methods (meu-diary and FFQ); Potential for dietary measurement error; [underlined: Funding:]; The Swedish Scientific Council, The Swedish Cancer Foundation, Anna Jonssons Memorial Fund, the Swedish Heart and Lung Foundation, The European Commission, and The Region of Skane, Sweden
Leosdottir, 2005 ^100^; Sweden, Malmo” Diet and Cancer cohort; N=27,959; ≥45 | % E in women by quartile of total fat intake | Q2 | 47 | 36.5 | 16.3 | ᴓ CVD-mortality across quartiles over 6.6y f/u
Leosdottir, 2005 ^100^; Sweden, Malmo” Diet and Cancer cohort; N=27,959; ≥45 | % E in women by quartile of total fat intake | Q3 | 43.8 | 40.3 | 15.8 | ᴓ CVD-mortality across quartiles over 6.6y f/u
Leosdottir, 2005 ^100^; Sweden, Malmo” Diet and Cancer cohort; N=27,959; ≥45 | % E in women by quartile of total fat intake | Q4 | 38.7 | 46.1 | 15.2 | ᴓ CVD-mortality across quartiles over 6.6y f/u
Leosdottir, 2005 ^100^; Sweden, Malmo” Diet and Cancer cohort; N=27,959; ≥45 | % E in men by quartile of total fat intake; Reported only g/d of fiber intake, vegetable and fruit intake and alcohol intake (pure ethanol | Q1, ref. | 51.7 | 31.8 | 16.1 | ↓CVD-mortality, Q4 vs. Q1 over 6.6y f/u
Leosdottir, 2005 ^100^; Sweden, Malmo” Diet and Cancer cohort; N=27,959; ≥45 | % E in men by quartile of total fat intake; Reported only g/d of fiber intake, vegetable and fruit intake and alcohol intake (pure ethanol | Q2 | 46.2 | 37.8 | 15.8 | ↓CVD-mortality, Q4 vs. Q1 over 6.6y f/u
Leosdottir, 2005 ^100^; Sweden, Malmo” Diet and Cancer cohort; N=27,959; ≥45 | % E in men by quartile of total fat intake; Reported only g/d of fiber intake, vegetable and fruit intake and alcohol intake (pure ethanol | Q3 | 42.9 | 41.7 | 15.3 | ↓CVD-mortality, Q4 vs. Q1 over 6.6y f/u
Leosdottir, 2005 ^100^; Sweden, Malmo” Diet and Cancer cohort; N=27,959; ≥45 | % E in men by quartile of total fat intake; Reported only g/d of fiber intake, vegetable and fruit intake and alcohol intake (pure ethanol | Q4 | 37.6 | 47.7 | 14.8 | ↓CVD-mortality, Q4 vs. Q1 over 6.6y f/u
Leosdottir, 2007 ^99^; Sweden, Malmo” Diet and Cancer cohort; N=27,959; ≥45y | % E in women by quartile of total fat intake | Q1, ref. | 52.2 | 30.8 | 16.6 | ᴓ CVD-events across quartiles over ~8y f/u; ᴓ acute coronary-events across quartiles over ~8y f/u; ᴓ ischemic stroke across quartiles over ~8y f/u | Confounders accounted for: Sex: Design; Age; Alcohol; Physical activity; Anthropometry: BMI; Smoking; Other: SES and marital status; Did not account for the following key confounders: Race/ethnicity (all Swedish); Diet assessed once at baseline using validated methods (meu-diary and FFQ); Potential for dietary measurement error; [underlined: Funding:]; The Swedish Scientific Council, The Swedish Cancer Foundation, Anna Jonssons Memorial Fund, the Swedish Heart and Lung Foundation, The European Commission, and The Region of Skane, Sweden
Leosdottir, 2007 ^99^; Sweden, Malmo” Diet and Cancer cohort; N=27,959; ≥45y | % E in women by quartile of total fat intake | Q2 | 47 | 36.5 | 16.3 | ᴓ CVD-events across quartiles over ~8y f/u; ᴓ acute coronary-events across quartiles over ~8y f/u; ᴓ ischemic stroke across quartiles over ~8y f/u
Leosdottir, 2007 ^99^; Sweden, Malmo” Diet and Cancer cohort; N=27,959; ≥45y | % E in women by quartile of total fat intake | Q3 | 43.8 | 40.3 | 15.8 | ᴓ CVD-events across quartiles over ~8y f/u; ᴓ acute coronary-events across quartiles over ~8y f/u; ᴓ ischemic stroke across quartiles over ~8y f/u
Leosdottir, 2007 ^99^; Sweden, Malmo” Diet and Cancer cohort; N=27,959; ≥45y | % E in women by quartile of total fat intake | Q4 | 38.7 | 46.1 | 15.2 | ᴓ CVD-events across quartiles over ~8y f/u; ᴓ acute coronary-events across quartiles over ~8y f/u; ᴓ ischemic stroke across quartiles over ~8y f/u
Leosdottir, 2007 ^99^; Sweden, Malmo” Diet and Cancer cohort; N=27,959; ≥45y | % E in men by quartile of total fat intake; Reported only g/d of fiber intake, vegetable and fruit intake and alcohol intake (pure ethanol | Q1, ref. | 51.7 | 31.8 | 16.1 | ᴓ CVD-events across quartiles over ~8y f/u; ᴓ acute coronary-events across quartiles over ~8y f/u; ᴓ ischemic stroke across quartiles over ~8y f/u
Leosdottir, 2007 ^99^; Sweden, Malmo” Diet and Cancer cohort; N=27,959; ≥45y | % E in men by quartile of total fat intake; Reported only g/d of fiber intake, vegetable and fruit intake and alcohol intake (pure ethanol | Q2 | 46.2 | 37.8 | 15.8 | ᴓ CVD-events across quartiles over ~8y f/u; ᴓ acute coronary-events across quartiles over ~8y f/u; ᴓ ischemic stroke across quartiles over ~8y f/u
Leosdottir, 2007 ^99^; Sweden, Malmo” Diet and Cancer cohort; N=27,959; ≥45y | % E in men by quartile of total fat intake; Reported only g/d of fiber intake, vegetable and fruit intake and alcohol intake (pure ethanol | Q3 | 42.9 | 41.7 | 15.3 | ᴓ CVD-events across quartiles over ~8y f/u; ᴓ acute coronary-events across quartiles over ~8y f/u; ᴓ ischemic stroke across quartiles over ~8y f/u
Leosdottir, 2007 ^99^; Sweden, Malmo” Diet and Cancer cohort; N=27,959; ≥45y | % E in men by quartile of total fat intake; Reported only g/d of fiber intake, vegetable and fruit intake and alcohol intake (pure ethanol | Q4 | 37.6 | 47.7 | 14.8 | ᴓ CVD-events across quartiles over ~8y f/u; ᴓ acute coronary-events across quartiles over ~8y f/u; ᴓ ischemic stroke across quartiles over ~8y f/u
Li, 2015 J Am Coll Cardiol^101^; United States, NHS, HPFS; N=84628; Excluded those with previously diagnosed cancer, CVD or diabetes | NHS Macro breakdown by quintiles of SFA intake | Q1, ref | 51.3 | 25.2 | 18.4 | ᴓ CHD after 30 y f/u | Confounders accounted for: Age, Sex, Race/ethnicity, Alcohol, Physical activity,; Anthropometry: BMI,; Smoking, Other: percentage of energy from all fat types simultaneously, total energy intake, energy contribution from protein, cholesterol intake, use of vitamins and aspirin, family history of MI and diabetes, and presence of baseline hypercholesterolemia and hypertension; Did not account for the following key confounders: NA; [underlined: Funding:]; NIH
Li, 2015 J Am Coll Cardiol^101^; United States, NHS, HPFS; N=84628; Excluded those with previously diagnosed cancer, CVD or diabetes | NHS Macro breakdown by quintiles of SFA intake | Q2 | 46.8 | 30.5 | 18.5 | ᴓ CHD after 30 y f/u
Li, 2015 J Am Coll Cardiol^101^; United States, NHS, HPFS; N=84628; Excluded those with previously diagnosed cancer, CVD or diabetes | NHS Macro breakdown by quintiles of SFA intake | Q3 | 44.2 | 33.4 | 18.7 | ᴓ CHD after 30 y f/u
Li, 2015 J Am Coll Cardiol^101^; United States, NHS, HPFS; N=84628; Excluded those with previously diagnosed cancer, CVD or diabetes | NHS Macro breakdown by quintiles of SFA intake | Q4 | 41.2 | 36.6 | 18.8 | ᴓ CHD after 30 y f/u
Li, 2015 J Am Coll Cardiol^101^; United States, NHS, HPFS; N=84628; Excluded those with previously diagnosed cancer, CVD or diabetes | NHS Macro breakdown by quintiles of SFA intake | Q5 | 34.2 | 43.9 | 19.4 | ᴓ CHD after 30 y f/u
Li, 2015 J Am Coll Cardiol^101^; United States, NHS, HPFS; N=84628; Excluded those with previously diagnosed cancer, CVD or diabetes | HPFS Macro breakdown by quintiles of SFA intake | Q1, ref | 55.1 | 23.4 | 18.2 | ᴓ CHD after 24 y f/u
Li, 2015 J Am Coll Cardiol^101^; United States, NHS, HPFS; N=84628; Excluded those with previously diagnosed cancer, CVD or diabetes | HPFS Macro breakdown by quintiles of SFA intake | Q2 | 49.8 | 28.6 | 18.4 | ᴓ CHD after 24 y f/u
Li, 2015 J Am Coll Cardiol^101^; United States, NHS, HPFS; N=84628; Excluded those with previously diagnosed cancer, CVD or diabetes | HPFS Macro breakdown by quintiles of SFA intake | Q3 | 47.5 | 31.3 | 18.4 | ᴓ CHD after 24 y f/u
Li, 2015 J Am Coll Cardiol^101^; United States, NHS, HPFS; N=84628; Excluded those with previously diagnosed cancer, CVD or diabetes | HPFS Macro breakdown by quintiles of SFA intake | Q4 | 45.3 | 33.8 | 18.5 | ᴓ CHD after 24 y f/u
Li, 2015 J Am Coll Cardiol^101^; United States, NHS, HPFS; N=84628; Excluded those with previously diagnosed cancer, CVD or diabetes | HPFS Macro breakdown by quintiles of SFA intake | Q5 | 41.3 | 38.2 | 18.8 | ᴓ CHD after 24 y f/u
Maddock, 2019 ^106^; United Kingdom, MRC National Survey of Health and Development; N=1562 | % E by quintiles of high-B vitamin dietary pattern, characterised by higher loadings of vegetables, fruit, and low fibre breakfast cereals, and lower processed meat, white bread and, sugar and preserves | Q1, ref | 45 | 35.4 | 15.9 | ᴓ SBP, DBP, TC, LDL, HDL after 24+ yf/u; ↓TG after 24+ y f/u | Confounders accounted for: Age, Sex, Other: Diet misreporting; Did not account for the following key confounders: Race/ethnicity, Alcohol, Physical activity, Anthropometry, Smoking; [underlined: Funding:]; British Medical Association and Medical Research Council
Maddock, 2019 ^106^; United Kingdom, MRC National Survey of Health and Development; N=1562 | | Q2 | 46 | 34.6 | 16.2 | ᴓ SBP, DBP, TC, LDL, HDL after 24+ yf/u; ↓TG after 24+ y f/u
Maddock, 2019 ^106^; United Kingdom, MRC National Survey of Health and Development; N=1562 | | Q3 | 47.1 | 33.9 | 16.6 | ᴓ SBP, DBP, TC, LDL, HDL after 24+ yf/u; ↓TG after 24+ y f/u
Maddock, 2019 ^106^; United Kingdom, MRC National Survey of Health and Development; N=1562 | | Q4 | 47.2 | 33.4 | 17.1 | ᴓ SBP, DBP, TC, LDL, HDL after 24+ yf/u; ↓TG after 24+ y f/u
Maddock, 2019 ^106^; United Kingdom, MRC National Survey of Health and Development; N=1562 | | Q5 | 49.2 | 32.6 | 17.6 | ᴓ SBP, DBP, TC, LDL, HDL after 24+ yf/u; ↓TG after 24+ y f/u
Mazidi, 2019 ^110^; United States, National Health and Nutrition Examination Survey (NHANES); N=24825; Attirtion: 0% | % E by quartile of adherence to ‘low-carbohydrate’ scores pooled men and women | Q1, ref | 66 | 27 | 13 | ↑ CHD-mortality Q4, Q3, vs. Q1 after ~144mof/u; ↑ Cerebrovascular disease mortality. Q4, Q3, Q2 vs. Q1 after ~144mo f/u | Confounders accounted for: Sex: Design; Age; Race/ethnicity (all Japaense); Alcohol; Physical activity; Anthropometry; Smoking; Other: SES; Did not account for the following key confounders: N/A; Diet assessed once at baseline using validated FFQ; Note: Macronutrient distribution NR for all quartiles of low-carbohydrate-high-protein diet, though reported results are similar to those for low-carbohydrate diet; [underlined: Funding:]; No company or institution supported this study
Mazidi, 2019 ^110^; United States, National Health and Nutrition Examination Survey (NHANES); N=24825; Attirtion: 0% | % E by quartile of adherence to ‘low-carbohydrate’ scores pooled men and women | Q2 | 57 | 32 | 15 | ↑ CHD-mortality Q4, Q3, vs. Q1 after ~144mof/u; ↑ Cerebrovascular disease mortality. Q4, Q3, Q2 vs. Q1 after ~144mo f/u
Mazidi, 2019 ^110^; United States, National Health and Nutrition Examination Survey (NHANES); N=24825; Attirtion: 0% | % E by quartile of adherence to ‘low-carbohydrate’ scores pooled men and women | Q3 | 49 | 36 | 17 | ↑ CHD-mortality Q4, Q3, vs. Q1 after ~144mof/u; ↑ Cerebrovascular disease mortality. Q4, Q3, Q2 vs. Q1 after ~144mo f/u
Mazidi, 2019 ^110^; United States, National Health and Nutrition Examination Survey (NHANES); N=24825; Attirtion: 0% | % E by quartile of adherence to ‘low-carbohydrate’ scores pooled men and women | Q4 | 39 | 43 | 19 | ↑ CHD-mortality Q4, Q3, vs. Q1 after ~144mof/u; ↑ Cerebrovascular disease mortality. Q4, Q3, Q2 vs. Q1 after ~144mo f/u
Nagata, 2012 ^119^; Japan, The Takayama Study; N=28356; Attirtion: 10% | % E from carbohydrate and protein and median % E from Fat by quintile in women | Q1, ref. | 69.7 | 16.9 | 13.2 | ᴓ CVD-mortality ~16y f/u | Confounders accounted for: Sex: Design; Age; Race/ethnicity (all Japaense); Alcohol; Physical activity; Anthropometry; Smoking; Other: SES; Did not account for the following key confounders: Race/ethnicity (all Japanese); Diet assessed once at baseline using validated FFQ; [underlined: Funding:]; Ministry of Education, Culture, Sports, Science, and Technology, Japan.
Nagata, 2012 ^119^; Japan, The Takayama Study; N=28356; Attirtion: 10% | % E from carbohydrate and protein and median % E from Fat by quintile in women | Q2 | 63.9 | 21 | 15 | ᴓ CVD-mortality ~16y f/u
Nagata, 2012 ^119^; Japan, The Takayama Study; N=28356; Attirtion: 10% | % E from carbohydrate and protein and median % E from Fat by quintile in women | Q3 | 60.5 | 23.7 | 15.9 | ᴓ CVD-mortality ~16y f/u
Nagata, 2012 ^119^; Japan, The Takayama Study; N=28356; Attirtion: 10% | % E from carbohydrate and protein and median % E from Fat by quintile in women | Q4 | 57.6 | 26.2 | 16.6 | ᴓ CVD-mortality ~16y f/u
Nagata, 2012 ^119^; Japan, The Takayama Study; N=28356; Attirtion: 10% | % E from carbohydrate and protein and median % E from Fat by quintile in women | Q5 | 52.9 | 29.6 | 17.6 | ᴓ CVD-mortality ~16y f/u
Nagata, 2012 ^119^; Japan, The Takayama Study; N=28356; Attirtion: 10% | % E from carbohydrate and protein and median % E from Fat by quintile in men; Reported intake of Meats, Dairy foods, Eggs, Fish, and Vegetable oil (g/4.19MJ) | Q1, ref. | 72 | 16.3 | 13.3 | ᴓ CVD-mortality ~16yf/u
Nagata, 2012 ^119^; Japan, The Takayama Study; N=28356; Attirtion: 10% | % E from carbohydrate and protein and median % E from Fat by quintile in men; Reported intake of Meats, Dairy foods, Eggs, Fish, and Vegetable oil (g/4.19MJ) | Q2 | 66.7 | 20.1 | 15 | ᴓ CVD-mortality ~16yf/u
Nagata, 2012 ^119^; Japan, The Takayama Study; N=28356; Attirtion: 10% | % E from carbohydrate and protein and median % E from Fat by quintile in men; Reported intake of Meats, Dairy foods, Eggs, Fish, and Vegetable oil (g/4.19MJ) | Q3 | 63.5 | 22.7 | 16 | ᴓ CVD-mortality ~16yf/u
Nagata, 2012 ^119^; Japan, The Takayama Study; N=28356; Attirtion: 10% | % E from carbohydrate and protein and median % E from Fat by quintile in men; Reported intake of Meats, Dairy foods, Eggs, Fish, and Vegetable oil (g/4.19MJ) | Q4 | 60.2 | 25.5 | 16.9 | ᴓ CVD-mortality ~16yf/u
Nagata, 2012 ^119^; Japan, The Takayama Study; N=28356; Attirtion: 10% | % E from carbohydrate and protein and median % E from Fat by quintile in men; Reported intake of Meats, Dairy foods, Eggs, Fish, and Vegetable oil (g/4.19MJ) | Q5 | 55.3 | 29.6 | 18.6 | ᴓ CVD-mortality ~16yf/u
Nakamura, 2014 ^120^; Japan, National Integrated Project for Prospective Observation of Noncommunicabl e Disease (NIPPON DATA); N=9200; Attirtion: 13% | % E by decile of adherence scores to a ‘low-carbohydrate’ diet; categorical and continuous analyses pooled in women and men, and analyzed separately; Reported intake of Rice, Flour, Fruits, Green-yellow vegetables, Fish and shellfish, Meats, Eggs in g/d | Pooled | | | | ᴓ CVD-mortality after 29y f/u, pooled | Confounders accounted for: Sex; Age; Race/ethnicity (all Japaense residents); Alcohol; Anthropometry; Smoking; Other: SES; Did not account for the following key confounders: Race/ethnicity (all Japanese); Diet assessed once at baseline with 3-d food record; [underlined: Funding:]; Ministry of Health, Labor and Welfare, Japanese Association for Cerebro-cardiovascular Disease Control; Ministry of Health, Labor and Welfare, and a Health and Labor Sciences Research Grant, Japan
Nakamura, 2014 ^120^; Japan, National Integrated Project for Prospective Observation of Noncommunicabl e Disease (NIPPON DATA); N=9200; Attirtion: 13% | Women | D1, ref. | 72.7 | 14.1 | 12.9 | ↑ CVD-mortality. D10vs. D1, ref. after 29y f/u
Nakamura, 2014 ^120^; Japan, National Integrated Project for Prospective Observation of Noncommunicabl e Disease (NIPPON DATA); N=9200; Attirtion: 13% | Women | D5 | 63.2 | 20.6 | 15.4 | ↑ CVD-mortality. D10vs. D1, ref. after 29y f/u
Nakamura, 2014 ^120^; Japan, National Integrated Project for Prospective Observation of Noncommunicabl e Disease (NIPPON DATA); N=9200; Attirtion: 13% | Women | D10 | 51.5 | 29.4 | 18.3 | ↑ CVD-mortality. D10vs. D1, ref. after 29y f/u
Nakamura, 2014 ^120^; Japan, National Integrated Project for Prospective Observation of Noncommunicabl e Disease (NIPPON DATA); N=9200; Attirtion: 13% | Men | D1, ref. | 69.8 | 13.1 | 12.6 | ᴓ CVD-mortality after 29y f/u
Nakamura, 2014 ^120^; Japan, National Integrated Project for Prospective Observation of Noncommunicabl e Disease (NIPPON DATA); N=9200; Attirtion: 13% | Men | D5 | 60.7 | 18.9 | 15 | ᴓ CVD-mortality after 29y f/u
Nakamura, 2014 ^120^; Japan, National Integrated Project for Prospective Observation of Noncommunicabl e Disease (NIPPON DATA); N=9200; Attirtion: 13% | Men | D10 | 50 | 26.6 | 17.9 | ᴓ CVD-mortality after 29y f/u
O’Neil, 2015 ^126^; Australia, Geelong Osteoporosis Study (GOS); N=1363; All male [0% female); Excluded those with previous cardiac related events | Anti-inflammatory diet | DIKO, ref. | 43.3 | 37.8 | 19.3 | ↑ CVD-event after 5yf/u | Confounders accounted for: Age, Sex, Alcohol, Physical activity, Anthropometry: Waist circumference, Smoking, Other: energy intake, diabetes, DBP, SBP; Did not account for the following key confounders: Race/ethnicity; Diet assessed once at baseline using validated FFQ; [underlined: Funding:]; National Health and Medical Research Counsel (Australia), National Cancer Institute
O’Neil, 2015 ^126^; Australia, Geelong Osteoporosis Study (GOS); N=1363; All male [0% female); Excluded those with previous cardiac related events | Pro-inflammatory diet | DII>0 | 44.5 | 37.6 | 18.5 | ↑ CVD-event after 5yf/u
O’Neil, 2015 ^126^; Australia, Geelong Osteoporosis Study (GOS); N=1363; All male [0% female); Excluded those with previous cardiac related events | Components that comprised the scoring for the inflammatory diets: carbohydrates, proteins, total fat, energy, fibre, cholesterol, SFA, MUFA, PUFA, n-3, n-6, niacin, thiamine, riboflavin, Fe, Mn, Zn, vitamin A, vitamin E, folic acid and (3-carotene
Preis, 2010 AJCN91^142^; United States, HFPS; N=43960; All male [0% female]; Excluded those with a hx of CVD or cancer at baseline. | % E by quintile of total protein at baseline | Q1, ref | 50.9 | 29.6 | 14.2 | ᴓ total stroke, ischemic stroke, hemorrhagic stroke after 18 y f/u | Confounders accounted for: Sex, Age, Alcohol, Race/ethnicity, Physical activity, Anthropometry: BMI, Smoking; Other: % of energy from SFA, individual types of fat, energy intake, family hx of MI, MVI use, chronic disease; Did not account for the following key confounders: NA; [underlined: Fundinq:]; NIH; Kirschstein-National Research Service Award, Aging Training
Preis, 2010 AJCN91^142^; United States, HFPS; N=43960; All male [0% female]; Excluded those with a hx of CVD or cancer at baseline. | % E by quintile of total protein at baseline | Q3 | 46.9 | 31 | 18.2 | ᴓ total stroke, ischemic stroke, hemorrhagic stroke after 18 y f/u
Preis, 2010 AJCN91^142^; United States, HFPS; N=43960; All male [0% female]; Excluded those with a hx of CVD or cancer at baseline. | % E by quintile of total protein at baseline | Q5 | 42.9 | 30.4 | 23.2 | ᴓ total stroke, ischemic stroke, hemorrhagic stroke after 18 y f/u
Preis, 2010 AJCN 92^141^; United States, HFPS; N=43960; All male [0% female]; Excluded those with a hx of CVD or cancer at baseline. | % E by quintile of total protein at baseline | Q1, ref | 50.9 | 29.6 | 14.2 | ᴓ total ischemic heart disease, nonfatal MI, fatal IHD after 18 yf/u; ᴓ HTN | Confounders accounted for: Sex, Age, Alcohol, Race/ethnicity, Physical activity, Anthropometry: BMI, Smoking, Other: % of energy from SFA, individual types of fat, energy intake, family hx of MI, MVI use, chronic disease; Did not account for the following key confounders: NA; [underlined: Funding:]; NIH; Kirschstein-National Research Service Award, Aging Training
Preis, 2010 AJCN 92^141^; United States, HFPS; N=43960; All male [0% female]; Excluded those with a hx of CVD or cancer at baseline. | % E by quintile of total protein at baseline | Q3 | 46.9 | 31 | 18.2 | ᴓ total ischemic heart disease, nonfatal MI, fatal IHD after 18 yf/u; ᴓ HTN
Preis, 2010 AJCN 92^141^; United States, HFPS; N=43960; All male [0% female]; Excluded those with a hx of CVD or cancer at baseline. | % E by quintile of total protein at baseline | Q5 | 42.9 | 30.4 | 23.2 | ᴓ total ischemic heart disease, nonfatal MI, fatal IHD after 18 yf/u; ᴓ HTN
Santiago, 2018 ^149^; Spain, SUN project; N=19341; Excluded those with CVD at baseline | % E by fertile of adherence to the Fat Quality Index; Reported intake g/d of tertiles for alcohol, fruits, vegetables, nuts, legumes, dairy products, meats fish, olive oil, and fast food | T1, ref. | 43.1 | 36.8 | 18.8 | ᴓ CVD after 10 y f/u; Stratifying by sex did not change the results. | Confounders accounted for: Sex, Age, Alcohol, Physical activity, Anthropometry: BMI, Smoking,; Other: Total energy intake, following special diet at baseline, weight gain 5 yr before entering cohort, SES, family hx of CVD or other chronic disease, snaking between meals, macro intake, adherence to Med diet; Did not account for the following key confounders: Race/ethnicity; [underlined: Funding:]; Spanish Ministry of Health –Instituto de Salud Carlos III and European Regional Development Fund (FEDER); CIBER-OBN; the Navarra Regional Government, and the University of Navarra.
Santiago, 2018 ^149^; Spain, SUN project; N=19341; Excluded those with CVD at baseline | % E by fertile of adherence to the Fat Quality Index; Reported intake g/d of tertiles for alcohol, fruits, vegetables, nuts, legumes, dairy products, meats fish, olive oil, and fast food | T2 | 43.7 | 36.6 | 18.3 | ᴓ CVD after 10 y f/u; Stratifying by sex did not change the results.
Santiago, 2018 ^149^; Spain, SUN project; N=19341; Excluded those with CVD at baseline | % E by fertile of adherence to the Fat Quality Index; Reported intake g/d of tertiles for alcohol, fruits, vegetables, nuts, legumes, dairy products, meats fish, olive oil, and fast food | T3 | 44.2 | 37.1 | 17.2 | ᴓ CVD after 10 y f/u; Stratifying by sex did not change the results.
Shikany, 2015 ^154^; United States, REGARDS; N=17418; Excluded those currently receiving treatment for cancer or chronic medical conditions | % E by quartile in each of 5 dietary patterns identified by factor analysis. | | | | | | Confounders accounted for: Sex, Age, Race/ethnicity, Physical activity, Anthropometry: BMI, WC, Smoking, Other: SES, total energy intake, Hx of HTN, dyslipidemia and DM; Did not account for the following key confounders: Alcohol; [underlined: Funding:]; National Institute of Neurological Disorders and Stroke; National Heart, Lung, and Blood Institute, NIH, Department of Health and Human Services.
Shikany, 2015 ^154^; United States, REGARDS; N=17418; Excluded those currently receiving treatment for cancer or chronic medical conditions | Convenience; Loaded highly on mixed dishes, pasta dishes, pizza, Mexican; food, and Chinese food. | Q1, ref | 52.0 | 36.2 | 13.0 | ᴓ CHD after 6 y f/u
Shikany, 2015 ^154^; United States, REGARDS; N=17418; Excluded those currently receiving treatment for cancer or chronic medical conditions | Convenience; Loaded highly on mixed dishes, pasta dishes, pizza, Mexican; food, and Chinese food. | Q2 | 48.9 | 37.1 | 14.1 | ᴓ CHD after 6 y f/u
Shikany, 2015 ^154^; United States, REGARDS; N=17418; Excluded those currently receiving treatment for cancer or chronic medical conditions | Convenience; Loaded highly on mixed dishes, pasta dishes, pizza, Mexican; food, and Chinese food. | Q3 | 47.4 | 37.6 | 14.8 | ᴓ CHD after 6 y f/u
Shikany, 2015 ^154^; United States, REGARDS; N=17418; Excluded those currently receiving treatment for cancer or chronic medical conditions | Convenience; Loaded highly on mixed dishes, pasta dishes, pizza, Mexican; food, and Chinese food. | Q4 | 45.3 | 38.7 | 15.5 | ᴓ CHD after 6 y f/u
Shikany, 2015 ^154^; United States, REGARDS; N=17418; Excluded those currently receiving treatment for cancer or chronic medical conditions | Plant-based; Loaded highly for vegetables, fruits, fruit juice, cereal, beans, fish, poultry, and yogurt. | Q1, ref | 45.7 | 38.9 | 13.5 | ᴓ CHD after 6 y f/u
Shikany, 2015 ^154^; United States, REGARDS; N=17418; Excluded those currently receiving treatment for cancer or chronic medical conditions | Plant-based; Loaded highly for vegetables, fruits, fruit juice, cereal, beans, fish, poultry, and yogurt. | Q2 | 47.8 | 37.9 | 14 | ᴓ CHD after 6 y f/u
Shikany, 2015 ^154^; United States, REGARDS; N=17418; Excluded those currently receiving treatment for cancer or chronic medical conditions | Plant-based; Loaded highly for vegetables, fruits, fruit juice, cereal, beans, fish, poultry, and yogurt. | Q3 | 48.5 | 37.4 | 14.6 | ᴓ CHD after 6 y f/u
Shikany, 2015 ^154^; United States, REGARDS; N=17418; Excluded those currently receiving treatment for cancer or chronic medical conditions | Plant-based; Loaded highly for vegetables, fruits, fruit juice, cereal, beans, fish, poultry, and yogurt. | Q4 | 50.4 | 35.9 | 15.4 | ᴓ CHD after 6 y f/u
Shikany, 2015 ^154^; United States, REGARDS; N=17418; Excluded those currently receiving treatment for cancer or chronic medical conditions | Sweets; Loaded highly for added sugars, desserts, chocolate, candy, and sweetened breakfast foods. | Q1, ref | 46.8 | 34.9 | 15.6 | ᴓ CHD after 6 y f/u
Shikany, 2015 ^154^; United States, REGARDS; N=17418; Excluded those currently receiving treatment for cancer or chronic medical conditions | Sweets; Loaded highly for added sugars, desserts, chocolate, candy, and sweetened breakfast foods. | Q2 | 48.6 | 36.6 | 14.9 | ᴓ CHD after 6 y f/u
Shikany, 2015 ^154^; United States, REGARDS; N=17418; Excluded those currently receiving treatment for cancer or chronic medical conditions | Sweets; Loaded highly for added sugars, desserts, chocolate, candy, and sweetened breakfast foods. | Q3 | 48.5 | 38.1 | 14.3 | ᴓ CHD after 6 y f/u
Shikany, 2015 ^154^; United States, REGARDS; N=17418; Excluded those currently receiving treatment for cancer or chronic medical conditions | Sweets; Loaded highly for added sugars, desserts, chocolate, candy, and sweetened breakfast foods. | Q4 | 48.4 | 39.6 | 13.2 | ᴓ CHD after 6 y f/u
Shikany, 2015 ^154^; United States, REGARDS; N=17418; Excluded those currently receiving treatment for cancer or chronic medical conditions | Southern; Loaded heavily on added fats, fried food, eggs and egg dishes, organ meats, processed meats, and SSBs. | Q1, ref | 49.6 | 35.8 | 15.1 | ↑ CHD after 6y f/u
Shikany, 2015 ^154^; United States, REGARDS; N=17418; Excluded those currently receiving treatment for cancer or chronic medical conditions | Southern; Loaded heavily on added fats, fried food, eggs and egg dishes, organ meats, processed meats, and SSBs. | Q2 | 48.4 | 37.4 | 14.2 | ↑ CHD after 6y f/u
Shikany, 2015 ^154^; United States, REGARDS; N=17418; Excluded those currently receiving treatment for cancer or chronic medical conditions | Southern; Loaded heavily on added fats, fried food, eggs and egg dishes, organ meats, processed meats, and SSBs. | Q3 | 48 | 37.9 | 13.9 | ↑ CHD after 6y f/u
Shikany, 2015 ^154^; United States, REGARDS; N=17418; Excluded those currently receiving treatment for cancer or chronic medical conditions | Southern; Loaded heavily on added fats, fried food, eggs and egg dishes, organ meats, processed meats, and SSBs. | Q4 | 46.4 | 38.6 | 14.2 | ↑ CHD after 6y f/u
Shikany, 2015 ^154^; United States, REGARDS; N=17418; Excluded those currently receiving treatment for cancer or chronic medical conditions | Alcohol and Salads; Loaded highly on beer, wine, liquor, green leafy vegetables, tomatoes, and salad dressing. | Q1, ref | 54.1 | 33.9 | 13.8 | ᴓ CHD after 6 y f/u
Shikany, 2015 ^154^; United States, REGARDS; N=17418; Excluded those currently receiving treatment for cancer or chronic medical conditions | Alcohol and Salads; Loaded highly on beer, wine, liquor, green leafy vegetables, tomatoes, and salad dressing. | Q2 | 50.1 | 36.8 | 14.2 | ᴓ CHD after 6 y f/u
Shikany, 2015 ^154^; United States, REGARDS; N=17418; Excluded those currently receiving treatment for cancer or chronic medical conditions | Alcohol and Salads; Loaded highly on beer, wine, liquor, green leafy vegetables, tomatoes, and salad dressing. | Q3 | 46.6 | 38.9 | 14.5 | ᴓ CHD after 6 y f/u
Shikany, 2015 ^154^; United States, REGARDS; N=17418; Excluded those currently receiving treatment for cancer or chronic medical conditions | Alcohol and Salads; Loaded highly on beer, wine, liquor, green leafy vegetables, tomatoes, and salad dressing. | Q4 | 41.1 | 41.1 | 15 | ᴓ CHD after 6 y f/u
Song, 2016 ^159^; United States, Nurses’ Health Study (NHS); Health Professionals Follow-up Study (HPFS); N=131342; Attrition: 24% | % E by 3 categories of adherence to an animal-protein pattern:; ’Animal’ pattern: major sources included processed and unprocessed red meat, poultry, dairy products, fish, and egg | ≤ 10% protein | 51.8 | 30.9 | 13.5 | ↑ CVD-mortality after 32y f/u | Confounders accounted for: Sex, Age, Alcohol, Physical activity, Anthropometry: BMI, Smoking; Did not account for the following key confounders: Race/ethnicity; Diet assessed every 2-4y using validated FFQ; Note that CVD-data were corrected and republished; [underlined: Funding:]; NIH
Song, 2016 ^159^; United States, Nurses’ Health Study (NHS); Health Professionals Follow-up Study (HPFS); N=131342; Attrition: 24% | % E by 3 categories of adherence to an animal-protein pattern:; ’Animal’ pattern: major sources included processed and unprocessed red meat, poultry, dairy products, fish, and egg | >12, ≤15%protein | 43.4 | 35.8 | 17.6 | ↑ CVD-mortality after 32y f/u
Song, 2016 ^159^; United States, Nurses’ Health Study (NHS); Health Professionals Follow-up Study (HPFS); N=131342; Attrition: 24% | % E by 3 categories of adherence to an animal-protein pattern:; ’Animal’ pattern: major sources included processed and unprocessed red meat, poultry, dairy products, fish, and egg | >18% protein | 35.9 | 37.7 | 23.9 | ↑ CVD-mortality after 32y f/u
Song, 2016 ^159^; United States, Nurses’ Health Study (NHS); Health Professionals Follow-up Study (HPFS); N=131342; Attrition: 24% | % E by 3 categories of adherence to a plant-protein pattern:; ’Plant’ pattern: major sources included bread, cereals, pasta, nuts, beans, and legumes | ≤3 % protein | 35.2 | 41.9 | 19.4 | ↓CVD-mortality after 32y f/u
Song, 2016 ^159^; United States, Nurses’ Health Study (NHS); Health Professionals Follow-up Study (HPFS); N=131342; Attrition: 24% | % E by 3 categories of adherence to a plant-protein pattern:; ’Plant’ pattern: major sources included bread, cereals, pasta, nuts, beans, and legumes | >4, ≤5% protein | 43.6 | 34.9 | 18.2 | ↓CVD-mortality after 32y f/u
Song, 2016 ^159^; United States, Nurses’ Health Study (NHS); Health Professionals Follow-up Study (HPFS); N=131342; Attrition: 24% | % E by 3 categories of adherence to a plant-protein pattern:; ’Plant’ pattern: major sources included bread, cereals, pasta, nuts, beans, and legumes | > 6% protein | 49.5 | 30.3 | 17.8 | ↓CVD-mortality after 32y f/u
Vissers, 2016 ^180^; Australia,; Australian Longitudinal Study on Women’s Health; N=6972; 100% women, excluded those late stage CKD, and prevalent CVD | Anti-inflammatory diet | DII<0 | 44.5 | 34.8 | 20.9 | ᴓ CVD, IHD, MI, Cebrebrovascular disease, and stroke after 11 y f/u | Confounders accounted for: Sex, Age, SES, Smoking, Alcohol, Physical activity, Other: Energy, diabetes, HTN; Did not account for Anthropometry; Diet assessed once at baseline; [underlined: Funding:]; Australian Government Department of Health; United States National Institute of Diabetes and Digestive and Kidney Diseases; Australian Research Council
Vissers, 2016 ^180^; Australia,; Australian Longitudinal Study on Women’s Health; N=6972; 100% women, excluded those late stage CKD, and prevalent CVD | Pro-inflammatory diet | DII>0 | 43.6 | 36.1 | 20.8 | ᴓ CVD, IHD, MI, Cebrebrovascular disease, and stroke after 11 y f/u
Vissers, 2016 ^180^; Australia,; Australian Longitudinal Study on Women’s Health; N=6972; 100% women, excluded those late stage CKD, and prevalent CVD | Pro-inflammatory components (energy, carbohydrate, protein, fat, saturated fat, iron, cholesterol) and anti-inflammatory components (alcohol, fibre, mono unsaturated fat, poly-unsaturated fat, omega-3, omega-6, niacin, thiamin, riboflavin, magnesium, zinc, vitamin A, vitamin C, vitamin E, folic acid, beta-carotene, garlic and onions) | | | | | ᴓ CVD, IHD, MI, Cebrebrovascular disease, and stroke after 11 y f/u
Wakai, 2014 ^183^; Japan; Japan Collaborative Cohort (JACC); N=58672; Excluded those with history of cancer, stroke, or myocardial infarction, and insufficient or implausible dietary data | % E by quintiles of fat intake (energy-adjusted) in women | Q1, ref. w | 71.7 | 13.7 | 12.3 | ᴓ CVD-mortality across quintiles in women | Confounders accounted for:; Sex; Age; SES; Alcohol; Physical activity; Anthropometry; Smoking; Other: total energy intake, sleep duration, vegetable and fruit intake; Did not account for the following key confounders: Race/ethnicity (all Japanese); Diet assessed once at baseline; nutrient residual models used for energy-adjustment; Critical risk of bias due to missing data for exposure and outcome; [underlined: Funding:]; Ministry of Education, Science, Sports and Culture of Japan (Monbusho), Japanese Ministry of Education, Culture, Sports, Science and Technology; National Cancer Center
Wakai, 2014 ^183^; Japan; Japan Collaborative Cohort (JACC); N=58672; Excluded those with history of cancer, stroke, or myocardial infarction, and insufficient or implausible dietary data | % E by quintiles of fat intake (energy-adjusted) in women | Q2 | 66.6 | 17.6 | 14.2 | ᴓ CVD-mortality across quintiles in women
Wakai, 2014 ^183^; Japan; Japan Collaborative Cohort (JACC); N=58672; Excluded those with history of cancer, stroke, or myocardial infarction, and insufficient or implausible dietary data | % E by quintiles of fat intake (energy-adjusted) in women | Q3 | 63.2 | 20.1 | 15.3 | ᴓ CVD-mortality across quintiles in women
Wakai, 2014 ^183^; Japan; Japan Collaborative Cohort (JACC); N=58672; Excluded those with history of cancer, stroke, or myocardial infarction, and insufficient or implausible dietary data | % E by quintiles of fat intake (energy-adjusted) in women | Q4 | 59.8 | 22.6 | 16.3 | ᴓ CVD-mortality across quintiles in women
Wakai, 2014 ^183^; Japan; Japan Collaborative Cohort (JACC); N=58672; Excluded those with history of cancer, stroke, or myocardial infarction, and insufficient or implausible dietary data | % E by quintiles of fat intake (energy-adjusted) in women | Q5 | 54.3 | 26.8 | 17.9 | ᴓ CVD-mortality across quintiles in women
Wakai, 2014 ^183^; Japan; Japan Collaborative Cohort (JACC); N=58672; Excluded those with history of cancer, stroke, or myocardial infarction, and insufficient or implausible dietary data | % E by quintiles of fat intake (energy-adjusted) in men | Q1, ref. m | 64.2 | 10.8 | 10.2 | ᴓ CVD-mortality across quintiles in men
Wakai, 2014 ^183^; Japan; Japan Collaborative Cohort (JACC); N=58672; Excluded those with history of cancer, stroke, or myocardial infarction, and insufficient or implausible dietary data | % E by quintiles of fat intake (energy-adjusted) in men | Q2 | 61.6 | 13.9 | 11.9 | ᴓ CVD-mortality across quintiles in men
Wakai, 2014 ^183^; Japan; Japan Collaborative Cohort (JACC); N=58672; Excluded those with history of cancer, stroke, or myocardial infarction, and insufficient or implausible dietary data | % E by quintiles of fat intake (energy-adjusted) in men | Q3 | 59.4 | 16.3 | 13.0 | ᴓ CVD-mortality across quintiles in men
Wakai, 2014 ^183^; Japan; Japan Collaborative Cohort (JACC); N=58672; Excluded those with history of cancer, stroke, or myocardial infarction, and insufficient or implausible dietary data | % E by quintiles of fat intake (energy-adjusted) in men | Q4 | 58.0 | 18.8 | 14.2 | ᴓ CVD-mortality across quintiles in men
Wakai, 2014 ^183^; Japan; Japan Collaborative Cohort (JACC); N=58672; Excluded those with history of cancer, stroke, or myocardial infarction, and insufficient or implausible dietary data | % E by quintiles of fat intake (energy-adjusted) in men | Q5 | 53.2 | 23.3 | 16.0 | ᴓ CVD-mortality across quintiles in men

Table 4 Risk of bias for observational studies examining dietary patterns consumed during childhood and risk of cardiovascular disease^xvi,^ ^xvii^

| Confounding | Selection of participants | Classification of exposures | Deviations from intended exposures | Missing data | Outcome measurement | Selection of the reported result
Bull, 2016^25^ | Serious | Low | Moderate | Serious | Serious | Low | Serious
Chan She Ping-Delfos, 2015^30^ | Serious | Low | Low | Serious | Moderate | Low | Moderate
Dahm, 2016^36^ | Serious | Serious | Moderate | Serious | Moderate | Low | Moderate
Pinto, 2019^139^ | Serious | Moderate | Moderate | Moderate | Serious | Low | Moderate

Table 5 Risk of bias for randomized controlled trials examining diets based on macronutrient distribution consumed by adults and risk of cardiovascular disease^xviii^

Article | Randomization | Deviation from classification of intervention – effect of assignment | Deviations from classification of intervention- per-protocol | Missing outcome data | Outcome measurement | Selection of the reported result
Arciero, 2008 ^8^ | Low | Low | Low | Low | Low | High
Bazzano, 2014 ^14^ | Low | Low | Low | Low | Low | Some concerns
Bladbjerg, 2010 ^18^ | Some concerns | Some concerns | Some concerns | Low | Some concerns | Some concerns
Dale, 2009 ^37^ | Low | Low | Low | Low | Low | Low
Daly, 2014 ^38^ | Low | Some concerns | Low | Low | Low | Some concerns
Davis, 2017 ^39^ | Low | Low | Low | Low | Low | Some concerns
Delbridge, 2009 ^42^ | Low | Low | Some concerns | Low | Low | Some concerns
Due, 2008 ^45^ | Some concerns | Some concerns | Some concerns | Low | Low | Low
Gardner, 2018 ^56^ | Low | Low | N/A | Low | Low | High
Howard, 2010 ^73^ | Low | Low | Some concerns | Some concerns | Low | Low
Kahleova, 2018 ^80^ | Low | Low | Low | Low | Low | Low
Paineau, 2008 ^130^ | Some concerns | Low | Low | Some concerns | Low | Low
Reidlinger, 2015 ^145^ | Low | Low | Low | Low | Low | Low
Sanders, 2013 ^148^ | Low | Low | Some concerns | Some concerns | Low | Some concerns
Saris, 2000 ^150^ | Low | Low | Low | Low | Low | Low
Tierney, 2011 ^169^ | Low | Low | N/A | Some concerns | Low | High
Uusitupa, 2013 ^176^ | Low | Low | Some concerns | High | Low | Some concerns
Vincent-Baudry, 2005 ^179^ | Some concerns | Low | N/A | Low | Low | Some concerns
Wan, 2017 ^184^ | Low | Low | Low | Low | Low | Low

Table 6 Risk of bias for observational studies examining diets based on macronutrient distribution consumed by adults and risk of cardiovascular disease^xix^

Article | Confounding | Selection of participants | Classification of exposures | Deviations from intended exposures | Missing data | Outcome measurement | Selection of the reported result
Brunner, 2008 ^23^ | Serious | Serious | Low | Serious | Moderate | Low | Moderate
Buckland, 2009 ^24^ | Moderate | Serious | Low | Serious | Serious | Low | Moderate
Cheng, 2018 ^31^ | Moderate | Serious | Low | Serious | Moderate | Low | Moderate
Diehr, 2003 ^43^ | Moderate | Serious | Moderate | Serious | Moderate | Low | Moderate
Ericson, 2019 ^47^ | Moderate | Moderate | Low | Serious | Moderate | Low | Moderate
Fung, 2010 ^54^ | Serious | Serious | Moderate | Moderate | Moderate | Low | Moderate
Guasch-Ferre, 2015 ^59^ | Serious | Low | Low | Moderate | Moderate | Low | Moderate
Halton, 2006 ^61^ | Serious | Serious | Moderate | Moderate | Moderate | Low | Moderate
Haring, 2014 ^65^ | Moderate | Moderate | Moderate | Serious | Moderate | Low | Moderate
Haring, 2015 ^66^ | Moderate | Moderate | Moderate | Serious | Moderate | Low | Moderate
Hernandez-Alonso, 2016 ^69^ | Serious | Serious | Moderate | Moderate | Moderate | Low | Moderate
Houston, 2011 ^72^ | Moderate | Serious | Low | Serious | Moderate | Low | Moderate
Kim, 2019 ^83^ | Serious | Serious | Low | Serious | Serious | Low | Moderate
Larsson, 2012 ^93^ | Moderate | Moderate | Moderate | Serious | Moderate | Low | Moderate
Leosdottir, 2004 ^98^ | Moderate | Serious | Low | Serious | Moderate | Low | Moderate
Leosdottir, 2005 ^100^ | Moderate | Serious | Low | Serious | Moderate | Low | Moderate
Leosdottir, 2007 ^99^ | Moderate | Serious | Low | Serious | Moderate | Low | Serious
Li, 2015 ^101^ | Moderate | Serious | Low | Moderate | Moderate | Low | Moderate
Maddock, 2019 ^106^ | Critical | Moderate | Low | Moderate | Serious | Low | Serious
Mazidi, 2019 ^110^ | Serious | Serious | Serious | Serious | Moderate | Low | Low
Nagata, 2012 ^119^ | Moderate | Moderate | Moderate | Serious | Moderate | Low | Moderate
Nakamura, 2014 ^120^ | Serious | Serious | Moderate | Serious | Serious | Low | Moderate
O’Neil, 2015 ^126^ | Serious | Serious | Moderate | Serious | Serious | Low | Moderate
Preis, 2010 – 91 ^142^ | Moderate | Serious | Low | Moderate | Moderate | Low | Moderate
Preis, 2010 – 92 ^141^ | Moderate | Serious | Low | Moderate | Moderate | Low | Moderate
Santiago, 2018 ^149^ | Serious | Moderate | Low | Serious | Serious | Low | Moderate
Shikany, 2015 ^154^ | Serious | Serious | Low | Serious | Moderate | Low | Moderate
Song, 2016 ^159^ | Serious | Serious | Moderate | Serious | Moderate | Low | Moderate
Vissers, 2016 ^180^ | Serious | Serious | Moderate | Serious | Serious | Low | Moderate
Wakai, 2014 ^183^ | Moderate | Serious | Moderate | Serious | Critical | Low | Moderate

ii Carbohydrate: 45 to 65% of energy; Fat: 25 to 35% of energy; Protein: 10 to 35% of energy. The AMDR for children are as follows: Carbohydrate: 45 to 65% of energy; Protein, ages 1-3y: 5 to 20% of energy, ages 4-18y: 10 to 30% of energy; Fat, ages 1-3y: 30 to 40% of energy, ages 4-18y: 25 to 35% of energy. Source: Institute of Medicine. Dietary Reference Intakes for Energy, Carbohydrate, Fiber, Fat, Fatty Acids, Cholesterol, Protein, and Amino Acids. Washington (DC): The National Academies Press; 2002 . For more details on the AMDR, see the Intervention/Exposure Inclusion and exclusion criteria

iii A detailed description of the methodology used for grading the strength of the evidence is available on the NESR website: https://nesr.usda.gov/2020-dietary-guidelines-advisory-committee-systematic-reviews and in Part C of the following reference: Dietary Guidelines Advisory Committee. 2020. Scientific Report of the 2020 Dietary Guidelines Advisory Committee: Advisory Report to the Secretary of Agriculture and the Secretary of Health and Human Services. U.S. Department of Agriculture, Agricultural Research Service, Washington, DC .

iv Dietary Guidelines Advisory Committee. 2015. Scientific Report of the 2015 Dietary Guidelines Advisory Committee: Advisory Report to the Secretary of Health and Human Services and the Secretary of Agriculture. U.S. Department of Agriculture, Agricultural Research Service, Washington, DC .

v A detailed description of the methodology used for grading the strength of the evidence is available on the NESR website: https://nesr.usda.gov/2020-dietary-guidelines-advisory-committee-systematic-reviews and in Part C of the following reference: Dietary Guidelines Advisory Committee. 2020. Scientific Report of the 2020 Dietary Guidelines Advisory Committee: Advisory Report to the Secretary of Agriculture and the Secretary of Health and Human Services. U.S. Department of Agriculture, Agricultural Research Service, Washington, DC .

vi Abbreviations: BMI, body mass index; CHD, coronary heart disease; CVD, cardiovascular disease; DBP, diastolic blood pressure; f/u, follow-up; HDL, high-density lipoprotein cholesterol; HF, heart failure; HTN, hypertension; LDL, low-density lipoprotein cholesterol; N/A, Not applicable; NHS, National Health Service (UK); NIH, National Institutes of Health; NR, Not reported; mo, month; MI, myocardial infarction; PAD, peripheral artery disease; SBP, systolic blood pressure; TAG, Tryacylglycerol; TG, Triglycerides; UK, United Kingdom; wk, week(s); y, year(s)

vii Includes last name of first author, publication year, country, name of the cohort or study if reported, analytic sample size, and select participant characteristics of the analytic sample

viii Symbols used in this table: ↑ , statistically significant higher outcome (i.e., positive directional association between higher adherence to DP/diet and higher risk of CVD); ᴓ no significant association or difference between DP/diet groups and risk of CVD; ↓ , statistically significant lower outcome (i.e., inverse association between higher adherence to DP/diet and lower risk of CVD)

ix Abbreviations: BMI, body mass index; CHD, coronary heart disease; CVD, cardiovascular disease; DBP, diastolic blood pressure; EI/EE, Total Energy Intake; f/u, follow-up; HDL, high-density lipoprotein cholesterol; HF, heart failure; HTN, hypertension; Hx, history; ISCIII, Instituto de Salud Carlos III; LDL, low-density lipoprotein cholesterol; N/A, Not applicable; NHS, National Health Service (United Kingdom); NIH, National Institutes of Health; NR, Not reported; mo, month(s); MI, myocardial infarction; PAD, peripheral artery disease; SBP, systolic blood pressure; TAG, Tryacylglycerol; TG, Triglycerides; wk, week(s); y, year(s)

x Includes last name of first author, publication year, country, analytic sample size, and select participant characteristics.

xi Unless otherwise noted, the first category listed was used as the referent (ref.) group.

xii Results use the following symbols:

- ↑ , statistically significant effect of diet on higher outcome (i.e., positive relationship between higher adherence to diet and higher risk of CVD);
- ᴓ, association or difference between diet groups and risk of CVD was not statistically significant;
- ↓ , statistically significant effect of diet on lower outcome (i.e., inverse association between higher adherence to diet and lower risk of CVD)

xiii Abbreviations: BMI, body mass index; CHD, coronary heart disease; CVD, cardiovascular disease; DBP, diastolic blood pressure; f/u, follow-up; HDL, high-density lipoprotein cholesterol; HF, heart failure; HTN, hypertension; LDL, low-density lipoprotein cholesterol; N/A, Not applicable; NHS, National Health Service (UK); NIH, National Institutes of Health; NR, Not reported; mo, month(s); MI, myocardial infarction; PAD, peripheral artery disease; Ref, reference group; SBP, systolic blood pressure; TAG, Tryacylglycerol; TG, Triglycerides; UK, United Kingdom; wk, week(s); y, year(s)

xiv Unless otherwise noted, the first category listed was used as the referent (ref.) group.

xv Symbols used in this table: ↑ , statistically significant effect of diet on higher outcome (i.e., positive relationship between higher adherence to diet and higher risk of CVD); ᴓ no significant association or difference between diet groups and risk of CVD; ↓ , statistically significant effect of diet on lower outcome (i.e., inverse association between higher adherence to diet and lower risk of CVD)

xvi A detailed description of the methodology used for assessing risk of bias is available on the NESR website: https://nesr.usda.gov/2020-dietary-guidelines-advisory-committee-systematic-reviews and in Part C of the following reference: Dietary Guidelines Advisory Committee. 2020. Scientific Report of the 2020 Dietary Guidelines Advisory Committee: Advisory Report to the Secretary of Agriculture and the Secretary of Health and Human Services. U.S. Department of Agriculture, Agricultural Research Service, Washington, DC .

xvii Possible ratings of low, moderate, serious, critical, or no information determined using the “Risk of Bias for Nutrition Observational Studies” tool (RoB-NObs) ( Dietary Guidelines Advisory Committee. 2020. Scientific Report of the 2020 Dietary Guidelines Advisory Committee: Advisory Report to the Secretary of Agriculture and the Secretary of Health and Human Services. U.S. Department of Agriculture, Agricultural Research Service, Washington, DC .)

xviii Possible ratings of low, some concerns, or high determined using the “Cochrane Risk-of-bias 2.0” (RoB 2.0) (https://www.riskofbias.info/welcome/rob-2-0-tool) (August 2016 version)” ( Higgins JPT, Sterne JAC, Savović J, Page MJ, Hróbjartsson A, Boutron I, Reeves B, Eldridge S. A revised tool for assessing risk of bias in randomized trials In: Chandler J, McKenzie J, Boutron I, Welch V (editors). Cochrane Methods. Cochrane Database of Systematic Reviews 2016, Issue 10 (Suppl 1). dx.doi.org/10.1002/14651858.CD201601 .)

xix Possible ratings of low, moderate, serious, critical, or no information determined using the “Risk of Bias for Nutrition Observational Studies” tool (RoB-NObs) ( Dietary Guidelines Advisory Committee. 2020. Scientific Report of the 2020 Dietary Guidelines Advisory Committee: Advisory Report to the Secretary of Agriculture and the Secretary of Health and Human Services. U.S. Department of Agriculture, Agricultural Research Service, Washington, DC .)