# List of abbreviations

Abbreviation: Full name
AHEI-2010: Alternative Healthy Eating Index-2010
AICR: American Institute for Cancer Research
aMED: alternate Mediterranean diet score
aMEDr: alternate Mediterranean diet score without alcohol
BMI: Body mass index
CSDLH: Canadian Study of Diet, Lifestyle and Health
DASH: Dietary Approaches to Stop Hypertension
DRE: Digital rectal exam
EDIH: Empirical dietary index for hyperinsulinemia
EDIP: Empirical dietary inflammatory pattern
ERDP: Estrogen-related dietary pattern
f/u: Follow-up
FSAm-NPS: Nutrient Profiling System of the British Food Standards Agency (modified version)
FSAm-NPS DI: Nutrient Profiling System of the British Food Standards Agency dietary index (modified version)
h: Hour(s)
HDI: Human development index
HEI-2010: Healthy Eating Index-2010
HER2: Human epidermal growth factor receptor 2
HHS: United States Department of Health and Human Services
MEDI-LITE: Mediterranean diet score (French NutriNet-Sante study)
MET: Metabolic equivalent of task
mMED: Modified Mediterranean Diet
NBSS: National Breast Screening Study
NESR: Nutrition Evidence Systematic Review
NIH: National Institutes of Health
PCA: Principal component analysis
PCS: Prospective cohort study
PNNS-GS: French National Nutrition Health Program-Guideline Score
PSA: Prostate-specific antigen
RCT: Randomized controlled trial
RRR: Reduced rank regression
SES: Socioeconomic status
USDA: United States Department of Agriculture
WCRF: World Cancer Research Fund
wk: Week(s)
y: Year(s)