# INTRODUCTION

This document describes a systematic review conducted to answer the following question: What is the relationship between dietary patterns consumed and risk of certain types of cancer? This systematic review was conducted by the 2020 Dietary Guidelines Advisory Committee, supported by USDA’s Nutrition Evidence Systematic Review (NESR).

More information about the 2020 Dietary Guidelines Advisory Committee is available at the following website: www.DietaryGuidelines.gov.

NESR specializes in conducting food- and nutrition-related systematic reviews using a rigorous, protocol-driven methodology. More information about NESR is available at the following website: NESR.usda.gov.

NESR’s systematic review methodology involves developing a protocol, searching for and selecting studies, extracting data from and assessing the risk of bias of each included study, synthesizing the evidence, developing conclusion statements, grading the evidence underlying the conclusion statements, and recommending future research. A detailed description of the systematic reviews conducted for the 2020 Dietary Guidelines Advisory Committee, including information about methodology, is available on the NESR website: https://nesr.usda.gov/2020-dietary-guidelines-advisory-committee-systematic-reviews. In addition, starting on page 214, this document describes the final protocol as it was applied in the systematic review. A description of and rationale for modifications made to the protocol are described in the 2020 Dietary Guidelines Advisory Committee Report, Part D: Chapter 8. Dietary Patterns.

The systematic review described in this document updates existing systematic reviews that were conducted by the 2015 Dietary Guidelines Advisory Committee with support from USDA’s Nutrition Evidence Systematic Review (NESR) team. Information about the 2015 Dietary Guidelines Advisory Committee’s review of the evidence on dietary patterns and cancer can be found in their report, which is available at the following website: https://nesr.usda.gov/dietary-patterns-foods-and-nutrients-and-health-outcomes-subcommittee.