# METHODOLOGY

The NESR team used its rigorous, protocol-driven methodology to support the 2020 Dietary Guidelines Advisory Committee in conducting this update to an existing systematic review.

NESR’s systematic review methodology involves:

- Developing a protocol,
- Searching for and selecting studies,
- Extracting data from and assessing the risk of bias of each included study,
- Synthesizing the evidence,
- Developing conclusion statements,
- Grading the evidence underlying the conclusion statement, and
- Recommending future research.

A detailed description of the methodology used in conducting this systematic review is available on the NESR website: https://nesr.usda.gov/2020-dietary-guidelines-advisory-committee-systematic-reviews, and can be found in the 2020 Dietary Guidelines Advisory Committee Report, Part C: Methodology.^lxxxviii^ This systematic review was peer reviewed by Federal scientists, and information about the peer review process can also be found in the Committee’s Report, Part C. Methodology. Additional information about this systematic review, including a description of and rationale for any modifications made to the protocol can be found in the 2020 Dietary Guidelines Advisory Committee Report, Part D: Chapter 8. Dietary Patterns.

The systematic review described in this document updates existing systematic reviews that were conducted by the 2015 Dietary Guidelines Advisory Committee with support from USDA’s Nutrition Evidence Systematic Review (NESR) team. Information about the 2015 Dietary Guidelines Advisory Committee’s review of the evidence on dietary patterns and cancer can be found in their report, which is available at the following website: https://nesr.usda.gov/dietary-patterns-foods-and-nutrients-and-health-outcomes-subcommittee.

Below are details of the final protocol for the systematic review described herein, including the:

- Analytic framework
- Literature search and screening plan
- Literature search and screening results

## ANALYTIC FRAMEWORK

The analytic framework (Figure 1) illustrates the overall scope of the systematic review, including the population, the interventions and/or exposures, comparators, and outcomes of interest. It also includes definitions of key terms and identifies key confounders and other factors to be considered in the systematic review. The inclusion and exclusion criteria that follow provide additional information about how parts of the analytic framework were defined and operationalized for the review.

Figure 1 Analytic framework

An analytic framework visually represents the overall scope of the systematic review question, and depicts the contributing elements that were examined and evaluated, including the target population, exposure, comparison, outcomes, and key confounders. This is the analytic framework for the systematic review question on dietary patterns consumed and risk of certain types of cancer. For this systematic review, the target population for the intervention/exposure considered was children through older adults, who are healthy and/or at risk of chronic disease. The target population for the outcomes of breast, colorectal, prostate, and lung cancer was children through older adults. The interventions or exposures considered were consumption of and/or adherence to a dietary pattern and their comparators were consumption of and/or adherence to a different dietary pattern or different levels of consumption of and/or adherence to a dietary pattern. The outcomes considered include breast, colorectal, prostate, and lung cancers. The key confounders were sex, age, race/ethnicity, socioeconomic status, alcohol intake (in adults), physical activity, smoking, anthropometry, family history of the cancer outcome, hormonal contraceptives (breast), menopausal status (breast), inflammatory bowel disease (colon and rectum cancer), colorectal polyps (colon and rectum cancer), lung disease (lung cancer), and environmental exposures to lung carcinogens (lung cancer). The other factors to be considered were total energy intake.

## LITERATURE SEARCH AND SCREENING PLAN

### Inclusion and exclusion criteria

This table provides the inclusion and exclusion criteria for this update to systematic reviews. The inclusion and exclusion criteria are a set of characteristics used to determine which articles identified in the literature search were included in or excluded from the systematic review.

Table 15 Inclusion and exclusion criteria

Category | Inclusion Criteria | Exclusion Criteria
Study design | - Randomized controlled trials; - Non-randomized controlled trials, including quasi-experimental and controlled before and after studies; - Prospective cohort studies; - Retrospective cohort studies; - Nested case-control studies | - Uncontrolled trials; - Cross-sectional studies; - Uncontrolled before-and-after studies; - Narrative reviews; - Systematic reviews; - Meta-analyses
Intervention/exposure | Studies that examine consumption of and/or adherence to a dietary pattern [i.e., the quantities, proportions, variety, or combination of different foods, drinks, and nutrients (when available) in diets, and the frequency with which they are habitually consumed], including, at a minimum, a description of the foods and beverages in the pattern; - Dietary patterns may be measured or derived using a variety of approaches, such as adherence to a priori patterns (indices/scores), data driven patterns (factor or cluster analysis), reduced rank regression, or other methods, including clinical trials | Studies that do not provide a description of the dietary pattern, which at minimum, must include the foods and beverages in the pattern (i.e., studies that examine a labeled dietary patterns, but do not describe the foods and beverages consumed)
Comparator | Dietary patterns described by foods and beverages consumed:; - Consumption of and/or adherence to a different dietary pattern; - Different levels of consumption of and/or adherence to a dietary pattern | - N/A
Outcomes | Incident cases of:; - Breast cancer; - Colorectal cancer; - Lung cancer; - Prostate cancer | - Studies that exclusively examine cancer-related mortality, prevalence, survivorship, or recurrence of cancer
Date of publication | - January 2014 - January 2020 (this date range is in addition to the original systematic review, which included articles published from January 2000 - January 2014) | - Articles published prior to January 2000 or after January 2020
Publication status | Articles that have been peer-reviewed | Articles that have not been peer-reviewed and are not published in peer-reviewed journals, including unpublished data, manuscripts, reports, abstracts, and conference proceedings
Language of publication | Articles published in English | Articles published in languages other than English
Country ^lxxxix^ | Studies conducted in countries ranked as high or higher human development | Studies conducted in countries ranked as medium or lower human development
Study participants | - Human participants; - Males; - Females | - Non-human participants (e.g., animal or in-vitro models)
Age of study participants | - Age at intervention or exposure:; ○ Children and adolescents (ages 2-18 years); ○ Adults (ages 19-64 years); ○ Older adults (ages 65 years and older) | - Age at intervention or exposure:; ○ Infants and toddlers (birth to 24 months)
| - Age at outcome:; ○ Children and adolescents (ages 2-18 years); ○ Adults (ages 19-64 years); ○ Older adults (ages 65 years and older) | - Age at outcome:; ○ Infants and toddlers (birth to 24 months)
Health status of study participants | - Studies that enroll participants who are healthy and/or at risk for chronic disease, including those with obesity; - Studies that enroll some participants diagnosed with a disease; - Studies that enroll some participants diagnosed with cancer | - Studies that exclusively enroll participants diagnosed with a disease, or hospitalized patients with illness or injury. (For this criterion, studies that exclusively enroll subjects with obesity will be included.); - Studies that exclusively enroll participants with cancer (i.e., studies that aim to treat participants who have already been diagnosed with the outcome of interest)

### Electronic databases and search terms

#### PubMed

- Provider: U.S. National Library of Medicine
- Date(s) Searched: January 13, 2020
- Date range searched: January 1, 2014-January 13, 2020
- Search Terms:
  - #1 - dietary pattern* OR diet pattern* OR eating pattern* OR food pattern* OR diet quality* OR eating habit* OR dietary habit* OR diet habit* OR food habit* OR beverage habit* OR “Feeding Behavior”[Mesh:NoExp] OR dietary profile* OR food profile* OR diet profile* OR eating profile* OR dietary guideline* OR dietary recommendation* OR dietary intake* OR eating style* OR “Diet, Mediterranean”[Mesh] OR Mediterranean Diet*[tiab] OR “Dietary Approaches To Stop Hypertension”[Mesh] OR Dietary Approaches To Stop Hypertension Diet* OR DASH diet* OR “Diet, Gluten-Free”[Mesh] OR Gluten Free diet* OR prudent diet* OR “Diet, Paleolithic”[Mesh] OR Paleolithic Diet* OR “Diet, Vegetarian”[Mesh] OR vegetarian diet*[tiab] OR vegan diet* OR “Diet, Healthy”[Mesh] OR plant based diet* OR “Diet, Western”[Mesh] OR western diet* OR “Diet, Carbohydrate-Restricted”[Mesh] OR low-carbohydrate diet* OR high carbohydrate diet* OR Ketogenic Diet* OR Nordic Diet* OR “Diet, Fat-Restricted”[Mesh] OR “Diet, HighFat”[Mesh] OR “Diet, High-Protein”[Mesh] OR high protein diet*[tiab] OR protein intake* OR high-fat diet* OR low fat diet* OR “Diet, Protein-Restricted”[Mesh] OR low protein diet* OR “Diet, Sodium-Restricted”[Mesh] OR low-sodium diet* OR low salt diet* OR ((“Dietary Proteins”[Mesh] OR dietary protein*[tiab] OR “Dietary Carbohydrates”[Mesh] OR dietary carbohydrate*[tiab] OR “Dietary Fats”[Mesh] OR dietary fat*[tiab] OR hypocaloric OR hypocaloric) AND (diet[tiab] OR diets[tiab] OR consumption[tiab] OR intake[tiab] OR supplement*[tiab])) OR ((“Guideline Adherence”[Mesh] OR guideline adherence*) AND (diet[tiab] OR dietary[tiab] OR food[tiab] OR beverage*[tiab] OR nutrition*[tiab])) OR diet score* OR diet quality score* OR diet quality index* OR kidmed OR diet index* OR dietary index* OR food score* OR MedDietScore OR healthy eating index[tiab] OR ((pattern[tiab] OR patterns[tiab] OR consumption[tiab] OR habit*[tiab]) AND (“Diet”[Mesh:NoExp] OR diet[tiab] OR diets[tiab] OR dietary[tiab] OR “Food”[Mesh] OR food[tiab] OR foods[tiab] OR “Beverages”[Mesh] OR beverage[tiab] OR beverages[tiab]))
  - #2 - “Breast Neoplasms”[Mesh] OR breast neoplasm* OR breast cancer*[tiab] OR breast carcino* OR “Colorectal Neoplasms”[Mesh] OR colorectal neoplasm* OR colorectal cancers* OR colorectal carcino* OR colon neoplasm* OR colon cancer* OR colon carcino* OR “Intestinal Polyps”[Mesh] OR intestinal polyp* OR colonic polyp* OR colorectal polyp* OR colorectal lesion* OR rectal neoplasm* OR rectal cancer* OR rectal carcino* OR “Prostatic Neoplasms”[Mesh] OR prostate neoplasm* OR prostate cancer* OR prostate carcino* OR “Lung Neoplasms”[Mesh] OR lung neoplasm* OR lung carcino* OR lung cancer* OR “Liver Neoplasms”[Mesh] OR liver neoplasm* OR liver cancer* OR hepatic neoplasm* OR hepatic cancer* OR hepatocellular carcino* OR “Pancreatic Neoplasms”[Mesh] OR pancreatic neoplasm* OR pancreatic cancer* OR pancreatic carcino* OR pancreatic adenocarcinoma* OR pancreatic neuro* OR ampullary cancer* OR ampullary carcino* OR exocrine cancer* OR exocrine carcino* OR “Endometrial Neoplasms”[Mesh] OR endometrial neoplasm* OR endometrial cancer* OR endometrial carcino* OR endometrioid neoplasm* OR endometrioid cancer* OR endometrioid carcino* OR “Endometrial Hyperplasia”[Mesh] OR endometrial hyperplasia* OR “Leukemia”[Mesh] OR leukem* OR leukaem* OR leucem* OR leucaem* OR ((cancer*[tiab] OR “Neoplasms”[Mesh] OR neoplasm*[tiab] OR carcino*[tiab] OR “Carcinogens”[Mesh] OR malignan*[tiab] OR adenocarcinoma*[tiab] OR sarcoma*[tiab] OR metastasis[tiab] OR metastases[tiab] OR tumor[tiab] OR tumors[tiab] OR tumour*[tiab] OR “Polyps”[Mesh] OR polyp[tiab] OR polyps[tiab]) AND (“Colon”[Mesh] OR colonic*[tiab] OR colon[tiab] OR colorect*[tiab] OR rectal[tiab] OR rectum[tiab] OR “Colonic Diseases”[Mesh:noexp] OR “Breast”[Mesh] OR “Breast Diseases”[Mesh:noexp] OR breast*[tiab] OR mammary[tiab] OR “Prostate”[Mesh] OR prostate*[tiab] OR prostatic[tiab] OR “Prostatic Diseases”[Mesh:noexp] OR “Lung”[Mesh] OR “Lung Diseases”[Mesh:noexp] OR lung[tiab] OR pulmonary[tiab] OR endometri* OR endometrium* OR “Uterine Diseases”[Mesh:noexp] OR “uterine diseases*” OR “Liver”[Mesh] OR liver[tiab] OR “Liver Diseases”[Mesh:noexp] OR “Pancreas”[Mesh] OR pancreas[tiab] OR pancreati*[tiab] OR “Pancreatic Diseases”[Mesh:noexp] OR “Ampulla of Vater”[Mesh] OR “ampulla of vater”))
  - #3 - (#1 AND #2) NOT (“Animals”[Mesh] NOT (“Animals”[Mesh] AND “Humans”[Mesh])) NOT editorial[ptyp] OR comment[ptyp] OR news[ptyp] OR letter[ptyp] OR review[ptyp] OR systematic review[ptyp] OR systematic review[ti] OR meta-analysis[ptyp] OR meta-analysis[ti] OR meta-analyses[ti] OR retracted publication[ptyp] OR retraction of publication[ptyp] OR retraction of publication[tiab] OR retraction notice[ti] Filters: Publication date from 2014/01/01 to 2020/01/13; English

#### Cochrane Central Register of Controlled Trials (CENTRAL)

- Provider: John Wiley & Sons
- Date(s) Searched: January 13, 2020
- Date range searched: January 1, 2014-January 13, 2020
- Search Terms:
  - #1 - “dietary pattern*” OR “diet pattern*” OR “eating pattern*” OR “food pattern*” OR “diet quality*” OR “eating habit*” OR “dietary habit*” OR “diet habit*” OR “food habit*” OR “beverage habit*” OR [mh ^“Feeding Behavior”] OR “feeding behavior*” OR “dietary profile*” OR “food profile*” OR “diet profile*” OR “eating profile*” OR “dietary guideline*” OR “dietary recommendation*” OR “dietary intake*” OR “eating style*” OR [mh “Diet, Mediterranean”] OR “Mediterranean Diet*” OR [mh “Dietary Approaches To Stop Hypertension”] OR “Dietary Approaches To Stop Hypertension Diet*” OR “DASH diet*” OR [mh “Diet, Gluten-Free”] OR “Gluten Free diet*” OR “prudent diet*” OR [mh “Diet, Paleolithic”] OR “Paleolithic Diet*” OR [mh “Diet, Vegetarian”] OR “vegetarian diet*” OR “vegan diet*” OR [mh “Diet, Healthy”] OR “healthy diet” OR “plant based diet*” OR [mh “Diet, Western”] OR “western diet*” OR [mh “Diet, Carbohydrate-Restricted”] OR “low-carbohydrate diet*” OR “high carbohydrate diet*” OR “Ketogenic Diet*” OR “Nordic Diet*” OR [mh “Diet, Fat-Restricted”] OR [mh “Diet, High-Fat”] OR [mh “Diet, High-Protein”] OR “high protein diet*” OR “protein intake*” OR “high-fat diet*” OR “low fat diet*” OR [mh “Diet, Protein-Restricted”] OR “low protein diet*” OR [mh “Diet, Sodium-Restricted”] OR “low-sodium diet*” OR “low salt diet*”
  - #2 - (([mh “Dietary Proteins”] OR “dietary protein*” OR [mh “Dietary Carbohydrates”] OR “dietary carbohydrate*” OR [mh “Dietary Fats”] OR “dietary fat*” OR hypocaloric OR hypocaloric) NEAR/6 (diet OR diets OR consumption OR intake OR supplement*))
  - #3 - (([mh “Guideline Adherence”] OR guideline adherence*) NEAR/6 (diet OR dietary OR food OR beverage* OR nutrition*))
  - #4 - (“diet score*” OR “diet quality score*” OR “diet quality index*” OR kidmed OR “diet index*” OR “dietary index*” OR “food score*” OR MedDietScore OR “healthy eating index*”):ti,ab,kw
  - #5 - ((pattern OR patterns OR consumption OR habit*) NEAR/6 ([mh ^“Diet”] OR diet OR diets OR dietary OR [mh “Food”] OR food OR foods OR [mh “Beverages”] OR beverage OR beverages))
  - #6 - #1 OR #2 OR #3 OR #4 OR #5
  - #7 - [mh “Breast Neoplasms”] OR [mh “Colorectal Neoplasms”] OR [mh “Intestinal Polyps”] OR [mh “Prostatic Neoplasms”] OR [mh “Lung Neoplasms”] OR [mh “Liver Neoplasms”] OR [mh “Pancreatic Neoplasms”] OR [mh “Endometrial Neoplasms”] OR [mh “Endometrial Hyperplasia”] OR [mh “Leukemia”]
  - #8 - (“breast neoplasm*” OR “breast cancer*” OR “breast carcino*” OR “colorectal neoplasm*” OR “colorectal cancers*” OR “colorectal carcino*” OR “colon neoplasm*” OR “colon cancer*” OR “colon carcino*” OR “intestinal polyp*” OR “colonic polyp*” OR “colorectal polyp*” OR “colorectal lesion*” OR “rectal neoplasm*” OR “rectal cancer*” OR “rectal carcino*” OR “prostate neoplasm*” OR “prostate cancer*” OR “prostate carcino*” OR “lung neoplasm*” OR “lung carcino*” OR “lung cancer*” OR “liver neoplasm*” OR “liver cancer*” OR “hepatic neoplasm*” OR “hepatic cancer*” OR “hepatocellular carcino*” OR “pancreatic neoplasm*” OR “pancreatic cancer*” OR “pancreatic carcino*” OR “pancreatic adenocarcinoma*” OR “pancreatic neuro*” OR “ampullary cancer*” OR “ampullary carcino*” OR “exocrine cancer*” OR “exocrine carcino*” OR “endometrial neoplasm*” OR “endometrial cancer*” OR “endometrial carcino*” OR “endometrioid neoplasm*” OR “endometrioid cancer*” OR “endometrioid carcino*” OR “endometrial hyperplasia*” OR leukem* OR leukaem* OR leucem* OR leucaem*):ti,ab,kw
  - #9 - ((cancer* OR [mh “Neoplasms”] OR neoplasm* OR carcino* OR [mh “Carcinogens”] OR malignan* OR adenocarcinoma* OR sarcoma* OR metastasis OR metastases OR tumor OR tumors OR tumour* OR [mh “Polyps”] OR polyp OR polyps) NEAR/6 ([mh “Colon”] OR colonic* OR colon OR colorect* OR rectal OR rectum OR [mh ^“Colonic Diseases”] OR [mh “Breast”] OR [mh ^“Breast Diseases”] OR breast* OR mammary OR [mh “Prostate”] OR prostate* OR prostatic OR [mh ^“Prostatic Diseases”] OR [mh “Lung”] OR [mh ^“Lung Diseases”] OR lung OR pulmonary OR endometri* OR endometrium* OR [mh ^“Uterine Diseases”] OR “uterine diseases*” OR [mh “Liver”] OR liver OR [mh ^“Liver Diseases”] OR [mh “Pancreas”] OR pancreas OR pancreati* OR [mh ^“Pancreatic Diseases”] OR [mh “Ampulla of Vater”] OR “ampulla of vater”))
  - #10 - #7 OR #8 OR #9
  - #11 - #6 AND #10" with Publication Year from 2014 to 2020, in Trials (Word variations have been searched)

#### Embase

- Provider: Elsevier
- Date(s) Searched: January 13, 2020
- Date range searched: January 1, 2014-January 13, 2020
- Search Terms
  - #1- ‘feeding behavior’/de OR ‘mediterranean diet’/exp OR ‘dash diet’/exp OR ‘gluten free diet’/exp OR ‘paleolithic diet’/de OR ‘vegetarian diet’/exp OR ‘healthy diet’/exp OR ‘western diet’/de OR ‘low carbohydrate diet’/exp OR ‘low fat diet’/de OR ‘lipid diet’/exp OR ‘protein diet’/exp OR ‘protein restriction’/exp OR ‘sodium restriction’/exp
  - #2 - ‘dietary pattern*’:ab,ti OR ‘diet pattern*’:ab,ti OR ‘eating pattern*’:ab,ti OR ‘food pattern*’:ab,ti OR ‘diet quality*’:ab,ti OR ‘eating habit*’:ab,ti OR ‘dietary habit*’:ab,ti OR ‘diet habit*’:ab,ti OR ‘food habit*’:ab,ti OR ‘beverage habit*’:ab,ti OR ‘feeding behavior*’:ab,ti OR ‘dietary profile*’:ab,ti OR ‘food profile*’:ab,ti OR ‘diet profile*’:ab,ti OR ‘eating profile*’:ab,ti OR ‘dietary guideline*’:ab,ti OR ‘dietary recommendation*’:ab,ti OR ‘dietary intake*’:ab,ti OR ‘eating style*’:ab,ti OR ‘mediterranean diet*’:ab,ti OR ‘dietary approaches to stop hypertension diet*’:ab,ti OR ‘dash diet*’:ab,ti OR ‘gluten free diet*’:ab,ti OR ‘prudent diet*’:ab,ti OR ‘paleolithic diet*’:ab,ti OR ‘vegetarian diet*’:ab,ti OR ‘vegan diet*’:ab,ti OR ‘healthy diet’:ab,ti OR ‘plant based diet*’:ab,ti OR ‘western diet*’:ab,ti OR ‘low-carbohydrate diet*’:ab,ti OR ‘high carbohydrate diet*’:ab,ti OR ‘ketogenic diet*’:ab,ti OR ‘nordic diet*’:ab,ti OR ‘high protein diet*’:ab,ti OR ‘protein intake*’:ab,ti OR ‘high-fat diet*’:ab,ti OR ‘low fat diet*’:ab,ti OR ‘low protein diet*’:ab,ti OR ‘low-sodium diet*’:ab,ti OR ‘low salt diet*’:ab,ti
  - #3 - ((‘dietary protein*’ OR ‘dietary carbohydrate*’ OR ‘dietary fat*’ OR hypocaloric OR ‘hypo caloric’) NEAR/6 (diet OR diets OR consumption OR intake OR supplement*)):ab,ti
  - #4 - (‘guideline adherence*’ NEAR/6 (diet OR dietary OR food OR beverage* OR nutrition*)):ab,ti
  - #5 - ‘diet score*’:ab,ti OR ‘diet quality score*’:ab,ti OR ‘diet quality index*’:ab,ti OR kidmed:ab,ti OR ‘diet index*’:ab,ti OR ‘dietary index*’:ab,ti OR ‘food score*’:ab,ti OR meddietscore:ab,ti OR ‘healthy eating index*’:ab,ti
  - #6 - ((pattern OR patterns OR consumption OR habit*) NEAR/6 (diet OR diets OR dietary OR food OR foods OR beverage OR beverages)):ab,ti
  - #7 - #1 OR #2 OR #3 OR #4 OR #5 OR #6
  - #8 - ‘breast cancer’/exp OR ‘colorectal cancer’/exp OR ‘intestine polyp’/exp OR ‘prostate cancer’/exp OR ‘lung cancer’/exp OR ‘liver cancer’/exp OR ‘pancreas cancer’/exp OR ‘endometrium cancer’/exp OR ‘endometrium hyperplasia’/exp OR ‘leukemia’/exp
  - #9 - ‘breast neoplasm*’:ab,ti OR ‘breast cancer*’:ab,ti OR ‘breast carcino*’:ab,ti OR ‘colorectal neoplasm*’:ab,ti OR ‘colorectal cancers*’:ab,ti OR ‘colorectal carcino*’:ab,ti OR ‘colon neoplasm*’:ab,ti OR ‘colon cancer*’:ab,ti OR ‘colon carcino*’:ab,ti OR ‘intestinal polyp*’:ab,ti OR ‘colonic polyp*’:ab,ti OR ‘colorectal polyp*’:ab,ti OR ‘colorectal lesion*’:ab,ti OR ‘rectal neoplasm*’:ab,ti OR ‘rectal cancer*’:ab,ti OR ‘rectal carcino*’:ab,ti OR ‘prostate neoplasm*’:ab,ti OR ‘prostate cancer*’:ab,ti OR ‘prostate carcino*’:ab,ti OR ‘lung neoplasm*’:ab,ti OR ‘lung carcino*’:ab,ti OR ‘lung cancer*’:ab,ti OR ‘liver neoplasm*’:ab,ti OR ‘liver cancer*’:ab,ti OR ‘hepatic neoplasm*’:ab,ti OR ‘hepatic cancer*’:ab,ti OR ‘hepatocellular carcino*’:ab,ti OR ‘pancreatic neoplasm*’:ab,ti OR ‘pancreatic cancer*’:ab,ti OR ‘pancreatic carcino*’:ab,ti OR ‘pancreatic adenocarcinoma*’:ab,ti OR ‘pancreatic neuro*’:ab,ti OR ‘ampullary cancer*’:ab,ti OR ‘ampullary carcino*’:ab,ti OR ‘exocrine cancer*’:ab,ti OR ‘exocrine carcino*’:ab,ti OR ‘endometrial neoplasm*’:ab,ti OR ‘endometrial cancer*’:ab,ti OR ‘endometrial carcino*’:ab,ti OR ‘endometrioid neoplasm*’:ab,ti OR ‘endometrioid cancer*’:ab,ti OR ‘endometrioid carcino*’:ab,ti OR ‘endometrial hyperplasia*’:ab,ti OR leukem*:ab,ti OR leukaem*:ab,ti OR leucem*:ab,ti OR leucaem*:ab,ti
  - #10 - ((cancer* OR neoplasm* OR carcino* OR malignan* OR adenocarcinoma* OR sarcoma* OR metastasis OR metastases OR tumor OR tumors OR tumour* OR polyp OR polyps) NEAR/6 (colonic* OR colon OR colorect* OR rectal OR rectum OR breast* OR mammary OR prostate* OR prostatic OR lung OR pulmonary OR endometri* OR endometrium* OR ‘uterine diseases*’ OR liver OR pancreas OR pancreati* OR ‘ampulla of vater’)):ab,ti
  - #11 - #8 OR #9 OR #10
  - #12 - #7 AND #11
  - #13 - #7 AND #11 AND [humans]/lim AND [english]/lim AND [2014-2020]/py NOT ([conference abstract]/lim OR [conference review]/lim OR [conference paper]/lim OR [editorial]/lim OR [erratum]/lim OR [letter]/lim OR [note]/lim OR [review]/lim OR [systematic review]/lim OR [meta analysis]/lim)

#### Cumulative Index of Nursing and Allied Health Literature (CINAHL)

- Provider: EBSCOhost
- Date(s) Searched: January 13, 2020
- Date range searched: January 1, 2014-January 13, 2020
- Search Strategy:
  - #S1 - (MH “Eating Behavior”) OR (MH “Mediterranean Diet”) OR (MH “DASH Diet”) OR (MH “Diet, Gluten-Free”) OR (MH “Diet, High Protein”) OR (MH “Diet, Ketogenic”) OR (MH “Diet, Low Carbohydrate”) OR (MH “Diet, Nordic”) OR (MH “Diet, Paleolithic”) OR (MH “Diet, Sodium-Restricted”) OR (MH “Diet, Western”) OR (MH “Vegetarianism”) OR (MH “Diet, Atherogenic”) OR (MH “Diet, Fat-Restricted”)
  - #S2 - (“dietary pattern*” OR “diet pattern*” OR “eating pattern*” OR “food pattern*” OR “diet quality*” OR “eating habit*” OR “dietary habit*” OR “diet habit*” OR “food habit*” OR “beverage habit*” OR “feeding behavior*” OR “dietary profile*” OR “food profile*” OR “diet profile*” OR “eating profile*” OR “dietary guideline*” OR “dietary recommendation*” OR “dietary intake*” OR “eating style*” OR “Mediterranean Diet*” OR “Dietary Approaches To Stop Hypertension Diet*” OR “DASH diet*” OR “Gluten Free diet*” OR “prudent diet*” OR “Paleolithic Diet*” OR “vegetarian diet*” OR “vegan diet*” OR “healthy diet" OR “plant based diet*” OR “western diet*” OR “low-carbohydrate diet*” OR “high carbohydrate diet*” OR “Ketogenic Diet*” OR “Nordic Diet*” OR “high protein diet*” OR “protein intake*” OR “high-fat diet*” OR “low fat diet*” OR “low protein diet*” OR “low-sodium diet*” OR “low salt diet*”)
  - #S3 - (((MH “Dietary Proteins+”) OR “dietary protein*” OR (MH “Dietary Carbohydrates+”) OR “dietary carbohydrate*” OR (MH “Dietary Fats+”) OR “dietary fat*”) N6 (diet OR diets OR consumption OR intake OR supplement*))
  - #S4 – ((MH “Guideline Adherence”) OR “guideline adherence*”) N6 (diet OR dietary OR food OR beverage* OR nutrition*))
  - #S5 - “diet score*” OR “diet quality score*” OR “diet quality index*” OR kidmed OR “diet index*” OR “dietary index*” OR “food score*” OR MedDietScore OR “healthy eating index*”
  - #S6 - ((pattern OR patterns OR consumption OR habit*) N6 ((MH “Diet”) OR diet OR diets OR dietary OR (MH “Food+”) OR food OR foods OR (MH “Beverages+”) OR beverage OR beverages))
  - #S7 - S1 OR S2 OR S3 OR S4 OR S5 OR S6
  - #S8 - (MH “Breast Neoplasms+”) OR (MH “Colorectal Neoplasms+”) OR (MH “Intestinal Polyps+”) OR (MH “Prostatic Neoplasms+”) OR (MH “Lung Neoplasms+”) OR (MH “Liver Neoplasms+”) OR (MH “Pancreatic Neoplasms+”) OR (MH “Endometrial Neoplasms”) OR (MH “Leukemia+”)
  - #S9 - “breast neoplasm*” OR “breast cancer*” OR “breast carcino*” OR “colorectal neoplasm*” OR “colorectal cancers*” OR “colorectal carcino*” OR “colon neoplasm*” OR “colon cancer*” OR “colon carcino*” OR “intestinal polyp*” OR “colonic polyp*” OR “colorectal polyp*” OR “colorectal lesion*” OR “rectal neoplasm*” OR “rectal cancer*” OR “rectal carcino*” OR “prostate neoplasm*” OR “prostate cancer*” OR “prostate carcino*” OR “lung neoplasm*” OR “lung carcino*” OR “lung cancer*” OR “liver neoplasm*” OR “liver cancer*” OR “hepatic neoplasm*” OR “hepatic cancer*” OR “hepatocellular carcino*” OR “pancreatic neoplasm*” OR “pancreatic cancer*” OR “pancreatic carcino*” OR “pancreatic adenocarcinoma*” OR “pancreatic neuro*” OR “ampullary cancer*” OR “ampullary carcino*” OR “exocrine cancer*” OR “exocrine carcino*” OR “endometrial neoplasm*” OR “endometrial cancer*” OR “endometrial carcino*” OR “endometrioid neoplasm*” OR “endometrioid cancer*” OR “endometrioid carcino*” OR “endometrial hyperplasia*” OR leukem* OR leukaem* OR leucem* OR leucaem*
  - #S10 - ((cancer* OR (MH “Neoplasms+”) OR neoplasm* OR carcino* OR (MH “Carcinogens+”) OR malignan* OR adenocarcinoma* OR sarcoma* OR metastasis OR metastases OR tumor OR tumors OR tumour* OR (MH “Polyps+”) OR polyp OR polyps) N6 (colonic* OR colon OR colorect* OR rectal OR rectum OR (MH “Colon+”) OR (MH “Colonic Diseases”) OR (MH “Breast+”) OR (MH “Breast Diseases”) OR breast* OR mammary OR (MH “Prostate”) OR prostate* OR prostatic OR (MH “Prostatic Diseases”) OR (MH “Lung+”) OR (MH “Lung Diseases”) OR lung OR pulmonary OR endometri* OR endometrium* OR (MH “Uterine Diseases”) OR “uterine diseases*” OR (MH “Liver”) OR liver OR (MH “Liver Diseases”) OR (MH “Pancreas+”) OR pancreas OR pancreati* OR (MH “Pancreatic Diseases”) OR “ampulla of vater”))
  - #S11 - S8 OR S9 OR S10
  - #S12 - S7 AND S11 NOT (MH “Literature Review" OR MH “Meta Analysis" OR MH “Systematic Review" OR MH “News" OR MH “Retracted Publication" OR MH “Retraction of Publication”) Limiters - Publication Year: 2014-2020; Peer Reviewed; English Language; Human

## LITERATURE SEARCH AND SCREENING RESULTS

The flow chart (Figure 2) below illustrates the literature search and screening results for articles in this update to existing systematic reviews. The results of the electronic database searches, after removal of duplicates, were screened independently by two NESR analysts using a step-wise process by reviewing titles, abstracts, and full-texts to determine which articles met the inclusion criteria. Refer to Table 15 for the rationale for exclusion for each excluded full-text article. A manual search was done to find articles that were not identified when searching the electronic databases; all manually identified articles were also screened to determine whether they meet criteria for inclusion.

Figure 2 Flow chart of literature search and screening results

This flow chart illustrates the literature search and screening results for articles examining the relationship between dietary patterns and cancer. The literature search yielded 6822 articles, and 4095 after duplicates were removed. During title screening, 3386 articles were screened out. During abstract screening, 597 articles were screened out. During full-text screening, 61 articles were screened out. During the hand search, no additional articles were identified to include. A total of 51 articles were included in the systematic review at the end of the search and screening process, 26 for breast cancer, 24 for colorectal cancer, 8 for lung cancer, and 8 for prostate cancer.

### Excluded articles from updated literature search

The table below lists the articles excluded after full-text screening for this update to existing systematic reviews. At least one reason for exclusion is provided for each article, which may not reflect all possible reasons for exclusion. Information about articles excluded after title and abstract screening is available upon request.

Table 16 Articles excluded after full-text screening with rationale for exclusion

| Citation | Rationale
1. | Mediterranean diet supplemented with extra virgin olive oil reduces the incidence of invasive breast cancer in a randomised controlled trial. Evidence-based medicine. 21 (2) (pp 72), 2016. Date of publication: April 2016. 2016.. doi:10.1136/ebmed-2015-110366 | Study design; Publication status
2. | Akinyemiju, T, Wiener, H, Pisu, M. Cancer-related risk factors and incidence of major cancers by race, gender and region; analysis of the NIH-AARP diet and health study. BMC Cancer. 2017. 17:597. doi:10.1186/s12885-017-3557-1 28854891 | Intervention or exposure
3. | Ax, E, Garmo, H, Grundmark, B, Bill-Axelson, A, Holmberg, L, Becker, W, Zethelius, B, Cederholm, T, Sjogren, P. Dietary patterns and prostate cancer risk: report from the population based ULSAM cohort study of Swedish men. Nutr Cancer. 2014. 66:77–87. doi:10.1080/01635581.2014.851712 24325263 | Publication date
4. | Berberian, P, Obimba, C, Glickman-Simon, R, Sethi, T. Herbs for Low-Back Pain, Acupuncture for Psychological Distress, Osteopathic Manipulative Therapy for Chronic Migraine, Honey Dressings for Burns, Vegetarian Diet and Risk of Colorectal Cancer. Explore (NY). 2015. 11:410–4. doi:10.1016/j.explore.2015.07.011 26238168 | Study design; Publication status
5. | Berstad, P, Botteri, E, Larsen, IK, Loberg, M, Kalager, M, Holme, O, Bretthauer, M, Hoff, G. Lifestyle changes at middle age and mortality: a population-based prospective cohort study. J Epidemiol Community Health. 2017. 71:59–66. doi:10.1136/jech-2015-206760 27312250 | Outcome
6. | Bradbury, KE, Murphy, N, Key, TJ. Diet and colorectal cancer in UK Biobank: a prospective study. Int J Epidemiol. 2019. doi:10.1093/ije/dyz064 | Intervention or exposure
7. | Brinton, LA, Smith, L, Gierach, GL, Pfeiffer, RM, Nyante, SJ, Sherman, ME, Park, Y, Hollenbeck, AR, Dallal, CM. Breast cancer risk in older women: results from the NIH-AARP Diet and Health Study. Cancer Causes Control. 2014. 25:843–57. doi:10.1007/s10552-014-0385-3 24810653 | Intervention or exposure
8. | Castro-Quezada, I, Sanchez-Villegas, A, Martinez-Gonzalez, MA, Salas-Salvado, J, Corella, D, Estruch, R, Schroder, H, Alvarez-Perez, J, Ruiz-Lopez, MD, Artacho, R, Ros, E, Bullo, M, Sorli, JV, Fito, M, Ruiz-Gutierrez, V, Toledo, E, Buil-Cosiales, P, Garcia Rodriguez, A, Lapetra, J, Pinto, X, Salaverria, I, Tur, JA, Romaguera, D, Tresserra-Rimbau, A, Serra-Majem, L. Glycemic index, glycemic load and invasive breast cancer incidence in postmenopausal women: The PREDIMED study. Eur J Cancer Prev. 2016. 25:524–32. doi:10.1097/cej.0000000000000209 26633163 | Intervention or exposure
9. | Catsburg, C, Miller, AB, Rohan, TE. Adherence to cancer prevention guidelines and risk of breast cancer. Int J Cancer. 2014. 135:2444–52. doi:10.1002/ijc.28887 24723234 | Intervention or exposure
10. | Cifu, G, Arem, H. Adherence to lifestyle-related cancer prevention guidelines and breast cancer incidence and mortality. Ann Epidemiol. 2018. 28:767–773.e1. doi:10.1016/j.annepidem.2018.09.002 30309689 | Intervention or exposure
11. | Dunneram, Y, Greenwood, DC, Cade, JE. Diet and risk of breast, endometrial and ovarian cancer: UK Women’s Cohort Study. Br J Nutr. 2019. 122:564–574. doi:10.1017/s0007114518003665 30526696 | Intervention or exposure
12. | Elwood, PC, Whitmarsh, A, Gallacher, J, Bayer, A, Adams, R, Heslop, L, Pickering, J, Morgan, G, Galante, J, Dolwani, S, Longley, M, Roberts, ZE. Healthy living and cancer: evidence from UK Biobank. Ecancermedicalscience. 2018. 12:792. doi:10.3332/ecancer.2018.792 29434658 | Intervention or exposure
13. | Er, V, Lane, JA, Martin, RM, Emmett, P, Gilbert, R, Avery, KN, Walsh, E, Donovan, JL, Neal, DE, Hamdy, FC, Jeffreys, M. Adherence to dietary and lifestyle recommendations and prostate cancer risk in the prostate testing for cancer and treatment (ProtecT) trial. Cancer Epidemiol Biomarkers Prev. 2014. 23:2066–77. doi:10.1158/1055-9965.Epi-14-0322 25017249 | Intervention or exposure
14. | Farvid, MS, Cho, E, Chen, WY, Eliassen, AH, Willett, WC. Adolescent meat intake and breast cancer risk. Int J Cancer. 2015. 136:1909–20. doi:10.1002/ijc.29218 25220168 | Intervention or exposure
15. | Freedland, SJ. The effect of diet and supplements on prostate cancer. Clin Adv Hematol Oncol. 2014. 12:538–40.25356578 | Study design; Publication status
16. | Gilsing, AM, Schouten, LJ, Goldbohm, RA, Dagnelie, PC, van den Brandt, PA, Weijenberg, MP. Vegetarianism, low meat consumption and the risk of colorectal cancer in a population based cohort study. Sci Rep. 2015. 5:13484. doi:10.1038/srep13484 26316135 | Intervention or exposure
17. | Gilsing, AM, Weijenberg, MP, Goldbohm, RA, Dagnelie, PC, van den Brandt, PA, Schouten, LJ. Vegetarianism, low meat consumption and the risk of lung, postmenopausal breast and prostate cancer in a population-based cohort study. Eur J Clin Nutr. 2016. 70:723–9. doi:10.1038/ejcn.2016.25 26931668 | Intervention or exposure
18. | Guinter, MA, McLain, AC, Merchant, AT, Sandler, DP, Steck, SE. An estrogen-related lifestyle score is associated with risk of postmenopausal breast cancer in the PLCO cohort. Breast Cancer Res Treat. 2018. 170:613–622. doi:10.1007/s10549-018-4784-0 29651647 | Outcome
19. | Haraldsdottir, A, Torfadottir, JE, Valdimarsdottir, UA, Adami, HO, Aspelund, T, Tryggvadottir, L, Thordardottir, M, Birgisdottir, BE, Harris, TB, Launer, LJ, Gudnason, V, Steingrimsdottir, L. Dietary habits in adolescence and midlife and risk of breast cancer in older women. PLoS One. 2018. 13:e0198017. doi:10.1371/journal.pone.0198017 29847592 | Intervention or exposure
20. | Harris, HR, Bergkvist, L, Wolk, A. Adherence to the World Cancer Research Fund/American Institute for Cancer Research recommendations and breast cancer risk. Int J Cancer. 2016. 138:2657–64. doi:10.1002/ijc.30015 26804371 | Intervention or exposure
21. | He, X, Wu, K, Zhang, X, Nishihara, R, Cao, Y, Fuchs, CS, Giovannucci, EL, Ogino, S, Chan, AT, Song, M. Dietary intake of fiber, whole grains and risk of colorectal cancer: An updated analysis according to food sources, tumor location and molecular subtypes in two large US cohorts. Int J Cancer. 2019. 145:3040–3051. doi:10.1002/ijc.32382 31044426 | Intervention or exposure
22. | Heitz, AE, Baumgartner, RN, Baumgartner, KB, Boone, SD. Healthy lifestyle impact on breast cancer-specific and all-cause mortality. Breast Cancer Res Treat. 2018. 167:171–181. doi:10.1007/s10549-017-4467-2 28861753 | Outcome; Health status
23. | Helander, S, Heinavaara, S, Sarkeala, T, Malila, N. Lifestyle in population-based colorectal cancer screening over 2-year follow-up. Eur J Public Health. 2018. 28:333–338. doi:10.1093/eurpub/ckx139 29020299 | Outcome
24. | Hidaka, BH, Kimler, BF, Fabian, CJ, Carlson, SE. An empirically derived dietary pattern associated with breast cancer risk is validated in a nested case-control cohort from a randomized primary prevention trial. Clin Nutr ESPEN. 2017. 17:8–17. doi:10.1016/j.clnesp.2016.10.008 28361752 | Outcome
25. | Hirko, KA, Willett, WC, Hankinson, SE, Rosner, BA, Beck, AH, Tamimi, RM, Eliassen, AH. Healthy dietary patterns and risk of breast cancer by molecular subtype. Breast Cancer Res Treat. 2016. 155:579–88. doi:10.1007/s10549-016-3706-2 26872903 | Outcome
26. | Jones, P, Cade, JE, Evans, CEL, Hancock, N, Greenwood, DC. Does adherence to the World Cancer Research Fund/American Institute of Cancer Research cancer prevention guidelines reduce risk of colorectal cancer in the UK Women’s Cohort Study?. Br J Nutr. 2018. 119:340–348. doi:10.1017/s0007114517003622 29352814 | Intervention or exposure
27. | Kenfield, SA, DuPre, N, Richman, EL, Stampfer, MJ, Chan, JM, Giovannucci, EL. Mediterranean diet and prostate cancer risk and mortality in the Health Professionals Follow-up Study. Eur Urol. 2014. 65:887–94. doi:10.1016/j.eururo.2013.08.009 23962747 | Publication date
28. | Key, TJ, Appleby, PN, Crowe, FL, Bradbury, KE, Schmidt, JA, Travis, RC. Cancer in British vegetarians: updated analyses of 4998 incident cancers in a cohort of 32,491 meat eaters, 8612 fish eaters, 18,298 vegetarians, and 2246 vegans. Am J Clin Nutr. 2014. 100 Suppl 1:378s–85s. doi:10.3945/ajcn.113.071266 24898235 | Intervention or exposure
29. | Kohler, LN, Harris, RB, Oren, E, Roe, DJ, Lance, P, Jacobs, ET. Adherence to Nutrition and Physical Activity Cancer Prevention Guidelines and Development of Colorectal Adenoma. Nutrients. 2018. 10. doi:10.3390/nu10081098 | Intervention or exposure
30. | Kouloulias, V, Platoni, K, Kantzou, I, Zygogianni, A, Kyriazi, K, Kougioumtzopoulou, A, Papaloucas, M, Papaloucas, C. Physical activity, early first delivery and residence as parameters for breast cancer prevention: an observational study. J buon. 2019. 24:1512–1515.31646800 | Intervention or exposure
31. | Lagerlund, M, Drake, I, Wirfalt, E, Sontrop, JM, Zackrisson, S. Health-related lifestyle factors and mammography screening attendance in a Swedish cohort study. Eur J Cancer Prev. 2015. 24:44–50. doi:10.1097/cej.0000000000000025 24787378 | Outcome
32. | Lecuyer, L, Dalle, C, Lefevre-Arbogast, S, Micheau, P, Lyan, B, Rossary, A, Demidem, A, Petera, M, Lagree, M, Centeno, D, Galan, P, Hercberg, S, Samieri, C, Assi, N, Ferrari, P, Viallon, V, Deschasaux, M, Partula, V, Srour, B, Latino-Martel, P, Kesse-Guyot, E, Druesne-Pecollo, N, Vasson, MP, Durand, S, Pujos-Guillot, E, Manach, C, Touvier, M. Diet-Related Metabolomic Signature of Long-Term Breast Cancer Risk Using Penalized Regression: An Exploratory Study in the SU.VI.MAX Cohort. Cancer Epidemiol Biomarkers Prev. 2019. doi:10.1158/1055-9965.Epi-19-0900 | Intervention or exposure
33. | Liao, LM, Loftfield, E, Etemadi, A, Graubard, BI, Sinha, R. Substitution of dietary protein sources in relation to colorectal cancer risk in the NIH-AARP cohort study. Cancer Causes Control. 2019. 30:1127–1135. doi:10.1007/s10552-019-01210-1 31327110 | Intervention or exposure
34. | Liu, L, Tabung, FK, Zhang, X, Nowak, JA, Qian, ZR, Hamada, T, Nevo, D, Bullman, S, Mima, K, Kosumi, K, da Silva, A, Song, M, Cao, Y, Twombly, TS, Shi, Y, Liu, H, Gu, M, Koh, H, Li, W, Du, C, Chen, Y, Li, C, Li, W, Mehta, RS, Wu, K, Wang, M, Kostic, AD, Giannakis, M, Garrett, WS, Hutthenhower, C, Chan, AT, Fuchs, CS, Nishihara, R, Ogino, S, Giovannucci, EL. Diets That Promote Colon Inflammation Associate With Risk of Colorectal Carcinomas That Contain Fusobacterium nucleatum. Clin Gastroenterol Hepatol. 2018. 16:1622–1631.e3. doi:10.1016/j.cgh.2018.04.030 29702299 | Outcome
35. | Llanos, AA, Krok, JL, Peng, J, Pennell, ML, Olivo-Marston, S, Vitolins, MZ, Degraffinreid, CR, Paskett, ED. Favorable effects of low-fat and low-carbohydrate dietary patterns on serum leptin, but not adiponectin, among overweight and obese premenopausal women: a randomized trial. Springerplus. 2014. 3:175. doi:10.1186/2193-1801-3-175 24790820 | Outcome
36. | Makarem, N, Lin, Y, Bandera, EV, Jacques, PF, Parekh, N. Concordance with World Cancer Research Fund/American Institute for Cancer Research (WCRF/AICR) guidelines for cancer prevention and obesity-related cancer risk in the Framingham Offspring cohort (1991-2008). Cancer Causes Control. 2015. 26:277–286. doi:10.1007/s10552-014-0509-9 25559553 | Intervention or exposure
37. | Marcondes, LH, Franco, OH, Ruiter, R, Ikram, MA, Mulder, M, Stricker, BH, Kiefte-de Jong, JC. Animal foods and postmenopausal breast cancer risk: a prospective cohort study. Br J Nutr. 2019. 122:583–591. doi:10.1017/s0007114519000072 30832747 | Intervention or exposure
38. | McBride, D. Vegetarian Diets May Decrease Risk of Colorectal Cancer. ONS Connect. 2015. 30:51. | Publication status
39. | Mehta, RS, Nishihara, R, Cao, Y, Song, M, Mima, K, Qian, ZR, Nowak, JA, Kosumi, K, Hamada, T, Masugi, Y, Bullman, S, Drew, DA, Kostic, AD, Fung, TT, Garrett, WS, Huttenhower, C, Wu, K, Meyerhardt, JA, Zhang, X, Willett, WC, Giovannucci, EL, Fuchs, CS, Chan, AT, Ogino, S. Association of Dietary Patterns With Risk of Colorectal Cancer Subtypes Classified by Fusobacterium nucleatum in Tumor Tissue. JAMA Oncol. 2017. 3:921–927. doi:10.1001/jamaoncol.2016.6374 28125762 | Outcome
40. | Nguyen, S, Li, H, Yu, D, Gao, J, Gao, Y, Tran, H, Xiang, YB, Zheng, W, Shu, XO. Adherence to dietary recommendations and colorectal cancer risk: results from two prospective cohort studies. Int J Epidemiol. 2019. doi:10.1093/ije/dyz118 | Country
41. | Nimptsch, K, Malik, VS, Fung, TT, Pischon, T, Hu, FB, Willett, WC, Fuchs, CS, Ogino, S, Chan, AT, Giovannucci, E, Wu, K. Dietary patterns during high school and risk of colorectal adenoma in a cohort of middle-aged women. Int J Cancer. 2014. 134:2458–67. doi:10.1002/ijc.28578 24493161 | Outcome
42. | Papadimitriou, N, Muller, D, van den Brandt, PA, Geybels, M, Patel, CJ, Gunter, MJ, Lopez, DS, Key, TJ, Perez-Cornago, A, Ferrari, P, Vineis, P, Weiderpass, E, Boeing, H, Agudo, A, Sanchez, MJ, Overvad, K, Kuhn, T, Fortner, RT, Palli, D, Drake, I, Bjartell, A, Santiuste, C, Bueno-de-Mesquita, BH, Krogh, V, Tjonneland, A, Lauritzen, DF, Gurrea, AB, Quiros, JR, Stattin, P, Trichopoulou, A, Martimianaki, G, Karakatsani, A, Thysell, E, Johansson, I, Ricceri, F, Tumino, R, Larranaga, N, Khaw, KT, Riboli, E, Tzoulaki, I, Tsilidis, KK. A nutrient-wide association study for risk of prostate cancer in the European Prospective Investigation into Cancer and Nutrition and the Netherlands Cohort Study. Eur J Nutr. 2019. doi:10.1007/s00394-019-02132-z | Intervention or exposure
43. | Park, YM, Steck, SE, Fung, TT, Merchant, AT, Elizabeth Hodgson, M, Keller, JA, Sandler, DP. Higher diet-dependent acid load is associated with risk of breast cancer: Findings from the sister study. Int J Cancer. 2019. 144:1834–1843. doi:10.1002/ijc.31889 30247761 | Intervention or exposure
44. | Printz, C. Vegetarian diet associated with lower risk of colorectal cancer. Cancer. 2015. 121:2667. doi:10.1002/cncr.29582 26249116 | Publication status
45. | Rada-Fernandez de Jauregui, D, Evans, CEL, Jones, P, Greenwood, DC, Hancock, N, Cade, JE. Common dietary patterns and risk of cancers of the colon and rectum: Analysis from the United Kingdom Women’s Cohort Study (UKWCS). Int J Cancer. 2018. 143:773–781. doi:10.1002/ijc.31362 29516512 | Intervention or exposure
46. | Shivappa, N, Blair, CK, Prizment, AE, Jacobs, DR, Hebert, JR. Prospective study of the dietary inflammatory index and risk of breast cancer in postmenopausal women. Mol Nutr Food Res. 2017. 61. doi:10.1002/mnfr.201600592 | Intervention or exposure
47. | Shivappa, N, Prizment, AE, Blair, CK, Jacobs, DR, Jr, Steck, SE, Hebert, JR. Dietary inflammatory index and risk of colorectal cancer in the Iowa Women’s Health Study. Cancer Epidemiol Biomarkers Prev. 2014. 23:2383–92. doi:10.1158/1055-9965.Epi-14-0537 25155761 | Intervention or exposure
48. | Shivappa, N, Wang, R, Hebert, JR, Jin, A, Koh, WP, Yuan, JM. Association between inflammatory potential of diet and risk of lung cancer among smokers in a prospective study in Singapore. Eur J Nutr. 2019. 58:2755–2766. doi:10.1007/s00394-018-1825-8 30255403 | Intervention or exposure
49. | Sieri, S. Consuming a high-fat diet is associated with increased risk of certain types of BC. J Natl Cancer Inst. 2014. 106. doi:10.1093/jnci/dju114 | Study design; Publication status
50. | Sieri, S, Agnoli, C, Pala, V, Grioni, S, Brighenti, F, Pellegrini, N, Masala, G, Palli, D, Mattiello, A, Panico, S, Ricceri, F, Fasanelli, F, Frasca, G, Tumino, R, Krogh, V. Dietary glycemic index, glycemic load, and cancer risk: results from the EPIC-Italy study. Sci Rep. 2017. 7:9757. doi:10.1038/s41598-017-09498-2 28851931 | Intervention or exposure
51. | Solbak, NM, Xu, JY, Vena, JE, Csizmadi, I, Whelan, HK, Robson, PJ. Diet quality is associated with reduced incidence of cancer and self-reported chronic disease: Observations from Alberta’s Tomorrow Project. Preventive Medicine. 2017. 101:178–187. doi:10.1016/j.ypmed.2017.06.009 28601618 | Outcome
52. | Sun, JW, Zheng, W, Li, HL, Gao, J, Yang, G, Gao, YT, Rothman, N, Lan, Q, Shu, XO, Xiang, YB. Dietary Glycemic Load, Glycemic Index, and Carbohydrate Intake on the Risk of Lung Cancer among Men and Women in Shanghai. Nutr Cancer. 2018. 70:671–677. doi:10.1080/01635581.2018.1460675 29668313 | Intervention or exposure
53. | Tabung, FK, Steck, SE, Liese, AD, Zhang, J, Ma, Y, Caan, B, Chlebowski, RT, Freudenheim, JL, Hou, L, Mossavar-Rahmani, Y, Shivappa, N, Vitolins, MZ, Wactawski-Wende, J, Ockene, JK, Hebert, JR. Association between dietary inflammatory potential and breast cancer incidence and death: results from the Women’s Health Initiative. Br J Cancer. 2016. 114:1277–85. doi:10.1038/bjc.2016.98 27100730 | Intervention or exposure
54. | Tabung, FK, Steck, SE, Liese, AD, Zhang, J, Ma, Y, Johnson, KC, Lane, DS, Qi, L, Snetselaar, L, Vitolins, MZ, Ockene, JK, Hebert, JR. Patterns of change over time and history of the inflammatory potential of diet and risk of breast cancer among postmenopausal women. Breast Cancer Res Treat. 2016. 159:139–49. doi:10.1007/s10549-016-3925-6 27475089 | Intervention or exposure
55. | Tabung, FK, Steck, SE, Ma, Y, Liese, AD, Zhang, J, Caan, B, Hou, L, Johnson, KC, Mossavar-Rahmani, Y, Shivappa, N, Wactawski-Wende, J, Ockene, JK, Hebert, JR. The association between dietary inflammatory index and risk of colorectal cancer among postmenopausal women: results from the Women’s Health Initiative. Cancer Causes Control. 2015. 26:399–408. doi:10.1007/s10552-014-0515-y 25549833 | Intervention or exposure
56. | Tabung, FK, Steck, SE, Ma, Y, Liese, AD, Zhang, J, Lane, DS, Ho, GYF, Hou, L, Snetselaar, L, Ockene, JK, Hebert, JR. Changes in the Inflammatory Potential of Diet Over Time and Risk of Colorectal Cancer in Postmenopausal Women. Am J Epidemiol. 2017. 186:514–523. doi:10.1093/aje/kwx115 28486621 | Intervention or exposure
57. | Thomson, CA, McCullough, ML, Wertheim, BC, Chlebowski, RT, Martinez, ME, Stefanick, ML, Rohan, TE, Manson, JE, Tindle, HA, Ockene, J, Vitolins, MZ, Wactawski-Wende, J, Sarto, GE, Lane, DS, Neuhouser, ML. Nutrition and physical activity cancer prevention guidelines, cancer risk, and mortality in the women’s health initiative. Cancer Prev Res (Phila). 2014. 7:42–53. doi:10.1158/1940-6207.Capr-13-0258 24403289 | Intervention or exposure
58. | Urquiza-Salvat, N, Pascual-Geler, M, Lopez-Guarnido, O, Rodrigo, L, Martinez-Burgos, A, Cozar, JM, Ocana-Peinado, FM, Alvarez-Cubero, MJ, Rivas, A. Adherence to Mediterranean diet and risk of prostate cancer. Aging Male. 2019. 22:102–108. doi:10.1080/13685538.2018.1450854 29542389 | Study design
59. | Wang, W, Fung, TT, Wang, M, Smith-Warner, SA, Giovannucci, EL, Tabung, FK. Association of the Insulinemic Potential of Diet and Lifestyle With Risk of Digestive System Cancers in Men and Women. JNCI Cancer Spectr. 2018. 2:pky080. doi:10.1093/jncics/pky080 30740588 | Publication status
60. | Wang, Z, Uchida, K, Ohnaka, K, Morita, M, Toyomura, K, Kono, S, Ueki, T, Tanaka, M, Kakeji, Y, Maehara, Y, Okamura, T, Ikejiri, K, Futami, K, Maekawa, T, Yasunami, Y, Takenaka, K, Ichimiya, H, Terasaka, R. Sugars, sucrose and colorectal cancer risk: the Fukuoka colorectal cancer study. Scand J Gastroenterol. 2014. 49:581–8. doi:10.3109/00365521.2013.822091 24716480 | Intervention or exposure
61. | Wie, GA, Cho, YA, Kang, HH, Ryu, KA, Yoo, MK, Kim, J, Shin, S, Chun, OK, Joung, H. Identification of major dietary patterns in Korean adults and their association with cancer risk in the Cancer Screening Examination Cohort. Eur J Clin Nutr. 2017. 71:1223–1229. doi:10.1038/ejcn.2017.6 28247859 | Outcome

lxxxviii Dietary Guidelines Advisory Committee. 2020. Scientific Report of the 2020 Dietary Guidelines Advisory Committee: Advisory Report to the Secretary of Agriculture and the Secretary of Health and Human Services. U.S. Department of Agriculture, Agricultural Research Service, Washington, DC .

lxxxix The Human Development classification was based on the Human Development Index (HDI) ranking from the year the study intervention occurred or data were collected (UN Development Program. HDI 1990-2017 HDRO calculations based on data from UNDESA (2017a), UNESCO Institute for Statistics (2018), United Nations Statistics Division (2018b), World Bank (2018b), Barro and Lee (2016) and IMF (2018). Available from: http://hdr.undp.org/en/data). If the study did not report the year in which the intervention occurred or data were collected, the HDI classification for the year of publication was applied. HDI values are available from 1980, and then from 1990 to present. If a study was conducted prior to 1990, the HDI classification from 1990 was applied. If a study was conducted in 2018 or 2019, the most current HDI classification was applied. When a country was not included in the HDI ranking, the current country classification from the World Bank was used instead (The World Bank. World Bank country and lending groups. Available from: https://datahelpdesk.worldbank.org/knowledgebase/articles/906519-world-country-and-lending-groups).