# List of abbreviations

Abbreviation: Full name
FEG: Federal Expert Group
HHS: Department of Health and Human Services
NEL: Nutrition Evidence Library
NESR: Nutrition Evidence Systematic Review
P/B-24: Pregnancy and Birth to 24 Months Project
TEC: Technical Expert Collaborative
USDA: United States Department of Agriculture